# Appendix A Summary of Lesions in Male Rats in the Two-year Inhalation Study of Antimony Trioxide

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Moribund | 15 | 19 | 22 | 29
Natural deaths | 5 | 1 | – | 3
Survivors
Terminal kill | 30 | 30 | 28 | 18
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Lymph node, bronchial | (9) | (8) | (10) | (10)
Lymph node, mandibular | (10) | (9) | (9) | (8)
Lymph node, mediastinal | (10) | (8) | (10) | (9)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Hemangiosarcoma | – | – | – | 1 (10%)
Spleen | (10) | (10) | (10) | (10)
Thymus | (10) | (10) | (10) | (10)
Systems Examined at 12 Months with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (49) | (50) | (50) | (49)
Intestine large, colon | (50) | (50) | (50) | (50)
Intestine large, rectum | (44) | (49) | (48) | (48)
Carcinoma | – | – | 1 (2%) | –
Intestine small, duodenum | (47) | (50) | (50) | (49)
Sarcoma, metastatic, tissue NOS | – | – | – | 1 (2%)
Intestine small, ileum | (48) | (50) | (50) | (49)
Leiomyosarcoma | – | – | 1 (2%) | –
Intestine small, jejunum | (46) | (49) | (50) | (48)
Liver | (50) | (50) | (50) | (50)
Hepatocellular adenoma | | 2 (4%) | 1 (2%) | –
Leiomyosarcoma, metastatic, intestine small, ileum | – | – | 1 (2%) | –
Mesentery | (50) | (50) | (50) | (50)
Hemangiosarcoma, metastatic, pancreas | – | – | – | 1 (2%)
Leiomyosarcoma, metastatic, intestine small, ileum | – | – | 1 (2%) | –
Sarcoma, metastatic, tissue NOS | – | – | – | 1 (2%)
Pancreas | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Sarcoma, metastatic, tissue NOS | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (50)
Myoepithelioma | 1 (2%) | – | – | –
Schwannoma malignant | – | – | – | 1 (2%)
Stomach, forestomach | (50) | (50) | (50) | (50)
Sarcoma, metastatic, tissue NOS | – | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Tongue | (1) | (1) | (0) | (1)
Squamous cell papilloma | – | 1 (100%) | – | –
Tooth | (2) | (1) | (1) | (1)
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (49)
Heart | (50) | (50) | (50) | (50)
Schwannoma malignant | – | – | 1 (2%) | –
Endocardium, schwannoma NOS | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Adenoma | 3 (6%) | – | 3 (6%) | –
Carcinoma | – | – | 1 (2%) | –
Adrenal medulla | (49) | (50) | (49) | (50)
Ganglioneuroma | – | 1 (2%) | – | –
Pheochromocytoma benign | 1 (2%) | – | 2 (4%) | 7 (14%)
Pheochromocytoma complex | 1 (2%) | – | – | –
Islets, pancreatic | (50) | (50) | (50) | (49)
Adenoma | – | 1 (2%) | 4 (8%) | 1 (2%)
Carcinoma | – | – | – | 1 (2%)
Parathyroid gland | (44) | (46) | (46) | (48)
Adenoma | – | – | 1 (2%) | –
Pituitary gland | (50) | (50) | (50) | (50)
Pars distalis, adenoma | 14 (28%) | 15 (30%) | 12 (24%) | 5 (10%)
Pars intermedia, adenoma | 1 (2%) | – | – | 2 (4%)
Thyroid gland | (50) | (50) | (50) | (50)
Bilateral, c-cell, adenoma | – | – | – | 1 (2%)
C-cell, adenoma | 5 (10%) | 9 (18%) | 5 (10%) | 3 (6%)
C-cell, adenoma, multiple | – | – | – | 1 (2%)
C-cell, carcinoma | 1 (2%) | 1 (2%) | – | –
Follicular cell, adenoma | – | 1 (2%) | 2 (4%) | –
Follicular cell, carcinoma | – | 1 (2%) | – | –
General Body System
Tissue NOS | (0) | (1) | (0) | (1)
Sarcoma | – | – | – | 1 (100%)
Mediastinum, carcinoma | – | 1 (100%) | – | –
Genital System
Coagulating gland | (0) | (0) | (0) | (1)
Epididymis | (50) | (50) | (50) | (50)
Sarcoma | – | – | – | 1 (2%)
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Carcinoma | – | 1 (2%) | – | –
Sarcoma, metastatic, tissue NOS | – | – | – | 1 (2%)
Seminal vesicle | (50) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Carcinoma, metastatic, prostate | – | 1 (2%) | – | –
Hemangioma | – | 1 (2%) | – | –
Testes | (50) | (50) | (50) | (50)
Hemangiosarcoma | 1 (2%) | – | – | –
Interstitial cell, adenoma | 6 (12%) | 2 (4%) | 1 (2%) | 1 (2%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Lymph node | (2) | (4) | (7) | (7)
Lumbar, hemangiosarcoma | – | 1 (25%) | – | –
Lymph node, bronchial | (41) | (40) | (48) | (47)
Lymph node, mandibular | (45) | (46) | (48) | (45)
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | –
Lymph node, mediastinal | (42) | (45) | (49) | (49)
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | –
Hemangioma | – | – | 1 (2%) | –
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Hemangioma | 1 (2%) | – | 2 (4%) | –
Hemangiosarcoma | 2 (4%) | 2 (4%) | 4 (8%) | 1 (2%)
Hemangiosarcoma, metastatic, pancreas | – | – | – | 1 (2%)
Leiomyosarcoma, metastatic, intestine small, ileum | – | – | 1 (2%) | –
Sarcoma, metastatic, epididymis | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | – | – | 1 (2%)
Thymus | (41) | (35) | (47) | (45)
Thymoma benign | 3 (7%) | – | 1 (2%) | 4 (9%)
Thymoma malignant | – | 1 (3%) | – | –
Integumentary System
Mammary gland | (6) | (9) | (7) | (8)
Skin | (50) | (50) | (50) | (50)
Hemangioma | – | – | – | 1 (2%)
Keratoacanthoma | 1 (2%) | 1 (2%) | – | –
Trichoepithelioma | – | 1 (2%) | – | –
Pinna, neural crest tumor, benign | – | – | 1 (2%) | –
Sebaceous gland, adenoma | – | 1 (2%) | – | –
Subcutaneous tissue, fibroma | 2 (4%) | – | 2 (4%) | –
Subcutaneous tissue, fibrosarcoma | – | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | – | 1 (2%) | – | –
Subcutaneous tissue, schwannoma malignant | – | – | 1 (2%) | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Maxilla, osteosarcoma | – | – | 1 (2%) | –
Skeletal muscle | (4) | (3) | (3) | (5)
Fibrosarcoma, metastatic, skin | – | – | – | 1 (20%)
Sarcoma | – | – | – | 1 (20%)
Sarcoma, metastatic, tissue NOS | – | – | – | 1 (20%)
Nervous System
Brain | (50) | (50) | (50) | (50)
Glioma malignant | – | – | 1 (2%) | –
Glioma NOS | – | – | – | 1 (2%)
Granular cell tumor benign | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Neurocytoma | – | – | 1 (2%) | –
Peripheral nerve | (3) | (3) | (2) | (0)
Spinal cord | (3) | (3) | (1) | (0)
Glioma NOS | – | 1 (33%) | – | –
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | –
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 3 (6%) | 3 (6%) | 6 (12%) | 5 (10%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | – | 3 (6%)
Alveolar/bronchiolar carcinoma | – | – | 1 (2%) | –
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | –
Fibrosarcoma, metastatic, skin | – | – | – | 1 (2%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%)
Mediastinum, alveolar/bronchiolar adenoma, multiple | – | – | – | 1 (2%)
Mediastinum, alveolar/bronchiolar carcinoma | – | – | 1 (2%) | –
Mediastinum | (0) | (1) | (2) | (10)
Nose | (50) | (49) | (50) | (50)
Adenoma | – | – | – | 1 (2%)
Osteosarcoma | – | – | 1 (2%) | –
Turbinate, chondroma | 1 (2%) | – | – | –
Trachea | (50) | (50) | (50) | (50)
Carcinoma, metastatic, thyroid gland | 1 (2%) | – | – | –
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (49) | (49) | (50) | (49)
Sarcoma | – | – | – | 1 (2%)
Sarcoma, metastatic, Harderian gland | – | 1 (2%) | – | –
Choroid, melanoma benign | – | 1 (2%) | – | –
Harderian gland | (50) | (50) | (50) | (50)
Sarcoma | – | 1 (2%) | – | –
Lacrimal gland | (1) | (0) | (1) | (0)
Urinary System
Kidney | (50) | (50) | (50) | (50)
Carcinoma | – | – | – | 1 (2%)
Sarcoma | – | – | 1 (2%) | –
Ureter | (0) | (1) | (0) | (0)
Carcinoma, metastatic, prostate | – | 1 (100%) | – | –
Urinary bladder | (50) | (50) | (50) | (50)
Serosa, carcinoma, metastatic, prostate | – | 1 (2%) | – | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | – | – | – | 1 (2%)
Leukemia mononuclear | 1 (2%) | 1 (2%) | 1 (2%) | –
Lymphoma malignant | – | – | 1 (2%) | –
Mesothelioma malignant | – | – | – | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^
Twelve-month interim evaluation | – | – | – | 1
Two-year study | 36 | 34 | 40 | 35
Total primary neoplasms
Twelve-month interim evaluation | – | – | – | 1
Two-year study | 51 | 55 | 66 | 54
Total animals with benign neoplasms
Two-year study | 34 | 31 | 32 | 26
Total benign neoplasms
Two-year study | 44 | 43 | 47 | 39
Total animals with malignant neoplasms
Twelve-month interim evaluation | – | – | – | 1
Two-year study | 6 | 8 | 17 | 14
Total malignant neoplasms
Twelve-month interim evaluation | – | – | – | 1
Two-year study | 6 | 11 | 18 | 14
Total animals with metastatic neoplasms
Two-year study | 1 | 2 | 1 | 5
Total metastatic neoplasms
Two-year study | 5 | 4 | 3 | 12
Total animals with uncertain neoplasms, benign or malignant
Two-year study | 1 | 1 | 1 | 1
Total uncertain neoplasms
Two-year study | 1 | 1 | 1 | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in Male Rats in the Two-year Inhalation Study of Antimony Trioxide

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Adrenal Cortex: Adenoma
Overall rate^a^ | 3/50 (6%) | 0/50 (0%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate^b^ | 7.2% | 0.0% | 6.9% | 0.0%
Terminal rate^c^ | 2/30 (7%) | 0/30 (0%) | 1/28 (4%) | 0/18 (0%)
First incidence (days) | 607 | –^e^ | 589 | –
Poly-3 test^d^ | P = 0.205N | P = 0.121N | P = 0.642N | P = 0.125N
Adrenal Medulla: Benign Pheochromocytoma
Overall rate | 1/49 (2%) | 0/50 (0%) | 2/49 (4%) | 7/50 (14%)
Adjusted rate | 2.5% | 0.0% | 4.8% | 17.2%
Terminal rate | 1/30 (3%) | 0/30 (0%) | 1/27 (4%) | 3/18 (17%)
First incidence (days) | 729 (T) | – | 537 | 590
Poly-3 test | P < 0.001 | P = 0.498N | P = 0.515 | P = 0.030
Adrenal Medulla: Benign or Complex Pheochromocytoma
Overall rate | 2/49 (4%) | 0/50 (0%) | 2/49 (4%) | 7/50 (14%)
Adjusted rate | 4.9% | 0.0% | 4.8% | 17.2%
Terminal rate | 1/30 (3%) | 0/30 (0%) | 1/27 (4%) | 3/18 (17%)
First incidence (days) | 680 | – | 537 | 590
Poly-3 test | P = 0.003 | P = 0.236N | P = 0.681N | P = 0.078
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 6/50 (12%) | 8/50 (16%)
Adjusted rate | 7.1% | 9.8% | 13.8% | 19.7%
Terminal rate | 1/30 (3%) | 4/30 (13%) | 2/28 (7%) | 4/18 (22%)
First incidence (days) | 369 | 729 (T) | 534 | 649
Poly-3 test | P = 0.057 | P = 0.478 | P = 0.253 | P = 0.083
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 0/50 (0%) | 0/50 (0%) | 2/50 (4%) | 0/50 (0%)
Adjusted rate | 0.0% | 0.0% | 4.7% | 0.0%
Terminal rate | 0/30 (0%) | 0/30 (0%) | 1/28 (4%) | 0/18 (0%)
First incidence (days) | – | – | 719 | –
Poly-3 test | P = 0.702N | –^f^ | P = 0.245 | –
Lung: Alveolar/Bronchiolar Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 8/50 (16%) | 8/50 (16%)
Adjusted rate | 7.1% | 9.8% | 18.4% | 19.7%
Terminal rate | 1/30 (3%) | 4/30 (13%) | 3/28 (11%) | 4/18 (22%)
First incidence (days) | 369 | 729 (T) | 534 | 649
Poly-3 test | P = 0.067 | P = 0.478 | P = 0.104 | P = 0.083
Lymph Node (Mesenteric): Hemangiosarcoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 4.8% | 4.9% | 9.3% | 2.5%
Terminal rate | 0/30 (0%) | 2/30 (7%) | 2/28 (7%) | 0/18 (0%)
First incidence (days) | 582 | 729 (T) | 576 | 660
Poly-3 test | P = 0.391N | P = 0.684 | P = 0.350 | P = 0.515N
Pancreatic Islets: Adenoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 4/50 (8%) | 1/49 (2%)
Adjusted rate | 0.0% | 2.5% | 9.2% | 2.6%
Terminal rate | 0/30 (0%) | 1/30 (3%) | 1/28 (4%) | 0/17 (0%)
First incidence (days) | – | 729 (T) | 576 | 691
Poly-3 test | P = 0.509 | P = 0.499 | P = 0.067 | P = 0.490
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 0/50 (0%) | 1/50 (2%) | 4/50 (8%) | 2/49 (4%)
Adjusted rate | 0.0% | 2.5% | 9.2% | 5.1%
Terminal rate | 0/30 (0%) | 1/30 (3%) | 1/28 (4%) | 1/17 (6%)
First incidence (days) | – | 729 (T) | 576 | 691
Poly-3 test | P = 0.265 | P = 0.499 | P = 0.067 | P = 0.226
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 14/50 (28%) | 15/50 (30%) | 12/50 (24%) | 5/50 (10%)
Adjusted rate | 31.4% | 34.3% | 26.8% | 12.1%
Terminal rate | 6/30 (20%) | 8/30 (27%) | 5/28 (18%) | 1/18 (6%)
First incidence (days) | 477 | 486 | 499 | 590
Poly-3 test | P = 0.010N | P = 0.474 | P = 0.406N | P = 0.027N
Testes: Adenoma
Overall rate | 6/50 (12%) | 2/50 (4%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 14.5% | 4.9% | 2.4% | 2.5%
Terminal rate | 4/30 (13%) | 2/30 (7%) | 1/28 (4%) | 1/18 (6%)
First incidence (days) | 659 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.083N | P = 0.137N | P = 0.051N | P = 0.060N
Thymus: Benign Thymoma
Overall rate | 3/41 (7%) | 0/35 (0%) | 1/47 (2%) | 4/45 (9%)
Adjusted rate | 8.8% | 0.0% | 2.5% | 11.0%
Terminal rate | 1/25 (4%) | 0/21 (0%) | 1/27 (4%) | 2/16 (13%)
First incidence (days) | 680 | – | 729 (T) | 607
Poly-3 test | P = 0.174 | P = 0.147N | P = 0.249N | P = 0.536
Thymus: Benign or Malignant Thymoma
Overall rate | 3/41 (7%) | 1/35 (3%) | 1/47 (2%) | 4/45 (9%)
Adjusted rate | 8.8% | 3.5% | 2.5% | 11.0%
Terminal rate | 1/25 (4%) | 1/21 (5%) | 1/27 (4%) | 2/16 (13%)
First incidence (days) | 680 | 729 (T) | 729 (T) | 607
Poly-3 test | P = 0.264 | P = 0.365N | P = 0.249N | P = 0.536
Thyroid Gland (C-Cell): Adenoma
Overall rate | 5/50 (10%) | 9/50 (18%) | 5/50 (10%) | 5/50 (10%)
Adjusted rate | 12.2% | 21.4% | 11.8% | 12.4%
Terminal rate | 5/30 (17%) | 7/30 (23%) | 4/28 (14%) | 3/18 (17%)
First incidence (days) | 729 (T) | 499 | 719 | 649
Poly-3 test | P = 0.358N | P = 0.201 | P = 0.609N | P = 0.620
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 10/50 (20%) | 5/50 (10%) | 5/50 (10%)
Adjusted rate | 14.5% | 23.8% | 11.8% | 12.4%
Terminal rate | 5/30 (17%) | 8/30 (27%) | 4/28 (14%) | 3/18 (17%)
First incidence (days) | 659 | 499 | 719 | 649
Poly-3 test | P = 0.248N | P = 0.210 | P = 0.480N | P = 0.517N
All Organs: Hemangiosarcoma
Overall rate | 3/50 (6%) | 4/50 (8%) | 4/50 (8%) | 3/50 (6%)
Adjusted rate | 7.0% | 9.8% | 9.3% | 7.2%
Terminal rate | 0/30 (0%) | 3/30 (10%) | 2/28 (7%) | 0/18 (0%)
First incidence (days) | 369 | 691 | 576 | 459
Poly-3 test | P = 0.522N | P = 0.475 | P = 0.504 | P = 0.648
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 4/50 (8%) | 5/50 (10%) | 6/50 (12%) | 4/50 (8%)
Adjusted rate | 9.2% | 12.2% | 13.9% | 9.6%
Terminal rate | 0/30 (0%) | 4/30 (13%) | 3/28 (11%) | 0/18 (0%)
First incidence (days) | 369 | 691 | 576 | 459
Poly-3 test | P = 0.523N | P = 0.460 | P = 0.363 | P = 0.617
All Organs: Benign Neoplasms
Overall rate | 34/50 (68%) | 31/50 (62%) | 32/50 (64%) | 26/50 (52%)
Adjusted rate | 72.4% | 68.7% | 67.6% | 59.6%
Terminal rate | 20/30 (67%) | 22/30 (73%) | 16/28 (57%) | 10/18 (56%)
First incidence (days) | 369 | 486 | 499 | 562
Poly-3 test | P = 0.115N | P = 0.433N | P = 0.387N | P = 0.131N
All Organs: Malignant Neoplasms
Overall rate | 6/50 (12%) | 8/50 (16%) | 17/50 (34%) | 14/50 (28%)
Adjusted rate | 13.7% | 18.7% | 37.4% | 32.6%
Terminal rate | 0/30 (0%) | 4/30 (13%) | 6/28 (21%) | 7/18 (39%)
First incidence (days) | 369 | 339 | 159 | 409
Poly-3 test | P = 0.033 | P = 0.369 | P = 0.008 | P = 0.030
All Organs: Benign or Malignant Neoplasms
Overall rate | 36/50 (72%) | 34/50 (68%) | 40/50 (80%) | 35/50 (70%)
Adjusted rate | 75.5% | 72.3% | 80.6% | 74.3%
Terminal rate | 20/30 (67%) | 22/30 (73%) | 20/28 (71%) | 12/18 (67%)
First incidence (days) | 369 | 339 | 113 | 409
Poly-3 test | P = 0.554N | P = 0.449N | P = 0.358 | P = 0.542N

(T) = terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal gland, lung, pancreatic islets, pituitary gland, testes, thymus, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the chamber control incidence is the P value associated with the trend test. Beneath the exposed group incidence are the P values corresponding to pairwise comparisons between the chamber controls and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in an exposure group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Historical Incidence of Alveolar/Bronchiolar Neoplasms in Control Male Wistar Han Rats^a^

Study (Study Start) | Adenoma | Carcinoma | Adenoma or Carcinoma
Historical Incidence: Inhalation Studies
Antimony trioxide (September 2008) | 3/50 | 0/50 | 3/50
CIMSTAR 3800 (April 2008) | 1/50 | 0/50 | 1/50
Trim VX (July 2009) | 0/50 | 0/50 | 0/50
Total (%) | 4/150 (2.7%) | 0/150 | 4/150 (2.7%)
Mean ± standard deviation | 2.7% ± 3.1% | – | 2.7% ± 3.1%
Range | 0%–6% | – | 0%–6%
Overall Historical Incidence: All Routes
Total (%) | 4/299 (1.3%) | 0/299 | 4/299 (1.3%)
Mean ± standard deviation | 1.3% ± 2.4% | – | 1.3% ± 2.4%
Range | 0%–6% | – | 0%–6%

^a^ Data as of November 2014.

Table A-4 Historical Incidence of Pheochromocytoma of the Adrenal Medulla in Control Male Wistar Han Rats^a^

Study (Study Start) | Benign | Benign or Complex
Historical Incidence: Inhalation Studies
Antimony trioxide (September 2008) | 1/49 | 2/49
CIMSTAR 3800 (April 2008) | 4/50 | 4/50
Trim VX (July 2009) | 0/50 | 0/50
Total (%) | 5/149 (3.4%) | 6/149 (4.0%)
Mean ± standard deviation | 3.4% ± 4.2% | 4.0% ± 4.0%
Range | 0%–8% | 0%–8%
Overall Historical Incidence: All Routes
Total (%) | 6/297 (2.0%) | 7/297 (2.4%)
Mean ± standard deviation | 2.0% ± 3.1% | 2.4% ± 3.2%
Range | 0%–8% | 0%–8%

^a^ Data as of November 2014.

Table A-5 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Inhalation Study of Antimony Trioxide^a^

| Chamber Control | 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Disposition Summary
Animals initially in study | 60 | 60 | 60 | 60
Twelve-month interim evaluation | 10 | 10 | 10 | 10
Early deaths
Moribund | 15 | 19 | 22 | 29
Natural deaths | 5 | 1 | – | 3
Survivors
Terminal kill | 30 | 30 | 28 | 18
Animals examined microscopically | 60 | 60 | 60 | 60
Twelve-month Interim Evaluation
Alimentary System
Esophagus | (10) | (10) | (10) | (10)
Intestine large, cecum | (10) | (10) | (10) | (10)
Intestine large, colon | (10) | (10) | (10) | (10)
Intestine large, rectum | (10) | (9) | (10) | (10)
Intestine small, duodenum | (10) | (10) | (10) | (10)
Intestine small, ileum | (10) | (10) | (10) | (10)
Intestine small, jejunum | (10) | (10) | (10) | (10)
Liver | (10) | (10) | (10) | (10)
Congestion | – | 1 (10%) | – | –
Pancreas | (10) | (10) | (10) | (10)
Atrophy | 3 (30%) | 2 (20%) | 2 (20%) | –
Inflammation, chronic active | 3 (30%) | 1 (10%) | 1 (10%) | –
Arteriole, inflammation, chronic active | – | – | 1 (10%) | –
Salivary glands | (10) | (10) | (10) | (10)
Stomach, forestomach | (10) | (10) | (10) | (10)
Ulcer | 1 (10%) | – | – | –
Stomach, glandular | (10) | (10) | (10) | (10)
Inflammation, chronic active | 1 (10%) | – | – | 2 (20%)
Cardiovascular System
Blood vessel | (10) | (10) | (10) | (10)
Heart | (10) | (10) | (10) | (10)
Cardiomyopathy | 3 (30%) | 2 (20%) | 5 (50%) | 2 (20%)
Endocrine System
Adrenal cortex | (10) | (10) | (10) | (10)
Hyperplasia | 1 (10%) | 3 (30%) | 2 (20%) | 3 (30%)
Adrenal medulla | (10) | (10) | (9) | (10)
Hypertrophy | 1 (10%) | – | – | –
Islets, pancreatic | (10) | (10) | (10) | (10)
Parathyroid gland | (10) | (10) | (9) | (8)
Pituitary gland | (10) | (10) | (10) | (10)
Pars distalis, hyperplasia | 1 (10%) | – | – | –
Thyroid gland | (10) | (10) | (10) | (10)
Hyperplasia, squamous | – | 1 (10%) | – | –
Genital System
Epididymis | (10) | (10) | (10) | (10)
Preputial gland | (10) | (10) | (10) | (9)
Inflammation, chronic active | 4 (40%) | 2 (20%) | 6 (60%) | 3 (33%)
Prostate | (10) | (10) | (10) | (10)
Inflammation, suppurative | 3 (30%) | – | – | 1 (10%)
Epithelium, hyperplasia | – | 1 (10%) | – | –
Seminal vesicle | (10) | (10) | (10) | (10)
Testes | (10) | (10) | (10) | (10)
Germinal epithelium, degeneration | 2 (20%) | 2 (20%) | – | –
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10)
Lymph node, bronchial | (9) | (8) | (10) | (10)
Foreign body | – | 8 (100%) | 10 (100%) | 10 (100%)
Hyperplasia, lymphoid | – | 2 (25%) | 5 (50%) | 2 (20%)
Lymph node, mandibular | (10) | (9) | (9) | (8)
Lymph node, mediastinal | (10) | (8) | (10) | (9)
Foreign body | – | 8 (100%) | 6 (60%) | 6 (67%)
Hyperplasia, lymphoid | – | 2 (25%) | 6 (60%) | 3 (33%)
Pigmentation | 5 (50%) | 5 (63%) | 8 (80%) | 5 (56%)
Lymph node, mesenteric | (10) | (10) | (10) | (10)
Spleen | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | 2 (20%) | 5 (50%) | 2 (20%) | 4 (40%)
Thymus | (10) | (10) | (10) | (10)
Integumentary System
Mammary gland | (4) | (1) | (1) | (3)
Skin | (10) | (10) | (10) | (10)
Fibrosis | – | – | 1 (10%) | –
Respiratory System
Larynx | (10) | (10) | (10) | (10)
Foreign body | – | 10 (100%) | 10 (100%) | 10 (100%)
Infiltration cellular, lymphocyte | 1 (10%) | – | – | –
Lung | (10) | (10) | (10) | (10)
Fibrosis | – | 10 (100%) | 10 (100%) | 10 (100%)
Foreign body | – | 10 (100%) | 10 (100%) | 10 (100%)
Inflammation, chronic active | 1 (10%) | 10 (100%) | 10 (100%) | 10 (100%)
Metaplasia, osseous | – | – | 1 (10%) | –
Proteinosis | – | 9 (90%) | 10 (100%) | 10 (100%)
Alveolar epithelium, hyperplasia | – | 10 (100%) | 10 (100%) | 10 (100%)
Alveolus, inflammation, suppurative | – | 1 (10%) | 2 (20%) | 2 (20%)
Bronchiole, epithelium, hyperplasia | – | 5 (50%) | 5 (50%) | 6 (60%)
Perivascular, infiltration cellular, lymphocyte | – | 4 (40%) | 4 (40%) | 3 (30%)
Nose | (10) | (10) | (10) | (10)
Foreign body | – | – | 1 (10%) | 9 (90%)
Inflammation, suppurative | – | 1 (10%) | – | 1 (10%)
Glands, respiratory epithelium, cyst | – | – | 1 (10%) | –
Olfactory epithelium, accumulation, hyaline droplet | 3 (30%) | 1 (10%) | 4 (40%) | 2 (20%)
Respiratory epithelium, accumulation, hyaline droplet | 2 (20%) | – | – | –
Respiratory epithelium, hyperplasia | – | – | 1 (10%) | 2 (20%)
Trachea | (10) | (10) | (10) | (10)
Foreign body | – | 8 (80%) | 9 (90%) | 10 (100%)
Infiltration cellular, polymorphonuclear | – | – | – | 1 (10%)
Special Senses System
Eye | (10) | (10) | (10) | (10)
Lens, degeneration | – | – | 1 (10%) | –
Retina, atrophy | 2 (20%) | 1 (10%) | – | –
Harderian gland | (10) | (10) | (10) | (10)
Urinary System
Kidney | (10) | (10) | (10) | (10)
Nephropathy | 6 (60%) | 3 (30%) | 4 (40%) | 5 (50%)
Pelvis, dilatation | 1 (10%) | – | – | –
Pelvis, inflammation, chronic active | – | 1 (10%) | – | –
Urinary bladder | (10) | (10) | (10) | (10)
Calculus gross observation | – | – | 3 (30%) | 2 (20%)
Systems Examined at 12 Months with No Lesions Observed
General Body System
Musculoskeletal System
Nervous System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Intestine large, cecum | (49) | (50) | (50) | (49)
Necrosis | – | – | – | 1 (2%)
Intestine large, colon | (50) | (50) | (50) | (50)
Edema | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | –
Intestine large, rectum | (44) | (49) | (48) | (48)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Intestine small, duodenum | (47) | (50) | (50) | (49)
Fibrosis | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | – | –
Intestine small, ileum | (48) | (50) | (50) | (49)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, suppurative | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | –
Necrosis | – | – | 1 (2%) | –
Epithelium, atrophy | – | – | – | 1 (2%)
Intestine small, jejunum | (46) | (49) | (50) | (48)
Fibrosis | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | –
Liver | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | 3 (6%) | 4 (8%) | 1 (2%)
Basophilic focus | 3 (6%) | 5 (10%) | 5 (10%) | 1 (2%)
Clear cell focus | 18 (36%) | 14 (28%) | 15 (30%) | 8 (16%)
Congestion | 3 (6%) | 8 (16%) | 6 (12%) | 6 (12%)
Cyst | 2 (4%) | 4 (8%) | 2 (4%) | 1 (2%)
Eosinophilic focus | – | 1 (2%) | 1 (2%) | 2 (4%)
Fatty change | 4 (8%) | 8 (16%) | 4 (8%) | 3 (6%)
Fibrosis | – | 1 (2%) | – | 1 (2%)
Hematopoietic cell proliferation | – | – | – | 1 (2%)
Hepatodiaphragmatic nodule | – | 2 (4%) | 3 (6%) | 1 (2%)
Inflammation, chronic active | 2 (4%) | – | 1 (2%) | 1 (2%)
Mineralization | – | 1 (2%) | – | –
Mixed cell focus | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | 1 (2%) | 2 (4%)
Bile duct, cyst, multiple | – | – | – | 1 (2%)
Bile duct, dilatation | – | – | 1 (2%) | –
Bile duct, hyperplasia | – | – | – | 3 (6%)
Sinusoid, dilatation | 1 (2%) | – | – | –
Vein, dilatation | – | 1 (2%) | – | –
Mesentery | (50) | (50) | (50) | (50)
Arteriole, inflammation, chronic active | 1 (2%) | – | – | –
Artery, inflammation, chronic active | – | – | – | 6 (12%)
Artery, necrosis | – | – | – | 3 (6%)
Fat, necrosis | 1 (2%) | 4 (8%) | 3 (6%) | 2 (4%)
Pancreas | (50) | (50) | (50) | (50)
Atrophy | 15 (30%) | 12 (24%) | 14 (28%) | 20 (40%)
Basophilic focus | 3 (6%) | 4 (8%) | – | –
Inflammation, chronic active | 1 (2%) | – | 2 (4%) | 2 (4%)
Arteriole, inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Artery, hemorrhage | – | – | 1 (2%) | –
Artery, inflammation, chronic active | 1 (2%) | – | 2 (4%) | 8 (16%)
Artery, necrosis | – | – | 1 (2%) | 4 (8%)
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | – | 2 (4%) | – | 2 (4%)
Basophilic focus | – | 1 (2%) | – | –
Inflammation, suppurative | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Cyst, squamous | 1 (2%) | – | – | –
Edema | – | – | – | 2 (4%)
Hyperplasia, squamous | 2 (4%) | 7 (14%) | 4 (8%) | 7 (14%)
Inflammation, suppurative | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | 1 (2%) | –
Ulcer | 1 (2%) | – | – | 1 (2%)
Stomach, glandular | (50) | (50) | (50) | (50)
Edema | – | – | – | 1 (2%)
Erosion | – | – | – | 1 (2%)
Fibrosis | – | 1 (2%) | – | –
Hemorrhage | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | 1 (2%) | 3 (6%)
Metaplasia, squamous | – | – | 1 (2%) | –
Mineralization | 1 (2%) | – | 1 (2%) | 1 (2%)
Ulcer | – | 1 (2%) | – | –
Arteriole, mineralization | – | 1 (2%) | – | –
Capillary, hyperplasia | – | – | – | 1 (2%)
Tongue | (1) | (1) | (0) | (1)
Epithelium, hyperplasia | 1 (100%) | – | – | 1 (100%)
Tooth | (2) | (1) | (1) | (1)
Inflammation, suppurative | – | 1 (100%) | – | –
Inflammation, chronic active | – | – | 1 (100%) | 1 (100%)
Malformation | 2 (100%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (50) | (50) | (49)
Angiomatous hyperplasia | – | – | 1 (2%) | –
Mineralization | 1 (2%) | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (50)
Angiectasis | – | – | – | 1 (2%)
Cardiomyopathy | 41 (82%) | 44 (88%) | 42 (84%) | 40 (80%)
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Thrombosis | – | – | – | 2 (4%)
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Valve, fibrosis | – | – | 1 (2%) | –
Valve, inflammation, suppurative | – | – | – | 1 (2%)
Valve, thrombosis | – | – | – | 2 (4%)
Endocrine System
Adrenal cortex | (50) | (50) | (50) | (50)
Accessory adrenal cortical nodule | – | 1 (2%) | 1 (2%) | –
Angiectasis | – | 2 (4%) | – | 3 (6%)
Atrophy | 1 (2%) | – | 2 (4%) | –
Degeneration, cystic | 3 (6%) | – | 1 (2%) | 3 (6%)
Hematopoietic cell proliferation | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia | 30 (60%) | 32 (64%) | 33 (66%) | 32 (64%)
Vacuolization cytoplasmic | 1 (2%) | – | – | –
Adrenal medulla | (49) | (50) | (49) | (50)
Degeneration, fatty | – | – | – | 1 (2%)
Hyperplasia | 1 (2%) | 2 (4%) | 4 (8%) | 8 (16%)
Thrombosis | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (49)
Parathyroid gland | (44) | (46) | (46) | (48)
Fibrosis | – | – | 1 (2%) | –
Hyperplasia | 4 (9%) | – | 1 (2%) | 1 (2%)
Pituitary gland | (50) | (50) | (50) | (50)
Angiectasis | 1 (2%) | – | – | –
Cyst | – | 1 (2%) | – | –
Hemorrhage | 1 (2%) | – | – | –
Pars distalis, hyperplasia | 11 (22%) | 11 (22%) | 14 (28%) | 15 (30%)
Pars intermedia, angiectasis | 1 (2%) | – | – | –
Pars intermedia, hyperplasia | 1 (2%) | 4 (8%) | – | 1 (2%)
Thyroid gland | (50) | (50) | (50) | (50)
C-cell, hyperplasia | 9 (18%) | 11 (22%) | 13 (26%) | 6 (12%)
Follicle, cyst | 1 (2%) | 1 (2%) | – | –
Follicular cell, hyperplasia | 1 (2%) | 2 (4%) | – | 2 (4%)
General Body System
Tissue NOS | (0) | (1) | (0) | (1)
Genital System
Coagulating gland | (0) | (0) | (0) | (1)
Inflammation, chronic active | – | – | – | 1 (100%)
Epididymis | (50) | (50) | (50) | (50)
Epithelium, cytoplasmic alteration | 1 (2%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Ectasia | 1 (2%) | 1 (2%) | 4 (8%) | –
Fibrosis | – | 1 (2%) | – | –
Inflammation, chronic active | 7 (14%) | 5 (10%) | 4 (8%) | 4 (8%)
Prostate | (50) | (50) | (50) | (50)
Inflammation, suppurative | 1 (2%) | 6 (12%) | 5 (10%) | 4 (8%)
Inflammation, chronic active | 8 (16%) | 3 (6%) | 5 (10%) | 3 (6%)
Epithelium, hyperplasia | 9 (18%) | 18 (36%) | 21 (42%) | 13 (26%)
Seminal vesicle | (50) | (50) | (50) | (50)
Congestion | – | – | – | 1 (2%)
Hyperplasia | – | 1 (2%) | – | –
Inflammation, suppurative | – | 1 (2%) | – | –
Inflammation, chronic active | 2 (4%) | – | – | 1 (2%)
Epithelium, hyperplasia | 1 (2%) | – | – | –
Testes | (50) | (50) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Edema | 30 (60%) | 37 (74%) | 31 (62%) | 26 (52%)
Fibrosis | – | 1 (2%) | – | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Arteriole, inflammation, chronic active | 1 (2%) | – | – | –
Germinal epithelium, degeneration | 3 (6%) | 6 (12%) | 6 (12%) | 4 (8%)
Interstitial cell, hyperplasia | 1 (2%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Depletion cellular | – | 1 (2%) | – | –
Fibrosis | – | 1 (2%) | – | –
Hyperplasia | – | 3 (6%) | 4 (8%) | 8 (16%)
Lymph node | (2) | (4) | (7) | (7)
Hyperplasia, plasma cell | – | – | 1 (14%) | –
Axillary, hyperplasia, plasma cell | – | 1 (25%) | – | –
Axillary, infiltration cellular, histiocyte | – | – | – | 1 (14%)
Iliac, ectasia | – | – | 2 (29%) | –
Iliac, hyperplasia, plasma cell | – | – | 1 (14%) | 1 (14%)
Lumbar, ectasia | – | – | – | 1 (14%)
Lumbar, hyperplasia, plasma cell | | 2 (50%) | 2 (29%) | 3 (43%)
Lumbar, infiltration cellular, histiocyte | – | – | – | 1 (14%)
Lumbar, renal, hyperplasia, plasma cell | 1 (50%) | – | – | –
Pancreatic, congestion | – | – | 1 (14%) | –
Renal, ectasia | 1 (50%) | – | – | 2 (29%)
Renal, infiltration cellular, histiocyte | – | – | – | 1 (14%)
Lymph node, bronchial | (41) | (40) | (48) | (47)
Ectasia | – | – | 1 (2%) | –
Foreign body | – | 35 (88%) | 45 (94%) | 42 (89%)
Hyperplasia, lymphoid | – | 21 (52%) | 29 (60%) | 26 (55%)
Pigmentation | 1 (2%) | 4 (10%) | 5 (10%) | 10 (21%)
Lymph node, mandibular | (45) | (46) | (48) | (45)
Hyperplasia, plasma cell | – | 1 (2%) | 2 (4%) | –
Lymph node, mediastinal | (42) | (45) | (49) | (49)
Congestion | – | – | – | 1 (2%)
Foreign body | – | 41 (91%) | 41 (84%) | 43 (88%)
Hyperplasia | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | 24 (53%) | 30 (61%) | 26 (53%)
Pigmentation | 24 (57%) | 23 (51%) | 29 (59%) | 26 (53%)
Lymph node, mesenteric | (50) | (50) | (50) | (50)
Angiomatous hyperplasia | – | 1 (2%) | – | 3 (6%)
Ectasia | – | – | – | 2 (4%)
Fibrosis | – | – | 1 (2%) | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Artery, inflammation, chronic active | – | – | – | 1 (2%)
Spleen | (50) | (50) | (50) | (50)
Accessory spleen | 1 (2%) | – | – | –
Cyst | | 1 (2%) | – | –
Depletion cellular | 1 (2%) | – | 1 (2%) | 1 (2%)
Depletion cellular, focal | – | – | 1 (2%) | –
Fibrosis | – | – | 1 (2%) | –
Hematopoietic cell proliferation | 41 (82%) | 45 (90%) | 43 (86%) | 46 (92%)
Hemorrhage | – | 1 (2%) | – | –
Mineralization | – | – | – | 1 (2%)
Necrosis | – | 1 (2%) | – | –
Thymus | (41) | (35) | (47) | (45)
Cyst | – | – | 1 (2%) | –
Depletion cellular | 5 (12%) | 6 (17%) | 6 (13%) | 9 (20%)
Hemorrhage | 1 (2%) | – | – | –
Epithelial cell, hyperplasia | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (6) | (9) | (7) | (8)
Galactocele | – | 1 (11%) | 1 (14%) | –
Skin | (50) | (50) | (50) | (50)
Cyst, squamous | 2 (4%) | – | – | –
Dysplasia | 1 (2%) | – | – | –
Foreign body | – | 1 (2%) | – | –
Inflammation, chronic active | 22 (44%) | 30 (60%) | 28 (56%) | 32 (64%)
Ulcer | 17 (34%) | 23 (46%) | 23 (46%) | 28 (56%)
Epidermis, hyperplasia | – | 1 (2%) | – | –
Hair follicle, hyperplasia | – | – | – | 1 (2%)
Subcutaneous tissue, hemorrhage | 1 (2%) | – | – | –
Subcutaneous tissue, inflammation, granulomatous | 1 (2%) | – | 1 (2%) | –
Subcutaneous tissue, inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (50)
Inflammation, chronic active | – | – | 1 (2%) | –
Epiphysis, femur, cyst | – | – | 1 (2%) | –
Femur, hyperostosis | – | 1 (2%) | – | –
Mandible, cyst, squamous | – | – | 1 (2%) | –
Maxilla, cyst, squamous | – | 1 (2%) | – | –
Maxilla, inflammation, chronic active | 3 (6%) | 4 (8%) | 2 (4%) | 1 (2%)
Vertebra, fibrosis | – | 1 (2%) | – | –
Skeletal muscle | (4) | (3) | (3) | (5)
Atrophy | – | 1 (33%) | – | –
Cyst | – | – | – | 1 (20%)
Hemorrhage | 1 (25%) | – | – | –
Inflammation, chronic active | – | – | – | 1 (20%)
Necrosis | – | – | 1 (33%) | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Compression | 7 (14%) | 11 (22%) | 8 (16%) | 2 (4%)
Hemorrhage | 1 (2%) | – | – | –
Meninges, hyperplasia | – | – | 1 (2%) | 1 (2%)
Peripheral nerve | (3) | (3) | (2) | (0)
Degeneration | – | 1 (33%) | 1 (50%) | –
Spinal cord | (3) | (3) | (1) | (0)
Respiratory System
Larynx | (50) | (50) | (50) | (50)
Foreign body | | 50 (100%) | 50 (100%) | 50 (100%)
Hyperplasia, squamous | – | – | – | 2 (4%)
Inflammation, chronic active | 2 (4%) | 5 (10%) | 2 (4%) | 4 (8%)
Metaplasia, squamous | – | 2 (4%) | – | 1 (2%)
Mineralization | – | – | 1 (2%) | –
Necrosis | 1 (2%) | – | – | 1 (2%)
Respiratory epithelium, hyperplasia | 2 (4%) | 4 (8%) | 1 (2%) | –
Lung | (50) | (50) | (50) | (50)
Congestion | – | 1 (2%) | – | –
Fibrosis | 2 (4%) | 50 (100%) | 49 (98%) | 49 (98%)
Foreign body | 1 (2%) | 50 (100%) | 50 (100%) | 50 (100%)
Hemorrhage | 2 (4%) | 2 (4%) | 1 (2%) | 3 (6%)
Inflammation, chronic active | 18 (36%) | 50 (100%) | 50 (100%) | 50 (100%)
Metaplasia, osseous | 1 (2%) | 2 (4%) | 2 (4%) | 9 (18%)
Proteinosis | – | 47 (94%) | 50 (100%) | 50 (100%)
Alveolar epithelium, hyperplasia | 4 (8%) | 50 (100%) | 48 (96%) | 49 (98%)
Alveolar epithelium, metaplasia, squamous | – | – | 1 (2%) | –
Alveolus, inflammation, suppurative | – | 12 (24%) | 24 (48%) | 28 (56%)
Artery, inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Bronchiole, epithelium, hyperplasia | 3 (6%) | 34 (68%) | 36 (72%) | 33 (66%)
Bronchus, hyperplasia | – | – | – | 1 (2%)
Bronchus, inflammation, chronic active | – | 1 (2%) | – | –
Bronchus, metaplasia, squamous | – | 1 (2%) | – | –
Perivascular, infiltration cellular, lymphocyte | 3 (6%) | 25 (50%) | 19 (38%) | 9 (18%)
Perivascular, infiltration cellular, lymphoid | – | – | – | 1 (2%)
Mediastinum | (0) | (1) | (2) | (10)
Artery, inflammation, chronic active | – | 1 (100%) | 2 (100%) | 10 (100%)
Artery, necrosis | – | – | 2 (100%) | 9 (90%)
Nose | (50) | (49) | (50) | (50)
Foreign body | – | – | 17 (34%) | 40 (80%)
Hyperplasia, squamous | 1 (2%) | – | – | –
Inflammation, suppurative | 4 (8%) | 4 (8%) | 6 (12%) | 7 (14%)
Inflammation, acute | – | – | – | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Mineralization | 1 (2%) | – | – | –
Glands, cyst | – | 1 (2%) | – | –
Glands, respiratory epithelium, cyst | 1 (2%) | – | – | 2 (4%)
Olfactory epithelium, accumulation, hyaline droplet | 16 (32%) | 15 (31%) | 15 (30%) | 18 (36%)
Olfactory epithelium, atrophy | – | – | 1 (2%) | –
Olfactory epithelium, hyperplasia | – | – | 1 (2%) | –
Olfactory epithelium, metaplasia, respiratory | – | 1 (2%) | – | 1 (2%)
Respiratory epithelium, hyperplasia | 6 (12%) | 15 (31%) | 13 (26%) | 25 (50%)
Respiratory epithelium, metaplasia, squamous | – | – | 2 (4%) | 6 (12%)
Respiratory epithelium, necrosis | 1 (2%) | – | 3 (6%) | 1 (2%)
Respiratory epithelium, regeneration | – | – | – | 2 (4%)
Turbinate, hyperostosis | – | – | 1 (2%) | 1 (2%)
Trachea | (50) | (50) | (50) | (50)
Foreign body | – | 28 (56%) | 43 (86%) | 48 (96%)
Inflammation, suppurative | – | 3 (6%) | 1 (2%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Metaplasia, squamous | 1 (2%) | 1 (2%) | 4 (8%) | 3 (6%)
Mineralization | – | – | 1 (2%) | 1 (2%)
Necrosis | – | – | – | 1 (2%)
Epithelium, hyperplasia | – | 1 (2%) | – | –
Epithelium, regeneration | – | – | – | 1 (2%)
Special Senses System
Ear | (0) | (0) | (1) | (0)
Eye | (49) | (49) | (50) | (49)
Ciliary body, inflammation, acute | – | – | 1 (2%) | 6 (12%)
Cornea, inflammation, chronic active | – | – | – | 2 (4%)
Iris, infiltration cellular, histiocyte | – | – | 1 (2%) | –
Lens, degeneration | 2 (4%) | 5 (10%) | 3 (6%) | 4 (8%)
Retina, atrophy | 8 (16%) | 11 (22%) | 9 (18%) | 6 (12%)
Harderian gland | (50) | (50) | (50) | (50)
Hyperplasia | 2 (4%) | 1 (2%) | – | 3 (6%)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Lacrimal gland | (1) | (0) | (1) | (0)
Atrophy | – | – | 1 (100%) | –
Hypertrophy | 1 (100%) | – | – | –
Urinary System
Kidney | (50) | (50) | (50) | (50)
Accumulation, hyaline droplet | – | – | 1 (2%) | –
Amyloid deposition | – | 1 (2%) | – | –
Cyst | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Fibrosis | – | – | – | 1 (2%)
Infarct | – | 1 (2%) | 2 (4%) | 1 (2%)
Inflammation, suppurative | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | – | 2 (4%)
Metaplasia, osseous | – | – | – | 1 (2%)
Nephropathy | 41 (82%) | 41 (82%) | 40 (80%) | 38 (76%)
Thrombosis | – | 1 (2%) | – | –
Artery, inflammation, chronic active | – | – | 1 (2%) | 4 (8%)
Artery, necrosis | – | – | 1 (2%) | 4 (8%)
Papilla, necrosis | – | – | – | 2 (4%)
Pelvis, dilatation | 2 (4%) | 2 (4%) | 1 (2%) | 3 (6%)
Pelvis, inflammation, suppurative | 2 (4%) | 3 (6%) | 5 (10%) | 2 (4%)
Pelvis, inflammation, chronic active | 4 (8%) | – | 1 (2%) | 1 (2%)
Pelvis, mineralization | 16 (32%) | 10 (20%) | 11 (22%) | 3 (6%)
Renal tubule, accumulation, hyaline droplet | – | 1 (2%) | 3 (6%) | 14 (28%)
Renal tubule, hyperplasia | 1 (2%) | – | – | 1 (2%)
Renal tubule, mineralization | 1 (2%) | – | – | 2 (4%)
Vein, thrombosis | – | 1 (2%) | – | –
Ureter | (0) | (1) | (0) | (0)
Urinary bladder | (50) | (50) | (50) | (50)
Calculus gross observation | – | – | – | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Inflammation, suppurative | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | –
Serosa, inflammation, chronic active | – | – | – | 1 (2%)
Transitional epithelium, hyperplasia | – | – | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.