# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology Studies of a Pentabromodiphenyl Ether Mixture [DE-71 (Technical Grade)] (CASRN 32534-81-9) in F344/N Rats and B6C3F1/N Mice and Toxicology and Carcinogenesis Studies of a Pentabromodiphenyl Ether Mixture [DE-71 (Technical Grade)] in Wistar Han [Crl:WI(Han)] Rats and B6C3F1/N Mice (Gavage Studies) on June 25, 2015, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- Kenneth M. Portier, Ph.D., Chairperson
  Statistics and Evaluation Center
  American Cancer Society
  Atlanta, Georgia, USA
- Russell C. Cattley, V.M.D., Ph.D.
  Department of Pathobiology
  College of Veterinary Medicine
  Auburn University
  Auburn, Alabama, USA
- Michael W. Conner, D.V.M.
  Theravance, Inc.
  San Francisco, California, USA
- Willem D. Faber, Ph.D.
  Willem Faber Toxicology Consulting, LLC
  Victor, New York, USA
- Susan P. Felter, Ph.D.
  Procter & Gamble
  West Chester, Ohio, USA
- Gabriele Ludewig, Ph.D.
  Department of Occupational and Environmental Health
  College of Public Health
  University of Iowa
  Iowa City, Iowa, USA
- Donald G. Stump, Ph.D.
  WIL Research
  Ashland, Ohio, USA