# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  J.K. Dunnick, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  H.C. Cunny, Ph.D.
  M.J. Devito, Ph.D.
  P.M. Foster, Ph.D.
  D.R. Germolec, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  B.A. Merrick, Ph.D.
  A.R. Pandiri, B.V.Sc. & A.H., Ph.D.
  J.M. Sanders, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results, conducted pathology review and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Conducted pathology review
  M.M. Gruebbel, D.V.M., Ph.D.
  R.R. Moore, D.V.M.
- Southern Research Institute, Birmingham, Alabama, USA
  Conducted studies and evaluated pathology findings
  C.D. Hébert, Ph.D., Principal Investigator
  R. Fulton, D.V.M., Ph.D.
  S.D. Grimes, D.V.M., Ph.D.
  G. Lathrop, Jr., D.V.M., M.S.
  J.F. Mann, D.V.M.
  J. Toomey, D.V.M.
- Pathology Associates International, A Charles River Company, Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Groups
  C.L. Johnson, D.V.M., Coordinated 2-year rats (November 19 & 20, 2013)
  S.A. Hayes, D.V.M., Ph.D., Co-coordinated 2-year mice (December 17 & 19, 2013)
  J.P. Morrison, D.V.M., Co-coordinated 2-year mice (December 17 & 19, 2013)
- Gene Logic Laboratories, Inc., Gaithersburg, Maryland, USA
  Provided SCVCE analysis
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.