# References

1 Agency for Toxic Substances and Disease Registry (ATSDR) Toxicological profile for polybrominated biphenyls and polybrominated diphenyl ethers, Atlanta (GA): U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2004.
2 U.S. Environmental Protection Agency (USEPA). An exposure assessment of polybrominated diphenyl ethers. 2010. EPA Report No. EPA/600/R-08/086F. https://cfpub.epa.gov/ncea/risk/recordisplay.cfm?deid=210404
3 U.S. Environmental Protection Agency (USEPA). Toxicological review of 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47) (CAS No. 5436-43-1). 2008. EPA Report No. EPA/635/R-07/005F. https://www.epa.gov/iris/
4 U.S. Environmental Protection Agency (USEPA) Toxicological review of 2,2′.4,4′,5-pentabromodiphenyl ether (BDE-99) (CAS No. 60348-60-9). 2008. EPA Report No. EPA/635/R-07/006F. https://www.epa.gov/iris/
5 U.S. Environmental Protection Agency (USEPA). Toxicological review of 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE-153) (CAS No. 68631-49-2). 2008. EPA Report No. EPA/635/R-07/007F. https://www.epa.gov/iris/
6 European Food Safety Authority (EFSA) Scientific opinion on polybrominated diphenyl ethers (PBDEs) in food. EFSA J. 2011;9:1–274.
7 Wu J-P Guan Y-T Zhang Y Luo X-J Zhi H Chen S-J Mai B-X Several current-use, non-PBDE brominated flame retardants are highly bioaccumulative: evidence from field determined bioaccumulation factors. Environ Int. 2011;37(1):210–215. 10.1016/j.envint.2010.09.006 20952068
8 Mackay D, Shiu WY, Ma K-C, Lee SC. Physical-chemical properties and environmental fate for organic chemicals, 2nd ed. Volume III: Oxygen containing compounds. Boca Raton, FL: CRC Press, Taylor & Francis Group; 2006. p. 2436, 2437, 2446-2447. 10.1201/9781420044393
9 Hale RC La Guardia MJ Harvey EP Gaylor MO Mainor TM Duff WH Flame retardants. Persistent pollutants in land-applied sludges. Nature. 2001;412(6843):140–141. 10.1038/35084130 11449259
10 Hale RC La Guardia MJ Harvey E Mainor TM Potential role of fire retardant-treated polyurethane foam as a source of brominated diphenyl ethers to the US environment. Chemosphere. 2002;46(5):729–735. 10.1016/S0045-6535(01)00237-5 11999796
11 Hale RC Alaee M Manchester-Neesvig JB Stapleton HM Ikonomou MG Polybrominated diphenyl ether flame retardants in the North American environment. Environ Int. 2003;29(6):771–779. 10.1016/s0160-4120(03)00113-2 12850095
12 Lee LK Ding C Yang K-L He J Complete debromination of tetra- and penta-brominated diphenyl ethers by a coculture consisting of dehalococcoides and desulfovibrio species. Environ Sci Technol. 2011;45(19):8475–8482. 10.1021/es201559g 21859110
13 Lee LK He J Reductive debromination of polybrominated diphenyl ethers by anaerobic bacteria from soils and sediments. Appl Environ Microbiol. 2010;76(3):794–802. 10.1128/aem.01872-09 20008168
14 Van Pee K-H Unversucht S Biological dehalogenation and halogenation reactions. Chemosphere. 2003;52(2):299–312. 10.1016/S0045-6535(03)00204-2 12738254
15 Rodenburg LA Meng Q Yee D Greenfield BK Evidence for photochemical and microbial debromination of polybrominated diphenyl ether flame retardants in San Francisco Bay sediment. Chemosphere. 2014;106:36–43. 10.1016/j.chemosphere.2013.12.083 24485321
16 Söderström G Sellström U de Wit CA Tysklind M Photolytic debromination of decabromodiphenyl ether (BDE 209). Environ Sci Technol. 2004;38(1):127–132. 10.1021/es034682c 14740727
17 Chen D Hale RC A global review of polybrominated diphenyl ether flame retardant contamination in birds. Environ Int. 2010;36(7):800–811. 10.1016/j.envint.2010.05.013 20557935
18 Huwe JK West M Polybrominated diphenyl ethers in U.S. meat and poultry from two statistically designed surveys showing trends and levels from 2002 to 2008. J Agric Food Chem. 2011;59(10):5428–5434. 10.1021/jf2003915 21491934
19 Stahl LL Snyder BD Olsen AR Walters LS A national probabilistic study of polybrominated diphenyl ethers in fish from US lakes and reservoirs. Environ Monit Assess. 2013;185(12):10351–10364. 10.1007/s10661-013-3337-6 23907489
20 Schecter A Smith S Colacino J Malik N Opel M Paepke O Birnbaum L Contamination of U.S. butter with polybrominated diphenyl ethers from wrapping paper. Environ Health Perspect. 2011;119(2):151–154. 10.1289/ehp.1002604 21138809
21 Chen S-J Ma Y-J Wang J Chen D Luo X-J Mai B-X Brominated flame retardants in children’s toys: Concentration, composition, and children’s exposure and risk assessment. Environ Sci Technol. 2009;43(11):4200–4206. 10.1021/es9004834 19569352
22 Frederiksen M Thomsen C Frøshaug M Vorkamp K Thomsen M Becher G Knudsen LE Polybrominated diphenyl ethers in paired samples of maternal and umbilical cord blood plasma and associations with house dust in a Danish cohort. Int J Hyg Environ Health. 2010;213(4):233–242. 10.1016/j.ijheh.2010.04.008 20471317
23 Huang H Zhang S Christie P Plant uptake and dissipation of PBDEs in the soils of electronic waste recycling sites. Environ Pollut. 2011;159(1):238–243. 10.1016/j.envpol.2010.08.034 20869797
24 Wyrzykowska-Ceradini B Gullett BK Tabor D Touati A PBDDs/Fs and PCDDs/Fs in the raw and clean flue gas during steady state and transient operation of a municipal waste combustor. Environ Sci Technol. 2011;45(13):5853–5860. 10.1021/es200364u 21657324
25 Stapleton HM Sharma S Getzinger G Ferguson PL Gabriel M Webster TF Blum A Novel and high volume use flame retardants in US couches reflective of the 2005 PentaBDE phase out. Environ Sci Technol. 2012;46(24):13432–13439. 10.1021/es303471d 23186002
26 Law RJ Covaci A Harrad S Herzke D Abdallah MA Fernie K Toms L-M Takigami H Levels and trends of PBDEs and HBCDs in the global environment: status at the end of 2012. Environ Int. 2014;65:147–158. 10.1016/j.envint.2014.01.006 24486972
27 Frederiksen M Vorkamp K Mathiesen L Mose T Knudsen LE Placental transfer of the polybrominated diphenyl ethers BDE-47, BDE-99 and BDE-209 in a human placenta perfusion system: an experimental study. Environ Health. 2010;9(1):32. 10.1186/1476-069X-9-32 20598165
28 Harrad S Goosey E Desborough J Abdallah MA Roosens L Covaci A Dust from U.K. primary school classrooms and daycare centers: the significance of dust as a pathway of exposure of young U.K. children to brominated flame retardants and polychlorinated biphenyls. Environ Sci Technol. 2010;44(11):4198–4202. 10.1021/es100750s 20441148
29 Johnson PI Stapleton HM Sjödin A Meeker JD Relationships between polybrominated diphenyl ether concentrations in house dust and serum. Environ Sci Technol. 2010;44(14):5627–5632. 10.1021/es100697q 20521814
30 Schecter A Colacino J Sjödin A Needham L Birnbaum L Partitioning of polybrominated diphenyl ethers (PBDEs) in serum and milk from the same mothers. Chemosphere. 2010;78(10):1279–1284. 10.1016/j.chemosphere.2009.12.016 20079522
31 Schecter A Papke O Harris TR Tung KC Musumba A Olson J Birnbaum L Polybrominated diphenyl ether (PBDE) levels in an expanded market basket survey of U.S. food and estimated PBDE dietary intake by age and sex. Environ Health Perspect. 2006;114(10):1515–1520. 10.1289/ehp.9121 17035135
32 Stapleton HM Misenheimer J Hoffman K Webster TF Flame retardant associations between children’s handwipes and house dust. Chemosphere. 2014;116:54–60. 10.1016/j.chemosphere.2013.12.100 24485814
33 Johnson-Restrepo B Kannan K Rapaport DP Rodan BD Polybrominated diphenyl ethers and polychlorinated biphenyls in human adipose tissue from New York. Environ Sci Technol. 2005;39(14):5177–5182. 10.1021/es050399x 16082945
34 Petreas M She J Brown FR Winkler J Windham G Rogers E Zhao G Bhatia R Charles MJ High body burdens of 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47) in California women. Environ Health Perspect. 2003;111(9):1175–1179. 10.1289/ehp.6220 12842770
35 Schecter A Haffner D Colacino J Patel K Päpke O Opel M Birnbaum L Polybrominated diphenyl ethers (PBDEs) and hexabromocyclodecane (HBCD) in composite U.S. food samples. Environ Health Perspect. 2010;118(3):357–362. 10.1289/ehp.0901345 20064778
36 Schecter A Smith S Haffner D Colacino J Malik N Patel K Harris TR Opel M Paepke O Does flying present a threat of polybrominated diphenyl ether exposure? J Occup Environ Med. 2010;52(12):1230–1235. 10.1097/JOM.0b013e3181fe0a8b 21124237
37 Sjödin A Jones RS Focant JF Lapeza C Wang RY McGahee EE 3rd Zhang Y Turner WE Slazyk B Needham LL Retrospective time-trend study of polybrominated diphenyl ether and polybrominated and polychlorinated biphenyl levels in human serum from the United States. Environ Health Perspect. 2004;112(6):654–658. 10.1289/ehp.112-1241957 15121506
38 Fischer D Hooper K Athanasiadou M Athanassiadis I Bergman Å Children show highest levels of polybrominated diphenyl ethers in a California family of four: A case study. Environ Health Perspect. 2006;114(10):1581–1584. 10.1289/ehp.8554 17035146
39 Woodruff TJ Zota AR Schwartz JM Environmental chemicals in pregnant women in the United States: NHANES 2003–2004. Environ Health Perspect. 2011;119(6):878–885. 10.1289/ehp.1002727 21233055
40 Stapleton HM Sjödin A Jones RS Niehüser S Zhang Y Patterson DG Jr Serum levels of polybrominated diphenyl ethers (PBDEs) in foam recyclers and carpet installers working in the United States. Environ Sci Technol. 2008;42(9):3453–3458. 10.1021/es7028813 18522133
41 Carignan CC Heiger-Bernays W McClean MD Roberts SC Stapleton HM Sjödin A Webster TF Flame retardant exposure among collegiate United States gymnasts. Environ Sci Technol. 2013;47(23):13848–13856. 10.1021/es4037868 24195753
42 Jiang H Lin Z Wu Y Chen X Hu Y Li Y Huang C Dong Q Daily intake of polybrominated diphenyl ethers via dust and diet from an e-waste recycling area in China. J Hazard Mater. 2014;276:35–42. 10.1016/j.jhazmat.2014.05.014 24858050
43 Labunska I Harrad S Wang M Santillo D Johnston P Human dietary exposure to PBDEs around E-waste recycling sites in Eastern China. Environ Sci Technol. 2014;48(10):5555–5564. 10.1021/es500241m 24735010
44 Sjödin A Jones RS Caudill SP Wong L-Y Turner WE Calafat AM Polybrominated diphenyl ethers, polychlorinated biphenyls, and persistent pesticides in serum from the national health and nutrition examination survey: 2003-2008. Environ Sci Technol. 2014;48(1):753–760. 10.1021/es4037836 24298999
45 European Parliament and the Council of the European Union (EPCEU). Directive 2003/11/EC of the European Parliament and of the Council of 6 February 2003, amending for the 24th time Council Directive 76/769/EEC relating to restrictions on the marketing and use of certain dangerous substances and preparations (pentabromodiphenyl ether, octobromodiphenyl ether). Off J Eur Union 2003; 15.2.2003:L42/45-L42/46.
46 United Nations Environmental Programme (UNEP). The 9 new POPs under the Stockholm Convention. Stockholm, Sweden; 2009. http://chm.pops.int/Programmes/NewPOPs/The9newPOPs/tabid/672/language/en-US/Default.aspx
47 United Nations Environmental Programme (UNEP). What are POPs? Secretariat of the Stockholm Convention. Stockholm, Sweden; 2008. http://chm.pops.int/TheConvention/ThePOPs/tabid/673/Default.aspx
48 United Nations Environmental Programme (UNEP). Stockholm convention on persistent organic pollutants, adoption of amendments to annexes A, B and C. Nairobi, Kenya; 2009. Reference: C.N.524.2009.TREATIES-4 (Depository Notification).
49 Eriksson P Jakobsson E Fredriksson A Brominated flame retardants: A novel class of developmental neurotoxicants in our environment? Environ Health Perspect. 2001;109(9):903–908. 10.1289/ehp.01109903 11673118
50 Viberg H Fredriksson A Eriksson P Investigations of strain and/or gender differences in developmental neurotoxic effects of polybrominated diphenyl ethers in mice. Toxicol Sci. 2004;81(2):344–353. 10.1093/toxsci/kfh215 15240897
51 Viberg H Fredriksson A Eriksson P Neonatal exposure to the brominated flame-retardant, 2, 2′, 4, 4′, 5-pentabromodiphenyl ether, decreases cholinergic nicotinic receptors in hippocampus and affects spontaneous behaviour in the adult mouse. Environ Toxicol Pharmacol. 2004;17(2):61–65. 10.1016/j.etap.2004.02.004 21782714
52 Viberg H Fredriksson A Eriksson P Neonatal exposure to polybrominated diphenyl ether (PBDE 153) disrupts spontaneous behaviour, impairs learning and memory, and decreases hippocampal cholinergic receptors in adult mice. Toxicol Appl Pharmacol. 2003;192(2):95–106. 10.1016/S0041-008X(03)00217-5 14550744
53 Federal Register. Certain polybrominated diphenylethers: significant new use rule and test rule. Fed Regist. 2012;77(19):862–919.
54 California Department of Consumer Affairs (CDCA). Proposed regulations: New flammability standards for upholstered furniture and articles exempt from flammability standards. Bureau of Electronic and Appliance Repair, Home Furnishings and Thermal Insulation; 2013. https://bhgs.dca.ca.gov/laws/ndis_updated.pdf
55 Chen LJ Lebetkin EH Sanders JM Burka LT Chen -J Lebetkin EH, Sanders JM, Burka LT. Metabolism and disposition of 2,2′,4,4′,5-pentabromodiphenyl ether (BDE99) following a single or repeated administration to rats or mice. Xenobiotica. 2006;36(6):515–534. 10.1080/00498250600674477 16769647
56 Darnerud PO Risberg S Tissue localisation of tetra- and pentabromodiphenyl ether congeners (BDE-47, -85 and -99) in perinatal and adult C57BL mice. Chemosphere. 2006;62(3):485–493. 10.1016/j.chemosphere.2005.04.004 15893803
57 Hakk H Huwe J Low M Rutherford D Larsen G Tissue disposition, excretion and metabolism of 2,2′,4,4′,6-pentabromodiphenyl ether (BDE-100) in male Sprague-Dawley rats. Xenobiotica. 2006;36(1):79–94. 10.1080/00498250500491675 16507514
58 Hakk H Huwe JK Larsen GL Absorption, distribution, metabolism and excretion (ADME) study with 2,2′,4,4′,5,6′-hexabromodiphenyl ether (BDE-154) in male Sprague-Dawley rats. Xenobiotica. 2009;39(1):46–56. 10.1080/00498250802546853 19219747
59 Hakk H Larsen G Klasson-Wehler E Tissue disposition, excretion and metabolism of 2,2′,4,4′,5-pentabromodiphenyl ether (BDE-99) in the male Sprague-Dawley rat. Xenobiotica. 2002;32(5):369–382. 10.1080/00498250110119117 12065060
60 Örn U Klasson-Wehler E Metabolism of 2,2′,4,4′-tetrabromodiphenyl ether in rat and mouse. Xenobiotica. 1998;28(2):199–211. 9522443
61 Sanders JM Lebetkin EH Chen L-J Burka LT Metabolism and disposition of 2,2′,4,4′- tetrabromodiphenyl ether following administration of single or multiple doses to rats and mice. Xenobiotica. 2006;36(1):103–117. 10.1080/00498250500485107 16507516
62 Sanders JM Lebetkin EH Chen LJ Burka LT Disposition of 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE153) and its interaction with other polybrominated diphenyl ethers (PBDEs) in rodents. Xenobiotica. 2006;36(9):824–837. 10.1080/00498250600815906 16971346
63 Staskal DF Diliberto JJ Birnbaum LS Disposition of BDE 47 in developing mice. Toxicol Sci. 2006;90(2):309–316. 10.1093/toxsci/kfj098 16407092
64 Staskal DF Diliberto JJ Birnbaum LS Impact of repeated exposure on the toxicokinetics of BDE 47 in mice. Toxicol Sci. 2006;89(2):380–385. 10.1093/toxsci/kfj038 16280385
65 Staskal DF Diliberto JJ DeVito MJ Birnbaum LS Toxicokinetics of BDE 47 in female mice: effect of dose, route of exposure, and time. Toxicol Sci. 2005;83(2):215–223. 10.1093/toxsci/kfi018 15509665
66 Staskal DF Hakk H Bauer D Diliberto JJ Birnbaum LS Toxicokinetics of polybrominated diphenyl ether congeners 47, 99, 100, and 153 in mice. Toxicol Sci. 2006;94(1):28–37. 10.1093/toxsci/kfl091 16936226
67 Braekevelt E Tittlemier SA Tomy GT Direct measurement of octanol–water partition coefficients of some environmentally relevant brominated diphenyl ether congeners. Chemosphere. 2003;51(7):563–567. 10.1016/S0045-6535(02)00841-X 12615110
68 Emond C Sanders JM Wikoff D Birnbaum LS Proposed mechanistic description of dose-dependent BDE-47 urinary elimination in mice using a physiologically based pharmacokinetic model. Toxicol Appl Pharmacol. 2013;273(2):335–344. 10.1016/j.taap.2013.09.007 24055880
69 Qiu X Mercado-Feliciano M Bigsby RM Hites RA Measurement of polybrominated diphenyl ethers and metabolites in mouse plasma after exposure to a commercial pentabromodiphenyl ether mixture. Environ Health Perspect. 2007;115(7):1052–1058. 10.1289/ehp.10011 17637922
70 Sanders JM Burka LT Smith CS Black W James R Cunningham ML Differential expression of CYP1A, 2B, and 3A genes in the F344 rat following exposure to a polybrominated diphenyl ether mixture or individual components. Toxicol Sci. 2005;88(1):127–133. 10.1093/toxsci/kfi288 16107549
71 Malmberg T Athanasiadou M Marsh G Brandt I Bergman Å Identification of hydroxylated polybrominated diphenyl ether metabolites in blood plasma from polybrominated diphenyl ether exposed rats. Environ Sci Technol. 2005;39(14):5342–5348. 10.1021/es050574 16082965
72 Marsh G Athanasiadou M Athanassiadis I Sandholm A Identification of hydroxylated metabolites in 2,2′,4,4′-tetrabromodiphenyl ether exposed rats. Chemosphere. 2006;63(4):690–697. 10.1016/j.chemosphere.2005.07.072 16213553
73 Chen G Konstantinov AD Chittim BG Joyce EM Bols NC Bunce NJ Synthesis of polybrominated diphenyl ethers and their capacity to induce CYP1A by the Ah receptor mediated pathway. Environ Sci Technol. 2001;35(18):3749–3756. 10.1021/es0107475 11783655
74 Zhou T Ross DG DeVito MJ Crofton KM Effects of short-term in vivo exposure to polybrominated diphenyl ethers on thyroid hormones and hepatic enzyme activities in weanling rats. Toxicol Sci. 2001;61(1):76–82. 10.1093/toxsci/61.1.76 11294977
75 Dallaire R Ayotte P Pereg D Déry S Dumas P Langlois E Dewailly E Determinants of plasma concentrations of perfluorooctanesulfonate and brominated organic compounds in Nunavik Inuit adults (Canada). Environ Sci Technol. 2009;43(13):5130–5136. 10.1021/es9001604 19673318
76 Eskenazi B Fenster L Castorina R Marks AR Sjödin A Rosas LG Holland N Guerra AG Lopez-Carillo L Bradman A A comparison of PBDE serum concentrations in Mexican and Mexican-American children living in California. Environ Health Perspect. 2011;119(10):1442–1448. 10.1289/ehp.1002874 21498147
77 Hurley S Reynolds P Goldberg D Nelson DO Jeffrey SS Petreas M Adipose levels of polybrominated diphenyl ethers and risk of breast cancer. Breast Cancer Res Treat. 2011;129(2):505–511. 10.1007/s10549-011-1481-7 21468638
78 Park J-S She J Holden A Sharp M Gephart R Souders-Mason G Zhang V Chow J Leslie B Hooper K High postnatal exposures to polybrominated diphenyl ethers (PBDEs) and polychlorinated biphenyls (PCBs) via breast milk in California: does BDE-209 transfer to breast milk? Environ Sci Technol. 2011;45(10):4579–4585. 10.1021/es103881n 21495631
79 Geyer HJ Schramm K-W Darnerud PO Aune M Feicht EA Fried KW Henkelmann B Lenoir D Schmid P McDonald TA Terminal elimination half-lives of the brominated flame retardants TBBPA, HBCD, and lower brominated PBDEs in humans. Organohalogen Compd. 2004;2004(66):3820–3825.
80 Petreas M Nelson D Brown FR Goldberg D Hurley S Reynolds P High concentrations of polybrominated diphenylethers (PBDEs) in breast adipose tissue of California women. Environ Int. 2011;37(1):190–197. 10.1016/j.envint.2010.09.001 20951435
81 Guvenius DM Aronsson A Ekman-Ordeberg G Bergman Å Norén K Human prenatal and postnatal exposure to polybrominated diphenyl ethers, polychlorinated biphenyls, polychlorobiphenylols, and pentachlorophenol. Environ Health Perspect. 2003;111(9):1235–1241. 10.1289/ehp.5946 12842779
82 Mazdai A Dodder NG Abernathy MP Hites RA Bigsby RM Polybrominated diphenyl ethers in maternal and fetal blood samples. Environ Health Perspect. 2003;111(9):1249–1252. 10.1289/ehp.6146 12842781
83 U.S. Environmental Protection Agency (USEPA) Design for the environment, an EPA partnership program. 2010. https://www.epa.gov/dfe/alternative_assessments.html
84 Herbstman JB Sjödin A Kurzon M Lederman SA Jones RS Rauh V Needham LL Tang D Niedzwiecki M Wang RY Prenatal exposure to PBDEs and neurodevelopment. Environ Health Perspect. 2010;118(5):712–719. 10.1289/ehp.0901340 20056561
85 Erratico CA Szeitz A Bandiera SM Oxidative metabolism of BDE-99 by human liver microsomes: predominant role of CYP2B6. Toxicol Sci. 2012;129(2):280–292. 10.1093/toxsci/kfs215 22738989
86 Erratico CA Szeitz A Bandiera SM Szeitz As, Bandiera SM. Biotransformation of 2, 2′, 4, 4′-tetrabromodiphenyl ether (BDE-47) by human liver microsomes: identification of cytochrome P450 2B6 as the major enzyme involved. Chem Res Toxicol. 2013;26(5):721–731. 10.1021/tx300522u 23537005
87 Feo ML Gross MS McGarrigle BP Eljarrat E Barceló D Aga DS Olson JR Biotransformation of BDE-47 to potentially toxic metabolites is predominantly mediated by human CYP2B6. Environ Health Perspect. 2013;121(4):440–446. 10.1289/ehp.1205446 23249762
88 Lupton SJ McGarrigle BP Olson JR Wood TD Aga DS Human liver microsome-mediated metabolism of brominated diphenyl ethers 47, 99, and 153 and identification of their major metabolites. Chem Res Toxicol. 2009;22(11):1802–1809. 10.1021/tx900215u 19835403
89 Stapleton HM Kelly SM Pei R Letcher RJ Gunsch C Metabolism of polybrominated diphenyl ethers (PBDEs) by human hepatocytes in vitro. Environ Health Perspect. 2009;117(2):197–202. 10.1289/ehp.11807 19270788
90 Athanasiadou M Cuadra SN Marsh G Bergman Å Jakobsson K Polybrominated diphenyl ethers (PBDEs) and bioaccumulative hydroxylated PBDE metabolites in young humans from Managua, Nicaragua. Environ Health Perspect. 2008;116(3):400–408. 10.1289/ehp.10713 18335110
91 Qiu X Bigsby RM Hites RA Hydroxylated metabolites of polybrominated diphenyl ethers in human blood samples from the United States. Environ Health Perspect. 2009;117(1):93–98. 10.1289/ehp.11660 19165393
92 Chen A Park J-S Linderholm L Rhee A Petreas M DeFranco EA Dietrich KN Ho S-M Hydroxylated polybrominated diphenyl ethers in paired maternal and cord sera. Environ Sci Technol. 2013;47(8):3902–3908. 10.1021/es3046839 23506475
93 Hamers T Kamstra JH Sonneveld E Murk AJ Kester MH Andersson PL Legler J Brouwer A In vitro profiling of the endocrine-disrupting potency of brominated flame retardants. Toxicol Sci. 2006;92(1):157–173. 10.1093/toxsci/kfj187 16601080
94 Richardson VM Staskal DF Ross DG Diliberto JJ DeVito MJ Birnbaum LS Possible mechanisms of thyroid hormone disruption in mice by BDE 47, a major polybrominated diphenyl ether congener. Toxicol Appl Pharmacol. 2008;226(3):244–250. 10.1016/j.taap.2007.09.015 17964624
95 Butt CM Wang D Stapleton HM Halogenated phenolic contaminants inhibit the in vitro activity of the thyroid-regulating deiodinases in human liver. Toxicol Sci. 2011;124(2):339–347. 10.1093/toxsci/kfr117 21565810
96 Meerts IA Letcher RJ Hoving S Marsh G Bergman Å Lemmen JG van der Burg B Brouwer A In vitro estrogenicity of polybrominated diphenyl ethers, hydroxylated PDBEs, and polybrominated bisphenol A compounds. Environ Health Perspect. 2001;109(4):399–407. 10.1289/ehp.01109399 11335189
97 Meerts IA van Zanden JJ Luijks EA van Leeuwen-Bol I Marsh G Jakobsson E Bergman Å Brouwer A Potent competitive interactions of some brominated flame retardants and related compounds with human transthyretin in vitro. Toxicol Sci. 2000;56(1):95–104. 10.1093/toxsci/56.1.95 10869457
98 World Health Organization (WHO) International programme on chemical safety. Environmental health criteria 162. Brominated diphenyl ethers. Geneva, Switzerland: World Health Organization; 1994.
99 Zhou T Taylor MM DeVito MJ Crofton KM Developmental exposure to brominated diphenyl ethers results in thyroid hormone disruption. Toxicol Sci. 2002;66(1):105–116. 10.1093/toxsci/66.1.105 11861977
100 Szabo DT Richardson VM Ross DG Diliberto JJ Kodavanti PR Birnbaum LS Effects of perinatal PBDE exposure on hepatic phase I, phase II, phase III, and deiodinase 1 gene expression involved in thyroid hormone metabolism in male rat pups. Toxicol Sci. 2009;107(1):27–39. 10.1093/toxsci/kfn230 18978342
101 Hallgren S Sinjari T Håkansson H Darnerud PO Effects of polybrominated diphenyl ethers (PBDEs) and polychlorinated biphenyls (PCBs) on thyroid hormone and vitamin A levels in rats and mice. Arch Toxicol. 2001;75(4):200–208. 10.1007/s002040000208 11482517
102 Talsness CE Kuriyama SN Sterner-Kock A Schnitker P Grande SW Shakibaei M Andrade A Grote K Chahoud I In utero and lactational exposures to low doses of polybrominated diphenyl ether-47 alter the reproductive system and thyroid gland of female rat offspring. Environ Health Perspect. 2008;116(3):308–314. 10.1289/ehp.10536 18335096
103 Sueyoshi T Li L Wang H Moore R Kodavanti PRS Lehmler H-J Negishi M Birnbaum LS Flame retardant BDE-47 effectively activates nuclear receptor CAR in human primary hepatocytes. Toxicol Sci. 2014;137(2):292–302. 10.1093/toxsci/kft243 24218150
104 Peters AK Nijmeijer S Gradin K Backlund M Bergman Å Poellinger L Denison MS Van den Berg M Interactions of polybrominated diphenyl ethers with the aryl hydrocarbon receptor pathway. Toxicol Sci. 2006;92(1):133–142. 10.1093/toxsci/kfj186 16601081
105 Peters AK Sanderson JT Bergman Å van den Berg M Antagonism of TCDD-induced ethoxyresorufin-O-deethylation activity by polybrominated diphenyl ethers (PBDEs) in primary cynomolgus monkey (Macaca fascicularis) hepatocytes. Toxicol Lett. 2006;164(2):123–132. 10.1016/j.toxlet.2005.12.002 16448790
106 Blanco J Mulero M Domingo JL Sánchez DJ Gestational exposure to BDE-99 produces toxicity through upregulation of CYP isoforms and ROS production in the fetal rat liver. Toxicol Sci. 2012;127(1):296–302. 10.1093/toxsci/kfs082 22331496
107 Blanco J Mulero M Heredia L Pujol A Domingo JL Sánchez DJ Perinatal exposure to BDE-99 causes learning disorders and decreases serum thyroid hormone levels and BDNF gene expression in hippocampus in rat offspring. Toxicology. 2013;308:122–128. 10.1016/j.tox.2013.03.010 23578391
108 Blanco J Mulero M Domingo JL Sanchez DJ Perinatal exposure to BDE-99 causes decreased protein levels of cyclin D1 via GSK3β activation and increased ROS production in rat pup livers. Toxicol Sci. 2014;137(2):491–498. 10.1093/toxsci/kft257 24218147
109 Fowles JR Fairbrother A Baecher-Steppan L Kerkvliet NI Immunologic and endocrine effects of the flame-retardant pentabromodiphenyl ether (DE-71) in C57BL/6J mice. Toxicology. 1994;86(1-2):49–61. 10.1016/0300-483X(94)90052-3 8134923
110 Fair PA Stavros H-C Mollenhauer MA DeWitt JC Henry N Kannan K Yun SH Bossart GD Keil DE Peden-Adams MM Immune function in female B6C3F1 mice is modulated by DE-71, a commercial polybrominated diphenyl ether mixture. J Immunotoxicol. 2012;9(1):96–107. 10.3109/1547691X.2011.643418 22214215
111 Frawley R DeVito M Walker NJ Birnbaum L White K Jr Smith M Maynor T Recio L Germolec D Relative potency for altered humoral immunity induced by polybrominated and polychlorinated dioxins/furans in female B6C3F1/N mice. Toxicol Sci. 2014;139(2):488–500. 10.1093/toxsci/kfu041 24713691
112 Bradner JM Suragh TA Wilson WW Lazo CR Stout KA Kim HM Wang MZ Walker DI Pennell KD Richardson JR Exposure to the polybrominated diphenyl ether mixture DE-71 damages the nigrostriatal dopamine system: role of dopamine handling in neurotoxicity. Exp Neurol. 2013;241:138–147. 10.1016/j.expneurol.2012.12.013 23287494
113 He P Wang A-G Xia T Gao P Niu Q Guo L-J Chen X-M Mechanisms underlying the developmental neurotoxic effect of PBDE-47 and the enhanced toxicity associated with its combination with PCB153 in rats. Neurotoxicology. 2009;30(6):1088–1095. 10.1016/j.neuro.2009.06.005 19576244
114 He P Wang A Niu Q Guo L Xia T Chen X Toxic effect of PBDE-47 on thyroid development, learning, and memory, and the interaction between PBDE-47 and PCB153 that enhances toxicity in rats. Toxicol Ind Health. 2011;27(3):279–288. 10.1177/0748233710387002 20947653
115 Ceccatelli R Faass O Schlumpf M Lichtensteiger W Gene expression and estrogen sensitivity in rat uterus after developmental exposure to the polybrominated diphenylether PBDE 99 and PCB. Toxicology. 2006;220(2-3):104–116. 10.1016/j.tox.2005.12.004 16414171
116 Dingemans MM Ramakers GM Gardoni F van Kleef RG Bergman Å Di Luca M van den Berg M Westerink RH Vijverberg HP Neonatal exposure to brominated flame retardant BDE-47 reduces long-term potentiation and postsynaptic protein levels in mouse hippocampus. Environ Health Perspect. 2007;115(6):865–870. 10.1289/ehp.9860 17589592
117 Gee JR Moser V Acute postnatal exposure to brominated diphenylether 47 delays neuromotor ontogeny and alters motor activity in mice. Neurotoxicol Teratol. 2008;30(2):79–87. 10.1016/j.ntt.2007.11.001 18166377
118 Dingemans MM van den Berg M Westerink RH Neurotoxicity of brominated flame retardants: (In)direct effects of parent and hydroxylated polybrominated diphenyl ethers on the (developing) nervous system. Environ Health Perspect. 2011;119(7):900–907. 10.1289/ehp.1003035 21245014
119 Kuriyama SN Talsness CE Grote K Chahoud I Developmental exposure to low dose PBDE 99: effects on male fertility and neurobehavior in rat offspring. Environ Health Perspect. 2005;113(2):149–154. 10.1289/ehp.7421 15687051
120 Kuriyama SN Wanner A Fidalgo-Neto AA Talsness CE Koerner W Chahoud I Developmental exposure to low-dose PBDE-99: tissue distribution and thyroid hormone levels. Toxicology. 2007;242(1-3):80–90. 10.1016/j.tox.2007.09.011 17964054
121 Cheng J Gu J Ma J Chen X Zhang M Wang W Neurobehavioural effects, redox responses and tissue distribution in rat offspring developmental exposure to BDE-99. Chemosphere. 2009;75(7):963–968. 10.1016/j.chemosphere.2009.01.004 19203780
122 Viberg H Fredriksson A Eriksson P Deranged spontaneous behaviour and decrease in cholinergic muscarinic receptors in hippocampus in the adult rat, after neonatal exposure to the brominated flame-retardant, 2, 2′, 4, 4′, 5-pentabromodiphenyl ether (PBDE 99). Environ Toxicol Pharmacol. 2005;20(2):283–288. 10.1016/j.etap.2005.02.004 21783602
123 Branchi I Alleva E Costa LG Effects of perinatal exposure to a polybrominated diphenyl ether (PBDE 99) on mouse neurobehavioural development. Neurotoxicology. 2002;23(3):375–384. 10.1016/S0161-813X(02)00078-5 12387364
124 Branchi I Santucci D Puopolo M Alleva E Neonatal behaviors associated with ultrasonic vocalizations in mice (mus musculus): A slow‐motion analysis. Dev Psychobiol. 2004;44(1):37–44. 10.1002/dev.10150 14704988
125 Branchi I Capone F Vitalone A Madia F Santucci D Alleva E Costa LG Early developmental exposure to BDE 99 or Aroclor 1254 affects neurobehavioural profile: interference from the administration route. Neurotoxicology. 2005;26(2):183–192. 10.1016/j.neuro.2004.11.005 15713339
126 Viberg H Eriksson P Differences in neonatal neurotoxicity of brominated flame retardants, PBDE 99 and TBBPA, in mice. Toxicology. 2011;289(1):59–65. 10.1016/j.tox.2011.07.010 21820030
127 Westerink RH Modulation of cell viability, oxidative stress, calcium homeostasis, and voltage-and ligand-gated ion channels as common mechanisms of action of (mixtures of) non-dioxin-like polychlorinated biphenyls and polybrominated diphenyl ethers. Environ Sci Pollut Res Int. 2014;21(10):6373–6383. 10.1007/s11356-013-1759-x 23686757
128 Chevrier J Harley KG Bradman A Gharbi M Sjödin A Eskenazi B Polybrominated diphenyl ether (PBDE) flame retardants and thyroid hormone during pregnancy. Environ Health Perspect. 2010;118(10):1444–1449. 10.1289/ehp.1001905 20562054
129 Herbstman JB Sjödin A Apelberg BJ Witter FR Halden RU Patterson DG Panny SR Needham LL Goldman LR Birth delivery mode modifies the associations between prenatal polychlorinated biphenyl (PCB) and polybrominated diphenyl ether (PBDE) and neonatal thyroid hormone levels. Environ Health Perspect. 2008;116(10):1376–1382. 10.1289/ehp.11379 18941581
130 Stapleton HM Eagle S Anthopolos R Wolkin A Miranda ML Associations between polybrominated diphenyl ether (PBDE) flame retardants, phenolic metabolites, and thyroid hormones during pregnancy. Environ Health Perspect. 2011;119(10):1454–1459. 10.1289/ehp.1003235 21715241
131 Zota AR Park J-S Wang Y Petreas M Zoeller RT Woodruff TJ Polybrominated diphenyl ethers, hydroxylated polybrominated diphenyl ethers, and measures of thyroid function in second trimester pregnant women in California. Environ Sci Technol. 2011;45(18):7896–7905. 10.1021/es200422b 21830753
132 Turyk ME Persky VW Imm P Knobeloch L Chatterton R Jr Anderson HA Hormone disruption by PBDEs in adult male sport fish consumers. Environ Health Perspect. 2008;116(12):1635–1641. 10.1289/ehp.11707 19079713
133 Yuan J Chen L Chen D Guo H Bi X Ju Y Jiang P Shi J Yu Z Yang J Elevated serum polybrominated diphenyl ethers and thyroid-stimulating hormone associated with lymphocytic micronuclei in Chinese workers from an E-waste dismantling site. Environ Sci Technol. 2008;42(6):2195–2200. 10.1021/es702295f 18411489
134 Darras VM Endocrine disrupting polyhalogenated organic pollutants interfere with thyroid hormone signalling in the developing brain. Cerebellum. 2008;7(1):26–37. 10.1007/s12311-008-0004-5 18418666
135 Lasky RE Widholm JJ Crofton KM Schantz SL Perinatal exposure to Aroclor 1254 impairs distortion product otoacoustic emissions (DPOAEs) in rats. Toxicol Sci. 2002;68(2):458–464. 10.1093/toxsci/68.2.458 12151642
136 World Health Organization (WHO) State of the science of endocrine disrupting chemicals-2012. Geneva, Switzerland: World Health Organization; 2012.
137 Stoker TE Laws SC Crofton KM Hedge JM Ferrell JM Cooper RL Assessment of DE-71, a commercial polybrominated diphenyl ether (PBDE) mixture, in the EDSP male and female pubertal protocols. Toxicol Sci. 2004;78(1):144–155. 10.1093/toxsci/kfh029 14999130
138 Stoker TE Cooper RL Lambright CS Wilson VS Furr J Gray LE In vivo and in vitro anti-androgenic effects of DE-71, a commercial polybrominated diphenyl ether (PBDE) mixture. Toxicol Appl Pharmacol. 2005;207(1):78–88. 10.1016/j.taap.2005.05.010 16005038
139 Kodavanti PR Coburn CG Moser VC MacPhail RC Fenton SE Stoker TE Rayner JL Kannan K Birnbaum LS Developmental exposure to a commercial PBDE mixture, DE-71: Neurobehavioral, hormonal, and reproductive effects. Toxicol Sci. 2010;116(1):297–312. 10.1093/toxsci/kfq105 20375078
140 van der Ven LT van de Kuil T Verhoef A Leonards PE Slob W Cantón RF Germer S Hamers T Visser TJ Litens S A 28-day oral dose toxicity study enhanced to detect endocrine effects of a purified technical pentabromodiphenyl ether (pentaBDE) mixture in Wistar rats. Toxicology. 2008;245(1-2):109–122. 10.1016/j.tox.2007.12.016 18243468
141 Berger RG Lefèvre PL Ernest SR Wade MG Ma Y-Q Rawn DF Gaertner DW Robaire B Hales BF Exposure to an environmentally relevant mixture of brominated flame retardants affects fetal development in Sprague-Dawley rats. Toxicology. 2014;320:56–66. 10.1016/j.tox.2014.03.005 24670387
142 Suvorov A Battista M-C Takser L Perinatal exposure to low-dose 2, 2′, 4, 4′-tetrabromodiphenyl ether affects growth in rat offspring: what is the role of IGF-1? Toxicology. 2009;260(1-3):126–131. 10.1016/j.tox.2009.03.018 19464578
143 Suvorov A Girard S Lachapelle S Abdelouahab N Sebire G Takser L Perinatal exposure to low-dose BDE-47, an emergent environmental contaminant, causes hyperactivity in rat offspring. Neonatology. 2009;95(3):203–209. 10.1159/000155651 18799892
144 Suzuki G Tue NM Malarvannan G Sudaryanto A Takahashi S Tanabe S Sakai S-i Brouwer A Uramaru N Kitamura S Similarities in the endocrine-disrupting potencies of indoor dust and flame retardants by using human osteosarcoma (U2OS) cell-based reporter gene assays. Environ Sci Technol. 2013;47(6):2898–2908. 10.1021/es304691a 23398518
145 Talsness CE Shakibaei M Kuriyama SN Grande SW Sterner-Kock A Schnitker P De Souza C Grote K Chahoud I Ultrastructural changes observed in rat ovaries following in utero and lactational exposure to low doses of a polybrominated flame retardant. Toxicol Lett. 2005;157(3):189–202. 10.1016/j.toxlet.2005.02.001 15917144
146 Lilienthal H Hack A Roth-Härer A Grande SW Talsness CE Effects of developmental exposure to 2,2, 4,4, 5-pentabromodiphenyl ether (PBDE-99) on sex steroids, sexual development, and sexually dimorphic behavior in rats. Environ Health Perspect. 2006;114(2):194–201. 10.1289/ehp.8391 16451854
147 Gosavi RA Knudsen GA Birnbaum LS Pedersen LC Mimicking of estradiol binding by flame retardants and their metabolites: A crystallographic analysis. Environ Health Perspect. 2013;121(10):1194–1199. 10.1289/ehp.1306902 23959441
148 Frederiksen M Thomsen M Vorkamp K Knudsen LE Patterns and concentration levels of polybrominated diphenyl ethers (PBDEs) in placental tissue of women in Denmark. Chemosphere. 2009;76(11):1464–1469. 10.1016/j.chemosphere.2009.07.017 19682725
149 Foster WG Gregorovich S Morrison KM Atkinson SA Kubwabo C Stewart B Teo K Human maternal and umbilical cord blood concentrations of polybrominated diphenyl ethers. Chemosphere. 2011;84(10):1301–1309. 10.1016/j.chemosphere.2011.05.028 21663933
150 Lorber M Exposure of Americans to polybrominated diphenyl ethers. J Expo Sci Environ Epidemiol. 2008;18(1):2–19. 10.1038/sj.jes.7500572 17426733
151 Marsh G Bergman Å Bladh L-G Gillner M Jakobsson E Synthesis of p-hydroxybromodiphenyl ethers and binding to the thyroid receptor. Organohalogen Compd. 1998;37:305–308.
152 Ausó E Lavado-Autric R Cuevas E del Rey FE Morreale de Escobar G Berbel P A moderate and transient deficiency of maternal thyroid function at the beginning of fetal neocorticogenesis alters neuronal migration. Endocrinology. 2004;145(9):4037–4047. 10.1210/en.2004-0274 15087434
153 Haddow JE Palomaki GE Allan WC Williams JR Knight GJ Gagnon J O’Heir CE Mitchell ML Hermos RJ Waisbren SE Maternal thyroid deficiency during pregnancy and subsequent neuropsychological development of the child. N Engl J Med. 1999;341(8):549–555. 10.1056/nejm199908193410801 10451459
154 Lazarus JH Thyroid disease in pregnancy and childhood. Minerva Endocrinol. 2005;30(2):71–87. 15988403
155 Lazarus JH Thyroid disorders associated with pregnancy: Etiology, diagnosis, and management. Treat Endocrinol. 2005;4(1):31–41. 10.2165/00024677-200504010-00004 15649099
156 Lignell S Aune M Darnerud PO Hanberg A Larsson SC Glynn A Prenatal exposure to polychlorinated biphenyls (PCBs) and polybrominated diphenyl ethers (PBDEs) may influence birth weight among infants in a Swedish cohort with background exposure: A cross-sectional study. Environ Health. 2013;12:44. 10.1186/1476-069x-12-44 23724965
157 Chao H-R Wang S-L Lee W-J Wang Y-F Päpke O Levels of polybrominated diphenyl ethers (PBDEs) in breast milk from central Taiwan and their relation to infant birth outcome and maternal menstruation effects. Environ Int. 2007;33(2):239–245. 10.1016/j.envint.2006.09.013 17079016
158 Harley KG Marks AR Chevrier J Bradman A Sjödin A Eskenazi B PBDE concentrations in women’s serum and fecundability. Environ Health Perspect. 2010;118(5):699–704. 10.1289/ehp.0901450 20103495
159 Roze E Meijer L Bakker A Van Braeckel KN Sauer PJ Bos AF Prenatal exposure to organohalogens, including brominated flame retardants, influences motor, cognitive, and behavioral performance at school age. Environ Health Perspect. 2009;117(12):1953–1958. 10.1289/ehp.0901015 20049217
160 Eskenazi B Chevrier J Rauch SA Kogut K Harley KG Johnson C Trujillo C Sjödin A Bradman A In utero and childhood polybrominated diphenyl ether (PBDE) exposures and neurodevelopment in the CHAMACOS study. Environ Health Perspect. 2013;121(2):257–262. 10.1289/ehp.1205597 23154064
161 Gascon M Vrijheid M Martínez D Forns J Grimalt JO Torrent M Sunyer J Effects of pre and postnatal exposure to low levels of polybromodiphenyl ethers on neurodevelopment and thyroid hormone levels at 4 years of age. Environ Int. 2011;37(3):605–611. 10.1016/j.envint.2010.12.005 21237513
162 Shy C-G Huang H-L Chang-Chien G-P Chao H-R Tsou T-C Neurodevelopment of infants with prenatal exposure to polybrominated diphenyl ethers. Bull Environ Contam Toxicol. 2011;87(6):643–648. 10.1007/s00128-011-0422-9 21953308
163 Zhang L Tian Y Yang X Cui C Gao Y Wang X Wang P Ding W Shi R Wang Y [Concentration of polybrominated diphenyl ethers in umbilical cord serum and the influence on newborns birth outcomes in Shanghai]. Zhonghua Yu Fang Yi Xue Za Zhi. Chin J Prev Med. 2011;45(6):490–493. 21914328
164 Harley KG Chevrier J Aguilar Schall R Sjödin A Bradman A Eskenazi B Association of prenatal exposure to polybrominated diphenyl ethers and infant birth weight. Am J Epidemiol. 2011;174(8):885–892. 10.1093/aje/kwr212 21878423
165 Chen A Yolton K Rauch SA Webster GM Hornung R Sjödin A Dietrich KN Lanphear BP Prenatal polybrominated diphenyl ether exposures and neurodevelopment in U.S. children through 5 years of age: the HOME study. Environ Health Perspect. 2014;122(8):856–862. 10.1289/ehp.1307562 24870060
166 Main KM Kiviranta H Virtanen HE Sundqvist E Tuomisto JT Tuomisto J Vartiainen T Skakkebaek NE Toppari J Flame retardants in placenta and breast milk and cryptorchidism in newborn boys. Environ Health Perspect. 2007;115(10):1519–1526. 10.1289/ehp.9924 17938745
167 Meijer L Martijn A Melessen J Brouwer A Weiss J de Jong FH Sauer PJ Influence of prenatal organohalogen levels on infant male sexual development: sex hormone levels, testes volume and penile length. Hum Reprod. 2012;27(3):867–872. 10.1093/humrep/der426 22215630
168 Abdelouahab N Ainmelk Y Takser L Polybrominated diphenyl ethers and sperm quality. Reprod Toxicol. 2011;31(4):546–550. 10.1016/j.reprotox.2011.02.005 21338668
169 Johnson PI Stapleton HM Mukherjee B Hauser R Meeker JD Associations between brominated flame retardants in house dust and hormone levels in men. Sci Total Environ. 2013;445-446:177–184. 10.1016/j.scitotenv.2012.12.017 23333513
170 Meeker JD Johnson PI Camann D Hauser R Polybrominated diphenyl ether (PBDE) concentrations in house dust are related to hormone levels in men. Sci Total Environ. 2009;407(10):3425–3429. 10.1016/j.scitotenv.2009.01.030 19211133
171 Hardell L Bavel B Lindström G Eriksson M Carlberg M In utero exposure to persistent organic pollutants in relation to testicular cancer risk. Int J Androl. 2006;29(1):228–234. 10.1111/j.1365-2605.2005.00622.x 16371110
172 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Speck W Salmonella mutagenicity tests: III. Results from the testing of 255 chemicals. Environ Mutagen. 1987;9 S9:61–109. 10.1002/em.2860090603 3552650
173 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry-and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008;649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
174 European Chemicals Bureau (ECB) European Union Risk Assessment Report. Diphenyl ether, pentabromo derivative, CAS No. 32534-81-9, ElNECS No. 251-084-2. Office for Official Publications of the European Communities; 2001.
175 Pellacani C Buschini A Galati S Mussi F Franzoni S Costa LG Evaluation of DNA damage induced by 2 polybrominated diphenyl ether flame retardants (BDE-47 and BDE-209) in SK-N-MC cells. Int J Toxicol. 2012;31(4):372–379. 10.1177/1091581812449663 22710639
176 He W He P Wang A Xia T Xu B Chen X Effects of PBDE-47 on cytotoxicity and genotoxicity in human neuroblastoma cells in vitro. Mutat Res. 2008;649(1-2):62–70. 10.1016/j.mrgentox.2007.08.001 17855158
177 He W Wang A Xia T Gao P Xu B Xu Z He P Chen X Cytogenotoxicity induced by PBDE-47 combined with PCB153 treatment in SH-SY5Y cells. Environ Toxicol. 2010;25(6):564–572. 10.1002/tox.20517 19562743
178 Gao P He P Wang A Xia T Xu B Xu Z Niu Q Guo L Chen X Influence of PCB153 on oxidative DNA damage and DNA repair–related gene expression induced by PBDE-47 in human neuroblastoma cells in vitro. Toxicol Sci. 2009;107(1):165–170. 10.1093/toxsci/kfn224 18948301
179 Barber JL Walsh MJ Hewitt R Jones KC Martin FL Low-dose treatment with polybrominated diphenyl ethers (PBDEs) induce altered characteristics in MCF-7 cells. Mutagenesis. 2006;21(5):351–360. 10.1093/mutage/gel038 16980705
180 An J Li S Zhong Y Wang Y Zhen K Zhang X Wang Y Wu M Yu Z Sheng G The cytotoxic effects of synthetic 6‐hydroxylated and 6‐methoxylated polybrominated diphenyl ether 47 (BDE47). Environ Toxicol. 2011;26(6):591–599. 10.1002/tox.20582 20549613
181 Ji K Choi K Giesy JP Musarrat J Takeda S Genotoxicity of several polybrominated diphenyl ethers (PBDEs) and hydroxylated PBDEs, and their mechanisms of toxicity. Environ Sci Technol. 2011;45(11):5003–5008. 10.1021/es104344e 21545137
182 Ernest SR Wade MG Lalancette C Ma Y-Q Berger RG Robaire B Hales BF Effects of chronic exposure to an environmentally relevant mixture of brominated flame retardants on the reproductive and thyroid system in adult male rats. Toxicol Sci. 2012;127(2):496–507. 10.1093/toxsci/kfs098 22387749
183 Bio-Rad Sadtler “KnowItAll”® Digital Infrared Libraries. IR-Polymers and Monomers (Basic) 1: (Unmodified Polymers and Monomers) library, spectrum BP: 962. 2003.
184 King-Herbert A Thayer K NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006;34(6):802–805. 10.1080/01926230600935938 17162538
185 Schenkman JB Cinti DL Preparation of microsomes with calcium. Methods Enzymol. 1978;52:83–89. 10.1016/S0076-6879(78)52008-9 672658
186 Lowry OH Rosebrough NJ Farr AL Randall RJ Protein measurement with the Folin phenol reagent. J Biol Chem. 1951;193(1):265–275. 14907713
187 Chang TK, Waxman DJ. Enzymatic analysis of cDNA-expressed human CYP1A1, CYP1A2, and CYP1B1 with 7-ethoxyresorufin as substrate. In: Cytochrome P450 Protocols. Springer; 1998. p. 103-110.
188 Lubet RA Mayer RT Cameron JW Nims RW Burke MD Wolff T Guengerich FP Dealkylation of pentoxyresorufin: A rapid and sensitive assay for measuring induction of cytochrome(s) P-450 by phenobarbital and other xenobiotics in the rat. Arch Biochem Biophys. 1985;238(1):43–48. 10.1016/0003-9861(85)90138-9 3985627
189 Hamm JT Ross DG Richardson VM Diliberto JJ Birnbaum LS Methoxyresorufin: an inappropriate substrate for CYP1A2 in the mouse. Biochem Pharmacol. 1998;56(12):1657–1660. 10.1016/S0006-2952(98)00241-X 9973187
190 Winsnes A Studies on the activation in vitro of glucuronyltranferase. Biochim Biophys Acta. 1969;191(2):279–291. 10.1016/0005-2744(69)90247-2 5354263
191 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
192 Boorman G Montgomery C Jr Eustis S Wolfe M McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman H Weisburger Eeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
193 National Research Council (NRC) Guide for the care and use of laboratory animals. 8th ed. Washington (DC): National Academies Press; 2011.
194 Brix AE Hardisty JF McConnell EE Combining neoplasms for evaluation of rodent carcinogenesis studies. In: Hsu C-H Stedeford Teditors. Cancer Risk Assessment: Chemical Carcinogenesis, Hazard Evaluation, and Risk Quantification. Hoboken (NJ): John Wiley & Sons, Inc; 2010. p. 699–715.10.1002/9780470622728.ch28
195 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53(282):457–481.10.1080/01621459.1958.10501452
196 Cox DR Regression models and life‐tables. J R Stat Soc B. 1972;34(2):187–202.
197 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690.10.1093/biomet/62.3.679
198 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. 10.2307/2531856 3390507
199 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
200 Piegorsch W, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, UK: Chapman and Hall; 1997.
201 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
202 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. 10.2307/2532200 8241374
203 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
204 McCullagh P Nelder JA Generalized Linear Models. 2nd ed. New York (NY): Chapman and Hall; 1989.10.1007/978-1-4899-3242-6
205 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121.10.1080/01621459.1955.10501294
206 Williams D A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
207 Williams D The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
208 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
209 Williams D A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
210 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252.10.1080/00401706.1964.10490181
211 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145.10.2307/2333011
212 Dixon WJ Massey FJ Introduction to statistical analysis. 2nd ed. New York: McGraw Hill Book Company, Inc; 1957. p. 276–278, 412.
213 Conover WJ Practical nonparametric statistics. New York (NY): John Wiley & Sons; 1971.
214 Girard D Sager D The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
215 Haseman JK Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26(2):191–200.10.1177/009286159202600210
216 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. 10.1177/019262339202000107 1411131
217 Haseman JK Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995;21(1):52–59, discussion 81–86. 10.1006/rtph.1995.1009 7784636
218 Code of Federal Regulations (CFR). 21(Part 58).
219 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
220 Schmid W The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
221 Miller J Miller E Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt H Waston J Winsten Jeditors. Origins of human cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. p. 605–627.
222 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology: Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co., Inc.; 1985. p. 13–59.
223 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
224 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991;257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
225 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987;236(4804):933–941. 10.1126/science.3554512 3554512
226 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Holden H Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutag. 1990; 16(S18):1-14. 10.1002/em.2850160502
227 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993;21(2):160–179. 10.1002/em.2850210210 8444144
228 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995;25(4):302–313. 10.1002/em.2850250407 7607185
229 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JT Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutag. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
230 Thoolen B Maronpot RR Harada T Nyska A Rousseaux C Nolte T Malarkey DE Kaufmann W Küttler K Deschl U Proliferative and nonproliferative lesions of the rat and mouse hepatobiliary system. Toxicol Pathol. 2010;38(7) 7S:5S–81S. 10.1177/0192623310386499 21191096
231 Slauson DO Cooper BJ Mechanisms of disease: A textbook of comparative general pathology. 3rd ed. Maryland Heights (MO): Mosby; 2001.
232 Farber E Toxicological significance of liver hypertrophy produced by inducers of drug-metabolizing enzymes. Ciba Found Symp. 1980;76:261–274. 10.1002/9780470720592.ch14 6906264
233 Duntas LH Brenta G The effect of thyroid disorders on lipid levels and metabolism. Med Clin North Am. 2012;96(2):269–281. 10.1016/j.mcna.2012.01.012 22443975
234 Dory L Roheim PS Rat plasma lipoproteins and apolipoproteins in experimental hypothyroidism. J Lipid Res. 1981;22(2):287–296. 6787158
235 Apostolopoulos JJ Howlett GJ Fidge N Effects of dietary cholesterol and hypothyroidism on rat apolipoprotein mRNA metabolism. J Lipid Res. 1987;28(6):642–648. 3112298
236 Takeuchi N Ito M Uchida K Yamamura Y Effect of modification of thyroid function on cholesterol 7α-hydroxylation in rat liver. Biochem J. 1975;148(3):499–503. 10.1042/bj1480499 1200990
237 Das KC Mukherjee M Sarkar TK Dash RJ Rastogi GK Erythropoiesis and erythropoietin in hypo- and hyperthyroidism. J Clin Endocrinol Metab. 1975;40(2):211–220. 10.1210/jcem-40-2-211 1117976
238 Perrin MC Blanchet JP Mouchiroud G Modulation of human and mouse erythropoiesis by thyroid hormone and retinoic acid: evidence for specific effects at different steps of the erythroid pathway. Hematol Cell Ther. 1997;39(1):19–26. 10.1007/s00282-997-0019-2 9088934
239 Donati RM Fletcher JW Warnecke MA Gallagher NI Erythropoiesis in hypothyroidism. Proc Soc Exp Biol Med. 1973;144(1):78–82. 10.3181/00379727-144-37531 4771586
240 Malgor LA Blanc CC Klainer E Irizar SE Torales PR Barrios L Direct effects of thyroid hormones on bone marrow erythroid cells of rats. Blood. 1975;45(5):671–679. 10.1182/blood.V45.5.671.671 1120189
241 Fruhman GJ Effects of starvation and refeeding on erythropoiesis in mice. Z Zellforsch Mikrosk Anat. 1966;75(1):258–271. 10.1007/BF00407159 5966243
242 Weiss G Goodnough LT Anemia of chronic disease. N Engl J Med. 2005;352(10):1011–1023. 10.1056/NEJMra041809 15758012
243 Creasy D Bube A de Rijk E Kandori H Kuwahara M Masson R Nolte T Reams R Regan K Rehm S Proliferative and nonproliferative lesions of the rat and mouse male reproductive system. Toxicol Pathol. 2012;40(6) Suppl:40s–121s. 10.1177/0192623312454337 22949412
244 Tsuchiya Y Nakajima M Yokoi T Cytochrome P450-mediated metabolism of estrogens and its regulation in human. Cancer Lett. 2005;227(2):115–124. 10.1016/j.canlet.2004.10.007 16112414
245 Ortega E Rodriguez E Ruiz E Osorio C Activity of the hypothalamo-pituitary ovarian axis in hypothyroid rats with or without triiodothyronine replacement. Life Sci. 1990;46(6):391–395. 10.1016/0024-3205(90)90081-2 2106058
246 Cooke PS Kirby JD Porcelli J Increased testis growth and sperm production in adult rats following transient neonatal goitrogen treatment: optimization of the propylthiouracil dose and effects of methimazole. J Reprod Fertil. 1993;97(2):493–499. 10.1530/jrf.0.0970493 8501721
247 Hardisty JF Boorman GA Thyroid gland. In: Boorman G Eustis S Elwell M Montgomery C MacKenzie Weditors. Pathology of the Fischer Rat: Reference and Atlas. San Diego (CA): Academic Press, Inc.; 1990. p. 519–536.
248 Boelaert K The association between serum TSH concentration and thyroid cancer. Endocr Relat Cancer. 2009;16(4):1065–1072. 10.1677/ERC-09-0150 19620248
249 Zabka TS Fielden MR Garrido R Tao J Fretland AJ Fretland JL Albassam MA Singer T Kolaja KL Characterization of xenobiotic-induced hepatocellular enzyme induction in rats: anticipated thyroid effects and unique pituitary gland findings. Toxicol Pathol. 2011;39(4):664–677. 10.1177/0192623311406934 21551028
250 Berry P Effect of diet or reproductive status on the histology of spontaneous pituitary tumors in female Wistar rats. Vet Pathol. 1986;23(5):610–618. 10.1177/030098588602300510 3535221
251 Pohjanvirta R Unkila M Tuomisto J Comparative acute lethality of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD), 1,2,3,7,8-pentachlorodibenzo-p-dioxin and 1,2,3,4,7,8-hexachlorodibenzo-p-dioxin in the most TCDD-susceptible and the most TCDD-resistant rat strain. Pharmacol Toxicol. 1993;73(1):52–56. 10.1111/j.1600-0773.1993.tb01958.x 8234194
252 Pohjanvirta R Wong JM Li W Harper PA Tuomisto J Okey AB Point mutation in intron sequence causes altered carboxyl-terminal structure in the aryl hydrocarbon receptor of the most 2,3,7,8-tetrachlorodibenzo-p-dioxin-resistant rat strain. Mol Pharmacol. 1998;54(1):86–93. 10.1124/mol.54.1.86 9658193
253 Pohjanvirta R Viluksela M Tuomisto JT Unkila M Karasinska J Franc MA Holowenko M Giannone JV Harper PA Tuomisto J Physicochemical differences in the AH receptors of the most TCDD-susceptible and the most TCDD-resistant rat strains. Toxicol Appl Pharmacol. 1999;155(1):82–95. 10.1006/taap.1998.8565 10036221
254 Waxman DJ Azaroff L Phenobarbital induction of cytochrome P-450 gene expression. Biochem J. 1992;281(3):577–592. 10.1042/bj2810577 1536639
255 Aragon AC Kopf PG Campen MJ Huwe JK Walker MK In utero and lactational 2, 3, 7, 8-tetrachlorodibenzo-p-dioxin exposure: effects on fetal and adult cardiac gene expression and adult cardiac and renal morphology. Toxicol Sci. 2008;101(2):321–330. 10.1093/toxsci/kfm272 17975115
256 Birnbaum LS Morrissey RE Harris MW Teratogenic effects of 2, 3, 7, 8-tetrabromodibenzo-p-dioxin and three polybrominated dibenzofurans in C57BL6N mice. Toxicol Appl Pharmacol. 1991;107(1):141–152. 10.1016/0041-008X(91)90338-F 1987653
257 Couture LA Abbott BD Birnbaum LS A critical review of the developmental toxicity and teratogenicity of 2,3,7,8-tetrachlorodibenzo-p-dioxin: recent advances toward understanding the mechanism. Teratology. 1990;42(6):619–627. 10.1002/tera.1420420606 2087682
258 Nishimura N Matsumura F Vogel CF Nishimura H Yonemoto J Yoshioka W Tohyama C Critical role of cyclooxygenase-2 activation in pathogenesis of hydronephrosis caused by lactational exposure of mice to dioxin. Toxicol Appl Pharmacol. 2008;231(3):374–383. 10.1016/j.taap.2008.05.012 18606429
259 Peters AK van Londen K Bergman Å Bohonowych J Denison MS van den Berg M Sanderson JT Effects of polybrominated diphenyl ethers on basal and TCDD-induced ethoxyresorufin activity and cytochrome P450-1A1 expression in MCF-7, HepG2, and H4IIE cells. Toxicol Sci. 2004;82(2):488–496. 10.1093/toxsci/kfh284 15456928
260 van den Berg M Birnbaum LS Denison M De Vito M Farland W Feeley M Fiedler H Hakansson H Hanberg A Haws L The 2005 World Health Organization reevaluation of human and mammalian toxic equivalency factors for dioxins and dioxin-like compounds. Toxicol Sci. 2006;93(2):223–241. 10.1093/toxsci/kfl055 16829543
261 van den Berg M Denison MS Birnbaum LS DeVito MJ Fiedler H Falandysz J Rose M Schrenk D Safe S Tohyama C Polybrominated dibenzo-p-dioxins, dibenzofurans, and biphenyls: inclusion in the toxicity equivalency factor concept for dioxin-like compounds. Toxicol Sci. 2013;133(2):197–208. 10.1093/toxsci/kft070 23492812
262 Venkatesan AK Halden RU Contribution of polybrominated dibenzo-p-dioxins and dibenzofurans (PBDD/Fs) to the toxic equivalency of dioxin-like compounds in archived biosolids from the US EPA’s 2001 National Sewage Sludge Survey. Environ Sci Technol. 2014;48(18):10843–10849. 10.1021/es503110j 25157505
263 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 2,3,7,8 tetrachlorodibenzo-p-dioxin (TCDD) (CAS No. 1746-01-6) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2006. Technical Report Series No. 521. NIH Publication No. 06-4455.
264 Elcombe CR Peffer RC Wolf DC Bailey J Bars R Bell D Cattley RC Ferguson SS Geter D Goetz A Mode of action and human relevance analysis for nuclear receptor-mediated liver toxicity: A case study with phenobarbital as a model constitutive androstane receptor (CAR) activator. Crit Rev Toxicol. 2014;44(1):64–82. 10.3109/10408444.2013.835786 24180433
265 Hall AP Elcombe CR Foster JR Harada T Kaufmann W Knippel A Küttler K Malarkey DE Maronpot RR Nishikawa A Liver hypertrophy: A review of adaptive (adverse and non-adverse) changes—conclusions from the 3rd International ESTP Expert Workshop. Toxicol Pathol. 2012;40(7):971–994. 10.1177/0192623312448935 22723046
266 Costa LG Pellacani C Dao K Kavanagh TJ Roque PJ The brominated flame retardant BDE-47 causes oxidative stress and apoptotic cell death in vitro and in vivo in mice. Neurotoxicology. 2015;48:68–76. 10.1016/j.neuro.2015.03.008 25797475
267 Usenko CY Abel EL Kudela M Janise A Bruce ED Comparison of PBDE congeners as inducers of oxidative stress in zebrafish. Environ Toxicol Chem. 2015;34(5):1154–1160. 10.1002/etc.2922 25663549
268 Su G Yu H Lam MH Giesy JP Zhang X Mechanisms of toxicity of hydroxylated polybrominated diphenyl ethers (HO-PBDEs) determined by toxicogenomic analysis with a live cell array coupled with mutagenesis in Escherichia coli. Environ Sci Technol. 2014;48(10):5929–5937. 10.1021/es5003023 24717064
269 Finkel T Holbrook NJ Oxidants, oxidative stress and the biology of ageing. Nature. 2000;408(6809):239–247. 10.1038/35041687 11089981
270 Sinha RA Singh BK Yen PM Thyroid hormone regulation of hepatic lipid and carbohydrate metabolism. Trends Endocrinol Metab. 2014;25(10):538–545. 10.1016/j.tem.2014.07.001 25127738
271 Hassan MM Kaseb A Li D Patt YZ Vauthey JN Thomas MB Curley SA Spitz MR Sherman SI Abdalla EK Association between hypothyroidism and hepatocellular carcinoma: A case-control study in the United States. Hepatology. 2009;49(5):1563–1570. 10.1002/hep.22793 19399911
272 Aydinlik H Nguyen TD Moennikes O Buchmann A Schwarz M Selective pressure during tumor promotion by phenobarbital leads to clonal outgrowth of β-catenin-mutated mouse liver tumors. Oncogene. 2001;20(53):7812–7816. 10.1038/sj.onc.1204982 11753661
273 Pitot HC Goldsworthy T Campbell HA Poland A Quantitative evaluation of the promotion by 2,3,7,8-tetrachlorodibenzo-p-dioxin of hepatocarcinogenesis from diethylnitrosamine. Cancer Res. 1980;40(10):3616–3620. 6108157
274 Schwarz M Buchmann A Stinchcombe S Kalkuhl A Bock K Ah receptor ligands and tumor promotion: survival of neoplastic cells. Toxicol Lett. 2000;112-113:69–77. 10.1016/S0378-4274(99)00247-7 10720714
275 Zeiger E Anderson B Haworth S Lawlor T Mortelmans KSalmonella mutagenicity tests. 5. Results from the testing of 311 chemicals. Environ Mol Mutag. 1992; 19(S21):2-141. 10.1002/em.2850190603
276 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256
277 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007;634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
278 Unkila M Pohjanvirta R Honkakoski P Törrönen R Tuomisto J 2, 3, 7, 8-Tetrachlorodibenzo-p-dioxin (TCDD) induced ethoxyresorufin-O-deethylase (EROD) and aldehyde dehydrogenase (ALDH3) activities in the brain and liver: A comparison between the most TCDD-susceptible and the most TCDD-resistant rat strain. Biochem Pharmacol. 1993;46(4):651–659. 10.1016/0006-2952(93)90551-7 8363638
279 Pohjanvirta R Unkila M Tuomisto JT Vuolteenaho O Leppaluoto J Tuomisto J Effect of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) on plasma and tissue beta-endorphin-like immunoreactivity in the most TCDD-susceptible and the most TCDD-resistant rat strain. Life Sci. 1993;53(19):1479–1487. 10.1016/0024-3205(93)90621-9 8412511
280 Pohjanvirta R Unkila M Tuomisto J TCDD-induced hypophagia is not explained by nausea. Pharmacol Biochem Behav. 1994;47(2):273–282. 10.1016/0091-3057(94)90010-8 8146218
281 Janecka A Adamczyk A Gasińska A Comparison of eight commercially available kits for DNA extraction from formalin-fixed paraffin-embedded tissues. Anal Biochem. 2015;476:8–10. 10.1016/j.ab.2015.01.019 25640584
282 Jiang T Bell DR Clode S Fan MQ Fernandes A Foster PM Loizou G MacNicoll A Miller BG Rose M A truncation in the aryl hydrocarbon receptor of the CRL: WI (Han) rat does not affect the developmental toxicity of TCDD. Toxicol Sci. 2009;107(2):512–521. 10.1093/toxsci/kfn252 19056935
283 Fox TR Schumann AM Watanabe PG Yano BL Maher VM McCormick JJ Mutational analysis of the H-ras oncogene in spontaneous C57BL/6 x C3H/He mouse liver tumors and tumors induced with genotoxic and nongenotoxic hepatocarcinogens. Cancer Res. 1990;50(13):4014–4019. 2191770
284 Hoenerhoff MJ Pandiri AR Snyder SA Hong HH Ton TV Peddada S Shockley K Witt K Chan P Rider C Hepatocellular carcinomas in B6C3F1 mice treated with Ginkgo biloba extract for two years differ from spontaneous liver tumors in cancer gene mutations and genomic pathways. Toxicol Pathol. 2013;41(6):826–841. 10.1177/0192623312467520 23262642
285 Yamada Y Yoshimi N Sugie S Suzui M Matsunaga K Kawabata K Hara A Mori H Beta-catenin (Ctnnb1) gene mutations in diethylnitrosamine (DEN)-induced liver tumors in male F344 rats. Jpn J Cancer Res. 1999;90(8):824–828. 10.1111/j.1349-7006.1999.tb00822.x 10543253
286 Jackson MA Lea I Rashid A Peddada SD Dunnick JK Genetic alterations in cancer knowledge system: analysis of gene mutations in mouse and human liver and lung tumors. Toxicol Sci. 2006;90(2):400–418. 10.1093/toxsci/kfj101 16410370
287 Jurnak F Heffron S Bergmann E Conformational changes involved in the activation of ras p21: implications for related proteins. Cell. 1990;60(4):525–528. 10.1016/0092-8674(90)90652-U 2105846
288 Mosteller RD Han J Broek D Identification of residues of the H-ras protein critical for functional interaction with guanine nucleotide exchange factors. Mol Cell Biol. 1994;14(2):1104–1112. 10.1128/MCB.14.2.1104 8289791
289 Radich JP Kopecky KJ Willman CL Weick J Head D Appelbaum F Collins SJ N-ras mutations in adult de novo acute myelogenous leukemia: prevalence and clinical significance. Blood. 1990;76(4):801–807. 10.1182/blood.V76.4.801.801 2200539
290 Lin SR Hsu CH Tsai JH Wang JY Hsieh TJ Wu CH Decreased GTPase activity of K-ras mutants deriving from human functional adrenocortical tumours. Br J Cancer. 2000;82(5):1035–1040. 10.1054/bjoc.1999.1039 10737386
291 Sung YJ Carter M Zhong JM Hwang YW Mutagenesis of the H-ras p21 at glycine-60 residue disrupts GTP-induced conformational change. Biochemistry. 1995;34(10):3470–3477. 10.1021/bi00010a040 7880841
292 Strathmann J Schwarz M Tharappel JC Glauert HP Spear BT Robertson LW Appel KE Buchmann A PCB 153, a non-dioxin-like tumor promoter, selects for beta-catenin (Catnb)-mutated mouse liver tumors. Toxicol Sci. 2006;93(1):34–40. 10.1093/toxsci/kfl041 16782779
293 Schrenk D Schmitz H-J Bohnenberger S Wagner B Wörner W Tumor promoters as inhibitors of apoptosis in rat hepatocytes. Toxicol Lett. 2004;149(1-3):43–50. 10.1016/j.toxlet.2003.12.019 15093247
294 Schwarz M Appel KE Carcinogenic risks of dioxin: mechanistic considerations. Regul Toxicol Pharmacol. 2005;43(1):19–34. 10.1016/j.yrtph.2005.05.008 16054739
295 Sills RC Boorman GA Neal JE Hong HL Devereux TR Mutations in ras genes in experimental tumours of rodents. IARC Sci Publ. 1999;(146):55–86. 10353384
296 Hayashi SM Ton TV Hong HH Irwin RD Haseman JK Devereux TR Sills RC Genetic alterations in the Catnb gene but not the H-ras gene in hepatocellular neoplasms and hepatoblastomas of B6C3F(1) mice following exposure to diethanolamine for 2 years. Chem Biol Interact. 2003;146(3):251–261. 10.1016/j.cbi.2003.07.001 14642737