# Conclusions

Under the conditions of these 2-year oral gavage studies, there was clear evidence of carcinogenic activity^a^ of DE-71 in male Wistar Han rats based on increased incidences of hepatocholangioma, hepatocellular adenoma, or hepatocellular carcinoma (combined). Increased incidences of thyroid gland follicular cell adenoma and increased incidences of pituitary gland (pars distalis) adenoma were also considered to be related to exposure. There was clear evidence of carcinogenic activity of DE-71 in female Wistar Han rats based on increased incidences of hepatocholangioma, hepatocellular adenoma, and hepatocellular carcinoma. The occurrence of cholangiocarcinoma of the liver was also considered related to treatment. The incidences of stromal polyp or stromal sarcoma (combined) of the uterus may have been related to treatment. There was clear evidence of carcinogenic activity of DE-71 in male B6C3F1/N mice based on increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma. There was clear evidence of carcinogenic activity of DE-71 in female B6C3F1/N mice based on increased incidences of hepatocellular adenoma and hepatocellular carcinoma.

a See Explanation of Levels of Evidence of Carcinogenic Activity. See summary of the peer review panel comments and the public discussion on this Technical Report appears in Appendix O.

Administration of DE-71 resulted in increased incidences of nonneoplastic lesions in the liver, thyroid gland, kidney, parotid salivary gland, prostate gland, preputial gland, thymus, and forestomach of male rats; liver, thyroid gland, uterus, cervix, kidney, and adrenal cortex of female rats; liver, thyroid gland, forestomach, adrenal cortex, and testes of male mice; and liver, thyroid gland, forestomach, and adrenal cortex of female mice.