# Discussion

These NTP gavage studies evaluated the toxic and carcinogenic potential of a mixture of polybrominated diphenyl ethers (PBDEs) (DE-71, technical grade; Appendix J). Three-month studies were conducted in adult F344/N rats and B6C3F1/N mice at doses of 0, 0.01, 5, 50, 100, or 500 mg DE-71/kg body weight per day. Two-year studies were conducted in Wistar Han [Crl:WI(Han)] rats (referred to as Wistar Han rats below) at doses of 0, 3, 15, or 50 mg/kg, after in utero, postnatal, and adult exposure. This exposure paradigm was used in the 2-year rat study because of reported PBDE exposure to the human fetus and infant.^3-5^ Decreased survival in the 50 mg/kg male rats was due to adenomas of the pars distalis of the pituitary gland. Two-year studies were conducted in adult B6C3F1/N mice at doses of 0, 3, 30, or 100 mg/kg. In male and female mice, the 100 mg/kg groups were sacrificed at 18 months because of the moribund condition of the animals due to the development of liver neoplasms.

A major finding from these studies was the toxic effects of DE-71 administration in the liver of rats and mice. In the 3-month study, treatment-related liver lesions in male and female rats and mice included hepatocyte hypertrophy and cytoplasmic vacuolization (except female mice), with the incidences and severities increasing with increasing dose. Hepatocyte necrosis in 500 mg/kg mice was also treatment-related. Proposed mechanisms for hepatocyte necrosis included marked hypertrophy leading to reduced sinusoidal blood circulation, hypoxia, and necrosis^231^ and/or metabolic activation forming more toxic active metabolites.^232^

Liver toxicity at 3 months was also characterized by increases in liver enzyme levels and liver weights. Hepatic 7-pentoxyresorufin-O-dealkylase (PROD), 7-ethoxyresorufin-O-deethylase (EROD), acetanilide-4-hydroxylase (A4H), and uridine diphosphate glucuronosyl transferase (UDPGT) activities increased in these studies and the increases were generally greater in rats than mice. Liver weights were increased in male and female rats administered 5 mg/kg or greater. In mice, liver weights were increased in males administered 50 mg/kg or greater and in females administered 100 or 500 mg/kg.

In the 3-month study, dose-related decreases in serum thyroxine (T_4_) concentrations occurred at all time points in male and female rats administered 5 mg/kg or greater. These findings are consistent with decreases in circulating T_4_ that have been observed in other rat and mouse studies of PBDEs.^94,99,101,107^ Mechanisms for the decrease in T_4_ have been suggested and may involve interference by a PBDE congener with T_4_ binding to the plasma transport protein transthyretin^93,97^ and increased glucuronidation and excretion of T_4_ after PBDE exposure.^94^ Decreases in serum T_4_, and the observed concomitant increases in thyroid stimulating hormone (TSH) in response, may help explain, and would be consistent with, the increased incidences of thyroid gland follicular hypertrophy observed histologically in treated rats.

Dose-related increases in serum cholesterol concentrations occurred in male and female rats in the 3-month study. It is well known that, in humans, thyroid hormones regulate cholesterol and lipoprotein metabolism.^233^ Additionally, in rats it has been demonstrated that a hypothyroid state results in increased serum cholesterol^234^ and altered cholesterol and lipoprotein metabolism.^234-236^ Thus, it seems that the increased serum cholesterol concentrations observed in this study can be explained by the hypothyroid state induced by DE-71 administration.

In both the rat and mouse 3-month studies, small decreases in the erythron were associated with DE-71 administration. In humans and mice, it has been demonstrated that a hypothyroid state resulted in a significant reduction in red blood cell mass and a decline of the erythropoietic activity of the bone marrow.^237,238^ Similar observations, which could be reversed with the administration of erythropoietin or thyroid hormone, have been reported in rats.^239^ Further, it has been demonstrated that thyroid hormones have a direct stimulatory effect on bone marrow erythropoiesis in the rat.^240^ Thus, the decreased erythron observed in the rat and mouse studies would be consistent with the hypothyroid state induced by DE-71 administration. Because in mice this erythron effect only occurred in the 500 mg/kg groups, this may have also been secondary to the severe liver toxicity that occurred in these groups.^241,242^

Reproductive tract findings were observed in male rats in the 3-month study. Epididymis hypospermia and decreased epididymis weight were observed in the 500 mg/kg group, and decreased spermatid heads per gram testis were observed in the 100 and 500 mg/kg groups. Abnormal residual bodies were seen in half of the 500 mg/kg male mice. Abnormal residual bodies are generally larger than normal residual bodies, which represent remaining cytoplasm shed from elongating spermatids during their maturation and have the appearance of apoptotic bodies. Their significance is unclear, but they may represent a disruption of the spermiation process.^243^

Disruption of the estrous cycle occurred in 500 mg/kg female rats. Liver toxicity in 500 mg/kg females may have impacted estrogen metabolism, causing reduced elimination of estrogen, because the liver is a major site for conjugation and elimination of estrogens.^244^ Hypothyroidism and decreased thyroid hormone levels can also disrupt normal estrous cycling patterns.^245^

In the 2-year rat study, after perinatal exposure to DE-71 there were no effects on littering parameters in Wistar Han rat dams or pups. At the 3-month interim evaluation of Wistar Han rats, which included the vehicle control and 50 mg/kg groups, liver and thyroid gland toxicity were observed in the 50 mg/kg group, as previously noted in the 3-month study in the F344/N rat. In 50 mg/kg male rats at the 3-month interim evaluation, there was an increase in testis weight (after in utero/postnatal/adult exposure to DE-71). This increase in testis weight at 3 months was not seen in F344/N male rats after adult-only DE-71 administration. This Wistar Han rat testicular effect may have been related to a decrease in T_4_ levels during organ development, which has been previously reported to be associated with increased testis weight.^246^

The occurrence of treatment-related benign and malignant liver neoplasms in male and female rats and mice was a major finding of these 2-year studies of DE-71. Some decreases in survival and/or decreases in mean body weights in dosed groups were attributed to the development of these liver neoplasms especially in the 100 mg/kg mouse groups that were terminated at 18 months.

In the 2-year male rat study, the combined incidences of hepatocholangioma, hepatocellular adenoma, or hepatocellular carcinoma were considered to be clear evidence of carcinogenic activity based on the positive trend, and the combined incidence was significantly increased in the 50 mg/kg group. In female rats, the individual incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatocholangioma were considered to be clear evidence of carcinogenic activity due to significantly increased incidences in the 50 mg/kg group. The combined incidence of these tumors was also significantly increased in the 50 mg/kg group. Liver neoplasm formation (first incidence) in 50 mg/kg male and female rats occurred earlier than in vehicle controls. In all dosed groups of male and female rats, the incidences of hepatocyte hypertrophy were significantly increased, and the severities of the lesion increased with increasing dose. The incidences of eosinophilic foci and fatty change were significantly increased in 15 and 50 mg/kg rats. There was a significant positive trend for the incidences of cholangiocarcinoma in female rats, an uncommon tumor in control rats (0/300 in the historical control database for Wistar Han female rats). This was considered to be related to treatment, and this was supported by the finding of cholangiofibrosis in a few 50 mg/kg female rats.

In the 2-year mouse study, there were treatment-related increases in the incidences of benign and malignant liver neoplasms in dosed groups of males and females. In male mice, the individual incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma were considered to be clear evidence of carcinogenic activity based on the significant pairwise comparisons in all the dosed groups (adenomas) or the 30 and 100 mg/kg dose groups (carcinomas and hepatoblastomas), in addition, these increases were generally above the NTP historical control ranges. In combination, incidences of these neoplasms were also significantly increased in the 30 and 100 mg/kg groups. In female mice, the individual increases in the incidences of hepatocellular adenoma (30 and 100 mg/kg groups) and hepatocellular carcinoma (100 mg/kg group) were determined to be clear evidence of carcinogenic activity. The combined incidences of hepatocellular adenoma or carcinoma in the 30 and 100 mg/kg groups were also significantly increased and occurred with a significant positive trend. Liver neoplasms in treated mice occurred earlier than those in vehicle controls; 100 mg/kg mice were euthanized at 18 months because of a moribund condition due to the occurrence of liver neoplasms. Liver toxicity was also seen in dosed groups of mice including centrilobular hepatocyte hypertrophy.

In addition to the liver tumor response in male rats, the incidences of thyroid gland follicular cell adenoma were also considered to be related to treatment because there was a significant increase in the incidence of follicular cell adenoma in 50 mg/kg males, and the incidences of this neoplasm occurred with a significant positive trend in dosed males. A few thyroid gland carcinomas occurred in the 3 and 15 mg/kg groups of males. Thyroid gland follicular cell adenomas are thought to be capable of progressing to thyroid gland follicular cell carcinomas.^247^ It is possible that the increased number of early deaths in the 50 mg/kg males prevented the development of thyroid gland carcinomas in that group. This thyroid gland neoplasm response was supported by significantly increased incidences of follicle hypertrophy in all dosed groups of male rats. In addition, there was an increased incidence of follicular cell hyperplasia in 50 mg/kg females.

There is mechanistic support for the thyroid gland tumor response to DE-71 exposure based on the findings from the 3-month studies which showed that DE-71 can induce UDPGT and produce decreases in serum T_4_ and increases in serum TSH, which can be associated with the development of thyroid gland cancer.^248,249^ Induction of hepatic UDP-GT activity increases the metabolic clearance of thyroid hormone and may act as a promoting stimulus for thyroid gland tumor growth in rats.^249^

In addition to the liver and thyroid gland neoplasm responses in male rats at 2 years, there was an increase in the incidence of adenoma of the pars distalis of the pituitary gland in 50 mg/kg males. Because the incidence of pituitary gland adenoma was significantly increased in the 50 mg/kg group and the incidences of this neoplasm occurred with a significant positive trend, pituitary gland adenoma was considered to be related to DE-71 administration. The effect was not considered to be part of clear evidence because this pituitary gland neoplasm is a benign neoplasm that typically does not progress to carcinoma.^250^

An extended evaluation of residual uterus, vagina, and cervix tissue was conducted due to concerns of toxicity in these target organs. When the original and residual evaluations were combined, there were significant increases in the incidences of stromal polyp or stromal sarcoma (combined) in the uterus in the 3 and 15 mg/kg groups. This combination consisted primarily of stromal polyps. In addition, two vaginal polyps occurred in the 50 mg/kg group. However, these uterine tumors were considered an equivocal effect because these neoplasms appear to be common, there was a lack of dose response, and the data from animals with both the original and residual evaluations indicates that the concurrent control value was at the low end of the range.

In addition to the neoplasms, there were increased incidences of nonneoplastic lesions in the liver, thyroid gland, and kidney (male and female rats); parotid salivary gland, prostate gland, preputial gland, thymus, and forestomach (male rats); uterus, cervix, and adrenal cortex (female rats); liver, thyroid gland, forestomach, and adrenal cortex (male and female mice); and testes (male mice). The liver and thyroid gland toxicity, as mentioned above, may be related to the increase in metabolic activation in the liver through interaction of PBDEs with nuclear receptors and/or decreases in thyroid hormones, which can alter liver metabolic activity resulting in accumulation of liver lipids. The thyroid gland lesions could be a result of decreased T_4_ resulting in increased stimulation of the thyroid gland due to increased TSH levels. The forestomach toxicity and lesions in some of the other organs may have been related to the ability of PBDE metabolites to cause oxidative damage, and species differences in metabolism of PBDEs may have been the reason that the toxic forestomach lesions were seen only in mice.

Because 100 mg/kg male mice were euthanized at 18 months, a number of nonneoplastic lesions occurred with decreased incidences in this group, including epididymal inflammation, pancreatic islet hyperplasia, lung infiltration, pancreas atrophy, and spleen pigmentation. In 100 mg/kg male and female mice (also sacrificed early), the incidences of thyroid gland follicle degeneration were decreased. Some of these nonneoplastic lesions are late occurring lesions and, because of the early sacrifice time, did not have time to develop as normally occurs in aging mice.

In conjunction with the current 2-year DE-71 study, analysis of the aryl hydrocarbon receptor (AhR) genotype at exon 10 in vehicle control and 50 mg/kg female rats was also performed. The “wild” genotype at this locus characterizes an AhR receptor that can bind dioxin-like ligands; the mutant AhR genotype reduces ligand binding and some types of AhR downstream effects.^251-253^ The purpose of this study was to determine if the liver neoplasms in treated female rats were associated with a particular AhR genotype. Findings indicated that the 50 mg/kg female rat liver neoplasm response was independent of AhR genotype (Appendix M).

DE-71-related increases in liver EROD (CYP1A1) and A4H (CYP1A2) activities as seen in the current 3-month studies are characteristic of 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD) and dioxin like chemicals.^70,254^ In addition, hydronephrosis in rats has previously been seen after in utero exposure to both dioxin and polybrominated dibenzofurans.^255-258^

The DE-71 used in these studies contained a mixture of lower molecular weight PBDEs (Appendix J). PBDEs have little or no ability to activate the AhR and are not assigned toxic equivalency factor (TEF) values.^70,259,260^ Chlorinated dioxins (e.g., TCDD) were below the limit of detection in the DE-71 mixture used in the current studies. Brominated dioxins and furans, which make up 7 × 10^−6%^ or approximately 70 ng/g of DE-71, were present in the mixture only at a low level (Appendix J). It is estimated that brominated dioxins and furans were delivered at approximately 3.5 ng/kg per day to rats at 50 mg/kg or 7 ng/kg per day to mice at 100 mg/kg. Generally, brominated dioxins and furans have lower TEFs than TCDD (Table J-4), based on a range of in vitro and in vivo toxicity studies.^111,261,262^ When applying the TEF methodology^261^ this would translate to brominated dioxins and furans TEF delivery of approximately 0.35 ng/kg per day for high dose rats (50 mg/kg) and approximately 0.7 ng/kg per day for high dose mice (100 mg/kg). To put this in context, exposure to dioxin-equivalents from the brominated dioxins and dibenzofurans in the highest dose groups of DE-71 is lower than the lowest dose used in the NTP carcinogenicity studies of TCDD.^263^ In contrast, the level of CYP1A1 induction observed in the current DE-71 study is consistent with that observed in the highest dose group of the NTP carcinogenicity studies of TCDD.^263^ This suggests that using the present TEF methodology for brominated dioxins and dibenzofurans cannot explain the magnitude of the dioxin-like effect of DE-71. Since the major constituents of DE-71 are BDE-47 and BDE-99, there are several possible reasons for this difference. The TEF values for the brominated dioxins and dibenzofurans were based on acute exposure studies in mice or in vitro studies^261^ and may not accurately predict the relative potency of these chemicals for chronic exposures. Alternatively, or in combination, there may be components of DE-71 or their metabolites that are AhR ligands.

The observed DE-71 liver toxicity is consistent with activation of several receptor pathways including constitutive androstane receptor (CAR), pregnane X receptor (PXR), and the AhR. Activation of CAR and PXR results in induction of CYP2B and CYP3A, a phenobarbital-like effect.^264^ Expression of CYP2B and CYP3A increased with an induction threshold between 1.5 and 15 mg/kg DE-71 in rats receiving three oral doses in corn oil by gavage for 3 consecutive days.^70^ These values are consistent with DE-71 effects on liver enzymes observed in the current 3-month studies. In vitro studies indicate that BDE-47 activation of CAR can also occur in human cells.^103^ Activation of these nuclear hormone receptors is associated with increases in liver weights, hepatocellular hypertrophy, cell proliferation, and hepatocarcinogenesis.^265^ Other mechanisms for PBDE carcinogenic activity in rats and mice may be related to oxidative stress and alterations in thyroid hormone homeostasis.^266,267^ The hydroxylated metabolites are considered to be more toxic than the parent compounds.^268^ Oxidative damage from PBDEs and metabolites may be due to free radical formation. When rat pups were exposed in utero to BDE-99 there was an increase in the formation of reactive oxygen species in the liver.^106,108^ Production of reactive oxygen species may produce DNA damage.^269^ PBDEs also affect levels of thyroid hormones which are critical regulators of hepatic lipid metabolism, and decreases in thyroid hormones may result in fatty livers^270^ as were observed in the current DE-71 studies. Hypothyroidism may be a risk factor for hepatocellular carcinoma.^271^

Significantly increased incidences of Ctnnb1 mutations were noted in mouse hepatocellular carcinomas resulting from chronic exposure to DE-71 in the current study (Appendix N). Initiation and promotion experiments with a diethylnitrosamine (DEN) and phenobarbital protocol have demonstrated that neoplastic hepatocytes harboring Ctnnb1 mutations have a selective growth advantage during the promotion stages of carcinogenesis.^272^ However, this effect was not noted in hepatocellular carcinomas of mice exposed to DEN alone suggesting that some of the phenobarbital promotion effects may be related to activation of CAR/PXR nuclear receptors. PBDE components within DE-71 can activate multiple nuclear receptors such as CAR, PXR, and AhR^70,74,103,106^ and may have contributed to the promotion effects of DE-71.^272-274^ DE-71 is nongenotoxic and may not directly cause somatic mutations and initiate carcinogenesis; however, metabolites of DE-71 including dihydroxylated PBDEs may cause oxidative stress^88,106^ and subsequent DNA damage and somatic mutations in specific genes.