# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-589.

## Three-month Study in F344/N Rats

All rats survived to the end of the study (Table 4). Final mean body weights and mean body weight gains were less than those of the vehicle controls in 500 mg/kg males by approximately 14% and 23%, respectively (Table 4 and Figure 5). In female rats, final mean body weights were decreased approximately 8% in the 100 mg/kg group and 15% in the 500 mg/kg group, while mean body weight gains were less than that of the vehicle controls by approximately 16% and 28% in these two groups. There were no clinical findings related to administration of DE-71.

Table 4 Survival and Body Weights of F344/N Rats in the Three-month Gavage Study of DE-71^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 110 ± 2 | 316 ± 6 | 206 ± 5
0.01 | 10/10 | 110 ± 2 | 335 ± 5 | 224 ± 6 | 106
5 | 10/10 | 109 ± 2 | 327 ± 6 | 218 ± 4 | 103
50 | 10/10 | 111 ± 2 | 330 ± 6 | 219 ± 6 | 104
100 | 10/10 | 110 ± 2 | 318 ± 8 | 208 ± 8 | 101
500 | 10/10 | 113 ± 1 | 272 ± 5** | 159 ± 5** | 86
Female
0 | 10/10 | 91 ± 1 | 197 ± 3 | 106 ± 3
0.01 | 10/10 | 90 ± 1 | 191 ± 2 | 101 ± 3 | 97
5 | 10/10 | 90 ± 1 | 203 ± 4 | 113 ± 4 | 103
50 | 10/10 | 92 ± 1 | 189 ± 2 | 97 ± 3 | 96
100 | 10/10 | 92 ± 1 | 181 ± 3** | 89 ± 3** | 92
500 | 10/10 | 92 ± 1 | 169 ± 4** | 76 ± 3** | 85

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 5

Growth Curves for F344/N Rats Administered DE-71 by Gavage for Three Months

Consistent, dose-related decreases in thyroxine (T_4_) concentration occurred at all time points in males and females administered 5 mg/kg or greater (Table 5 and Table F-1). In the 100 and 500 mg/kg groups, the T_4_ concentrations were less than or equal to 15% of that of the vehicle control on day 4 and week 14. For the 5 and 50 mg/kg groups, the decrease appeared progressive with the strongest effect detected at week 14 (approximately 50% and less than or equal to 15% of the vehicle control concentration for the 5 and 50 mg/kg groups, respectively). The decreases in T_4_ concentrations were accompanied by increases in thyroid stimulating hormone (TSH) concentrations. TSH increases were first apparent on day 25 and persisted to week 14. While strong decreases in T_4_ occurred in males and females administered 5 mg/kg or greater, increases in TSH were most consistently detected in the 100 and 500 mg/kg groups, and at week 14 demonstrated a 60% to 70% increase compared to that of the vehicle control group. The decreases in T_4_ were not accompanied by decreases in triiodothyronine (T_3_) concentrations.

Table 5 Selected Clinical Chemistry Data for F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n
Day 4 | 9 | 9 | 9 | 9 | 9 | 9
Day 25 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Cholesterol (mg/dL)
Day 4 | 105 ± 4 | 101 ± 3 | 106 ± 2 | 135 ± 3** | 148 ± 4** | 185 ± 6**
Day 25 | 77 ± 2 | 89 ± 2** | 89 ± 2** | 101 ± 3** | 112 ± 4** | 217 ± 3**
Week 14 | 88 ± 1 | 87± 2 | 83 ± 2 | 106 ± 3** | 117 ± 3** | 235 ± 5**
Bile salts (µmol/L)
Day 4 | 20.3 ± 2.0 | 18.6 ± 1.4 | 21.5 ± 2.0 | 27.1 ± 1.2* | 31.9 ± 2.1** | 33.8 ± 1.6**
Day 25 | 21.1 ± 2.3 | 16.4 ± 0.7 | 22.8 ± 1.8 | 25.5 ± 1.5* | 32.7 ± 1.4** | 39.1 ± 2.2**
Week 14 | 15.5 ± 0.9 | 20.8 ± 2.2 | 22.3 ± 1.9* | 20.8 ± 0.9** | 27.0 ± 1.6** | 32.9 ± 1.6**
Total thyroxine (µg/dL)
Day 4 | 5.97 ± 0.34^b^ | 5.72 ± 0.12^b^ | 5.67 ± 0.29^b^ | 1.35 ± 0.10**^b^ | 0.87 ± 0.13**^b^ | 0.62 ± 0.11**^b^
Day 25 | 6.55 ± 0.26 | 6.54 ± 0.48 | 5.02 ± 0.31** | 1.33 ± 0.16** | 0.72 ± 0.10** | 0.48 ± 0.07**
Week 14 | 4.25 ± 0.20 | 4.53 ± 0.18 | 2.29 ± 0.16** | 0.50 ± 0.11** | 0.10 ± 0.05** | 0.46 ± 0.09**
Total triiodothyronine (ng/dL)
Day 25 | 100.9 ± 3.1 | 113.1 ± 7.6 | 90.8 ± 6.5 | 79.4 ± 4.1* | 80.0 ± 3.9 | 108.6 ± 3.9
Week 14 | 81.1 ± 4.5 | 75.7 ± 3.7 | 63.7 ± 5.6 | 77.9 ± 5.8 | 73.4 ± 5.3 | 120.7 ± 5.6
Thyroid stimulating hormone (ng/mL)
Day 4 | 5.70 ± 0.41^b^ | 5.20 ± 0.40^b^ | 5.04 ± 0.47^b^ | 5.82 ± 0.55 | 5.10 ± 0.39^b^ | 4.42 ± 0.39^b^
Day 25 | 3.66 ± 0.15 | 4.69 ± 0.38 | 5.16 ± 0.64 | 5.57 ± 0.66 | 6.55 ± 0.84** | 4.63 ± 0.60
Week 14 | 3.75 ± 0.33 | 3.61 ± 0.47 | 3.74 ± 0.46 | 4.62 ± 0.48 | 4.69 ± 0.57 | 6.19 ± 0.84*
Female
n
Day 4 | 3 | 3 | 3 | 4 | 6 | 2
Day 25 | 10 | 10 | 10 | 10 | 9 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Cholesterol (mg/dL)
Day 4 | 112 ± 6^c^ | 108 ± 4^c^ | 113 ± 3^c^ | 136 ± 3**^b^ | 147 ± 7**^d^ | 176 ± 4**^b^
Day 25 | 75 ± 2 | 82 ± 3* | 87 ± 3** | 117 ± 4** | 144 ± 4**^c^ | 244 ± 5**
Week 14 | 72 ± 2 | 74 ± 2 | 94 ± 3** | 145 ± 4** | 183 ± 9** | 310 ± 9**
Bile acids (µmol/L)
Day 4 | 16.2 ± 3.7 | 19.9 ± 2.8 | 16.4 ± 3.9 | 27.1 ± 4.9 | 26.4 ± 2.1 | 23.4 ± 0.2
Day 25 | 19.3 ± 1.9 | 25.4 ± 5.4 | 18.1 ± 1.9 | 25.0 ± 1.4* | 31.6 ± 1.8** | 32.3 ± 1.7**
Week 14 | 20.2 ± 6.0 | 16.8 ± 1.5 | 17.3 ± 0.6* | 20.9 ± 1.1** | 24.3 ± 0.9** | 32.2 ± 2.5**
Total thyroxine (µg/dL)
Day 4 | 4.88 ± 0.22^b^ | 4.90 ± 0.13^b^ | 4.12 ± 0.20*^b^ | 0.95 ± 0.12**^b^ | 0.57 ± 0.07**^b^ | 0.41 ± 0.08**^b^
Day 25 | 5.09 ± 0.17 | 4.89 ± 0.26 | 4.13 ± 0.25* | 1.02 ± 0.11** | 0.56 ± 0.14** | 0.30 ± 0.07**
Week 14 | 3.19 ± 0.24 | 3.36 ± 0.16 | 1.68 ± 0.12** | 0.41 ± 0.06** | 0.48 ± 0.09** | 0.50 ± 0.07**
Total triiodothyronine (ng/dL)
Day 25 | 94.1 ± 5.1 | 98.1 ± 3.4 | 91.5 ± 4.5 | 95.7 ± 4.1 | 98.7 ± 4.0 | 120.4 ± 4.6**
Week 14 | 79.0 ± 5.8 | 75.2 ± 4.1 | 62.6 ± 2.0 | 74.9 ± 4.1 | 83.6 ± 6.2 | 137.3 ± 5.7**
Thyroid stimulating hormone (ng/mL)
Day 4 | 4.57 ± 0.46^b^ | 4.08 ± 0.42^b^ | 5.80 ± 0.47^b^ | 4.51 ± 0.44^b^ | 4.55 ± 0.38^b^ | 3.61 ± 0.35^b^
Day 25 | 3.99 ± 0.26 | 3.96 ± 0.18 | 4.84 ± 0.32 | 5.27 ± 0.20** | 4.86 ± 0.43* | 5.56 ± 0.52*
Week 14 | 2.69 ± 0.20 | 2.95 ± 0.29 | 2.83 ± 0.28 | 3.40 ± 0.36 | 4.66 ± 0.72** | 4.32 ± 0.34**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 10.

^c^ n = 9.

^d^ n = 7.

At all time points, the serum concentrations of cholesterol were consistently increased in males and females administered 50 mg/kg or greater (Table 5 and Table F-1). The increases demonstrated a dose relationship and progressed in severity with time (e.g., an approximate 60% increase in the 500 mg/kg females on day 4 increased to an approximate fourfold increase at week 14). Serum concentrations of bile salts, a marker of hepatic function/injury and cholestasis, also demonstrated consistent, dose-related increases in males and females administered 50 mg/kg or greater at essentially all time points. For bile salts, the absolute increases remained consistent across time and appeared to be of minimal (less than or equal to twofold) severity. Another marker of cholestasis, alkaline phosphatase activity, however, demonstrated no increases. Thus, it would appear the increases in bile salt concentration were probably not related to a cholestatic event, but rather were an effect of hepatic function. Markers of hepatocellular leakage/injury, serum activities of alanine aminotransferase and sorbitol dehydrogenase, generally demonstrated minimal increases in the 100 and 500 mg/kg groups (most consistently in 500 mg/kg males and females). On day 25 and at week 14, small (less than 20%) increases occurred in serum albumin concentrations, and by extension, total protein concentrations in the 50 mg/kg or greater treatment groups, which would be suggestive of a physiological decrease in plasma volume (i.e., dehydration). Minimal increases in serum urea nitrogen concentration, but not creatinine concentration, in the 500 mg/kg groups at these time points would support the physiological nature of the protein increase.

At week 14, the hematology findings suggested small (less than or equal to 12%), dose-related decreases in the estimators of the circulating red cell mass in the 100 and 500 mg/kg males and females. The erythron decreases were evidenced by decreases in hematocrit values and hemoglobin concentrations, but not erythrocyte counts (Table F-1). The erythron decreases were accompanied by dose-related decreases in erythrocyte size (i.e., mean cell volume) and mass of hemoglobin (i.e., mean cell hemoglobin). However, there was no change in the erythrocyte concentration of hemoglobin (i.e., mean cell hemoglobin concentration), and the statistical identification of minimally increased reticulocyte numbers in the males, but not females (which had the slightly bigger percentage erythron decreases), were of questionable importance.

The absolute and relative liver weights of male and female rats administered 5 mg/kg or greater were significantly greater than those of the vehicle controls (Table 6 and Table G-1). The absolute liver weight of 500 mg/kg males was approximately double that of the vehicle control group, while in females, the absolute liver weight of the 500 mg/kg group was approximately 220% that of the vehicle controls. The changes in liver weights correlated with hepatocyte hypertrophy observed histologically in both male and female rats.

Table 6 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 316 ± 6 | 335 ± 5 | 327 ± 6 | 330 ± 6 | 318 ± 8 | 272 ± 5**
R. Kidney
Absolute | 0.93 ± 0.02 | 0.99 ± 0.03 | 1.00 ± 0.03 | 1.07 ± 0.03** | 1.07 ± 0.03** | 1.08 ± 0.02**
Relative | 2.932 ± 0.023 | 2.942 ± 0.056 | 3.050 ± 0.054 | 3.240 ± 0.036** | 3.349 ± 0.027** | 3.958 ± 0.035**
Liver
Absolute | 10.09 ± 0.17 | 11.22 ± 0.33 | 12.13 ± 0.44** | 16.04 ± 0.52** | 17.42 ± 0.46** | 20.01 ± 0.58**
Relative | 31.940 ± 0.252 | 33.482 ± 0.536 | 37.037 ± 0.774** | 48.628 ± 1.130** | 54.787 ± 0.524** | 73.381 ± 1.224**
Thymus
Absolute | 0.230 ± 0.012 | 0.243 ± 0.014 | 0.241 ± 0.012 | 0.221 ± 0.011 | 0.245 ± 0.020 | 0.163 ± 0.014**
Relative | 0.727 ± 0.038 | 0.727 ± 0.041 | 0.739 ± 0.037 | 0.672 ± 0.038 | 0.772 ± 0.059 | 0.598 ± 0.048
Female
Necropsy body wt | 197 ± 3 | 191 ± 2 | 203 ± 4 | 189 ± 2 | 181 ± 3** | 169 ± 4**
R. Kidney
Absolute | 0.62 ± 0.01 | 0.65 ± 0.01 | 0.68 ± 0.01** | 0.68 ± 0.01** | 0.68 ± 0.02** | 0.79 ± 0.01**
Relative | 3.132 ± 0.047 | 3.378 ± 0.063* | 3.333 ± 0.050* | 3.617 ± 0.055** | 3.737 ± 0.048** | 4.716 ± 0.105**
Liver
Absolute | 5.56 ± 0.16 | 5.92 ± 0.10 | 6.47 ± 0.13** | 8.73 ± 0.16** | 9.85 ± 0.27** | 12.16 ± 0.35**
Relative | 28.191 ± 0.616 | 31.009 ± 0.599* | 31.891 ± 0.490** | 46.139 ± 0.590** | 54.511 ± 1.135** | 72.195 ± 1.448**
Thymus
Absolute | 0.226 ± 0.011 | 0.212 ± 0.009 | 0.209 ± 0.007 | 0.174 ± 0.009** | 0.152 ± 0.011** | 0.099 ± 0.009**
Relative | 1.149 ± 0.055 | 1.114 ± 0.051 | 1.032 ± 0.035 | 0.922 ± 0.051** | 0.836 ± 0.055** | 0.587 ± 0.050**

Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Absolute kidney weights were significantly greater than that of the vehicle controls by approximately 15% to 16% in the 50, 100, and 500 mg/kg male groups; these groups also had increased relative kidney weights (Table 6 and Table G-1). In females, absolute kidney weights were significantly increased in the groups administered 5 mg/kg or greater; the greatest increase (approximately 27%) occurred in the 500 mg/kg group. Relative kidney weights were significantly greater than that of the vehicle controls in all dosed groups of females, with the largest increase in the 500 mg/kg group. No histological lesions were observed in either male or female rats that correlated with the changes in kidney weights.

The absolute thymus weight in 500 mg/kg male rats and absolute and relative thymus weights in female rats administered 50 mg/kg or greater were significantly decreased compared to those of the vehicle controls (Table 6 and Table G-1). In 500 mg/kg males, the decreased absolute thymus weight was consistent with decreased body weight. In female rats administered 50, 100, or 500 mg/kg, the decreased absolute (23%, 33%, and 56%, respectively) and relative thymus weights could not be explained simply by decreased body weights. The decreased thymic weights in 500 mg/kg females correlated with thymic atrophy observed histologically, but this lesion was not observed in the 50 or 100 mg/kg groups.

In the male rats, relative heart weights of the 50, 100, and 500 mg/kg groups were significantly greater than that of the vehicle controls (Table G-1). The relative weight increase of the 500 mg/kg group was considered secondary to decreased mean body weight compared to the vehicle control group; the increases in the other dose groups were considered biological variation. In female rats, relative heart weights of the 100 and 500 mg/kg groups were significantly greater than that of the vehicle controls and were attributed to decreased mean body weights in those groups. Significantly decreased absolute lung weights of 500 mg/kg males and females were also attributed to decreases in mean body weights.

Compared to the vehicle controls, uridine diphosphate glucuronosyl transferase (UDPGT) activities were significantly increased in male rats administered 0.01 mg/kg on day 25 and in male and female rats administered 5 mg/kg or greater on day 25 and at week 14 (Table 7). UDPGT activity at week 14 reached a peak induction of approximately 12.5-fold and 26-fold in 500 mg/kg males and females, respectively.

Table 7 Liver Enzyme Activities for F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n
Day 25 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Uridine diphosphate glucuronosyl transferase (UDPGT) (nmol/minute per mg microsomal protein)
Day 25 | 2.9 ± 0.1 | 4.0 ± 0.2** | 4.5 ± 0.2** | 12.9 ± 0.4** | 15.6 ± 0.8** | 28.4 ± 0.8**
Week 14 | 4.2 ± 0.4 | 3.7 ± 0.3 | 5.9 ± 0.4* | 21.4 ± 1.1** | 35.8 ± 1.8** | 52.6 ± 2.6**
7-Ethoxyresorufin-O-deethylase (EROD) (nmol/minute per mg microsomal protein)
Day 25 | 0.007 ± 0.000 | 0.008 ± 0.001 | 0.037 ± 0.003** | 0.386 ± 0.025** | 0.444 ± 0.056** | 1.034 ± 0.096**
Week 14 | 0.008 ± 0.001 | 0.006 ± 0.000 | 0.012 ± 0.001 | 0.282 ± 0.019** | 0.358 ± 0.030** | 0.843 ± 0.053**
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 25 | 0.020 ± 0.002 | 0.009 ± 0.002 | 0.034 ± 0.004^b^ | 0.420 ± 0.045**^c^ | 0.441 ± 0.032** | 0.704 ± 0.038**
Week 14 | 0.255 ± 0.020 | 0.185 ± 0.011 | 0.355 ± 0.019* | 0.923 ± 0.041** | 1.455 ± 0.050** | 2.903 ± 0.071**
7-Pentoxyresorufin-O-dealkylase (PROD) (nmol/minute per mg microsomal protein)
Day 25 | 0.001 ± 0.000 | 0.001 ± 0.000 | 0.022 ± 0.002** | 0.133 ± 0.006** | 0.124 ± 0.010** | 0.077 ± 0.005**
Week 14 | 0.002 ± 0.000 | 0.001 ± 0.000 | 0.099 ± 0.006** | 0.262 ± 0.016** | 0.218 ± 0.014** | 0.281 ± 0.013**
Female
n
Day 25 | 10 | 10 | 10 | 10 | 9 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 10
Uridine diphosphate glucuronosyl transferase (UDPGT) (nmol/minute per mg microsomal protein)
Day 25 | 3.2 ± 0.2 | 2.8 ± 0.2 | 6.4 ± 0.8* | 12.4 ± 0.5** | 15.0 ± 0.7** | 50.8 ± 1.5**
Week 14 | 2.9 ± 0.3 | 3.2 ± 0.4 | 8.0 ± 0.2** | 32.1 ± 0.9** | 53.5 ± 2.0** | 75.5 ± 3.2**
7-Ethoxyresorufin-O-deethylase (EROD) (nmol/minute per mg microsomal protein)
Day 25 | 0.014 ± 0.001 | 0.017 ± 0.001 | 0.081 ± 0.004** | 1.023 ± 0.044** | 0.958 ± 0.052** | 1.402 ± 0.079**
Week 14 | 0.004 ± 0.001 | 0.003 ± 0.000 | 0.075 ± 0.008** | 0.648 ± 0.053** | 0.650 ± 0.067** | 0.836 ± 0.073**
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
Day 25 | 0.023 ± 0.002 | 0.023 ± 0.004 | 0.036 ± 0.005* | 0.589 ± 0.050** | 0.599 ± 0.110** | 0.802 ± 0.040**^b^
Week 14 | 0.231 ± 0.013 | 0.205 ± 0.015 | 0.490 ± 0.022**^b^ | 1.400 ± 0.065** | 1.723 ± 0.069** | 2.384 ± 0.109**
7-Pentoxyresorufin-O-dealkylase (PROD) (nmol/minute per mg microsomal protein)
Day 25 | 0.001 ± 0.000 | 0.001 ± 0.000 | 0.011 ± 0.001** | 0.105 ± 0.011** | 0.099 ± 0.008** | 0.122 ± 0.011**
Week 14 | 0.001 ± 0.000 | 0.001 ± 0.000 | 0.054 ± 0.006** | 0.233 ± 0.016** | 0.112 ± 0.005** | 0.086 ± 0.005**

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s test.

** P ≤ 0.01.

^a^ Enzyme activities are given as mean ± standard error.

^b^ n = 9.

^c^ n = 8.

Hepatic 7-ethoxyresorufin-O-deethylase (EROD) activities on day 25 displayed generally dose-related increases with approximately 148-fold and 100-fold increases in 500 mg/kg males and females, respectively (Table 7). Significant increases were observed in males and females administered 5 mg/kg or greater. By week 14, EROD activity in 500 mg/kg males was induced approximately 105-fold, while in 500 mg/kg females, it was induced approximately 209-fold. Significant but smaller increases were observed in 50 and 100 mg/kg males and females administered 5 mg/kg or greater.

On day 25, hepatic acetanilide-4-hydroxylase (A4H) activities were significantly increased in male rats administered 50 mg/kg or greater and in female rats administered 5 mg/kg or greater, with maximal induction increased approximately 35-fold for males and females administered 500 mg/kg (Table 7). At week 14, maximal A4H induction was approximately 11-fold for male rats and 10-fold for female rats in the 500 mg/kg groups, and significant dose-related increases were observed in both male and female rats administered 5 mg/kg or greater.

Hepatic 7-pentoxyresorufin-O-dealkylase (PROD) activities were increased in male and female rats administered 5 mg/kg or greater on day 25 and at week 14 (Table 7). The greatest increase in PROD activity was seen at week 14 in males administered 500 mg/kg (approximately a 141-fold increase) and females administered 50 mg/kg (approximately a 233-fold increase).

Concentrations of BDE-47, BDE-99 and BDE-153 were determined in adipose and liver in special study males and females on day 25 and core study rats at the end of the study (Appendix I). In males and females administered 5 mg/kg or greater, the concentrations of all three congeners in adipose and liver increased with increasing dose and were higher than those of the respective vehicle controls at both time points (Table I-1). The concentrations of congeners in adipose were higher than in liver suggesting preferential accumulation in the adipose. BDE-47 and BDE-99 concentrations in adipose were similar and were higher than the BDE-153 concentrations in both sexes; however, BDE-47, BDE-99, and BDE-153 concentrations were similar in the liver. In general, the congener concentration in adipose was higher in females compared to males; however, there was no sex difference in congener concentration in the liver. In the adipose, levels of congeners were higher at the end of the study (week 14) compared to day 25, supporting accumulation. Although there was no difference in BDE-153 concentrations on day 25 and at week 14 in the liver, BDE-47 and BDE-99 concentrations at week 14 were lower than on day 25, suggesting that BDE-47 and BDE-99 induce their own metabolism.

Epididymis and cauda epididymis weights were significantly decreased in 500 mg/kg males (Table 8 and Table H-1). The 500 mg/kg group also exhibited significantly decreased sperm per cauda and sperm per gram of cauda. Histologically, this correlated with hypospermia of the epididymis. In general, dosed males exhibited fewer total spermatids per testis, and sperm per gram of testis were significantly decreased in the 100 and 500 mg/kg groups; however, no histologic alterations were observed in testes. Sperm motility was significantly decreased in the 500 mg/kg group. All 500 mg/kg females failed to cycle and remained in persistent diestrus throughout the examination period (Table 9, Table H-2, Table H-3; Figure H-1). Based on these findings, DE-71 exhibits the potential to be a reproductive toxicant in both male and female rats.

Table 8 Summary of Reproductive Tissue Evaluations for Male F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 50 mg/kg | 100 mg/kg | 500 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 316 ± 6 | 335 ± 7.9 | 318 ± 8 | 282 ± 12*
L. Cauda epididymis | 0.1289 ± 0.0050 | 0.1385 ± 0.0119^b^ | 0.1328 ± 0.0087 | 0.0724 ± 0.0047**
L. Epididymis | 0.4284 ± 0.0102 | 0.4485 ± 0.0168 | 0.4184 ± 0.0141 | 0.3135 ± 0.0128**
L. Testis | 1.4061 ± 0.0343 | 1.5028 ± 0.0337 | 1.4981 ± 0.0279 | 1.4818 ± 0.0291
Spermatid measurements
Spermatid heads (10^6^/testis) | 181.38 ± 3.90 | 186.38 ± 7.34 | 170.50 ± 5.90 | 164.88 ± 9.49
Spermatid heads (10^6^/g testis) | 152.48 ± 4.13 | 151.01 ± 6.13 | 137.20 ± 3.96* | 130.36 ± 6.20**
Epididymal spermatozoal measurements
Sperm motility (%) | 86.6 ± 0.7 | 86.5 ± 0.9 | 87.0 ± 0.6 | 82.7 ± 0.8**
Sperm (10^6^/cauda epididymis) | 78.3 ± 4.2 | 63.2 ± 8.9 | 81.3 ± 4.9 | 9.9 ± 1.1**
Sperm (10^6^/g cauda epididymis) | 608.5 ± 25.8 | 457.2 ± 77.4 | 591.2 ± 44.2 | 137.1 ± 14.6**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s (body weights) or Shirley’s (spermatid heads/g testis) test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ (cauda epididymis and epididymis weights) or Shirley’s (spermatid heads/g testis and epididymal spermatozoal measurements) test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s (testis weights) or Dunn’s (spermatid heads/testis) test.

^b^ n = 9.

Table 9 Estrous Cycle Characterization for Female F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 50 mg/kg | 100 mg/kg | 500 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 197 ± 3 | 189 ± 2 | 181 ± 3** | 169 ± 4**
Proportion of regular cycling females^b^ | 7/10 | 8/10 | 10/10* | 0/10*
Estrous cycle length (days) | 5.8 ± 0.40 | 5.8 ± 0.29 | 5.3 ± 0.15 | –^c^
Estrous stages (% of cycle)
Diestrus | 61.7 | 60.0 | 56.7 | 100.0
Proestrus | 13.3 | 12.5 | 18.3 | 0.0
Estrus | 20.0 | 20.0 | 18.3 | 0.0
Metestrus | 5.0 | 7.5 | 6.7 | 0.0

* Significantly different (P ≤ 0.05) from the vehicle control group by the Chi-square test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated a significantly higher probability of extended diestrus in the 500 mg/kg group compared to the vehicle control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 10 of 10 animals.

Relevant gross findings included liver enlargement in both male and female rats, as well as small thymus and thin carcass in female rats. Statistically significant histologic changes occurred in the liver and thyroid gland of male and female rats, the epididymis and glandular stomach of male rats and the thymus of female rats.

In the liver, there were significantly increased incidences of hepatocyte hypertrophy in males and females administered 5 mg/kg or greater (Table 10). The incidences of cytoplasmic vacuolization of the hepatocytes were significantly increased in 50 mg/kg males and 100 and 500 mg/kg males and females. The severity of hepatocyte hypertrophy also increased with increasing dose. Hepatocyte hypertrophy was characterized by enlarged hepatocytes, which often contained larger than average nuclei (Figure 15). Hepatocyte hypertrophy appeared to affect the centrilobular hepatocytes first, and as the severity of the lesion increased, the zonal specificity of the lesion decreased. Cytoplasmic vacuolization was represented by enlarged cells with discrete cytoplasmic vacuoles that varied in size (Figure 15). In some cells, the vacuoles were so small they appeared indistinguishable, giving the cytoplasm a pale, eosinophilic, almost granular appearance. In other cells, the vacuoles were distinct and recognizable as discrete vacuoles of lipid. Cytoplasmic vacuolization had a centrilobular distribution and tended to occur within hypertrophied areas of the liver. This change was characteristically similar to that of hepatocellular fatty change seen in the 2-year study.

Table 10 Incidences of Selected Nonneoplastic Lesions in F344/N Rats in the Three-month Gavage Study of DE-71

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
Liver^a^ | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, Hypertrophy^b^ | 0 | 0 | 9** (1.0) | 10** (2.7) | 10** (3.4) | 10** (3.7)^c^
Hepatocyte, Cytoplasmic Vacuolization | 0 | 0 | 0 | 10** (1.2) | 10** (2.0) | 10** (1.7)
Thyroid Gland | 10 | 9 | 10 | 10 | 10 | 10
Follicle, Hypertrophy | 0 | 0 | 0 | 0 | 1 (1.0) | 9** (1.0)
Epididymis | 10 | 10 | 10 | 10 | 10 | 10
Hypospermia | 0 | 0 | 0 | 0 | 0 | 9** (1.9)
Stomach, Glandular | 10 | 10 | 10 | 10 | 10 | 10
Erosion | 0 | 0 | 1 (1.0) | 2 (1.5) | 3 (1.7) | 4* (1.5)
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, Hypertrophy | 0 | 2 (1.0) | 5* (1.4) | 10** (2.2) | 10** (3.1) | 10** (4.0)
Hepatocyte, Cytoplasmic Vacuolization | 0 | 0 | 0 | 3 (1.0) | 10** (1.1) | 10** (1.0)
Thyroid Gland | 10 | 0 | 10 | 10 | 10 | 10
Follicle, Hypertrophy | 0 | – | 0 | 8** (1.0) | 9** (1.4) | 10** (2.9)
Stomach, Glandular | 10 | 10 | 10 | 10 | 10 | 10
Erosion | 0 | 0 | 0 | 0 | 0 | 3 (1.0)
Thymus | 10 | 10 | 10 | 10 | 9 | 10
Atrophy | 0 | 0 | 0 | 0 | 0 | 4* (1.3)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 15

Hepatocyte Hypertrophy (Enlarged Hepatocytes) and Cytoplasmic Vacuolization (Vacuolated Hepatocytes) in the Liver of a Male F344/N Rat Administered 500 mg/kg DE-71 by Gavage for Three Months (H&E)

There were significantly increased incidences of thyroid gland follicle hypertrophy in females administered 50 mg/kg or greater and in 500 mg/kg males (Table 10). In females, there was a concomitant increase in the average severity grade. The lesion was characterized by an increase in the number of small follicles lined by cuboidal to low columnar epithelial cells (Figure 16 and Figure 17). Some of the follicles contained pale, often vacuolated colloid. Severity grading was based on the subjective number of thyroid follicles involved compared to the number of normal appearing follicles.

Figure 16

Normal Thyroid Gland in a Vehicle Control Female F344/N Rat in the Three-month Gavage Study of DE-71 (H&E)

The follicles are lined by flattened epithelium and contain abundant amounts of brightly eosinophilic colloid.

Figure 17

Follicle Hypertrophy in the Thyroid Gland of a Female F344/N Rat Administered 500 mg/kg DE-71 by Gavage for Three Months (H&E)

Follicle hypertrophy is characterized by small follicles lined by cuboidal epithelial cells.

In the epididymis, there was a significantly increased incidence of hypospermia in 500 mg/kg males (Table 10). Histologically, the overall area of the cauda epididymis was smaller in affected animals and there were fewer, smaller, tubule cross sections. Tubules in these animals contained spermatids, but they were lined by tall cuboidal to columnar epithelial cells, compared to the flattened to cuboidal epithelium in vehicle control animals. While the smaller amount of tissue present might have been due to artifact or plane of sectioning differences, the sizes of the epididymides were consistent among animals within dose groups. Histology is not a sensitive indicator of decreased spermatid numbers, but the histologic observations and interpretations were confirmed by decreased sperm counts.

Erosion of the glandular stomach occurred only in dosed animals, and the incidence was significantly increased in 500 mg/kg males (Table 10). This lesion occurred with a positive trend in both males and females. Erosion of the glandular stomach was recorded when there was necrosis of the mucosa that did not extend below the basement membrane into the underlying lamina propria.

In the thymus of 500 mg/kg females, there was a significantly increased incidence of atrophy that was characterized by a small thymus with a thin cortex (Table 10).

Dose Selection Rationale: Due to reduced body weights observed in 100 mg/kg females and 500 mg/kg males and females, increased absolute and relative liver weights, and increased incidences and severities of hepatocyte hypertrophy and hepatocyte cytoplasmic vacuolization in males and females, the high dose selected for the 2-year gavage study in Wistar Han rats was 50 mg/kg. The low dose (3 mg/kg) and mid dose (15 mg/kg) were selected to give a broad range of exposure.

## Two-year Study in Wistar Han Rats

### Litter Effects Through Postnatal Day 21

Administration of DE-71 had no biologically relevant effect on survival or body weights of pups or dams, and no apparent effects on the percentage of mated females producing pups, litter size, pup sex distribution, weights of dams, or numbers of male or female pups (Table 11, Table 12, Table 13, Table 14, Figure 6, and Figure 7). There were no clinical findings associated with exposure to DE-71 in the dams before or after parturition. Pups born to dams administered DE-71 during gestation were weaned on PND 21, and this was considered day 1 of the 2-year perinatal and postnatal study. There was no effect on the growth of the pups.

Table 11 Summary of Disposition During Perinatal Exposure and F_1_ Allocation in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Time-Mated Females (GD 6) | 62 | 52 | 52 | 62
Females Pregnant (%) | 54 (87%) | 42 (81%) | 43 (83%) | 51 (82%)
Females Not Pregnant (%) | 8 (13%) | 10 (19%) | 9 (17%) | 11 (18%)
Dams Not Delivering with Evidence of Pregnancy (%) | 2 (4%) | 1 (2%) | 4 (9%) | 2 (4%)
Dams with Litters on PND 0 (%) | 52 (96%) | 41 (98%) | 39 (91%) | 49 (96%)
Dams, Moribund | 0 | 0 | 0 | 0
Dams, Natural Deaths | 0 | 0 | 0 | 0
Litters Post-Standardization (PND 4) | 36 | 29 | 28 | 37
Post-Weaning Allocation
F_1_ Males – Interim^a^ (litters) | 10 (9) | – | – | 10 (9)
F_1_ Females – Interim^a^ (litters) | 10 (10) | – | – | 10 (8)
F_1_ Males – Core^b^ (litters) | 50 (29) | 50 (25) | 50 (25) | 50 (29)
F_1_ Females – Core^b^ (litters) | 50 (30) | 50 (25) | 50 (25) | 50 (28)

^a^ 3-month interim evaluation.

^b^ 105-week evaluation.

Table 12 Mean Body Weights of F_0_ Female Wistar Han Rats During Gestation and Lactation in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Gestation Day
5 | 209.0 ± 2.6 [52] | 209.0 ± 3.3 [41] | 207.4 ± 2.5 [39] | 210.8 ± 2.9 [49]
6 | 208.8 ± 2.6 [52] | 209.4 ± 3.2 [41] | 209.7 ± 2.5 [39] | 211.7 ± 2.9 [49]
7 | 213.4 ± 2.5 [52] | 211.6 ± 3.2 [41] | 212.2 ± 2.5 [39] | 217.8 ± 3.0 [49]
8 | 216.1 ± 2.5 [52] | 219.3 ± 3.2 [41] | 214.8 ± 2.5 [39] | 219.8 ± 2.9 [49]
9 | 221.1 ± 2.7 [52] | 218.2 ± 3.3 [41] | 218.9 ± 2.6 [39] | 220.5 ± 3.0 [49]
10 | 224.7 ± 2.7 [52] | 224.7 ± 3.2 [41] | 221.2 ± 2.6 [39] | 226.1 ± 3.1 [49]
11 | 231.6 ± 2.7 [52] | 227.3 ± 3.2 [41] | 227.3 ± 2.7 [39] | 230.8 ± 3.1 [49]
12 | 235.4 ± 2.8 [52] | 233.0 ± 3.3 [41] | 230.6 ± 2.8 [39] | 234.8 ± 3.2 [49]
13 | 238.7 ± 2.7 [52] | 235.7 ± 3.2 [41] | 233.8 ± 2.8 [39] | 239.6 ± 3.3 [49]
14 | 242.4 ± 2.8 [52] | 244.0 ± 3.5 [41] | 240.8 ± 2.8 [39] | 243.2 ± 3.3 [49]
15 | 250.4 ± 2.9 [52] | 245.9 ± 3.6 [41] | 243.7 ± 2.9 [39] | 247.9 ± 3.4 [49]
16 | 253.9 ± 2.9 [52] | 251.3 ± 3.6 [41] | 249.9 ± 2.9 [39] | 256.6 ± 3.4 [49]
17 | 261.4 ± 3.1 [52] | 257.8 ± 3.7 [41] | 258.1 ± 3.0 [39] | 263.4 ± 3.7 [49]
18 | 271.4 ± 3.3 [52] | 266.7 ± 3.9 [41] | 268.5 ± 3.1 [39] | 272.9 ± 3.7 [49]
19 | 279.9 ± 3.5 [52] | 273.8 ± 4.3 [41] | 275.4 ± 3.4 [39] | 280.5 ± 3.8 [49]
20 | 290.2 ± 3.6 [52] | 283.3 ± 4.3 [41] | 285.5 ± 3.7 [39] | 291.7 ± 4.0 [49]
21 | 301.6 ± 4.0 [52] | 293.1 ± 4.7 [41] | 295.0 ± 3.9 [39] | 302.4 ± 4.3 [49]
Lactation Day
0 | 247.1 ± 3.2 [47] | 248.5 ± 4.9 [37] | 255.2 ± 5.5 [36] | 249.1 ± 4.5 [44]
1 | 244.8 ± 2.9 [52] | 242.4 ± 3.7 [41] | 243.6 ± 3.1 [39] | 245.4 ± 3.3 [49]
2 | 246.6 ± 2.8 [51] | 243.8 ± 3.9 [41] | 247.3 ± 3.1 [39] | 247.1 ± 3.3 [49]
3 | 250.9 ± 2.9 [48] | 248.0 ± 4.1 [37] | 249.4 ± 3.4 [36] | 248.2 ± 3.6 [41]
4 | 254.0 ± 3.3 [38] | 250.8 ± 4.4 [32] | 250.6 ± 3.0 [31] | 253.8 ± 4.1 [37]
5 | 257.3 ± 3.4 [36] | 252.1 ± 4.6 [29] | 251.9 ± 2.9 [28] | 255.7 ± 4.3 [37]
6 | 259.9 ± 3.2 [36] | 256.7 ± 4.7 [29] | 255.8 ± 3.1 [28] | 261.1 ± 3.9 [37]
7 | 263.5 ± 3.2 [36] | 260.6 ± 4.4 [29] | 259.8 ± 3.1 [28] | 264.7 ± 4.0 [37]
8 | 266.1 ± 3.2 [36] | 260.0 ± 4.3 [29] | 261.8 ± 3.1 [28] | 266.9 ± 4.0 [37]
9 | 269.8 ± 3.2 [36] | 265.6 ± 4.4 [29] | 266.8 ± 3.3 [28] | 271.0 ± 4.2 [37]
10 | 272.7 ± 3.5 [36] | 270.8 ± 5.0 [29] | 270.2 ± 3.4 [28] | 273.3 ± 4.4 [37]
11 | 274.2 ± 3.8 [36] | 274.7 ± 5.0 [29] | 274.3 ± 3.4 [28] | 279.1 ± 4.2 [37]
12 | 276.1 ± 4.0 [36] | 278.2 ± 5.0 [29] | 280.9 ± 3.6 [28] | 282.9 ± 4.4 [36]
13 | 277.5 ± 4.2 [36] | 278.3 ± 5.0 [29] | 277.6 ± 3.6 [28] | 282.2 ± 4.4 [37]
14 | 279.4 ± 4.6 [36] | 279.4 ± 5.0 [29] | 277.0 ± 3.5 [28] | 284.1 ± 4.4 [36]
15 | 275.5 ± 3.9 [36] | 264.6 ± 3.5 [29] | 265.7 ± 3.5 [28] | 278.1 ± 4.2 [37]
16 | 276.5 ± 3.5 [36] | 275.2 ± 5.2 [29] | 276.9 ± 3.6 [28] | 280.5 ± 4.3 [36]
17 | 278.4 ± 3.3 [36] | 277.7 ± 4.2 [29] | 278.5 ± 3.2 [28] | 278.8 ± 4.2 [36]
18 | 274.5 ± 3.1 [36] | 275.9 ± 4.2 [29] | 272.7 ± 2.9 [28] | 277.6 ± 4.1 [35]
19 | 274.2 ± 3.5 [36] | 273.5 ± 4.5 [29] | 270.1 ± 3.9 [27] | 273.9 ± 4.1 [36]
20 | 275.0 ± 3.4 [36] | 273.8 ± 4.3 [29] | 269.6 ± 3.2 [28] | 272.5 ± 4.0 [36]
21 | 276.8 ± 3.5 [34] | 270.2 ± 4.8 [27] | 267.3 ± 3.1 [26] | 272.1 ± 5.0 [33]

^a^ Data are presented as mean ± standard error [number of dams]. Differences from the vehicle control group are not significant by Dunnett’s test.

Table 13 Mean Number of Surviving F_1_ Male and Female Wistar Han Rats During Lactation in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

Postnatal Day | Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Males
1 | 4.00 ± 0.26 [52] | 3.76 ± 0.31 [41] | 4.18 ± 0.30 [38] | 4.22 ± 0.28 [49]
4^b^ | 3.96 ± 0.27 [52] | 3.76 ± 0.31 [41] | 4.18 ± 0.30 [38] | 4.16 ± 0.28 [49]
4^c^ | 4.57 ± 0.29 [35] | 4.48 ± 0.29 [29] | 4.69 ± 0.32 [29] | 4.65 ± 0.29 [37]
7 | 3.89 ± 0.16 [35] | 3.79 ± 0.19 [29] | 4.07 ± 0.24 [29] | 3.83 ± 0.19 [36]
12 | 3.89 ± 0.16 [35] | 3.79 ± 0.19 [29] | 4.07 ± 0.25 [28] | 3.83 ± 0.19 [36]
15 | 3.86 ± 0.15 [35] | 3.79 ± 0.19 [29] | 4.07 ± 0.25 [28] | 3.83 ± 0.19 [36]
18 | 3.83 ± 0.16 [35] | 3.79 ± 0.19 [29] | 4.07 ± 0.25 [28] | 3.83 ± 0.19 [36]
21 | 3.80 ± 0.16 [35] | 3.72 ± 0.20 [29] | 4.00 ± 0.27 [28] | 3.69 ± 0.22 [36]
Females
1 | 4.52 ± 0.29 [52] | 4.02 ± 0.31 [41] | 3.74 ± 0.34 [38] | 4.41 ± 0.32 [49]
4^b^ | 4.48 ± 0.30 [52] | 4.00 ± 0.31 [41] | 3.74 ± 0.34 [38] | 4.35 ± 0.32 [49]
4^c^ | 5.33 ± 0.28 [36] | 4.83 ± 0.32 [29] | 4.34 ± 0.34 [29] | 5.05 ± 0.33 [37]
7 | 4.22 ± 0.19 [36] | 4.07 ± 0.19 [29] | 3.83 ± 0.26 [29] | 4.03 ± 0.19 [36]
12 | 4.22 ± 0.19 [36] | 4.03 ± 0.19 [29] | 3.93 ± 0.25 [28] | 4.03 ± 0.19 [36]
15 | 4.22 ± 0.19 [36] | 4.03 ± 0.19 [29] | 3.86 ± 0.26 [28] | 4.03 ± 0.19 [36]
18 | 4.17 ± 0.20 [36] | 4.03 ± 0.19 [29] | 3.86 ± 0.26 [28] | 4.03 ± 0.19 [36]
21 | 4.11 ± 0.21 [36] | 3.90 ± 0.19 [29] | 3.68 ± 0.26 [28] | 3.89 ± 0.19 [36]
Combined
1 | 8.52 ± 0.35 [52] | 7.78 ± 0.45 [41] | 7.92 ± 0.41 [38] | 8.63 ± 0.38 [49]
4^b^ | 8.44 ± 0.36 [52] | 7.76 ± 0.45 [41] | 7.92 ± 0.41 [38] | 8.51 ± 0.39 [49]
4^c^ | 9.78 ± 0.25 [36] | 9.31 ± 0.29 [29] | 9.03 ± 0.24 [29] | 9.70 ± 0.29 [37]
7 | 8.00 ± 0.00 [36] | 7.86 ± 0.07 [29]* | 7.90 ± 0.10 [29] | 7.86 ± 0.11 [36]
12 | 8.00 ± 0.00 [36] | 7.83 ± 0.07 [29]** | 8.00 ± 0.00 [28] | 7.86 ± 0.11 [36]
15 | 7.97 ± 0.03 [36] | 7.83 ± 0.07 [29] | 7.93 ± 0.05 [28] | 7.86 ± 0.11 [36]
18 | 7.89 ± 0.07 [36] | 7.83 ± 0.07 [29] | 7.93 ± 0.05 [28] | 7.86 ± 0.11 [36]
21 | 7.81 ± 0.10 [36] | 7.62 ± 0.16 [29] | 7.68 ± 0.20 [28] | 7.58 ± 0.19 [36]

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s test.

** P ≤ 0.01.

^a^ Data are presented as mean number of surviving pups ± standard error [number of dams].

^b^ Pre-standardization of litters.

^c^ Post-standardization of litters.

Table 14 Mean Body Weights of F_1_ Male and Female Wistar Han Rats During Lactation in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

Postnatal Day | Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Males
1 | 7.54 ± 0.12 [51] | 7.36 ± 0.13 [39] | 7.89 ± 0.20 [38] | 7.48 ± 0.14 [48]
4^b^ | 11.60 ± 0.20 [35] | 11.49 ± 0.24 [29] | 12.19 ± 0.20 [28] | 11.56 ± 0.25 [37]
7 | 17.58 ± 0.28 [35] | 17.22 ± 0.35 [29] | 17.86 ± 0.28 [29] | 17.34 ± 0.37 [36]
12 | 29.20 ± 0.44 [35] | 28.79 ± 0.48 [29] | 29.64 ± 0.49 [28] | 29.24 ± 0.60 [36]
15 | 36.40 ± 0.63 [35] | 35.86 ± 0.58 [29] | 36.62 ± 0.62 [28] | 36.31 ± 0.72 [36]
18 | 43.65 ± 0.80 [35] | 42.57 ± 0.66 [28] | 44.28 ± 0.75 [28] | 43.35 ± 0.89 [36]
21 | 55.03 ± 1.04 [34] | 54.68 ± 0.87 [28] | 55.19 ± 1.16 [28] | 54.48 ± 1.17 [36]
Females
1 | 7.06 ± 0.16 [52] | 7.26 ± 0.12 [40] | 7.51 ± 0.19 [36] | 7.32 ± 0.13 [48]
4^b^ | 11.27 ± 0.20 [36] | 11.26 ± 0.23 [29] | 11.74 ± 0.21 [28] | 11.30 ± 0.25 [37]
7 | 17.05 ± 0.29 [36] | 16.78 ± 0.32 [29] | 17.32 ± 0.27 [29] | 16.85 ± 0.33 [36]
12 | 28.35 ± 0.46 [36] | 28.20 ± 0.44 [29] | 28.82 ± 0.44 [28] | 28.52 ± 0.53 [36]
15 | 35.49 ± 0.66 [36] | 35.15 ± 0.50 [29] | 35.69 ± 0.55 [28] | 35.30 ± 0.66 [36]
18 | 42.19 ± 0.79 [36] | 41.55 ± 0.57 [28] | 43.10 ± 0.68 [28] | 42.09 ± 0.82 [36]
21 | 52.92 ± 0.95 [35] | 52.64 ± 0.80 [28] | 54.04 ± 0.87 [28] | 52.64 ± 1.02 [36]
Combined
1 | 7.30 ± 0.11 [52] | 7.33 ± 0.11 [41] | 7.68 ± 0.13 [38] | 7.38 ± 0.12 [49]
4^b^ | 11.41 ± 0.20 [36] | 11.34 ± 0.23 [29] | 11.95 ± 0.20 [28] | 11.43 ± 0.25 [37]
7 | 17.31 ± 0.28 [36] | 16.95 ± 0.33 [29] | 17.56 ± 0.27 [29] | 17.09 ± 0.35 [36]
12 | 28.76 ± 0.44 [36] | 28.43 ± 0.46 [29] | 29.20 ± 0.45 [28] | 28.87 ± 0.56 [36]
15 | 35.93 ± 0.63 [36] | 35.43 ± 0.53 [29] | 36.16 ± 0.57 [28] | 35.78 ± 0.68 [36]
18 | 42.89 ± 0.78 [36] | 41.97 ± 0.61 [28] | 43.75 ± 0.69 [28] | 42.71 ± 0.85 [36]
21 | 53.95 ± 0.98 [35] | 53.53 ± 0.82 [28] | 54.77 ± 0.93 [28] | 53.53 ± 1.07 [36]

^a^ Data are presented as mean ± standard error [number of dams]. Weights were calculated on postnatal day 1 by collecting total weights and dividing by number of pups; weights after postnatal day 1 are based on individual pup weights. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Post-standardization of litters.

Figure 6

Mean Body Weights of F_0_ Female Wistar Han Rats During Gestation and Lactation in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure 7

Mean Body Weights of F_1_ Male and Female Wistar Han Rats During Lactation in the Two-year Perinatal and Postnatal Gavage Study of DE-71

### Survival

Estimates of 2-year survival probabilities for F_1_ male and female rats are shown in Table 15 and in the Kaplan-Meier survival curves (Figure 8). Survival of 50 mg/kg males was significantly less than that of the vehicle controls. Decreased survival in the 50 mg/kg males was due to a higher number of adenomas of the pituitary gland pars distalis compared to the vehicle control group. There was a significant trend of decreased survival in dosed groups of females, but the survival of individual dosed groups was not significantly different from that of the vehicle control group.

Table 15 Survival of F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Number of litters contributing to groups | 52 | 41 | 39 | 49
Male
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | | | 10
Accidental deaths^b^ | 1 | 1 | 0 | 1
Other^b,c^ | 1 | 0 | 0 | 0
Moribund | 8 | 7 | 10 | 12
Natural deaths | 4 | 7 | 2 | 12
Animals surviving to study termination | 36 | 35 | 38 | 25
Percent probability of survival at end of study^d^ | 75 | 72 | 76 | 51
Mean survival (days)^e^ | 671 | 664 | 683 | 657
Survival analysis | P = 0.011 | P = 0.814 | P = 1.000 | P = 0.030
Female
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | | | 10
Accidental deaths^b^ | 2 | 1 | 0 | 0
Other^b,c^ | 0 | 0 | 0 | 1
Moribund | 8 | 10 | 13 | 11
Natural deaths | 3 | 0 | 4 | 10
Animals surviving to study termination | 37^g^ | 39 | 33 | 28
Percent probability of survival at end of study | 77 | 80 | 66 | 57
Mean survival (days) | 676 | 705 | 689 | 640
Survival analysis | P = 0.007 | P = 0.852N | P = 0.350 | P = 0.054

^a^ Excluded from survival analysis.

^b^ Censored from survival analysis.

^c^ Animals not necropsied.

^d^ Kaplan-Meier determinations.

^e^ Mean of all deaths (uncensored, censored, and terminal kill).

^f^ The result of the life table trend test^197^ is in the vehicle control column, and the results of the life table pairwise comparisons^196^ with the vehicle controls are in the dosed group columns. A lower mortality in a dose group is indicated by N.

^g^ Includes one animal that died during the last week of the study.

Figure 8

Kaplan-Meier Survival Curves for F_1_ Wistar Han Rats Administered DE-71 by Gavage for Two Years

### Body Weights and Clinical Findings

Mean body weights of dosed groups of males were similar to those of the vehicle controls throughout the study (Figure 9 and Table 16). In 50 mg/kg females, mean body weights were at least 10% less than those of the vehicle controls after week 37, and the incidence of thinness was increased (Figure 9 and Table 17).

Figure 9

Growth Curves for F_1_ Wistar Han Rats Administered DE-71 by Gavage for Two Years

Table 16 Mean Body Weights and Survival of F_1_ Male Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Day | Vehicle Control | | 3 mg/kg | | | 15 mg/kg | | | 50 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 62 | 60 | 60 | 97 | 50 | 60 | 97 | 50 | 61 | 98 | 60
4 | 73 | 58 | 72 | 99 | 49 | 72 | 98 | 50 | 71 | 97 | 60
10 | 109 | 58 | 106 | 97 | 49 | 107 | 99 | 50 | 105 | 97 | 60
17 | 155 | 58 | 151 | 98 | 49 | 153 | 99 | 50 | 153 | 99 | 60
24 | 197 | 58 | 193 | 98 | 49 | 196 | 99 | 50 | 197 | 100 | 60
31 | 241 | 58 | 236 | 98 | 49 | 240 | 100 | 50 | 244 | 101 | 60
38 | 276 | 58 | 271 | 98 | 49 | 276 | 100 | 50 | 281 | 102 | 60
45 | 307 | 57 | 300 | 98 | 49 | 300 | 98 | 50 | 310 | 101 | 60
52 | 331 | 57 | 322 | 97 | 49 | 323 | 97 | 50 | 335 | 101 | 60
59 | 352 | 57 | 342 | 97 | 49 | 347 | 99 | 50 | 361 | 102 | 60
66 | 364 | 57 | 356 | 98 | 49 | 363 | 100 | 50 | 375 | 103 | 60
73 | 378 | 57 | 374 | 99 | 49 | 375 | 99 | 50 | 393 | 104 | 60
80 | 392 | 57 | 382 | 98 | 49 | 392 | 100 | 50 | 406 | 104 | 60
87 | 401 | 57 | 391 | 98 | 49 | 403 | 100 | 50 | 416 | 104 | 60
115 | 439 | 47^a^ | 424 | 97 | 49 | 437 | 99 | 50 | 451 | 103 | 50^a^
143 | 463 | 47 | 448 | 97 | 49 | 463 | 100 | 50 | 481 | 104 | 50
171 | 484 | 47 | 473 | 98 | 49 | 484 | 100 | 50 | 507 | 105 | 50
199 | 503 | 47 | 487 | 97 | 49 | 499 | 99 | 50 | 526 | 105 | 50
227 | 517 | 47 | 501 | 97 | 49 | 517 | 100 | 50 | 544 | 105 | 50
255 | 527 | 47 | 518 | 98 | 49 | 532 | 101 | 50 | 558 | 106 | 50
283 | 544 | 47 | 529 | 97 | 48 | 544 | 100 | 50 | 571 | 105 | 50
310 | 563 | 47 | 551 | 98 | 47 | 565 | 100 | 49 | 591 | 105 | 49
339 | 579 | 47 | 564 | 97 | 47 | 583 | 101 | 49 | 608 | 105 | 49
367 | 593 | 47 | 575 | 97 | 47 | 598 | 101 | 49 | 620 | 105 | 48
395 | 604 | 47 | 592 | 98 | 47 | 608 | 101 | 49 | 635 | 105 | 48
423 | 611 | 47 | 601 | 98 | 47 | 619 | 101 | 49 | 637 | 104 | 48
451 | 622 | 47 | 610 | 98 | 47 | 632 | 102 | 48 | 653 | 105 | 46
479 | 633 | 47 | 627 | 99 | 46 | 643 | 102 | 47 | 669 | 106 | 45
507 | 638 | 47 | 635 | 100 | 44 | 654 | 103 | 46 | 675 | 106 | 43
535 | 651 | 45 | 643 | 99 | 44 | 659 | 101 | 46 | 681 | 105 | 43
563 | 639 | 43 | 648 | 101 | 43 | 660 | 103 | 44 | 674 | 105 | 42
591 | 646 | 42 | 661 | 102 | 41 | 660 | 102 | 44 | 677 | 105 | 41
619 | 656 | 41 | 661 | 101 | 40 | 687 | 105 | 39 | 695 | 106 | 36
647 | 667 | 39 | 668 | 100 | 38 | 693 | 104 | 39 | 693 | 104 | 35
675 | 671 | 38 | 668 | 100 | 37 | 698 | 104 | 38 | 691 | 103 | 31
703 | 673 | 37 | 669 | 99 | 35 | 695 | 103 | 38 | 678 | 101 | 27
Mean for Weeks
1–13 | 260 | | 254 | 98 | | 258 | 99 | | 265 | 102
14–52 | 521 | | 507 | 97 | | 522 | 100 | | 546 | 105
53–100 | 643 | | 640 | 100 | | 659 | 102 | | 672 | 105

^a^ Interim evaluation occurred during week 14.

Table 17 Mean Body Weights and Survival of F_1_ Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Day | Vehicle Control | | 3 mg/kg | | | 15 mg/kg | | | 50 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 59 | 60 | 57 | 97 | 50 | 58 | 98 | 50 | 57 | 97 | 60
5 | 72 | 60 | 71 | 99 | 50 | 72 | 100 | 50 | 68 | 95 | 57
11 | 102 | 60 | 99 | 97 | 50 | 99 | 97 | 50 | 95 | 93 | 57
18 | 129 | 60 | 126 | 97 | 50 | 127 | 98 | 50 | 122 | 95 | 57
25 | 152 | 60 | 147 | 97 | 50 | 148 | 97 | 50 | 144 | 94 | 57
32 | 168 | 60 | 163 | 97 | 50 | 164 | 98 | 50 | 158 | 94 | 57
39 | 181 | 59 | 177 | 97 | 50 | 177 | 98 | 50 | 173 | 95 | 57
46 | 195 | 59 | 190 | 97 | 50 | 190 | 97 | 50 | 184 | 94 | 57
53 | 207 | 59 | 199 | 96 | 50 | 199 | 96 | 50 | 194 | 93 | 57
60 | 216 | 59 | 205 | 95 | 50 | 205 | 95 | 50 | 203 | 94 | 57
67 | 221 | 59 | 211 | 96 | 50 | 212 | 96 | 50 | 206 | 93 | 57
74 | 227 | 59 | 216 | 95 | 50 | 215 | 95 | 50 | 210 | 93 | 57
81 | 230 | 59 | 222 | 97 | 50 | 216 | 94 | 50 | 216 | 94 | 57
88 | 236 | 59 | 224 | 95 | 50 | 223 | 95 | 50 | 217 | 92 | 57
116 | 241 | 49^a^ | 239 | 99 | 50 | 237 | 98 | 50 | 231 | 96 | 47^a^
144 | 254 | 49 | 245 | 97 | 50 | 240 | 95 | 50 | 239 | 94 | 47
172 | 261 | 49 | 250 | 96 | 50 | 246 | 95 | 50 | 244 | 94 | 47
200 | 267 | 49 | 256 | 96 | 50 | 256 | 96 | 50 | 247 | 93 | 47
228 | 271 | 49 | 262 | 97 | 50 | 257 | 95 | 50 | 248 | 91 | 46
256 | 276 | 49 | 267 | 97 | 50 | 265 | 96 | 50 | 251 | 91 | 46
284 | 284 | 49 | 272 | 96 | 50 | 270 | 95 | 50 | 255 | 90 | 46
311 | 290 | 48 | 279 | 96 | 50 | 276 | 95 | 50 | 259 | 90 | 46
340 | 298 | 48 | 285 | 96 | 50 | 284 | 95 | 50 | 264 | 89 | 46
368 | 307 | 48 | 294 | 96 | 49 | 288 | 94 | 49 | 265 | 86 | 46
396 | 315 | 48 | 303 | 96 | 49 | 292 | 93 | 49 | 269 | 86 | 44
424 | 320 | 48 | 308 | 97 | 49 | 297 | 93 | 49 | 274 | 86 | 44
452 | 327 | 47 | 316 | 97 | 49 | 303 | 93 | 49 | 275 | 84 | 44
480 | 338 | 47 | 327 | 97 | 49 | 313 | 93 | 48 | 288 | 85 | 44
508 | 343 | 46 | 335 | 98 | 49 | 323 | 94 | 47 | 294 | 86 | 43
536 | 347 | 45 | 342 | 99 | 48 | 334 | 96 | 47 | 295 | 85 | 43
564 | 351 | 45 | 346 | 99 | 48 | 329 | 94 | 45 | 297 | 85 | 40
592 | 360 | 41 | 355 | 99 | 47 | 339 | 94 | 44 | 302 | 84 | 40
620 | 370 | 41 | 363 | 98 | 46 | 349 | 94 | 42 | 309 | 84 | 37
648 | 379 | 39 | 360 | 95 | 46 | 349 | 92 | 42 | 308 | 81 | 33
676 | 382 | 39 | 368 | 96 | 43 | 352 | 92 | 37 | 313 | 82 | 32
704 | 390 | 38 | 374 | 96 | 40 | 358 | 92 | 34 | 314 | 81 | 28
Mean for Weeks
1–13 | 171 | | 165 | 96 | | 165 | 96 | | 161 | 94
14–52 | 275 | | 265 | 96 | | 262 | 95 | | 250 | 91
53–100 | 352 | | 341 | 97 | | 328 | 93 | | 295 | 84

^a^ Interim evaluation occurred during week 14.

### Three-month Interim Evaluation Organ Weights

At the 3-month interim evaluation, organ weights were measured in vehicle controls and 50 mg/kg rats. The absolute and relative liver weights of 50 mg/kg males and females were significantly increased compared to those of the vehicle controls at the 3-month interim evaluation (Table 18 and Table G-2). In 50 mg/kg males, the mean absolute liver weight was approximately 43% greater than that of the vehicle controls and in 50 mg/kg females, the absolute liver weight was 17% greater than that of the vehicle controls. The increased liver weights correlated with hepatocellular hypertrophy in the liver, and reflected what was observed in the 3-month study in F344/N rats (Table 6 and Table G-1).

Table 18 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for F_1_ Wistar Han Rats at the Three-month Interim Evaluation in the Two-year Perinatal and Postnatal Gavage Study^a^

| Vehicle Control | 50 mg/kg
n | 10 | 10
Male
Necropsy body wt | 403 ± 10 | 433 ± 16
R. Kidney
Absolute | 1.29 ± 0.04 | 1.57 ± 0.08**
Relative | 3.198 ± 0.102 | 3.618 ± 0.113*
Liver
Absolute | 13.68 ± 0.39 | 19.53 ± 0.76**
Relative | 33.938 ± 0.702 | 45.180 ± 1.191**
R. Testis
Absolute | 1.836 ± 0.069 | 2.168 ± 0.075**
Female
Necropsy body wt | 246 ± 4 | 213 ± 7**
Liver
Absolute | 7.94 ± 0.18 | 9.28 ± 0.43*
Relative | 32.350 ± 0.579 | 43.369 ± 0.745**
Thymus
Absolute | 0.362 ± 0.020 | 0.264 ± 0.016**
Relative | 1.473 ± 0.071 | 1.239 ± 0.070*

* Significantly different (P ≤ 0.05) from the vehicle control group by a t-test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

The absolute and relative kidney weights of 50 mg/kg males were significantly increased (approximately 22% for the absolute weight; Table 18 and Table G-2). Similar increases in kidney weights were observed in the 3-month study in male F344/N rats (Table 6 and Table G-1). In contrast to the 3-month study in F344/N rats, there were minimal changes in kidney weights in the female rats at the 3-month interim evaluation.

The absolute testis weight of 50 mg/kg males was significantly increased (Table 18 and Table G-2). The absolute testis weight was 18% greater than that of the vehicle control group; however, no histologic changes were observed in the testes that correlated with this weight difference.

The absolute thymus weight of 50 mg/kg females was significantly decreased by approximately 27% (Table 18 and Table G-2). This degree of difference was considered greater than that expected from the difference in body weights, but the toxicologic significance of this change is unknown. Similar changes were seen in the thymus weights of female F344/N rats in the 3-month study (Table 6 and Table G-1). In that study, thymic atrophy was seen in 500 mg/kg females but not in 50 or 100 mg/kg females (Table 10). Thymic atrophy was not observed in 50 mg/kg females in this 3-month interim evaluation (Table B-4).

In 50 mg/kg female rats, increased relative heart and kidney weights and a decreased absolute lung weight were considered secondary to the decrease in mean body weight when compared to the vehicle control group (Table G-2).

### Tissue Concentrations

Concentrations of 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47), 2,2′,4,4′,5-pentabromodiphenyl ether (BDE-99), and 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE-153) were determined in the following tissues following perinatal exposure of dams to DE-71; liver and carcass from PND 4 pups at litter standardization; adipose and liver from dams assigned to the tissue distribution study and their pups at PND 21; adipose, liver, and plasma in F_1_ rats at the end of the study (Table I-2, Table I-3, and Table I-4). In PND 4 and PND 21 pup liver, the tissue concentrations of all congeners measured increased with increasing dose and were higher than corresponding vehicle control values. The concentrations in PND 4 pup liver were higher than those in the PND 21 pup liver, which is likely due to the increased metabolic capacity at PND 21 compared to PND 4. In PND 21 dam liver, the concentrations of all congeners were below the limit of quantitation except at 50 mg/kg; at 50 mg/kg, the dam liver values were lower than the corresponding pup liver values. The concentrations of all congeners in PND 21 pup and dam adipose was higher than the corresponding concentrations in liver, suggesting preferential accumulation in the adipose. The concentrations of BDE-99 and BDE-47 were similar in adipose from both dams and pups and were higher than BDE-153 concentrations. There were no sex differences in congener concentrations. In all matrices at the end of the study, concentrations of congeners increased with the dose and were higher than the corresponding vehicle control values (Figure 10). The concentrations were lowest in plasma and highest in adipose. In a given matrix, the concentrations of BDE-47, BDE-99, and BDE-153 were similar, regardless of the different percent of these congeners in DE-71. This suggests a higher rate of accumulation of BDE-153 regardless of the lower percentage of BDE-153 in DE-71. In general, there were no sex differences except plasma concentrations in 3 mg/kg (BDE-153 only) and 15 mg/kg (all three congeners) females were higher than concentrations in males.

Figure 10

Concentrations of BDE-47, BDE-99, and BDE-153 in Adipose, Liver, and Plasma in F_1_ Male and Female Wistar Han Rats Administered DE-71 by Gavage for Two Years

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and nonneoplastic lesions of the liver, thyroid gland, pituitary gland, uterus, vagina, cervix, kidney, parotid salivary gland, prostate gland, epididymis, preputial gland, thymus, spleen, forestomach, adrenal cortex, and mammary gland. Summaries of the incidences of neoplasms and nonneoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

Liver: At the 3-month interim evaluation, the incidences of hepatocyte hypertrophy were significantly increased in 50 mg/kg males and females (Table 19, Table A-4, and Table B-4). The incidence of fatty change of the hepatocytes was also significantly increased in 50 mg/kg male rats. Hepatocyte hypertrophy was characterized by enlarged hepatocytes with granular eosinophilic cytoplasm and variably enlarged nuclei. Hepatocyte hypertrophy involved primarily the centrilobular area, with the midzonal region being affected in more severe cases. The grading criteria for the diagnosis of hepatocyte hypertrophy were as follows: if less than 10% of the hepatocytes in the section were affected, it was recorded as minimal severity; if 10% or more but less than 50% of the hepatocytes in the section were affected, it was recorded as mild severity; if 50% or more but less than 75% of the hepatocytes in the section were affected, it was recorded as moderate severity; if more than 75% of the hepatocytes in the section were affected, it was recorded as marked severity. Fatty change of the hepatocytes consisted of a centrally located nucleus in cytoplasm that contained small discrete vacuoles. This change was characteristically the same as that observed as cytoplasmic vacuolization in the 3-month study in F344/N rats but was recorded as fatty change.

Table 19 Incidences of Neoplasms and Nonneoplastic Lesions of the Liver in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Male
Three-month Interim Evaluation
Number Examined Microscopically | 10 | – | – | 10
Fatty Change^a^ | 2 (1.0)^b^ | – | – | 8* (1.5)
Hepatocyte, Hypertrophy | 0 | – | – | 10** (3.1)
Two-year Study
Number Examined Microscopically | 49 | 50 | 50 | 50
Eosinophilic Focus | 3 | 3 | 12* | 15**
Fatty Change | 32 (1.5) | 37 (1.5) | 48** (1.8) | 48** (2.1)
Hyperplasia, Nodular | 0 | 0 | 3 (1.7) | 0
Inflammation, Chronic | 1 (1.0) | 2 (1.0) | 0 | 5 (1.2)
Pigmentation | 0 | 0 | 1 (2.0) | 6* (1.0)
Hepatocyte, Hypertrophy | 1 (1.0) | 44** (2.0) | 50** (3.0) | 50** (3.8)
Oval Cell, Hyperplasia | 0 | 0 | 2 (1.0) | 3 (1.0)
Hepatocholangioma^c^ | 0 | 0 | 0 | 2
Hepatocellular Adenoma, Multiple | 0 | 0 | 0 | 1
Hepatocellular Adenoma (includes multiple)^d^
Number of litters with at least one neoplasm/total number of litters | 3/29 | 2/25 | 4/25 | 8/29
Overall rate^e^ | 3/49 (6%) | 2/50 (4%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate^f^ | 7.1% | 4.8% | 9.2% | 19.8%
Terminal rate^g^ | 3/36 (8%) | 1/35 (3%) | 4/38 (11%) | 3/25 (12%)
First incidence (days) | 729 (T) | 658 | 729 (T) | 595
Poly-3 test^h^ | P = 0.016 | P = 0.503N | P = 0.512 | P = 0.081
Litter-adjusted Poly-3 test | –^i^ | – | – | –
Hepatocellular Carcinoma^c^ | 0 | 0 | 0 | 2
Hepatocellular Adenoma or Carcinoma^d^
Number of litters with at least one neoplasm/total number of litters | 3/29 | 2/25 | 4/25 | 9/29
Overall rate | 3/49 (6%) | 2/50 (4%) | 4/50 (8%) | 9/50 (18%)
Adjusted rate | 7.1% | 4.8% | 9.2% | 22.3%
Terminal rate | 3/36 (8%) | 1/35 (3%) | 4/38 (11%) | 4/25 (16%)
First incidence (days) | 729 (T) | 658 | 729 (T) | 595
Poly-3 test | P = 0.006 | P = 0.503N | P = 0.512 | P = 0.047
Litter-adjusted Poly-3 test | – | – | – | –
Hepatocholangioma, Hepatocellular Adenoma, or Hepatocellular Carcinoma^d^
Number of litters with at least one neoplasm/total number of litters | 3/29 | 2/25 | 4/25 | 11/29
Overall rate | 3/49 (6%) | 2/50 (4%) | 4/50 (8%) | 11/50 (22%)
Adjusted rate | 7.1% | 4.8% | 9.2% | 27.2%
Terminal rate | 3/36 (8%) | 1/35 (3%) | 4/38 (11%) | 5/25 (20%)
First incidence (days) | 729 (T) | 658 | 729 (T) | 595
Poly-3 test | P < 0.001 | P = 0.503N | P = 0.512 | P = 0.014
Litter-adjusted Poly-3 test | – | – | – | –
Female
Three-month Interim Evaluation
Number Examined Microscopically | 9 | – | – | 10
Fatty Change | 0 | – | – | 3 (1.0)
Hepatocyte, Hypertrophy | 0 | – | – | 10** (3.0)
Two-year Study
Number Examined Microscopically | 50 | 49 | 50 | 47
Cholangiofibrosis | 0 | 0 | 0 | 3 (2.3)
Eosinophilic Focus | 5 | 7 | 21** | 31**
Fatty Change | 15 (1.4) | 12 (2.5) | 28** (1.6) | 39** (1.3)
Hyperplasia, Nodular | 0 | 0 | 2 (2.5) | 7** (2.6)
Bile Duct, Cyst | 2 (1.0) | 2 (1.5) | 5 (1.4) | 7* (2.0)
Hepatocyte, Hypertrophy | 0 | 48** (1.9) | 49** (3.0) | 45** (3.9)
Hepatocyte, Necrosis | 4 (1.3) | 2 (1.0) | 1 (1.0) | 8 (1.4)
Oval Cell, Hyperplasia | 1 (1.0) | 3 (1.0) | 3 (1.0) | 10** (1.2)
Cholangiocarcinoma, Multiple | 0 | 0 | 0 | 1
Cholangiocarcinoma (includes multiple)^j^
Number of litters with at least one neoplasm/total number of litters | 0/30 | 0/25 | 0/25 | 2/27
Overall rate | 0/50 (0%) | 0/49 (0%) | 0/50 (0%) | 2/47 (4%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 5.4%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 0/33 (0%) | 2/28 (7%)
First incidence (days) | –^k^ | – | – | 729 (T)
Poly-3 test | P = 0.030 | –^i^ | – | P = 0.203
Litter-adjusted Poly-3 test | – | – | – | –
Hepatocholangioma, Multiple | 0 | 0 | 0 | 3
Hepatocholangioma (includes multiple)^j^
Number of litters with at least one neoplasm/total number of litters | 0/30 | 0/25 | 0/25 | 7/27
Overall rate | 0/50 (0%) | 0/49 (0%) | 0/50 (0%) | 8/47 (17%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 21.5%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 0/33 (0%) | 7/28 (25%)
First incidence (days) | – | – | – | 619
Poly-3 test | P < 0.001 | – | – | P < 0.001
Litter-adjusted Poly-3 test | – | – | – | –
Hepatocellular Adenoma, Multiple | 1 | 0 | 2 | 8*
Hepatocellular Adenoma (includes multiple)^l^
Number of litters with at least one neoplasm/total number of litters | 3/30 | 2/25 | 8/25 | 12/27
Overall rate | 3/50 (6%) | 2/49 (4%) | 8/50 (16%) | 16/47 (34%)
Adjusted rate | 6.9% | 4.4% | 18.2% | 41.4%
Terminal rate | 3/37 (8%) | 2/39 (5%) | 6/33 (18%) | 11/28 (39%)
First incidence (days) | 729 (T) | 729 (T) | 656 | 490
Poly-3 test | P < 0.001 | P = 0.476N | P = 0.103 | P < 0.001
Litter-adjusted Poly-3 test | P < 0.001 | P = 0.878 | P = 0.151 | P = 0.003
Hepatocellular Carcinoma, Multiple | 0 | 0 | 0 | 3
Hepatocellular Carcinoma (includes multiple)^j^
Number of litters with at least one neoplasm/total number of litters | 0/30 | 0/25 | 1/25 | 6/27
Overall rate | 0/50 (0%) | 0/49 (0%) | 1/50 (2%) | 6/47 (13%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 16.2%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 0/33 (0%) | 5/28 (18%)
First incidence (days) | – | – | 686 | 677
Poly-3 test | P < 0.001 | – | P = 0.503 | P = 0.008
Litter-adjusted Poly-3 test | – | – | – | –
Hepatocellular Adenoma or Carcinoma^l^
Number of litters with at least one neoplasm/total number of litters | 3/30 | 2/25 | 8/25 | 13/27
Overall rate | 3/50 (6%) | 2/49 (4%) | 8/50 (16%) | 17/47 (36%)
Adjusted rate | 6.9% | 4.4% | 18.2% | 44.0%
Terminal rate | 3/37 (8%) | 2/39 (5%) | 6/33 (18%) | 12/28 (43%)
First incidence (days) | 729 (T) | 729 (T) | 656 | 490
Poly-3 test | P < 0.001 | P = 0.476N | P = 0.103 | P < 0.001
Litter-adjusted Poly-3 test | P < 0.001 | P = 0.877 | P = 0.146 | P = 0.002
Hepatocholangioma, Hepatocellular Adenoma, or Hepatocellular Carcinoma^l^
Number of litters with at least one neoplasm/total number of litters | 3/30 | 2/25 | 8/25 | 15/27
Overall rate | 3/50 (6%) | 2/49 (4%) | 8/50 (16%) | 21/47 (45%)
Adjusted rate | 6.9% | 4.4% | 18.2% | 53.8%
Terminal rate | 3/37 (8%) | 2/39 (5%) | 6/33 (18%) | 15/28 (54%)
First incidence (days) | 729 (T) | 729 (T) | 656 | 490
Poly-3 test | P < 0.001 | P = 0.476N | P = 0.103 | P < 0.001
Litter-adjusted Poly-3 test | P < 0.001 | P = 0.877 | P = 0.151 | P < 0.001

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** Significantly different (P ≤ 0.01) from the vehicle control group by the Fisher exact test (interim evaluation) or Poly-3 test (2-year study).

(T) Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 0/99; all routes: 0/299.

^d^ Historical incidence for corn oil gavage studies: 3/99 (3.1% ± 4.3%), range 0%–6%; all routes: 4/299 (1.4% ± 2.5%), range 0%–6%.

^e^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

^i^ Value of statistic cannot be computed.

^j^ Historical incidence for corn oil gavage studies: 0/100; all routes: 0/300.

^k^ Not applicable; no neoplasms in animal group.

^l^ Historical incidence for corn oil gavage studies: 4/100 (4.0% ± 2.8%), range 2%–6%; all routes: 6/300 (2.0% ± 2.2%), range 0%–6%.

At 2 years, there were positive trends in the incidences of hepatocellular adenoma or carcinoma (combined) and hepatocholangioma, hepatocellular adenoma, or hepatocellular carcinoma (combined) in males and females, and the incidences of these combined lesions were significantly increased in the 50 mg/kg groups (Table 19, Table A-1, Table A-2, Table B-1, and Table B-2). The incidences of hepatocholangioma, hepatocellular adenoma, and hepatocellular carcinoma were also significantly increased in 50 mg/kg females. Hepatocellular adenomas typically consisted of well-circumscribed masses that caused compression of the surrounding hepatic parenchyma. These neoplasms were composed of a uniform population of hepatocytes and lacked the normal lobular architecture. Some adenomas displayed a little cellular atypia, but it was less common and less pronounced than that seen in the hepatocellular carcinomas. Hepatocellular carcinomas were also invasive and less well-demarcated than adenomas, and frequently contained areas of necrosis and blood-filled spaces (Figure 18). Their growth pattern was characterized by thickened hepatic trabeculae at least three cell layers wide compared with single-cell width trabeculae found in normal liver. Hepatocholangiomas are thought to arise from cells that can differentiate into either hepatocytes or biliary cells. They were nodular proliferative lesions similar to hepatocellular adenomas but also contained proliferations of single-layered, well-differentiated biliary epithelium, which formed cystic acini with occasional papillary infoldings (Figure 19). Hepatocholangiomas were distinguished from hepatocellular adenomas with dilated nonneoplastic bile ducts by the increased number of bile ducts within hepatocholangiomas and the fact that hepatocellular adenomas typically lack bile ducts. The epithelium of the biliary component of the hepatocholangiomas was cuboidal in contrast to the typically flattened epithelium found in biliary cysts.

Figure 18

Hepatocellular Carcinoma in the Liver of an F_1_ Female Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

There are thickened trabeculae of hepatocytes (arrows) separated by dilated spaces filled with blood (asterisks).

Figure 19

Hepatocholangioma in the Liver of an F_1_ Female Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

There is a well demarcated mass (arrows) composed of hepatocytes and proliferations of dilated bile ducts.

Cholangiocarcinoma occurred in two 50 mg/kg females and cholangiofibrosis occurred in three different 50 mg/kg female rats (Table 19 and Table B-1). Cholangiofibrosis is believed to be a precursor lesion to cholangiocarcinoma.^230^ Cholangiocarcinoma consisted of an irregular, relatively large, noncircumscribed lesion that effaced and invaded normal liver parenchyma (Figure 20 and Figure 21). The lesion consisted of fibrous connective tissue stroma containing numerous atypical bile ducts, which frequently contained mucinous material and cellular debris. The epithelium forming the atypical bile ducts was often discontinuous, consisted of large atypical cells and intestinal goblet cells, and displayed degenerative changes. Cholangiofibrosis was smaller in size than cholangiocarcinoma, was well demarcated, and did not show evidence of localized invasion. Distinction between cholangiofibrosis and cholangiocarcinoma was primarily based upon liver invasion. Cholangiocarcinoma and cholangiofibrosis are uncommon in control rats but have been observed in previous NTP studies of rats exposed to hepatic carcinogens. Consequently, the observations of these neoplasms in the livers of rats exposed to DE-71 were considered related to exposure.

Figure 20

Cholangiocarcinoma in the Liver of an F_1_ Female Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

The neoplasm is large, effacing much of the lobe of the liver.

Figure 21

Cholangiocarcinoma in the Liver of an F_1_ Female Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

The neoplasm is characterized by invasive areas of atypical bile ducts and fibrous connective tissue.

The incidence of nodular hyperplasia was significantly increased in 50 mg/kg females and slightly increased in 15 mg/kg males (Table 19, Table A-4, and Table B-4). Nodular hyperplasia did not occur in the vehicle control groups.

There were significantly increased incidences of eosinophilic focus in 15 and 50 mg/kg male and female rats. The increased incidences of eosinophilic foci correlated with an increase in the number of multiple foci; multiple foci were not recorded in vehicle control males or females. Nodular hyperplasia, which was often difficult to distinguish from eosinophilic foci, was characterized by nodular proliferations of hepatocytes that were distinct from the surrounding parenchyma (Figure 22). These lesions were composed primarily of large, eosinophilic hepatocytes, which sometimes contained lipid and/or glycogen. Scattered among the hepatocytes were bile ducts and oval cells which differentiated them from hepatocellular adenomas. They tended to be larger and more compressive than eosinophilic foci, which were also discrete lesions made up of enlarged, eosinophilic hepatocytes. Foci also tended to merge more with surrounding hepatocytes when compared with nodular hyperplasia.

Figure 22

Nodular Hyperplasia in the Liver of an F_1_ Female Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

The lesion is characterized by areas of large hepatocytes separated by thin bands of fibrous connective tissue, with bile duct and oval cell hyperplasia.

There were significantly increased incidences of hepatocyte hypertrophy in all dosed groups of male and female rats (Table 19, Table A-4, and Table B-4). The severities of this lesion were greater than those in the vehicle controls (males) and increased with increasing dose. Hepatocellular hypertrophy was characterized by hepatocytes that were enlarged due to increased amounts of cytoplasm (Figure 23). This change primarily affected hepatocytes in the centrilobular regions, with larger portions of the lobules being affected with increased severity. Severity grading was based on how much of the liver section was involved, how much of each individual hepatic lobule was involved, and how enlarged the individual hepatocytes were.

Figure 23

Marked Hypertrophy of the Centrilobular Hepatocytes in the Liver of an F_1_ Female Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

CV=central vein.

Incidences of fatty change were significantly increased in 15 and 50 mg/kg male and female rats (Table 19, Table A-4, and Table B-4). Histologically, fatty change consisted of discrete vacuoles within the cytoplasm of hepatocytes (Figure 24 and Figure 25). The fatty change observed in these livers included both macrovesicular and microvesicular vacuoles. Although cells containing a single large vacuole were more obvious, the majority of the cells actually contained small, discrete vacuoles, often with a centrally located nucleus. This change was characteristically similar to that observed as cytoplasmic vacuolization in the 3-month study in F344/N rats.

Figure 24

Marked Fatty Change with Discrete, Large Vacuoles Filling the Cytoplasm of the Majority of Hepatocytes in the Liver of an F_1_ Female Wistar Han Rat Administered 15 mg/kg DE-71 by Gavage for Two Years (H&E)

Figure 25

High Magnification of the Liver of an F_1_ Male Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

There is both macrovesicular fatty change (arrowheads) indicated by single large vacuoles within the hepatocellular cytoplasm and microvesicular fatty change (arrows) evidenced by a lacey appearance of the cytoplasm due to many small vacuoles. Microvesicular and macrovesicular fatty change were not given separate diagnoses, but recorded under “liver - fatty change.”

A significantly increased incidence of oval cell hyperplasia occurred in 50 mg/kg females (Table 19 and Table B-4). This lesion also occurred in 15 and 50 mg/kg males, and the incidences were associated with a positive trend (Table 19 and Table A-4). Oval cell hyperplasia was characterized by proliferations of single or double rows of oval to spindle-shaped cells typically in the periportal regions but extending into the midzonal areas with increasing severity.

There were significantly increased incidences of pigmentation in 50 mg/kg males and bile duct cyst in 50 mg/kg females (Table 19, Table A-4, and Table B-4). There were positive trends in the incidences of chronic inflammation in males and hepatocyte necrosis in females. Pigmentation was recorded when globular, golden-brown material was present within the cytoplasm of hepatocytes in the periportal region. Staining with Perls’ Prussian Blue was positive, indicating the pigment was consistent with hemosiderin, although lipofuschin cannot be ruled out. Bile duct cysts were lined by a flattened epithelium and were often multilocular. Chronic inflammation was characterized by focal collections of mixed mononuclear cells; these foci lacked a particular distribution and could be found randomly throughout the hepatic parenchyma. Hepatocyte necrosis consisted of either randomly scattered individual shrunken eosinophilic cells or small clusters of such cells. Nuclei of affected cells were often pyknotic or karyorrhectic.

There were significantly decreased incidences of basophilic focus in 50 mg/kg females and clear cell focus in 3 and 15 mg/kg females and 50 mg/kg males (Table A-4 and Table B-4). These foci are common background findings in older rats and the biological significance of these decreases is unknown. Basophilic foci were discrete areas of hepatocytes with a more basophilic cytoplasm than surrounding hepatocytes; the hepatocytes within the foci were frequently smaller than normal. Clear cell foci were focal areas of hepatocytes containing glycogen within their cytoplasm; depending on the amount of cytoplasmic glycogen, these cells could be larger than surrounding, uninvolved hepatocytes.

Thyroid Gland: At 3 months, there were significantly increased incidences of follicle hypertrophy in 50 mg/kg males and females (Table 20, Table A-4, and Table B-4). This lesion was characterized by a preponderance of small follicles that contained little colloid and were lined by cuboidal to low columnar epithelial cells.

Table 20 Incidences of Neoplasms and Nonneoplastic Lesions of the Thyroid Gland in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Male
Three-month Interim Evaluation
Number Examined Microscopically | 10 | – | – | 10
Follicle, Hypertrophy^a^ | 0 | – | – | 4* (1.3)^b^
Two-year Study
Number Examined Microscopically | 45 | 45 | 48 | 46
Follicle, Hypertrophy | 1 (2.0) | 26** (1.3) | 34** (1.1) | 23** (1.4)
Follicular Cell Adenoma^c^
Number of litters with at least one neoplasm/total number of litters | 1/29 | 3/25 | 2/25 | 6/29
Overall rate^d^ | 1/45 (2%) | 3/45 (7%) | 2/48 (4%) | 6/46 (13%)
Adjusted rate^e^ | 2.5% | 7.6% | 4.7% | 16.1%
Terminal rate^f^ | 1/36 (3%) | 2/35 (6%) | 2/38 (5%) | 4/25 (16%)
First incidence (days) | 729 (T) | 647 | 729 (T) | 609
Poly-3 test^g^ | P = 0.028 | P = 0.297 | P = 0.518 | P = 0.042
Litter-adjusted Poly-3 test | –^h^ | – | – | –
Follicular Cell Carcinoma^i^ | 0 | 2 | 1 | 0
Follicular Cell Adenoma or Carcinoma^c^
Number of litters with at least one neoplasm/total number of litters | 1/29 | 5/25 | 3/25 | 6/29
Overall rate | 1/45 (2%) | 5/45 (11%) | 3/48 (6%) | 6/46 (13%)
Adjusted rate | 2.5% | 12.6% | 7.0% | 16.1%
Terminal rate | 1/36 (3%) | 4/35 (11%) | 3/38 (8%) | 4/25 (16%)
First incidence (days) | 729 (T) | 647 | 729 (T) | 609
Poly-3 test | P = 0.089 | P = 0.095 | P = 0.324 | P = 0.042
Litter-adjusted Poly-3 test | – | – | – | –
Female
Three-month Interim Evaluation
Number Examined Microscopically | 10 | – | – | 10
Follicle, Hypertrophy | 1 (1.0) | – | – | 5* (1.2)
Two-year Study
Number Examined Microscopically | 45 | 49 | 47 | 42
Follicle, Hypertrophy | 8 (1.1) | 17 (1.3) | 22** (1.4) | 35** (1.9)
Follicular Cell Hyperplasia | 1 (1.0) | 5 (1.0) | 4 (1.8) | 6* (1.3)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test (interim evaluation) or the Poly-3 test (2-year study).

** P ≤ 0.01.

(T)Terminal kill.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 4/95 (4.1% ± 2.7%), range 2%–6%; all routes: 5/295 (1.7% ± 2.4%), range 0%–6%.

^d^ Number of animals with neoplasm per number of animals with thyroid gland examined microscopically.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Value of statistic cannot be computed.

^i^ Historical incidence for corn oil gavage studies: 0/95; all routes: 0/295.

At 2 years, there were significantly increased incidences of follicular cell adenoma in 50 mg/kg males (Table 20, Table A-1, and Table A-2). Follicular cell carcinoma occurred in two 3 mg/kg males and one 15 mg/kg male; although this neoplasm did not occur in the vehicle controls, these increased incidences were not statistically significant. In 50 mg/kg female rats, there was a significantly increased incidence of follicular cell hyperplasia (Table 20 and Table B-4). Follicular cell adenoma was a discrete, compressive mass composed of proliferations of follicular cells forming complex papillary infoldings and irregular follicular structures. The cells were slightly pleomorphic and larger than normal follicular cells. Follicular cell carcinoma displayed more disorganized growth patterns and cellular pleomorphism and invaded through the thyroid gland capsule. Follicular cell hyperplasia, like follicular cell adenoma, was a focal lesion. However, unlike adenomas, follicular cell hyperplasia was associated with little to no compression. Follicular cell hyperplasia was composed of follicles that were enlarged and cystic and occasionally contained a few simple papillary infoldings.

There were significantly increased incidences of follicle hypertrophy in all dosed male groups and in 15 and 50 mg/kg females (Table 20, Table A-4, and Table B-4). Hypertrophic thyroid follicles were small and lined by cuboidal to columnar epithelial cells with pale eosinophilic to light golden-brown cytoplasm (Figure 26 and Figure 27). Hypertrophy of the thyroid follicle was recorded when at least 50% of the follicles in both lobes (combined) of the thyroid gland were affected. Involvement of less than 50% was not recorded because the thyroid glands from the vehicle control animals were frequently observed to have this change in up to 50% of the follicles.

Figure 26

Normal Thyroid Gland in a Vehicle Control F_1_ Male Wistar Han Rat in the Two-year Gavage Study of DE-71 (H&E)

Figure 27

Hypertrophy in the Thyroid Gland Follicles of an F_1_ Male Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

The follicular epithelium is cuboidal, and the lumens are smaller with less colloid than seen in the vehicle control animal in Figure 26. Same magnification as Figure 26.

Pituitary Gland: At 2 years, there was a significantly increased incidence of adenoma in the pars distalis of the pituitary gland in 50 mg/kg males (Table 21, Table A-1, and Table A-2). Pars distalis adenomas were typically composed of sheets of chromophobes, although scattered acidophils and basophils could be found in some neoplasms. Variable-sized blood vessels, some angiectatic, as well as hemorrhage, were present in many of the neoplasms. The adenomas were usually well-demarcated masses that caused compression of the surrounding parenchyma, with larger neoplasms causing dorsal compression of the hypothalamic region of the brain.

Table 21 Incidences of Adenoma of the Pituitary Gland (Pars Distalis) in F_1_ Male Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Number Examined Microscopically | 49 | 49 | 50 | 50
Adenoma, Multiple^a^ | 0 | 0 | 1 | 1
Adenoma (includes multiple)^b^
Number of litters with at least one neoplasm/total number of litters | 16/29 | 9/25 | 18/25 | 26/29
Overall rate^c^ | 19/49 (39%) | 12/49 (24%) | 22/50 (44%) | 35/50 (70%)
Adjusted rate^d^ | 40.7% | 28.1% | 47.4% | 71.7%
Terminal rate^e^ | 10/36 (28%) | 7/35 (20%) | 16/38 (42%) | 13/25 (52%)
First incidence (days) | 508 | 485 | 436 | 351
Poly-3 test^f^ | P < 0.001 | P = 0.152N | P = 0.328 | P < 0.001
Litter-adjusted Poly-3 test | P < 0.001 | P = 0.983 | P = 0.495 | P = 0.007

^a^ Number of animals with neoplasm.

^b^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 40/99 (40.4% ± 2.3%), range 39%–42%; all routes: 101/298 (33.9% ± 5.7%), range 28%–42%.

^c^ Number of animals with neoplasm per number of animals with pituitary gland examined microscopically.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal kill.

^f^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by an N.

Female Reproductive System: Statistical evaluation was done for the incidence of uterine and vaginal lesions for the original cross-sectional evaluation, the additional residual longitudinal section evaluation, and for the combination of the original and longitudinal evaluations.

At 2 years, there were significantly increased incidences of uterine stromal polyp in 3 and 15 mg/kg females in the combined evaluations (Table 22 and Table B-2). The incidences of uterine stromal polyp or uterine stromal sarcoma (combined) were significantly increased in the 3 and 15 mg/kg groups in the combined evaluation. Two 50 mg/kg females had multiple vaginal polyp in the combined evaluations; vaginal polyps were not recorded in any other treatment group.

Table 22 Incidences of Neoplasms and Nonneoplastic Lesions of the Uterus, Vagina, and Cervix in F_1_ Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Uterus^a^ | 50 | 50 | 50 | 49
Squamous Metaplasia
Original Cross Sectional Evaluation^b^ | 0 | 0 | 1 (1.0)^c^ | 4* (1.3)
Residual Longitudinal Evaluation | 0 | 2 | 5* | 6*
Original and Residual Evaluations (combined) | 0 | 2 | 5* | 6*
Stromal Polyp
Original Cross Sectional Evaluation^d^
Number of litters with at least one neoplasm/total number of litters | 3/30 | 6/25 | 6/25 | 5/28
Overall rate^e^ | 3/50 (6%) | 6/50 (12%) | 7/50 (14%) | 5/49 (10%)
Adjusted rate^f^ | 6.9% | 12.8% | 15.9% | 12.8%
Terminal rate^g^ | 2/37 (5%) | 5/39 (13%) | 6/33 (18%) | 4/28 (14%)
First incidence (days) | 592 | 585 | 655 | 553
Poly-3 test^h^ | P = 0.388 | P = 0.277 | P = 0.158 | P = 0.296
Litter-adjusted Poly-3 test | –^i^ | – | – | –
Residual Longitudinal Evaluation^j^
Overall rate | 3/50 (6%) | 10/50 (20%) | 6/50 (12%) | 7/49 (14%)
Adjusted rate | 6.9% | 21.5% | 13.5% | 17.8%
Terminal rate | 2/37 (5%) | 8/39 (21%) | 4/33 (12%) | 5/28 (18%)
First incidence (days) | 592 | 694 | 614 | 553
Poly-3 test | P = 0.351 | P = 0.045 | P = 0.249 | P = 0.117
Litter-adjusted Poly-3 test | – | – | – | –
Original and Residual Evaluations (combined)^k^
Overall rate | 4/50 (8%) | 12/50 (24%) | 11/50 (22%) | 9/49 (18%)
Adjusted rate | 9.2% | 25.5% | 24.8% | 22.8%
Terminal rate | 3/37 (8%) | 9/39 (23%) | 9/33 (27%) | 7/28 (25%)
First incidence (days) | 592 | 585 | 614 | 553
Poly-3 test | P = 0.283 | P = 0.037 | P = 0.045 | P = 0.077
Litter-adjusted Poly-3 test | – | – | – | –
Stromal Sarcoma
Original Cross Sectional Evaluation^l^ | 0 | 0 | 1 | 0
Residual Longitudinal Evaluation^m^ | 0 | 0 | 1 | 0
Original and Residual Evaluations (combined)^n^ | 0 | 0 | 1 | 0
Stromal Polyp or Stromal Sarcoma
Original and Residual Evaluations (combined)^o^
Overall rate | 4/50 (8%) | 12/50 (24%) | 12/50 (24%) | 9/49 (18%)
Adjusted rate | 9.2% | 25.5% | 27.1% | 22.8%
Terminal rate | 3/37 (8%) | 9/39 (23%) | 10/33 (30%) | 7/28 (25%)
First incidence (days) | 592 | 585 | 614 | 553
Poly-3 test | P = 0.284 | P = 0.037 | P = 0.026 | P = 0.077
Vagina | 50 | 50 | 50 | 49
Polyp, Multiple
Original Cross Sectional Evaluation | 0 | 0 | 0 | 1
Residual Longitudinal Evaluation | 0 | 0 | 0 | 1
Original and Residual Evaluations (combined) | 0 | 0 | 0 | 2
Polyp (includes multiple)
Original and Residual Evaluations (combined)^p^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 2/49 (4%)
Adjusted rate | 0% | 0% | 0% | 5.2%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 0/33 (0%) | 2/28 (7%)
First incidence (days) | –^q^ | – | – | 729 (T)
Poly-3 test | P = 0.033 | –^i^ | – | P = 0.212
Cervix | 50 | 50 | 50 | 49
Squamous Hyperplasia
Original Cross Sectional Evaluation | 0 | 0 | 0 | 2 (2.5)
Residual Longitudinal Evaluation | 2 | 3 | 4 | 8*
Original and Residual Evaluations (combined) | 2 | 3 | 4 | 8*

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

(T) Terminal kill.

^a^ Number necropsied.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 5/100 (5.0% ± 1.4%), range 4%–6%; all routes: 13/194 (6.7% ± 2.5%), range 4%–10%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^i^ Value of statistic cannot be computed.

^j^ Historical incidence for all routes: 20/194 (10.3% ± 2.9%), range 6%–12%.

^k^ Historical incidence for all routes: 27/194 (14.0% ± 5.2%), range 8%–20%.

^l^ Historical incidence for corn oil gavage studies: 0/100; all routes: 3/194 (1.6% ± 1.9%), range 0%–4%.

^m^ Historical incidence for all routes: 2/194 (1.1% ± 1.2%), range 0%–2%.

^n^ Historical incidence for all routes: 3/194 (1.6% ± 1.9%), range 0%–4%.

^o^ Historical incidence for all routes: 29/194 (15.1% ± 6.3%), range 8%–22%.

^p^ Historical incidence for all routes: 1/194 (0.6% ± 1.1%), range 0%–2%.

^q^ Not applicable; no neoplasms in animal group.

In the original evaluation of the uterus and cervical gross lesions, there was a significantly increased incidence of squamous metaplasia of the uterus in 50 mg/kg females and two animals in this group had squamous hyperplasia of the cervix (which is normally lined by squamous epithelium) (Table 22 and Table B-4). Additional occurrences of these lesions were recorded in the longitudinal evaluation of these tissues. When the incidences from the original and longitudinal evaluations were combined, the incidences of squamous metaplasia of the uterus were significantly increased in the 15 and 50 mg/kg groups, and the incidence of squamous hyperplasia of the cervix was significantly increased in the 50 mg/kg group.

Histologically, stromal polyps were solitary exophytic nodules that projected into the uterine lumen. They were covered by normal-appearing endometrial surface epithelium and supported by a broad stalk of endometrial stroma, blood vessels, and a few entrapped glands. Polyps in the vagina were similar to those found in the uterus. Stromal sarcomas were composed of spindle-shaped cells with indistinct cytoplasmic borders that invaded into the uterine wall. Squamous metaplasia was recorded in the uterus when the normal cuboidal to columnar epithelium lining the uterus or endometrial glands was replaced by stratified squamous epithelium. In the cervix, squamous hyperplasia was characterized by increased layers of the normally present squamous epithelium.

Kidney: At 3 months, there was a slightly increased incidence of hydronephrosis in 50 mg/kg male rats (Table 23 and Table A-4). At 2 years, there were significantly increased incidences of hydronephrosis in 15 mg/kg males and 50 mg/kg males and females and in the incidence of pigmentation in 50 mg/kg females (Table 23, Table A-4, and Table B-4). In the renal pelvis, there were significantly decreased incidences of chronic active inflammation in 15 and 50 mg/kg males and females and mineralization in all dosed male groups. The incidence of pelvic mineralization was slightly decreased in 50 mg/kg females. Hydronephrosis was typically grossly observed as unilateral enlargement of the kidney, most often the right kidney. Microscopically, a dilated pelvis, with remaining cortical tissue compressed into a thin band, characterized hydronephrosis. Pigmentation was golden brown and found scattered within the epithelium of the renal tubules. It was similar in nature to the pigment observed in the liver and spleen, and stained positive with Perl’s Prussian Blue, consistent with hemosiderin. Chronic active inflammation of the pelvis consisted of a mixed cell population within the urothelium and underlying lamina propria of the renal pelvis. Pelvic mineralization was characterized by dark basophilic material (consistent with mineral deposition) within the urothelium of the renal pelvis; mineralized debris was occasionally also found within the urinary space. The biological significance of the pelvic pigmentation or of the decreased pelvic inflammation and mineralization is unknown.

Table 23 Incidences of Nonneoplastic Lesions of the Kidney in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Male
Three-month Interim Evaluation
Number Examined Microscopically | 10 | – | – | 10
Hydronephrosis^a^ | 1 (1.0)^b^ | – | – | 3 (2.7)
Two-year Study
Number Examined Microscopically | 49 | 46 | 50 | 50
Hydronephrosis | 1 (3.0) | 5 (1.4) | 8* (2.9) | 10** (2.7)
Pelvis, Inflammation, Chronic Active | 22 (1.4) | 14 (1.2) | 8** (1.5) | 2** (1.0)
Pelvis, Mineralization | 18 (1.3) | 5** (1.0) | 5** (1.0) | 3** (1.0)
Female
Two-year Study
Number Examined Microscopically | 50 | 50 | 49 | 47
Hydronephrosis | 1 (3.0) | 1 (2.0) | 1 (4.0) | 6* (2.5)
Pelvis, Inflammation, Chronic Active | 16 (1.2) | 10 (1.1) | 6* (1.0) | 3** (1.0)
Pelvis, Mineralization | 31 (1.2) | 29 (1.1) | 23 (1.0) | 19 (1.1)
Pigmentation | 0 | 1 (1.0) | 3 (1.0) | 4* (1.0)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Parotid Salivary Gland: At 2 years, there were significantly increased incidences of atrophy and cytoplasmic vacuolization in 50 mg/kg male rats (Table 24 and Table A-4). Atrophy was characterized by a decrease in the number and size of the acini, along with a prominence of the stroma, often including an increase in adipocytes and infiltrates of inflammatory cells. Cytoplasmic vacuolization consisted of multiple, discrete, clear vacuoles within the cytoplasm of the acinar cells (Figure 28).

Table 24 Incidences of Selected Nonneoplastic Lesions in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Male
Salivary Gland, Parotid Gland^a^ | 46 | 48 | 50 | 50
Atrophy^b^ | 2 (2.5)^c^ | 2 (1.0) | 4 (1.8) | 13** (1.4)
Cytoplasmic Vacuolization | 4 (1.5) | 4 (2.0) | 7 (1.9) | 17** (1.7)
Prostate Gland | 49 | 50 | 50 | 50
Inflammation, Chronic Active | 17 (1.2) | 20 (1.3) | 28* (1.4) | 27* (1.3)
Epididymis | 49 | 50 | 50 | 50
Inflammation, Chronic | 0 | 0 | 0 | 3 (1.0)
Preputial Gland | 49 | 49 | 50 | 50
Duct, Ectasia | 2 (2.0) | 2 (1.5) | 5 (2.2) | 15** (2.2)
Thymus | 45 | 49 | 49 | 50
Atrophy | 14 (2.2) | 11 (2.5) | 15 (1.9) | 26* (2.5)
Spleen | 47 | 46 | 50 | 49
Pigmentation | 12 (1.3) | 11 (1.1) | 17 (1.1) | 27** (1.4)
Lymphoid Follicle, Atrophy | 0 | 0 | 1 (2.0) | 5* (1.8)
Hematopoietic Cell Proliferation | 23 (1.3) | 30 (1.2) | 22 (1.2) | 13* (1.5)
Stomach, Forestomach | 49 | 50 | 50 | 50
Epithelium Hyperplasia | 8 (2.6) | 6 (2.0) | 5 (2.8) | 17* (2.1)
Hyperkeratosis | 9 (2.0) | 5 (1.8) | 5 (2.2) | 17 (1.8)
Mammary Gland | 33 | 38 | 39 | 41
Pigmentation, Hemosiderin | 3 (1.0) | 9 (1.0) | 2 (1.5) | 13** (1.0)
Female
Spleen | 50 | 49 | 50 | 45
Hematopoietic Cell Proliferation | 27 (1.7) | 24 (1.5) | 19 (1.8) | 17 (1.8)
Adrenal Cortex | 50 | 49 | 50 | 46
Focal Hyperplasia | 8 (1.1) | 6 (1.0) | 12 (1.3) | 19** (1.2)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 28

Cytoplasmic Vacuolization in the Parotid Salivary Gland of an F_1_ Male Wistar Han Rat Administered 50 mg/kg DE-71 by Gavage for Two Years (H&E)

Most of the cells contain a single, large, discrete vacuole. There is also minimal atrophy of the gland, with infiltration of adipocytes (arrows).

Male Reproductive System: At 2 years, there were significantly increased incidences of chronic active inflammation of the prostate gland in 15 and 50 mg/kg males and ectasia of the preputial gland duct in 50 mg/kg males (Table 24 and Table A-4). In the epididymis, there was a positive trend in the incidences of chronic active inflammation, but the incidences in the individual dosed groups were not significantly different from that of the vehicle control group. Chronic active inflammation of the prostate gland and epididymis were similar in character, and consisted of focal to focally extensive accumulations of mononuclear cells with scattered neutrophils. Inflammatory cells could be found in the stroma as well as within acinar or tubular lumens of the prostate gland or epididymis, respectively. Ductal ectasia was characterized by a markedly enlarged duct lined by attenuated squamous epithelium and filled with keratin and cell debris.

Thymus: There was a significantly increased incidence of atrophy in 50 mg/kg males (Table 24 and Table A-4) at 2 years. Atrophy was characterized by an overall decrease in the size of the thymus, with a thin, indistinct cortex, a loss of lymphocytes, and an increase in adipocytes.

Spleen: At 2 years, there were significantly increased incidences of pigmentation and lymphoid follicle atrophy in 50 mg/kg males (Table 24 and Table A-4). There was a significantly decreased incidence of hematopoietic cell proliferation in 50 mg/kg males and a slightly decreased incidence of this lesion in females (Table 24, Table A-4, and Table B-4). Pigmentation in the spleen was qualitatively similar to that seen in the liver and kidney and was characterized by globules of golden-brown pigment found scattered throughout the red pulp that stained positively with Perl’s Prussian Blue, consistent with hemosiderin. Lymphoid follicle atrophy was evidenced by fewer, or smaller, lymphoid follicles within the spleen. Hematopoietic cell proliferation consisted of increased numbers of hematopoietic cells, including megakaryocytes, within the red pulp. The biological significance of the splenic changes is unknown. While the mechanism is not known, it is possible the changes were due to stress or erythrocyte breakdown.

Forestomach: At 2 years, there was a significantly increased incidence of epithelium hyperplasia in 50 mg/kg males and a positive trend in the incidences of hyperkeratosis in males (Table 24 and Table A-4). These lesions often occurred together and sometimes occurred in association with ulceration or inflammation of the forestomach. Hyperkeratosis was characterized by a thickened layer of keratin overlying the epithelium, while epithelium hyperplasia was diagnosed when there was an increase in the number of layers of squamous epithelium.

Adrenal Cortex: At 2 years, there was a significantly increased incidence of focal hyperplasia in 50 mg/kg females (Table 24 and Table B-4). Focal hyperplasia consisted of focal areas of increased numbers of cells, usually within the zona fasciculata. The cells within these lesions may have been smaller and more basophilic or larger with slightly vacuolated eosinophilic cytoplasm when compared to normal cortical cells, but there was no evidence of atypia.

Mammary Gland: In 50 mg/kg male rats, there was a significantly increased incidence of hemosiderin pigmentation at 2 years (Table 24 and Table A-4). This change was typically minimal and was characterized by clumps and granules of brown to golden-brown material (consistent with hemosiderin) in macrophages or in epithelial cells lining the ducts. The biological significance of this lesion is unknown. The pigment may represent erythrocyte breakdown with subsequent phagocytosis by macrophages in the mammary gland or surrounding connective tissue. It was not considered a primary effect of exposure to DE-71.

## Mice

### Three-month Study

Survival of the 500 mg/kg groups was decreased, with seven males removed from the study from weeks 4 to 12 and one female mouse removed during week 5 and one female mouse removed during week 12 (Table 25). Six female mice were removed from the study during week 1 due to gavage accidents; one mouse each in the vehicle control and 50 and 100 mg/kg groups and three mice in the 500 mg/kg group. Abnormal breathing, lethargy, and tremors, attributed to their moribund condition, were observed in two 500 mg/kg female mice. No clinical findings directly attributed to administration of DE-71 were observed.

Table 25 Survival and Body Weights of Mice in the Three-month Gavage Study of DE-71^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.3 ± 0.4 | 39.3 ± 0.8 | 17.0 ± 0.6
0.01 | 10/10 | 22.3 ± 0.5 | 38.8 ± 0.7 | 16.5 ± 0.6 | 99
5 | 10/10 | 22.3 ± 0.3 | 39.3 ± 1.0 | 17.0 ± 0.8 | 100
50 | 10/10 | 22.4 ± 0.3 | 37.3 ± 1.1 | 14.9 ± 0.9* | 95
100 | 10/10 | 22.3 ± 0.2 | 35.9 ± 0.7** | 13.7 ± 0.6** | 91
500 | 3/10^c^ | 22.5 ± 0.2 | 28.6 ± 0.9** | 5.9 ± 0.9** | 73
Female
0 | 9/10^d^ | 18.8 ± 0.2 | 32.8 ± 0.5 | 13.9 ± 0.5
0.01 | 10/10 | 18.8 ± 0.3 | 29.9 ± 0.6 | 11.1 ± 0.6* | 91
5 | 10/10 | 18.8 ± 0.3 | 29.5 ± 1.1* | 10.7 ± 0.8* | 90
50 | 9/10^d^ | 18.7 ± 0.4 | 30.3 ± 1.0 | 11.7 ± 1.0 | 92
100 | 9/10^d^ | 18.7 ± 0.4 | 31.0 ± 1.0 | 12.3 ± 0.7 | 94
500 | 5/10^e^ | 18.7 ± 0.3 | 27.3 ± 0.3** | 8.3 ± 0.6** | 83

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Weeks of deaths: 4, 4, 5, 5, 9, 10, 12.

^d^ Week of death: 1.

^e^ Weeks of deaths: 1, 1, 1, 5, 12.

Final mean body weights were significantly lower in the 100 and 500 mg/kg males and mean body weight gains were significantly lower in males administered 50 mg/kg or greater relative to the vehicle controls (Table 25 and Figure 11). In 500 mg/kg males, the final mean body weight was approximately 27% less than that of the vehicle controls, and the mean body weight gain was approximately 65% less than that of the vehicle controls. In female mice, final mean body weights were significantly lower in the 5 and 500 mg/kg groups, and mean body weight gains were significantly lower in the 0.01, 5, and 500 mg/kg groups. In 500 mg/kg females, the final mean body weight was approximately 17% less than that of the vehicle controls.

Figure 11

Growth Curves for Mice Administered DE-71 by Gavage for Three Months

Similar to those of the 3-month rat study, the hematology findings suggested a small (approximately 10%) decrease in the erythron in the 500 mg/kg males and females (Table F-2). In this study, the erythron decrease was evidenced by decreases in hematocrit values, hemoglobin concentrations, and erythrocyte counts; there were no decreases in mean cell volume or mean cell hemoglobin. In general, reticulocyte counts were lower in males and females administered 50 mg/kg or greater, and the values for females demonstrated a dose-response relationship.

The absolute and relative liver weights of 50 mg/kg males and 100 and 500 mg/kg males and females were significantly greater than those of the vehicle controls; in 500 mg/kg males and females, the absolute liver weights were increased by approximately threefold (Table 26 and Table G-3). The absolute kidney weight of 500 mg/kg males was significantly less (26%) than that of the vehicle controls. The relative kidney weights of all dosed female groups were significantly greater than that of the vehicle controls. The absolute heart weights of 500 mg/kg males and females were significantly less (15% and 17%, respectively) than those of the vehicle controls. The absolute testis weight of 500 mg/kg males was significantly less than that of the vehicle controls. In males, the relative heart weights of the 100 and 500 mg/kg groups and the relative thymus weight of the 500 mg/kg group were significantly greater than those of the vehicle controls and were consistent with decreased body weights.

Table 26 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 3
Necropsy body wt | 39.3 ± 0.8 | 38.8 ± 0.7 | 39.3 ± 1.0 | 37.3 ± 1.1 | 35.9 ± 0.7** | 28.6 ± 0.9**
Heart
Absolute | 0.13 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.11 ± 0.00**
Relative | 3.411 ± 0.090 | 3.562 ± 0.078 | 3.529 ± 0.093 | 3.582 ± 0.081 | 3.648 ± 0.055* | 3.966 ± 0.091**
R. Kidney
Absolute | 0.27 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.27 ± 0.01 | 0.26 ± 0.01 | 0.20 ± 0.01**
Relative | 6.784 ± 0.133 | 7.145 ± 0.175 | 7.067 ± 0.164 | 7.129 ± 0.148 | 7.245 ± 0.188 | 6.995 ± 0.056
Liver
Absolute | 1.38 ± 0.02 | 1.31 ± 0.05 | 1.50 ± 0.03 | 1.79 ± 0.08** | 2.18 ± 0.07** | 4.11 ± 0.02**
Relative | 35.024 ± 0.417 | 33.701 ± 1.195 | 38.207 ± 0.870 | 48.005 ± 1.761** | 60.684 ± 1.827** | 144.118 ± 4.508**
R. Testis
Absolute | 0.115 ± 0.002 | 0.114 ± 0.002 | 0.116 ± 0.002 | 0.116 ± 0.002 | 0.112 ± 0.003 | 0.102 ± 0.007*
Female
n | 9 | 10 | 10 | 9 | 9 | 5
Necropsy body wt | 32.8 ± 0.5 | 29.9 ± 0.6 | 29.5 ± 1.1* | 30.3 ± 1.0 | 31.0 ± 1.0 | 27.3 ± 0.3**
Heart
Absolute | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.12 ± 0.01 | 0.10 ± 0.00**
Relative | 3.596 ± 0.084 | 3.932 ± 0.103 | 3.849 ± 0.155 | 3.798 ± 0.083 | 3.813 ± 0.121 | 3.803 ± 0.072
R. Kidney
Absolute | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.01
Relative | 4.954 ± 0.151 | 5.740 ± 0.162** | 5.323 ± 0.157** | 5.578 ± 0.111** | 5.436 ± 0.115** | 6.289 ± 0.190**
Liver
Absolute | 1.29 ± 0.20 | 1.10 ± 0.02 | 1.10 ± 0.03 | 1.51 ± 0.04 | 1.83 ± 0.05** | 3.74 ± 0.10**
Relative | 39.495 ± 6.272 | 36.887 ± 0.526 | 37.404 ± 0.887 | 50.224 ± 1.481* | 59.150 ± 1.078** | 137.002 ± 3.891**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

UDPGT activities were significantly increased in all dosed groups of females, with a maximal induction of approximately 1.7-fold over the vehicle controls in the 500 mg/kg group (Table 27). Hepatic EROD activities were significantly increased in females administered 5 mg/kg or greater, with a maximal induction of approximately 5.3-fold in the 500 mg/kg group. Hepatic A4H activities were significantly increased in males administered 50 mg/kg or greater, and in females administered 5 mg/kg or greater. Maximal A4H induction occurred in the 500 mg/kg groups and was approximately twofold and threefold in males and females, respectively. Hepatic PROD activities were significantly increased in male and female mice administered 5 mg/kg or greater. Maximal PROD induction occurred in the 50 mg/kg males and females, with approximately 15-fold and sixfold increases, respectively.

Table 27 Liver Enzyme Activities for Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 3
Uridine diphosphate glucuronosyl transferase (UDPGT) (nmol/minute per mg microsomal protein)
| 13.7 ± 0.2 | 11.8 ± 0.3 | 14.3 ± 0.3 | 14.6 ± 0.4 | 14.6 ± 0.4 | 14.1 ± 0.6
7-Ethoxyresorufin-O-deethylase (EROD) (nmol/minute per mg microsomal protein)
| 0.012 ± 0.001 | 0.013 ± 0.000 | 0.005 ± 0.001* | 0.008 ± 0.002 | 0.016 ± 0.001 | 0.125 ± 0.006
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
| 0.400 ± 0.028 | 0.439 ± 0.013 | 0.390 ± 0.035b | 0.580 ± 0.030** | 0.688 ± 0.035** | 0.799 ± 0.061**
7-Pentoxyresorufin-O-dealkylase (PROD) (nmol/minute per mg microsomal protein)
| 0.002 ± 0.000 | 0.002 ± 0.000 | 0.014 ± 0.001** | 0.029 ± 0.002** | 0.011 ± 0.001** | 0.006 ± 0.002**
Female
n | 9 | 10 | 10 | 9 | 9 | 5
Uridine diphosphate glucuronosyl transferase (UDPGT) (nmol/minute per mg microsomal protein)
| 8.2 ± 0.2 | 10.1 ± 0.3** | 9.4 ± 0.5** | 13.4 ± 0.9** | 13.6 ± 0.9** | 13.8 ± 0.9**
7-Ethoxyresorufin-O-deethylase (EROD) (nmol/minute per mg microsomal protein)
| 0.009 ± 0.001 | 0.008 ± 0.001 | 0.014 ± 0.001* | 0.022 ± 0.003** | 0.017 ± 0.003** | 0.048 ± 0.004**
Acetanilide-4-hydroxylase (A4H) (nmol/minute per mg microsomal protein)
| 0.366 ± 0.030 | 0.355 ± 0.038 | 0.583 ± 0.050** | 0.814 ± 0.066** | 0.822 ± 0.081** | 1.120 ± 0.155**
7-Pentoxyresorufin-O-dealkylase (PROD) (nmol/minute per mg microsomal protein)
| 0.005 ± 0.000 | 0.003 ± 0.000 | 0.014 ± 0.002** | 0.028 ± 0.006** | 0.013 ± 0.002** | 0.009 ± 0.001*

* Significantly different (P ≤ 0.05) from the vehicle control group by Shirley’s or Dunn’s test.

** P ≤ 0.01.

^a^ Enzyme activities are given as mean ± standard error.

^b^ n = 9.

Concentrations of BDE-47, BDE-99, and BDE-153 were determined in adipose collected from mice at the end of the study (Table 15). In males, the concentrations of all three congeners increased linearly with dose up to 100 mg/kg, above which the concentrations increased more than proportional to the dose indicating saturation of metabolism at or above 500 mg/kg. The concentrations were higher than that in the vehicle control group except at 0.01 mg/kg. In females, the concentrations of all congeners increased proportionally to the dose and were higher than the vehicle control concentration except at 0.01 mg/kg. In general, the concentrations of BDE-99 were higher than those of the other two congeners; the concentrations of BDE-47 and BDE-153 were similar (except in 500 mg/kg males) suggesting a higher rate of accumulation of BDE-153 regardless of the lower percentage of BDE-153 in DE-71.

Due to early deaths in the 500 mg/kg groups, reproductive system evaluations including sperm and spermatid counts and vaginal cytology were performed on vehicle controls, 5, 50, and 100 mg/kg groups (Table 28, Table H-4, Table H-5, Table H-6, and Figure H-2). Left cauda epididymis weight and sperm motility were significantly decreased in 100 mg/kg males. There were no histological correlates recorded in the testis or epididymis of 100 mg/kg males, but there were significantly increased incidences of abnormal residual bodies in the 500 mg/kg male group. Based on these findings, DE-71 exhibits the potential to be a reproductive toxicant in male mice. In female mice, there were no significant differences between the vehicle control and dosed groups in cycle length, number of cycling females, number of females with regular cycles, or relative amount of time spent in the estrous stages (Table H-5, Table H-6, and Figure H-2).

Table 28 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 5 mg/kg | 50 mg/kg | 100 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 39.3 ± 0.8 | 39.3 ± 1.0 | 37.3 ± 1.1 | 35.9 ± 0.7*
L. Cauda epididymis | 0.0274 ± 0.0011 | 0.0246 ± 0.0015 | 0.0237 ± 0.0015 | 0.0214 ± 0.0010**
L. Epididymis | 0.0560 ± 0.0019 | 0.0541 ± 0.0033 | 0.0554 ± 0.0028 | 0.0514 ± 0.0017
L. Testis | 0.1143 ± 0.0024 | 0.1149 ± 0.0018 | 0.1188 ± 0.0028 | 0.1112 ± 0.0021
Spermatid measurements
Spermatid heads (10^6^/testis) | 22.83 ± 0.77 | 23.39 ± 0.75 | 22.67 ± 0.58 | 23.10 ± 0.55
Spermatid heads (10^6^/g testis) | 221.67 ± 6.18 | 238.55 ± 9.18 | 218.16 ± 7.04 | 238.72 ± 4.68
Epididymal spermatozoal measurements
Sperm motility (%) | 88.5 ± 1.2 | 89.5 ± 0.2 | 88.7 ± 0.3 | 85.3 ± 0.8**
Sperm (10^6^/cauda epididymis) | 16.7 ± 0.8 | 15.8 ± 1.6 | 9.4 ± 2.4 | 12.1 ± 2.1
Sperm (10^6^/g cauda epididymis) | 614.1 ± 34.7 | 676.7 ± 86.4 | 425.9 ± 120.0 | 555.3 ± 92.1

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ (cauda epididymis weights) or Shirley’s (sperm motility) test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (epididymis and testis weights) or Dunn’s test (spermatid measurements, sperm/cauda epididymis, and sperm/g cauda epididymis).

Relevant gross lesions included liver enlargement, discoloration (mottling) of the glandular stomach wall, and thin carcass in male and female mice, and forestomach wall focus and liver focus in male mice.

In the liver, there were significantly increased incidences of hepatocyte hypertrophy in males administered 50 mg/kg or greater and in 100 and 500 mg/kg females (Table 29). There were also significantly increased incidences of hepatocyte necrosis in 500 mg/kg males and females and hepatocyte cytoplasmic vacuolization in 500 mg/kg males. There was a positive trend in the incidences of focal necrosis in males, but the incidences were not significantly increased in any dosed group. Hepatocyte hypertrophy was characterized by enlargement of hepatocytes up to two or three times normal size (Figure 29). The hypertrophic hepatocytes had increased amounts of cytoplasm and sometimes contained enlarged nuclei. In both male and female mice, the centrilobular hepatocytes were affected first and as severity increased, midzonal and periportal hepatocytes became affected.

Table 29 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Gavage Study of DE-71

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
Liver^a^ | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, Hypertrophy^b^ | 0 | 0 | 1 (1.0)^c^ | 10** (1.8) | 10** (2.7) | 10** (3.1)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 1 (1.0) | 10** (1.3)
Hepatocyte Cytoplasmic Vacuolization | 0 | 0 | 0 | 0 | 0 | 6** (1.2)
Necrosis, Focal | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Adrenal Cortex | 10 | 10 | 9 | 10 | 10 | 10
Degeneration, Fatty | 0 | 0 | 0 | 0 | 0 | 4* (1.3)
Zona Fasciculata, Hypertrophy | 0 | 0 | 0 | 0 | 0 | 5* (1.0)
Thymus | 10 | 10 | 9 | 10 | 10 | 9
Atrophy | 0 | 0 | 0 | 0 | 0 | 6** (2.5)
Testis | 10 | 10 | 10 | 10 | 10 | 10
Abnormal Residual Bodies | 0 | 0 | 1 (2.0) | 0 | 1 (2.0) | 5* (2.0)
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10
Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 9** (1.2) | 6** (2.5)
Hepatocyte, Necrosis | 0 | 0 | 0 | 0 | 0 | 6** (1.2)
Adrenal Cortex | 10 | 10 | 10 | 10 | 10 | 10
Degeneration, Fatty | 0 | 0 | 0 | 0 | 0 | 2 (2.0)
Thymus | 9 | 10 | 10 | 10 | 9 | 8
Atrophy | 0 | 0 | 0 | 1 (2.0) | 0 | 3 (3.3)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 29

Hepatocyte Hypertrophy in the Liver of a Male B6C3F1/N Mouse Administered 500 mg/kg DE-71 by Gavage for Three Months (H&E)

The hepatocytes are larger than normal and there are scattered necrotic hepatocytes (arrows).

Hepatocyte necrosis was characterized by a single hepatocyte, or clusters of two or three hepatocytes, having a shrunken, condensed appearance. This was in contrast to focal necrosis of the liver, which consisted of randomly located foci of coagulative necrosis. Hepatocyte cytoplasmic vacuolization consisted of very small discrete vacuoles that filled the cytoplasm, usually in enlarged hepatocytes.

In the adrenal cortex, there were significantly increased incidences of fatty degeneration and hypertrophy of the zona fasciculata in 500 mg/kg males (Table 29). In females, there was a positive trend in the incidences of fatty degeneration but the incidence in the 500 mg/kg group was not significantly increased. Fatty degeneration consisted of discrete, colorless vacuoles within cortical cells, consistent with fat accumulation. Hypertrophy was characterized by eosinophilic cells with increased amounts of cytoplasm within the zona fasciculata (Figure 30).

Figure 30

Zona Fasciculata Hypertrophy and Fatty Degeneration in the Adrenal Gland of a Male B6C3F1/N Mouse Administered 500 mg/kg DE-71 by Gavage for Three Months (H&E)

The cells are larger than normal and there are large discrete vacuoles consistent with fat accumulation.

In the thymus, there was a significantly increased incidence of atrophy in 500 mg/kg males and a positive trend in the incidences of the lesion in females (Table 29). Atrophy was characterized by a reduction of the cortical region by thymocyte depletion.

In the testis of 500 mg/kg male mice, there was a significantly increased incidence of abnormal residual bodies (Table 29). This lesion was characterized by the presence of large, round to oval, amphophilic to eosinophilic bodies in the seminiferous tubules (Figure 31). These abnormal residual bodies were primarily seen at the luminal surface or in the lumen of the tubules.

Figure 31

Abnormal Residual Bodies (Arrows) in the Testis of a Male B6C3F1/N Mouse Administered 500 mg/kg DE-71 by Gavage for Three Months (H&E)

Dose Selection Rationale: Due to reduced survival and increased incidences of hepatocyte necrosis of the liver in the 500 mg/kg groups, the high dose selected for the 2-year gavage study in mice was 100 mg/kg. The low dose (3 mg/kg) and mid dose (30 mg/kg) were selected to give a broad range of exposure.

### Two-year Study

#### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 30 and in the Kaplan-Meier survival curves (Figure 12). Survival of 100 mg/kg males and females was significantly less than that of the vehicle controls leading to these groups being removed from the study at 18 months. The cause of most early deaths in 100 mg/kg males and females was liver tumors. Survival of all other dosed groups was similar to that of the vehicle controls.

Table 30 Survival of Mice in the Two-year Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Male
Animals initially in study | 50 | 50 | 50 | 50
Accidental deaths^a^ | 1 | 0 | 0 | 2
Moribund | 15 | 7 | 14 | 36
Natural deaths | 5 | 10 | 5 | 12
Animals surviving to study termination | 29 | 33 | 31 | 0
Percent probability of survival at end of study^b^ | 59 | 66 | 62 | 0
Mean survival (days)^c^ | 657 | 689 | 691 | 505
Survival analysis^d^ | P < 0.001 | P = 0.520N | P = 0.673N | P < 0.001
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental deaths^a^ | 1 | 0 | 1 | 0
Moribund | 10 | 10 | 9 | 46
Natural deaths | 6 | 5 | 3 | 4
Animals surviving to study termination | 33 | 35 | 37 | 0
Percent probability of survival at end of study | 67 | 70 | 76 | 0
Mean survival (days) | 678 | 695 | 695 | 532
Survival analysis | P < 0.001 | P = 0.932N | P = 0.443N | P < 0.001

^a^ Censored from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal kill).

^d^ The result of the life table trend test^197^ is in the vehicle control column, and the results of the life table pairwise comparisons^196^ with the vehicle controls are in the dosed group columns. A lower mortality in a dose group is indicated by N.

Figure 12

Kaplan-Meier Survival Curves for Mice Administered DE-71 by Gavage for Two Years

#### Body Weights and Clinical Findings

Mean body weights of 100 mg/kg males and females were at least 10% less than those of the vehicle control groups after weeks 17 and 21, respectively (Figure 13, Table 31, and Table 32). The mean body weights of 30 mg/kg males were at least 10% less than those of the vehicle controls after week 87. The mean body weight of the 30 mg/kg males was 84% that of the control group at terminal sacrifice. Clinical findings included increased occurrences of distended abdomen and thinness in 30 mg/kg males, and increased masses on appendages in all groups of males dosed with DE-71. Clinical findings of distended abdomen correlated with liver neoplasms. Clinical findings of masses on appendages were all related to lesions on the tail. Many of these did not have correlating lesions at necropsy or histologic examination, but several correlated to malformations of coccygeal vertebrae or associated skin lesions and were not considered related to DE-71 administration.

Figure 13

Growth Curves for Mice Administered DE-71 by Gavage for Two Years

Table 31 Mean Body Weights and Survival of Male Mice in the Two-year Gavage Study of DE-71

Day | Vehicle Control | | 3 mg/kg | | | 30 mg/kg | | | 100 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 22.4 | 50 | 22.3 | 99 | 50 | 22.3 | 100 | 50 | 22.4 | 100 | 50
4 | 21.9 | 49 | 21.9 | 100 | 50 | 22.0 | 100 | 50 | 22.2 | 101 | 48
11 | 23.6 | 49 | 23.3 | 99 | 50 | 23.6 | 100 | 50 | 23.4 | 99 | 48
18 | 25.1 | 49 | 24.8 | 99 | 50 | 25.1 | 100 | 50 | 24.6 | 98 | 48
25 | 25.9 | 49 | 25.8 | 100 | 50 | 25.9 | 100 | 50 | 25.7 | 99 | 48
32 | 27.1 | 49 | 26.5 | 98 | 50 | 26.6 | 98 | 50 | 26.3 | 97 | 48
39 | 27.6 | 49 | 27.3 | 99 | 50 | 27.7 | 101 | 50 | 27.3 | 99 | 48
46 | 28.4 | 49 | 28.8 | 101 | 50 | 28.9 | 102 | 50 | 27.9 | 98 | 48
53 | 29.7 | 49 | 29.4 | 99 | 50 | 29.5 | 99 | 50 | 28.6 | 96 | 48
60 | 30.8 | 49 | 30.9 | 100 | 50 | 30.7 | 100 | 50 | 29.5 | 96 | 48
67 | 30.9 | 49 | 31.0 | 100 | 50 | 30.8 | 100 | 50 | 30.0 | 97 | 48
74 | 31.8 | 49 | 32.0 | 101 | 50 | 31.7 | 100 | 50 | 30.4 | 96 | 48
81 | 33.2 | 49 | 33.0 | 100 | 50 | 32.5 | 98 | 50 | 31.1 | 94 | 48
88 | 34.2 | 49 | 34.1 | 100 | 50 | 33.9 | 99 | 50 | 32.4 | 95 | 48
116 | 38.0 | 49 | 38.0 | 100 | 50 | 37.5 | 99 | 50 | 35.2 | 93 | 48
144 | 41.8 | 49 | 41.2 | 99 | 50 | 40.2 | 96 | 50 | 37.2 | 89 | 48
172 | 44.3 | 49 | 43.8 | 99 | 50 | 43.0 | 97 | 50 | 38.9 | 88 | 48
200 | 46.4 | 49 | 46.2 | 100 | 50 | 44.4 | 96 | 50 | 38.9 | 84 | 48
228 | 48.4 | 49 | 47.7 | 99 | 50 | 46.7 | 96 | 50 | 40.5 | 84 | 48
256 | 50.6 | 49 | 49.8 | 99 | 50 | 48.8 | 96 | 50 | 41.7 | 82 | 48
284 | 51.6 | 49 | 51.2 | 99 | 50 | 50.0 | 97 | 50 | 42.5 | 82 | 48
311 | 52.2 | 48 | 52.0 | 100 | 50 | 50.9 | 98 | 50 | 43.1 | 83 | 48
340 | 52.7 | 48 | 52.5 | 100 | 50 | 51.5 | 98 | 50 | 43.5 | 83 | 48
368 | 53.2 | 48 | 53.3 | 100 | 50 | 52.1 | 98 | 50 | 43.6 | 82 | 48
396 | 53.7 | 48 | 53.7 | 100 | 50 | 52.7 | 98 | 50 | 42.7 | 80 | 48
424 | 53.9 | 48 | 53.1 | 99 | 50 | 52.0 | 97 | 50 | 41.0 | 76 | 48
452 | 54.5 | 48 | 53.9 | 99 | 49 | 52.2 | 96 | 49 | 40.0 | 73 | 45
480 | 54.6 | 48 | 54.0 | 99 | 49 | 53.3 | 98 | 47 | 38.3 | 70 | 42
508 | 55.3 | 46 | 54.2 | 98 | 49 | 54.0 | 98 | 47 | 36.5 | 66 | 38
536 | 54.5 | 45 | 53.4 | 98 | 49 | 53.1 | 98 | 47 | 34.6 | 64 | 27
550 | 53.3 | 45 | 52.4 | 98 | 48 | 51.3 | 96 | 47 | | | 0
564 | 52.9 | 45 | 52.4 | 99 | 45 | 50.2 | 95 | 46 | | | 0
578 | 52.3 | 43 | 51.9 | 99 | 45 | 49.2 | 94 | 46 | | | 0
592 | 52.3 | 40 | 51.9 | 99 | 44 | 48.7 | 93 | 45 | | | 0
606 | 51.0 | 35 | 50.2 | 99 | 42 | 47.0 | 92 | 45 | | | 0
620 | 51.2 | 35 | 50.0 | 98 | 39 | 45.7 | 89 | 43 | | | 0
634 | 52.3 | 34 | 49.2 | 94 | 38 | 43.9 | 84 | 42 | | | 0
648 | 52.3 | 33 | 50.1 | 96 | 38 | 43.5 | 83 | 42 | | | 0
662 | 51.5 | 32 | 49.7 | 97 | 38 | 42.8 | 83 | 40 | | | 0
674 | 49.9 | 32 | 48.8 | 98 | 38 | 41.0 | 82 | 40 | | | 0
690 | 47.7 | 30 | 48.6 | 102 | 36 | 40.4 | 85 | 37 | | | 0
704 | 46.3 | 30 | 47.5 | 102 | 34 | 39.3 | 85 | 37 | | | 0
718 | 45.7 | 30 | 46.4 | 102 | 33 | 38.2 | 84 | 31 | | | 0
Mean for Weeks
1–13 | 28.0 | | 27.9 | 100 | | 27.9 | 100 | | 27.3 | 97
14–52 | 47.3 | | 46.9 | 99 | | 45.9 | 97 | | 40.2 | 85
53–102 | 51.9 | | 51.2 | 99 | | 47.5 | 92 | | 39.5 | 76

Table 32 Mean Body Weights and Survival of Female Mice in the Two-year Gavage Study of DE-71

Day | Vehicle Control | | 3 mg/kg | | | 30 mg/kg | | | 100 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 18.4 | 50 | 18.3 | 100 | 50 | 18.4 | 100 | 50 | 18.4 | 101 | 50
5 | 17.9 | 49 | 18.0 | 100 | 50 | 17.9 | 100 | 49 | 18.2 | 102 | 50
12 | 18.9 | 49 | 19.2 | 102 | 50 | 19.4 | 102 | 49 | 19.4 | 102 | 50
19 | 20.3 | 49 | 20.2 | 100 | 50 | 20.3 | 100 | 49 | 20.4 | 100 | 50
26 | 21.1 | 49 | 21.1 | 100 | 50 | 21.4 | 101 | 49 | 21.3 | 101 | 50
33 | 21.7 | 49 | 22.0 | 101 | 50 | 21.8 | 100 | 49 | 22.0 | 101 | 50
40 | 22.6 | 49 | 22.6 | 100 | 50 | 22.8 | 101 | 49 | 23.0 | 102 | 50
47 | 22.7 | 49 | 23.1 | 102 | 50 | 23.0 | 101 | 49 | 22.9 | 101 | 50
54 | 23.5 | 49 | 23.9 | 102 | 50 | 23.7 | 101 | 49 | 23.8 | 101 | 50
61 | 23.9 | 49 | 24.3 | 102 | 50 | 23.5 | 99 | 49 | 24.3 | 102 | 50
68 | 24.9 | 49 | 24.7 | 99 | 50 | 25.0 | 101 | 49 | 25.0 | 100 | 50
75 | 26.4 | 49 | 26.1 | 99 | 50 | 26.0 | 99 | 49 | 25.9 | 98 | 50
82 | 26.5 | 49 | 26.4 | 100 | 50 | 25.9 | 98 | 49 | 25.7 | 97 | 50
89 | 26.9 | 49 | 26.9 | 100 | 50 | 26.7 | 99 | 49 | 26.4 | 98 | 50
117 | 29.5 | 49 | 29.8 | 101 | 50 | 29.7 | 101 | 49 | 28.8 | 98 | 50
145 | 32.9 | 49 | 33.6 | 102 | 50 | 33.3 | 101 | 49 | 31.2 | 95 | 50
173 | 36.6 | 49 | 35.9 | 98 | 50 | 35.4 | 97 | 49 | 33.0 | 90 | 50
201 | 37.7 | 49 | 37.3 | 99 | 50 | 36.9 | 98 | 49 | 33.8 | 90 | 50
229 | 40.2 | 49 | 39.4 | 98 | 50 | 38.3 | 95 | 49 | 35.3 | 88 | 50
257 | 43.3 | 49 | 42.6 | 98 | 50 | 42.0 | 97 | 49 | 37.1 | 86 | 50
285 | 45.5 | 49 | 45.7 | 100 | 50 | 43.9 | 97 | 49 | 38.0 | 84 | 50
313 | 47.1 | 49 | 47.1 | 100 | 50 | 44.0 | 94 | 49 | 38.2 | 81 | 50
341 | 49.5 | 48 | 50.3 | 102 | 50 | 48.0 | 97 | 49 | 40.4 | 82 | 50
369 | 50.9 | 48 | 51.7 | 102 | 50 | 48.5 | 95 | 49 | 40.4 | 79 | 49
397 | 52.8 | 48 | 54.0 | 102 | 50 | 50.1 | 95 | 49 | 40.6 | 77 | 49
425 | 53.9 | 48 | 55.7 | 103 | 49 | 51.3 | 95 | 49 | 41.5 | 77 | 49
453 | 54.0 | 47 | 56.4 | 105 | 49 | 51.5 | 95 | 49 | 41.5 | 77 | 48
481 | 55.7 | 47 | 57.2 | 103 | 48 | 52.2 | 94 | 49 | 41.4 | 74 | 47
509 | 56.9 | 47 | 58.4 | 103 | 48 | 53.0 | 93 | 49 | 40.4 | 71 | 46
537 | 57.7 | 47 | 58.4 | 101 | 47 | 53.8 | 93 | 48 | 39.4 | 68 | 40
551 | 57.2 | 47 | 57.4 | 101 | 47 | 52.5 | 92 | 48 | | | 0
565 | 56.8 | 47 | 56.3 | 99 | 47 | 52.0 | 92 | 47 | | | 0
579 | 55.0 | 46 | 56.3 | 102 | 45 | 51.1 | 93 | 46 | | | 0
593 | 55.7 | 43 | 56.5 | 101 | 44 | 50.8 | 91 | 46 | | | 0
607 | 52.8 | 42 | 54.3 | 103 | 44 | 49.5 | 94 | 45 | | | 0
621 | 53.4 | 42 | 55.1 | 103 | 43 | 50.2 | 94 | 45 | | | 0
635 | 53.7 | 41 | 55.7 | 104 | 42 | 51.3 | 96 | 45 | | | 0
649 | 53.2 | 41 | 55.0 | 103 | 41 | 50.9 | 96 | 45 | | | 0
663 | 54.1 | 40 | 56.5 | 104 | 41 | 52.4 | 97 | 44 | | | 0
675 | 53.0 | 40 | 54.9 | 104 | 40 | 51.5 | 97 | 44 | | | 0
691 | 51.4 | 36 | 54.7 | 106 | 37 | 50.1 | 98 | 40 | | | 0
705 | 52.0 | 33 | 54.3 | 104 | 37 | 49.4 | 95 | 38 | | | 0
719 | 51.7 | 33 | 53.4 | 103 | 35 | 48.5 | 94 | 38 | | | 0
Mean for Weeks
1–13 | 22.6 | | 22.6 | 100 | | 22.6 | 100 | | 22.6 | 100
14–52 | 40.3 | | 40.2 | 100 | | 39.1 | 97 | | 35.1 | 87
53–103 | 54.1 | | 55.6 | 103 | | 51.0 | 94 | | 40.7 | 75

#### Tissue Concentrations

Concentrations of BDE-47, BDE-99, and BDE-153 were determined in adipose and liver of male and female mice at the end of the 2-year study, except for 30 mg/kg males. For the 30 mg/kg male group, samples were not collected due to insufficient normal tissue. The data are presented in Table 16 and Figure 14. In both males and females, the tissue concentrations of all three congeners in adipose and liver increased with increasing dose and were higher than those of the respective vehicle controls. The tissue concentrations of congeners in adipose were higher than in liver suggesting preferential accumulation in adipose. Regardless of the lower percentage of BDE-153 in DE-71 compared to the other two congeners, concentrations of BDE-153 were relatively higher in both adipose and liver suggesting a higher rate of accumulation of BDE-153.

Figure 14

Concentrations of BDE-47, BDE-99, and BDE-153 in Adipose and Liver in Male and Female Mice Administered DE-71 by Gavage for Two Years

#### Pathology and Statistical Analysis

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and nonneoplastic lesions of the liver, thyroid gland, forestomach, spleen, adrenal cortex, and testes. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice. The 100 mg/kg males and females were terminated at 18 months. To adjust for differences in survival, statistical analyses were based on the poly-k test, as noted in the methods.

Liver: There were significantly increased incidences of hepatocellular adenoma in all dosed groups of male mice and in 30 and 100 mg/kg female mice (Table 33, Table C-1, Table C-2, Table D-1, and Table D-2). There were significantly increased incidences of hepatocellular carcinoma in 30 mg/kg males and in 100 mg/kg males and females. Hepatoblastomas only occurred in male mice, with significantly increased incidences in the 30 and 100 mg/kg groups. There were also significantly increased incidences of hepatocellular adenoma, hepatocellular carcinoma, or hepatoblastoma (combined) in 30 and 100 mg/kg males and hepatocellular adenoma or carcinoma (combined) in 30 and 100 mg/kg males and females.

Table 33 Incidences of Neoplasms and Nonneoplastic Lesions of the Liver in Mice in the Two-year Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg^a^
Male
Number Examined Microscopically | 50 | 50 | 50 | 50
Centrilobular, Hepatocyte, Hypertrophy^b^ | 0 | 28** (1.4)^c^ | 46** (3.7) | 48** (3.9)
Clear Cell Focus | 10 | 13 | 20* | 7
Basophilic Focus | 6 | 3 | 1* | 5
Necrosis, Focal | 2 (3.0) | 2 (1.0) | 16** (1.1) | 2 (2.5)
Kupffer Cell, Pigmentation | 5 (1.0) | 15* (1.3) | 33** (1.6) | 25** (1.3)
Hepatocellular Adenoma, Multiple | 10 | 23** | 45** | 33**
Hepatocellular Adenoma (includes multiple)^d^
Overall rate^e^ | 23/50 (46%) | 35/50 (70%) | 49/50 (98%) | 40/50 (80%)
Adjusted rate^f^ | 53.2% | 72.9% | 98.8% | 93.5%
Terminal rate^g^ | 15/29 (52%) | 25/33 (76%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 491 | 428 | 431 | 451
Poly-3 test^h^ | P < 0.001 | P = 0.034 | P < 0.001 | P < 0.001
Hepatocellular Carcinoma, Multiple | 4 | 2 | 17** | 35**
Hepatocellular Carcinoma (includes multiple)^i^
Overall rate | 18/50 (36%) | 15/50 (30%) | 30/50 (60%) | 45/50 (90%)
Adjusted rate | 40.7% | 33.0% | 65.2% | 97.7%
Terminal rate | 8/29 (28%) | 9/33 (27%) | 21/31 (68%) | 0/0 (0%)
First incidence (days) | 491 | 540 | 453 | 451
Poly-3 test | P < 0.001 | P = 0.293N | P = 0.013 | P < 0.001
Hepatocellular Adenoma or Carcinoma^j^
Overall rate | 31/50 (62%) | 40/50 (80%)^k^ | 49/50 (98%) | 47/50 (94%)
Adjusted rate | 68.1% | 81.6% | 98.8% | 99.5%
Terminal rate | 18/29 (62%) | 26/33 (79%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 491 | 428 | 431 | 451
Poly-3 test | P < 0.001 | P = 0.092 | P < 0.001 | P < 0.001
Hepatoblastoma, Multiple | 0 | 0 | 4 | 0
Hepatoblastoma (includes multiple)^l^
Overall rate | 1/50 (2%) | 1/50 (2%) | 16/50 (32%) | 5/50 (10%)
Adjusted rate | 2.5% | 2.3% | 35.0% | 23.4%
Terminal rate | 1/29 (3%) | 1/33 (3%) | 9/31 (29%) | 0/0 (0%)
First incidence (days) | 729 (T) | 729 (T) | 453 | 477
Poly-3 test | P < 0.001 | P = 0.743N | P < 0.001 | P = 0.020
Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma^m^
Overall rate | 31/50 (62%) | 40/50 (80%)^k^ | 49/50 (98%) | 47/50 (94%)
Adjusted rate | 68.1% | 81.6% | 98.8% | 99.5%
Terminal rate | 18/29 (62%) | 26/33 (79%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 491 | 428 | 431 | 451
Poly-3 test | P < 0.001 | P = 0.092 | P < 0.001 | P < 0.001
Female
Number Examined Microscopically | 50 | 49 | 50 | 49
Centrilobular, Hepatocyte, Hypertrophy | 0 | 7** (1.0) | 45** (2.2) | 47** (2.9)
Eosinophilic Focus | 3 | 2 | 16** | 15**
Fatty Change | 18 (1.4) | 18 (1.4) | 39** (1.6) | 20* (1.2)
Necrosis, Focal | 1 (1.0) | 1 (2.0) | 4 (1.8) | 3 (2.7)
Kupffer Cell, Pigmentation | 3 (1.3) | 10* (1.1) | 24** (1.2) | 27** (1.4)
Hepatocellular Adenoma, Multiple | 0 | 2 | 21** | 42**
Hepatocellular Adenoma (includes multiple)^n^
Overall rate | 5/50 (10%) | 7/49 (14%) | 32/50 (64%) | 46/49 (94%)
Adjusted rate | 11.6% | 16.0% | 68.0% | 97.9%
Terminal rate | 5/33 (15%) | 7/35 (20%) | 26/37 (70%) | 0/0 (0%)
First incidence (days) | 729 (T) | 729 (T) | 563 | 432
Poly-3 test | P < 0.001 | P = 0.385 | P < 0.001 | P < 0.001
Hepatocellular Carcinoma, Multiple | 0 | 1 | 1 | 8*
Hepatocellular Carcinoma (includes multiple)^o^
Overall rate | 4/50 (8%) | 2/49 (4%) | 6/50 (12%) | 27/49 (55%)
Adjusted rate | 9.2% | 4.6% | 13.0% | 75.5%
Terminal rate | 3/33 (9%) | 1/35 (3%) | 4/37 (11%) | 0/0 (0%)
First incidence (days) | 696 | 712 | 598 | 432
Poly-3 test | P < 0.001 | P = 0.333N | P = 0.411 | P < 0.001
Hepatocellular Adenoma or Carcinoma^p^
Overall rate | 8/50 (16%) | 8/49 (16%) | 33/50 (66%) | 47/49 (96%)
Adjusted rate | 18.4% | 18.3% | 69.5% | 98.8%
Terminal rate | 7/33 (21%) | 7/35 (20%) | 26/37 (70%) | 0/0 (0%)
First incidence (days) | 696 | 712 | 563 | 432
Poly-3 test | P < 0.001 | P = 0.602N | P < 0.001 | P < 0.001

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

(T) Terminal kill.

^a^ Groups terminated at 18 months.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 168/300 (56.0% ± 6.7%), range 46%–64%; all routes: 437/700 (62.4% ± 10.5%), range 46%–78%.

^e^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

^i^ Historical incidence for corn oil gavage studies: 105/300 (35.0% ± 9.8%), range 22%–44%; all routes: 262/700 (37.4% ± 11.2%), range 22%–52%.

^j^ Historical incidence for corn oil gavage studies: 220/300 (73.3% ± 6.3%), range 62%–78%; all routes: 541/700 (77.3% ± 8.3%), range 62%–90%.

^k^ A single incidence of hepatocholangiocarcinoma occurred in an animal that also had an adenoma.

^l^ Historical incidence for corn oil gavage studies: 10/300 (3.3% ± 2.4%), range 0%–6%; all routes: 34/700 (4.9% ± 3.7%), range 0%–12%.

^m^ Historical incidence for corn oil gavage studies: 221/300 (73.7% ± 6.1%), range 62%–78%; all routes: 545/700 (77.9% ± 8.3%), range 62%–90%.

^n^ Historical incidence for corn oil gavage studies: 67/300 (22.3% ± 10.5%), range 10%–34%; all routes: 272/698 (39.1% ± 21.9%), range 10%–78%.

^o^ Historical incidence for corn oil gavage studies: 30/300 (10.0% ± 5.1%), range 4%–18%; all routes: 112/698 (16.1% ± 8.1%), range 4%–34%.

^p^ Historical incidence for corn oil gavage studies: 85/300 (28.3% ± 10.2%), range 16%–40%; all routes: 320/698 (45.9% ± 21.9%), range 16%–82%.

Hepatocellular adenomas were discrete, well-circumscribed lesions that compressed surrounding parenchyma (Figure 32). They were composed of irregular plates of hepatocytes, which were most commonly eosinophilic, but also basophilic or vacuolated. Central veins and portal areas were generally absent. Hepatocellular carcinomas were large lesions, frequently with areas of necrosis, which caused compression of, and invasion into, surrounding parenchyma. Typically, hepatocellular carcinomas were characterized by hepatocytes forming trabeculae that were at least three cells thick, although some of the areas of carcinomas were of a solid pattern of growth (Figure 33). Cells within the hepatocellular carcinomas ranged from eosinophilic to basophilic in staining, and displayed marked pleomorphism and an increased mitotic rate. Hepatoblastomas were composed of small cells with scant cytoplasm and hyperchromatic, oval nuclei (Figure 34 and Figure 35). Cells were often arranged in rows around variably sized vascular spaces. Typically, hepatoblastomas arose from within a hepatocellular adenoma or carcinoma, and when this occurred only the hepatoblastoma was recorded.

Figure 32

Hepatocellular Adenoma in the Liver of a Male B6C3F1/N Mouse Administered 30 mg/kg DE-71 by Gavage for Two Years (H&E)

The large discrete mass (arrows) has a solid growth pattern that makes it distinct from the rest of the liver.

Figure 33

A Large Hepatocellular Carcinoma in the Liver of a Male B6C3F1/N Mouse Administered 30 mg/kg DE-71 by Gavage for Two Years (H&E)

The neoplasm is characterized by trabeculae that are three or more cells wide (arrowheads) and by blunt-ended trabeculae (arrows).

Figure 34

Hepatoblastoma in the Liver of a Male B6C3F1/N Mouse Administered 30 mg/kg DE-71 by Gavage for Two Years (H&E)

The neoplasm contains a large area of hemorrhage and necrosis (asterisk).

Figure 35

Higher Magnification of Figure 34 (H&E)

The cells are densely packed and small with oval, deeply basophilic nuclei.

There were significantly increased incidences of centrilobular hepatocyte hypertrophy in all dosed groups of male and female mice, and the severity of this lesion increased with increasing dose (Table 33, Table C-4, and Table D-4). There were significantly increased incidences of eosinophilic focus in 30 and 100 mg/kg female mice. In 30 mg/kg males, there was a significantly increased incidence of clear cell focus and a significantly decreased incidence of basophilic focus. There were significantly increased incidences of fatty change in 30 and 100 mg/kg females. The incidence of focal necrosis was significantly increased in 30 mg/kg males, and there was a significant positive trend in the incidences of this lesion in male and female mice. There were significantly increased incidences of Kupffer cell pigmentation in all dosed groups of males and females.

Centrilobular hepatocyte hypertrophy was characterized by an accentuated lobular pattern due to the presence of very large, polygonal centrilobular hepatocytes with abundant granular eosinophilic cytoplasm containing clumped basophilic material. Nuclei were frequently enlarged and had stippled chromatin, prominent nucleoli, and occasional bright eosinophilic inclusions. Eosinophilic foci were discrete groups of enlarged hepatocytes with brightly eosinophilic cytoplasm (Figure 36). Some foci caused compression of some of the surrounding parenchyma, but not to the extent of hepatocellular adenomas. Hepatocytes within foci were generally aligned with hepatocytes in the normal liver, in contrast to those in hepatocellular adenomas. Foci typically lacked cellular atypia and mitotic figures. Clear cell foci consisted of small groups of cells with cytoplasm that was clear and vacuolated due to glycogen accumulation. Clear cell foci were found randomly scattered throughout the liver and were not associated with a particular zone. Basophilic foci were composed of clusters of hepatocytes that were smaller than normal hepatocytes, and whose cytoplasm was basophilic in color.

Figure 36

Eosinophilic Focus in the Liver of a Male B6C3F1/N Mouse Administered 30 mg/kg DE-71 by Gavage for Two Years (H&E)

The focal area of enlarged hepatocytes (arrows) is not causing compression of the surrounding liver parenchyma. The liver also has marked hepatocyte hypertrophy.

The large majority of hepatocytes with fatty change were characterized by a single, or a few, discrete vacuoles within the cytoplasm of the hepatocytes that displaced the nucleus peripherally, consistent with macrovesicular fatty change. Less commonly, microvesicular fatty change was also present and characterized by small, almost indistinct vacuoles filling the cytoplasm. Fatty change was most commonly found in the periportal regions. Focal necrosis was characterized by the loss of cellular detail and hypereosinophilia of small clusters of hepatocytes and was typically associated with a neutrophilic infiltrate. Kupffer cell pigmentation was a subtle change consisting of pale tan to brown pigment within the cytoplasm of Kupffer cells. The pigment appeared to be consistent with lipofuscin and may represent an increase in hepatocellular turnover.

Thyroid Gland: There were significantly increased incidences of follicle hypertrophy in all dosed groups of male mice and in 30 and 100 mg/kg female mice, and the severities were increased in the 100 mg/kg groups (Table 34, Table C-4, and Table D-4). The incidences of follicle degeneration, an age-associated degenerative change in mice, were significantly decreased in 30 mg/kg males and 100 mg/kg females. The decreases in the incidences of this degenerative change are most likely due to an increase in thyroid gland stimulation in the 30 mg/kg males, and an increase in early deaths in the 100 mg/kg females.

Table 34 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-year Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg^a^
Male
Thyroid Gland^b^ | 50 | 49 | 50 | 49
Follicle, Hypertrophy^c^ | 25 (1.2)^d^ | 35* (1.4) | 41** (2.0) | 45** (2.4)
Follicle, Degeneration | 21 (1.6) | 19 (1.6) | 12* (1.4) | 6 (1.3)
Stomach, Forestomach | 50 | 50 | 50 | 50
Epithelium, Hyperplasia | 26 (2.1) | 19 (2.2) | 40** (2.4) | 29* (2.9)
Ulcer | 9 (2.3) | 8 (1.9) | 14 (2.1) | 11* (2.5)
Inflammation | 18 (1.7) | 18 (1.6) | 34** (1.7) | 19* (1.7)
Spleen | 50 | 47 | 47 | 47
Hematopoietic Cell Proliferation | 14 (2.1) | 10 (2.2) | 13 (2.2) | 25** (1.8)
Adrenal Cortex | 50 | 50 | 49 | 48
Hypertrophy, Diffuse | 1 (1.0) | 0 | 3 (1.3) | 20** (1.4)
Testes | 50 | 50 | 50 | 49
Germinal Epithelium, Atrophy | 11 (1.5) | 8 (1.4) | 20 (1.4) | 13* (1.5)
Female
Thyroid Gland | 50 | 49 | 48 | 47
Follicle, Hypertrophy | 24 (1.3) | 31 (1.5) | 37** (1.5) | 42** (2.4)
Follicle, Degeneration | 34 (1.9) | 28 (2.0) | 26 (1.5) | 11** (1.3)
Stomach, Forestomach | 50 | 50 | 50 | 49
Epithelium, Hyperplasia | 9 (1.9) | 5 (1.6) | 6 (2.7) | 16** (2.6)
Spleen | 50 | 47 | 48 | 48
Hematopoietic Cell Proliferation | 15 (1.9) | 10 (2.9) | 11 (2.8) | 24** (2.3)
Lymphoid Follicle, Hyperplasia | 12 (1.7) | 20 (1.7) | 7 (2.3) | 21** (1.6)
Adrenal Cortex | 50 | 50 | 49 | 47
Hypertrophy, Diffuse | 0 | 0 | 4 (1.0) | 8** (1.4)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Groups terminated at 18 months.

^b^ Number of animals with tissue examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Follicle hypertrophy was recorded when more than 50% of the follicles were lined by cuboidal epithelial cells with round nuclei and cytoplasm containing hyaline droplets; the colloid was generally eosinophilic, but often contained clumps of dark eosinophilic to pale basophilic material. With increasing severity, an increasing percentage of follicles were involved. Epithelial cells progressed from cuboidal to columnar, and the cytoplasm was often vacuolated; colloid was generally basophilic and contained clear vacuoles, clumps of dark basophilic material, and occasionally mineralized material. Morphologically, follicle degeneration was characterized by a loss of stainable colloid with coalescence of contiguous follicles and formation of multilocular spaces lined by flattened epithelium. The colloid in affected follicles tended to have a pale blue hue and increased interfollicular connective tissue surrounding affected follicles was common.

Forestomach: There were significantly increased incidences of epithelium hyperplasia in 30 and 100 mg/kg males and in 100 mg/kg females (Table 34, Table C-4, and Table D-4). In male mice, there were significantly increased incidences of ulcer in the 100 mg/kg group and inflammation in the 30 and 100 mg/kg groups. Epithelium hyperplasia, characterized by thickened squamous epithelium, usually lacked the solitary stalk of the papillomas; rather it had a broad base, and did not protrude as far into the lumen. Epithelium hyperplasia was sometimes associated with ulceration or erosion of the stomach epithelium but was often found in the absence of other lesions. Ulceration of the forestomach involved the loss of the entire thickness of the epithelium and generally extended through the basement membrane into the submucosa and muscularis mucosa. Ulcers were often associated with an inflammation, typically of mixed cell types, including neutrophils, macrophages, lymphocytes, and plasma cells. Eosinophilic cell debris, sloughed keratin, and bacteria could be found on the surface of some of the lesions. The biological significance of the forestomach ulcers is unknown.

Spleen: There were significantly increased incidences of hematopoietic cell proliferation in 100 mg/kg male and female mice (Table 34, Table C-4, and Table D-4). In the 100 mg/kg females, there was a significantly increased incidence of lymphoid follicle hyperplasia. Hematopoietic cell proliferation was characterized by an increased number of hematopoietic and myeloid cell precursors and megakaryocytes at different stages of maturation within the red pulp of the spleen. Lymphoid follicle hyperplasia was characterized by follicles that were enlarged and almost coalescing with one another. The changes in the spleen were considered secondary, and not primary, effects of exposure to DE-71.

Adrenal Cortex: In 100 mg/kg males and females, there were significantly increased incidences of diffuse hypertrophy (Table 34, Table C-4, and Table D-4). Diffuse cortical hypertrophy was characterized by enlargement of the majority of cortical epithelial cells, and was usually a bilateral finding.

Testes: There was a positive trend in the incidences of germinal epithelium atrophy in males, and the incidence in the 100 mg/kg group was significantly increased (Table 34 and Table C-4). Germinal epithelium atrophy was characterized by thinning of the germinal epithelium layer due to reduced numbers of germ cells.

## Genetic Toxicology

DE-71 was tested for mutagenic activity in bacteria in three independent studies at three separate laboratories using a total of six different bacterial tester strains (Salmonella typhimurium TA98, TA100, TA102, TA1535, and TA1537 and Escherichia coli WP2 uvrA/pKM101) with and without 10% rat or hamster liver metabolic activation enzymes (S9). The study conducted by SITEK Research Laboratories used the same lot of DE-71 (2550OA30A) that was used in the 2-year gavage studies. No evidence of mutagenicity was observed^172^ (Table E-1 and Table E-2). In all three studies, dose levels ranged up to 10,000 µg/plate in the absence of observable toxicity, although precipitation occurred in one of the three studies at 1,000 µg/plate and above.

Three related test articles, BDE-47, BDE-99, and BDE-153 were tested for mutagenic activity in three bacterial tester strains (S. typhimurium TA98, TA100, and TA102) with and without rat liver S9 mix, and no evidence of mutagenicity was observed with any of the three test articles in any of the tests that were conducted (Table E-3, Table E-4, and Table E-5).

In vivo, no increases in the frequencies of micronucleated normochromatic erythrocytes (NCEs) were observed in peripheral blood samples from male or female mice in the 3-month gavage study of DE-71 (0.01 to 500 mg/kg; Table E-6). Five mice were examined in each dose group except in the 500 mg/kg group only three male mice were available. In a second micronucleus study conducted in male B6C3F1/N mice, no increases in the frequencies of polychromatic erythrocytes (PCEs) or NCEs were seen in peripheral blood samples following administration of DE-71 (312.5 to 1,250 mg/kg) by gavage once daily for 3 days; blood samples were evaluated using flow cytometric methods^173^ (Table E-7). In these same mice, slide-based data acquisition methods were used to evaluate bone marrow smears for induction of micronucleated PCEs and results were consistent with the results from blood samples (Table E-8). In none of the micronucleus tests conducted with DE-71 were significant alterations in the percentage of PCEs seen over the dose range tested, suggesting that DE-71 did not induce toxicity in the bone marrow of treated mice. In the 3-day gavage study evaluated using flow cytometric methods, the trend test for percentage of PCEs gave a significant P value (0.023), but pairwise comparison of the top dose to the vehicle control group was not significant; thus, the small increase detected by flow cytometry (but not by slide scoring in the bone marrow) was not considered to be biologically significant.