# Materials and Methods

## Procurement and Characterization

### DE-71

DE-71 was obtained from Great Lakes Chemical Corporation (El Dorado, AR) in two lots (2550OA30A and 1550OK07A). Lot 2550OA30A was used during the 3-month and 2-year studies; lot 1550OK07A was used for dose formulation development studies performed by the analytical chemistry laboratory at Battelle Columbus Operations (Columbus, OH) and was not used in any of the animal studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and by the study laboratory at Southern Research Institute (Birmingham, AL) (Appendix J). Karl Fischer titration was performed by Galbraith Laboratories, Inc. (Knoxville, TN). Reports on analyses performed in support of the DE-71 studies are on file at the National Institute of Environmental Health Sciences.

Lot 2550OA30A of the test chemical, a viscous, sticky brown liquid, was identified as DE-71 by the analytical chemistry laboratory using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using IR spectroscopy. IR spectra were consistent with the literature spectra^183^ and for the structures for a polybrominated diphenyl ether (PBDE) mixture. Proton and carbon-13 NMR spectra were consistent with computer-calculated spectra and the structures for a PBDE mixture.

For lot 2550OA30A, the moisture content was determined by Karl Fischer titration and the purity profile was determined by the analytical chemistry laboratory using gas chromatography (GC) with flame ionization detection (FID). The purity profile of the bulk chemical was also determined by the study laboratory using GC/FID analysis. In further analyses of the bulk chemical using GC coupled with mass spectrometry (MS) detection, the analytical chemistry laboratory confirmed the identity of the peaks observed in the purity profiles and screened for the presence of polychlorinated and polybrominated dibenzodioxins and furans.

Karl Fischer titration indicated less than 0.1% water. GC/FID yielded a purity profile containing 16 reportable peaks, 11 of which were PBDEs tentatively identified by retention time matching to standards of PBDEs prepared in chloroform (Table J-2). Six peaks in this profile contained areas exceeding 2% of the total peak area; 2,2′,4,4′,5-pentabromodiphenyl ether (BDE-99; 41.67%), 2,2',4,4'-tetrabromodiphenyl ether (BDE-47; 35.68%), 2,2′,4,4′,6-pentabromodiphenyl ether (BDE-100; 10.44%), 2,2′,4,4′,5,6′-hexabromodiphenyl ether (BDE-154; 3.63%), 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE-153; 3.33%), and 2,2′,3,4,4′-pentabromodiphenyl ether (BDE-85; 2.03%) (Table 2). The identities of peaks in the GC/FID purity profile were confirmed by GC/MS using authentic PBDE standards for 11 peaks. The specific identity of an individual PBDE was based on the retention time and the mass spectrum of the standard to a peak in DE-71. It should be noted that other positional isomers with the same number of bromines might elute at the same retention time and would give the same mass spectrum. Therefore, the identity of the specific isomer should be considered tentative. Using polychlorinated analytical standards and high-resolution GC/MS, samples of the bulk chemical were found to contain no polychlorinated dibenzodioxins or furans (Table J-3). Polybrominated analytical standards and a second high resolution GC/MS system were used to determine that polybrominated dibenzodioxins and furans were present in the test article; concentrations of 2,3,7,8-tetrabromodibenzofuran (2,3,7,8-TBDF), 1,2,3,7,8-pentabromodibenzofuran (1,2,3,7,8-PeBDF), 2,3,4,7,8-pentabromodibenzofuran (2,3,4,7,8-PeBDF), and coeluting 1,2,3,4,7,8-hexabromodibenzofuran (1,2,3,4,7,8-HxBDF) and 1,2,3,6,7,8-hexabromodibenzofuran (1,2,3,6,7,8-HxBDF) were quantifiable (Table 2 and Table J-4). Taken together, these analyses indicated that the test article consisted of a mixture of approximately 54% pentabromodiphenyl ethers, 36% tetrabromodiphenyl ethers, 7% hexabromodiphenyl ethers, and low levels of a few polybrominated dibenzodioxins and furans (Table 2).

Table 2 Composition of the DE-71 Lot Used in the Current Studies

Constituent | Name | CAS Number | % in DE71^a^ | Concentration in DE-71 (pg/g)^b^
BDE-47 | 2,2',4,4'-Tetrabromodiphenyl ether | 5436-43-1 | 35.68 | –
BDE-100 | 2,2′,4,4′,6-Pentabromodiphenyl ether | 189084-64-8 | 10.44 | –
BDE-99 | 2,2′,4,4′,5-Pentabromodiphenyl ether | 60348-60-9 | 41.67 | –
BDE-85 | 2,2′,3,4,4′-Pentabromodiphenyl ether | 182346-21-0 | 2.03 | –
BDE-154 | 2,2′,4,4′,5,6′-Hexabromodiphenyl ether | 207122-15-4 | 3.63 | –
BDE-153 | 2,2′,4,4′,5,5′-Hexabromodiphenyl ether | 68631-49-2 | 3.33 | –
2,3,7,8-TBDF | 2,3,7,8-Tetrabromodibenzofuran | 67733-57-7 | – | 3,680
1,2,3,7,8-PeBDF | 1,2,3,7,8-Pentabromodibenzofuran | 107555-93-1 | – | 19,790
2,3,4,7,8-PeBDF | 2,3,4,7,8-Pentabromodibenzofuran | 131166-92-2 | – | 5,381
1,2,3,4,7,8-HxBDF^c^ | 1,2,3,4,7,8,Hexabromodibenzofuran | 129880-08-6
1,2,3,6,7,8-HxBDF^c^ | 1,2,3,6,7,8,Hexabromodibenzofuran | 107555-94-2 | – | 43,088

^a^ BDE congeners above 2% are shown. Other congeners detected are given in Table J-2.

^b^ Constituents detected above the limits of quantitation from duplicate analyses are reported.

^c^ Quantified together due to coelution in chromatography.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory using GC/FID and indicated that DE-71 was stable as a bulk chemical for 15 days when stored in sealed amber glass bottles at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature, protected from light, in sealed glass containers. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month and 2-year studies with GC/FID and no degradation of the bulk chemical was detected.

### Corn Oil

Mazola corn oil was obtained in multiple lots from Red Diamond Foodservice, Inc. (Birmingham, AL), and Sam’s Club (Birmingham, AL) and was used as the vehicle in the 3-month and 2-year studies. Periodic analyses of the corn oil vehicle performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times during the 3-month studies and approximately every 4 weeks during the 2-year studies by mixing DE-71 with corn oil to give the required concentrations (Table J-5). Dose formulations were stored at approximately 5°C in amber glass containers sealed with Teflon^®^-lined lids for up to 46 days.

Stability studies of 0.05 mg/mL formulations were performed by the analytical chemistry laboratory using GC with electron capture detection (ECD). Stability was confirmed for at least 46 days for dose formulations stored in amber glass containers sealed with Teflon^®^-lined lids at temperatures up to 25°C and for 3 hours under simulated animal room conditions. An additional stability study was performed by the study laboratory on the 0.001 mg/mL dose formulation using a similar GC/ECD system, and stability was confirmed for at least 55 days for dose formulations stored in amber glass containers sealed with Teflon^®^-lined lids at 5°C and for 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of DE-71 were conducted by the study laboratory using GC/ECD. Determinations of the concentrations of DE-71 in corn oil were based on quantification of peak areas produced by the marker compound BDE-99. During the 3-month studies, the dose formulations were analyzed three times; all 15 dose formulations for rats and 14 of 15 for mice were within 10% of the target concentrations (Table J-6 and Table J-7). Animal room samples of these dose formulations were also analyzed; 11 of 15 for rats and 12 of 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 2 months (Table J-8 and Table J-9). Of the dose formulations analyzed and used during the studies, 38 of 39 for rats and all 36 for mice were within 10% of the target concentrations; 23 of 24 animal room samples for rats and 13 of 14 for mice were within 10% of the target concentrations.

## Animal Source

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY), for the 3-month studies and the 2-year mouse study. For the 2-year rat study, pregnant female Wistar Han [Crl:WI(Han)] rats were obtained from Charles River Laboratories (Raleigh, NC) on gestational day (GD) 2. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP time to evaluate different rat models between 2005 and 2006.^184^ The Wistar Han rat, an outbred rat stock, was then selected because it was projected to have a long lifespan, resistance to disease, large litter size, and low neonatal mortality.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Southern Research Institute Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The doses for the 3-month studies were set at 0, 0.01, 5, 50, 100, and 500 mg/kg in order to examine the toxic effects in rats and mice at doses expected to cause liver toxicity (100 to 500 mg/kg) based on a previous 3-month rodent study where at 100 mg/kg there was no effect on survival although hepatomegaly, focal liver necrosis, and thyroid gland hyperplasia occurred.^1^ The oral LD_50_ for DE-71 was reported as greater than 5,000 mg/kg.^1^ The lower doses were added to expand the range of doses. The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to DE-71 and to determine the appropriate doses to be used in the 2-year studies.

On receipt, the rats and mice were 4 to 5 weeks old. Animals were quarantined for 11 to 14 days and were 5 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program and there were no relevant findings (Appendix L). All tests results were negative.

Groups of 10 male and 10 female rats and mice were administered DE-71 in corn oil by gavage at doses of 0.01, 5, 50, 100, or 500 mg/kg body weight 5 days per week for 14 weeks. Additional groups of 10 male and 10 female special study rats were administered the same doses for 25 days. Vehicle control animals received the corn oil vehicle alone. Dosing volumes were 5 mL/kg body weight for rats and 10 mL/kg for mice. Feed and water were available ad libitum. Rats and female mice were housed five per cage and male mice were housed singly. Clinical findings were recorded weekly for core study rats and mice. The animals were weighed initially, on day 2 (female mice), day 3 (male rats and mice), day 4 (female rats), then weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 3.

Table 3 Experimental Design and Materials and Methods in the Gavage and Perinatal and Postnatal Gavage Studies of DE-71

Three-month Studies | Two-year Studies
Study Laboratory
Southern Research Institute (Birmingham, AL) | Southern Research Institute (Birmingham, AL)
Strain and Species
F344/N rats B6C3F1/N mice | Wistar Han rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Rats: Charles River Laboratories (Raleigh, NC) Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 11 (females) or 12 (males) days Mice: 13 (males) or 14 (females) days | Rats: 4 days (F_0_ females) Mice: 12 days
Average Age When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks | Rats: 12 to 13 weeks (F_0_ females) or gestational day 6 (F_1_ offspring) Mice: 4 to 7 weeks
Date of First Dose
Rats (core and special study): July 19 (females) or 20 (males), 2004 Mice: July 21 (males) or 22 (females), 2004 | Rats: July 18, 2008 Mice: February 25, 2008
Duration of Dosing
Rats (core) and mice: 5 days/week for 14-weeks (gavage) Rats (special study): 5 days/week for 25 days (gavage) | Rats: F_0_ females from gestational day 6 to postnatal day 20; F_1_ offspring from gestation day 6 to 105 weeks after weaning, Mice: 105 weeks
Date of Last Dose
Rats (core): October 18 (females) or 19 (males), 2004 Rats (special study): August 12 (females) or 13 (males), 2004 Mice: October 20 (males) or 21 (females), 2004 | Rats: August 25, 2008 (F0 females); November 25, 2008 (F_1_ offspring, 3-month interim evaluation); August 26 to 30, 2010 (F_1_ offspring, 2-year study) Mice: February 25, 2010
Necropsy Dates
Rats: October 19 (females) or 20 (males), 2004 Mice: October 21 (males) or 22 (females), 2004 | Rats: November 26, 2008 (F_1_ offspring, 3-month interim evaluation); August 24 to 31, 2010 (F_1_ offspring, 2-year study) Mice: February 22 to 26, 2010
Average Age at Necropsy
Female rats 19 weeks, male rats and male and female mice 19 to 20 weeks | Rats: 17 weeks (3-month interim evaluation) or 107 to 109 weeks Mice: 108 to 112 weeks
Size of Study Groups
10 males and 10 females | Rats: F_0_ females: 52 (3 and 15 mg/kg groups), or 62 (vehicle control and 50 mg/kg groups) F_1_ offspring: 50 males and 50 females (3 and 15 mg/kg groups) or 60 males and 60 females (vehicle control and 50 mg/kg groups) Mice: 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
Rats: 5 Mice: 1 (males) or 5 (females) | Rats: pregnant F_0_ females housed individually, nursing F_0_ females housed with pups, and F_1_ offspring housed 3 (males) or 5 (females) per cage after postnatal day 20 Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo | Rats: F_0_ females: tail tattoo F_1_ offspring: paw tattoo on postnatal day 4 and then tail tattoo on postnatal day 20 Mice: tail tattoo
Diet
Irradiated NTP-2000 open formula wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Rats: F_0_ females and F_1_ pups, irradiated NIH-07 open formula wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly F_1_ Rats (after postnatal day 20) and mice; same as 3-month studies.
Water
Tap water (Birmingham, AL municipal supply) via automatic watering system (Edstrom Industries, Inc. Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Polycarbonate solid-bottom (Lab Products, Inc., Maywood, NJ), changed twice weekly (rats and female mice) or once weekly (male mice). | Same as 3-month studies, except changed weekly during gestation (rats) and rotated every 2 weeks
Bedding
Irradiated hardwood bedding chips (P.J. Murphy Forest Products Corporation, Montville, NJ), changed twice weekly (rats and female mice) or once weekly (male mice). | Same as 3-month studies
Rack Filters
Reemay^®^ spun-bonded polyester (Andico, Birmingham, AL), changed every 2 weeks. | Same as 3-month studies
Racks
Stainless steel (Lab Products, Inc., Maywood, NJ), changed every 2 weeks | Same as 3-month studies, except rotated every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Doses
0, 0.01, 5, 50, 100, or 500 mg/kg in corn oil; dosing volumes of 5 mL/kg (rats) or 10 mL/kg (mice) | Rats: 0, 3, 15, or 50 mg/kg in corn oil; dosing volume of 5 mL/kg Mice: 0, 3, 30, or 100 mg/kg in corn oil; dosing volume of 10 mL/kg
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on day 2 (female mice), day 3 (male rats and mice), day 4 (female rats), then weekly, and at the end of the studies; clinical findings were recorded weekly for core study rats and mice. | Rats: Observed twice daily F_0_ females: Body weights recorded on gestational day 5 through postnatal day 20. Clinical findings recorded on gestational day 6 through postnatal day 21. F_1_ offspring (perinatal): Number, sex, and viability status of pups determined on postnatal day 1. Body weights recorded on postnatal days 1 (litter weights by sex), 4, 7, 12, 15, 18, and 21. F_1_ offspring (2-year study): Body weights recorded on days 1, 4 (males), 5 (females), weekly for the first 13 weeks, at 4-week intervals thereafter, and at necropsy. Clinical findings recorded at 4-week intervals. Mice: Observed twice daily. Body weights recorded on days 1, 4 (males); 5 (females); weekly for the first 13 weeks, at 4-week intervals thereafter until week 77, at 2-week intervals beginning week 77, and at necropsy. Clinical findings recorded at 4-week intervals until week 77 and at 2-week intervals thereafter.
Method of Kill
Carbon dioxide asphyxiation | Same as 3-month studies
Necropsy
Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all 2- year rats and mice. At the 3-month interim evaluation in rats the heart, right kidney, liver, lung, right testis, and thymus were weighed in the 0 and 50 mg/kg groups.
Clinical Pathology
Blood was collected via the retroorbital sinus on days 4 and 25 (special study rats) and from all animals surviving to the end of the studies for hematology and clinical chemistry (rats). Hematology: hematocrit; hemoglobin concentration; erythrocyte, nucleated erythrocytes, reticulocyte, and platelet counts; erythrocyte and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials. Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, bile acids, total thyroxine, total triiodothyronine, and thyroid stimulating hormone. | None
Histopathology
Complete histopathology was performed on 0 and 500 mg/kg core study rats and mice as well as 100 mg/kg mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, pleura (female mice) preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. In the remaining groups of rats and mice, the liver, lung, stomach (glandular), testis and thymus were examined. In the remaining groups of rats, the epididymis, lymph node (mesenteric), ovary, thyroid gland (except 0.01 mg/kg females), and uterus were examined. In the remaining groups of mice, the adrenal gland, esophagus, heart (females), pleura (females), spleen (males), and stomach (forestomach) were examined. | Complete histopathology was performed on 2-year rats and all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone, brain, cervix (rats), clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, uterus, and vagina (rats).
Sperm Motility and Vaginal Cytology
At the end of the studies, spermatid and sperm samples were collected from male rats in the vehicle control, 50, 100, and 500 mg/kg groups and male mice in the vehicle control, 5, 50, and 100 mg/kg groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from female rats in the vehicle control, 50, 100, and 500 mg/kg groups and female mice in the vehicle control, 5, 50, and 100 mg/kg groups. | None
Liver Enzyme Activities
Liver samples were collected on day 25 (special study rats) and at the end of the studies (rats and mice) 7-ethoxy-O-deethylase, acetanilide-4-hydroxylase, 7-pentoxy-O-dealkylase, and uridine diphosphate glucuronosyl transferase activities. | None
Tissue Concentration Studies
Adipose and liver samples were collected from rats on day 25 (special study) and at the end of the study (core study), and adipose samples were collected from mice at the end of the study for analysis of concentrations of 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47), 2,2′,4,4′,5-pentabromodiphenyl ether (BDE-99), and 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE-153). | Adipose, liver, plasma, and carcasses were collected for analysis of concentrations of 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47), 2,2′,4,4′,5-pentabromodiphenyl ether (BDE-99), and 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE-153). Lipid content was determined for all adipose and liver samples. Rats (F_0_ and F_1_): Carcasses and whole livers were collected from six male and six or seven female F_1_ offspring per dose group at the time of litter adjustment on postnatal day 4. Adipose and whole liver samples were collected on postnatal day 21 from six F_0_ females per dose group and one male and one female F_1_ offspring from each of their litters. Rats (F_1_) and Mice: Adipose, liver, and plasma (rats only) samples were collected from up to 16 males and 16 females per dose group at the end of the studies.
Study on the Relationship of the AhR to DE-71 Liver Tumor Formation
None | DNA was extracted from formalin-fixed paraffin-embedded blocks of liver (n = 118) and kidney (n = 122) tissues obtained at necropsy from vehicle control and 50 mg/kg female rats and analyzed for AhR genotype. DNA was also extracted from fresh-frozen liver samples from the control female Wistar Han (n = 5) and Sprague Dawley (n = 1) rats and analyzed for AhR genotype.
Evaluation of Hras and Ctnnb1 Mutations in Hepatocellular Tumors
None | At necropsy, male and female rat and mouse hepatocellular tumor tissues and normal liver tissue were obtained as formalin-fixed paraffin-embedded blocks. Hot-spot mutations were evaluated in the Hras and Ctnnb1 genes in hepatocellular tumors representing all groups dosed with DE-71 (35 from rats and 62 from mice) and in spontaneous hepatocellular tumors from vehicle controls (5 from rats and 17 from mice). In addition, age-matched non-tumor livers from rats (n = 10) and mice (n = 8) were analyzed.

On days 4 and 25 (special study rats) and at the end of the 3-month studies (core groups), blood was collected from the retroorbital plexus under CO_2_/O_2_ anesthesia for hematology analyses in rats and mice as well as for clinical chemistry and thyroid hormone analyses in rats. Blood for hematology analyses was collected into tubes containing EDTA as an anticoagulant. Erythrocyte, reticulocyte, and platelet counts, automated hematocrit values, hemoglobin concentration, mean cell volume, mean cell hemoglobin, and mean cell hemoglobin concentration were analyzed on the day of collection using an ADVIA 120 Hematology System (Bayer, Inc.; Tarrytown, NY) using reagents supplied by Bayer or Fisher Scientific (Norcross, GA). Manual hematocrit was determined using a Micro-MB microcentrifuge (Thermo Scientific, Waltham, MA). Blood smears were prepared within 3 hours of collection and stained with modified Wright’s stain using an Ames HEMATEK slide stainer for evaluation of platelet and erythrocyte morphology by light microscopy. Blood for clinical chemistry and thyroid hormone analyses was collected into tubes with no anticoagulant and centrifuged. Clinical chemistry analyses were conducted using a Hitachi 911 Clinical Chemistry Analyzer (Roche Diagnostics Corporation; Indianapolis, IN) and thyroid hormone analyses were conducted by radioimmunoassay using a Packard Cobra Quantum 5005 Gamma Counter (Packard Instrument Company, Meriden, CT). The parameters measured are listed in Table 3.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats in the vehicle control, 50, 100, and 500 mg/kg groups and mice in the vehicle control, 5, 50, and 100 mg/kg groups. The parameters evaluated are listed in Table 3. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

On day 25 for special study rats and at the end of the studies for core study rats and mice, samples of liver were taken from the median and lateral lobes for determination of enzyme activities including expression of cytochrome P450 1A1-associated 7-ethoxyresorufin-O-deethylase (EROD) activity, CYP1A2-associated acetanilide-4-hydroxylase (A4H) activity (known to be associated with dioxin-like activity), and CYP2B-associated pentoxyresorufin-O-dealkylase (PROD) activity. The samples from each lobe were minced, combined, frozen in liquid nitrogen, and then stored at approximately −70°C. Microsomes were prepared by the CaCl_2_ aggregation method.^185^ Microsome protein concentration was determined using the Lowry method.^186^ The enzymes measured were EROD (7-ethoxyresorufin as substrate), A4H (acetanilide as substrate), PROD (7-pentoxyresorufin as substrate), and uridine diphosphate glucuronosyl transferase (UDPGT; 4-nitrophenol as a substrate). CYP1A1 and CYP2B activities were determined by spectrofluorometric methods described by Chang and Waxman^187^ and Lubet et al.,^188^ respectively. CYP1A2 was determined using HPLC as described by Hamm et al.^189^ UDPGT was determined by a spectrophotometric method described by Winsnes.^190^ Adipose and liver samples were collected for analysis of concentrations BDE-47, BDE-99, and BDE-153. Samples of adipose and liver were collected from up to 10 male and 10 female special study F344/N rats on day 25 and from 10 male and 10 female core study rats at week 14. Adipose samples were collected from up to 10 male and 10 female mice at week 14. All samples were frozen at −70°C and shipped to the analytical chemistry laboratory. Details of analysis may be found in Appendix I.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on 0 and 500 mg/kg core study rats and mice as well as 100 mg/kg mice. The liver, lung, glandular stomach, testis, and thymus of rats and mice; the epididymis, mesenteric lymph node, ovary, thyroid gland (except 0.01 mg/kg females), and uterus of rats; and the adrenal gland, esophagus, heart (females), pleura (females), spleen (males), and forestomach of mice were examined in the remaining dose groups. Table 3 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathologist’s Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^191^ and Boorman et al.^192^

## Two-year Studies

### Rat Study Design

In order to evaluate potential toxicity that arises from in utero and early postnatal exposure, an exposure for these developmental windows was included in the rat study. Time-mated Wistar Han female rats, 12 to 13 weeks old, were received on the same day from Charles River Laboratories (Raleigh, NC) on gestational day 2 (GD 2). GD 1 was defined as the day females were determined to have evidence of mating. Upon receipt, time-mated female rats were quarantined, which continued throughout the perinatal period. Five non-mated female rats (from the same shipment) were used for parasite evaluation and gross observation for disease. The health of the animals was monitored during the studies according to the NTP Sentinel Animal Program (Appendix L). All test results were negative.

Time-mated female rats were housed individually during gestation; dams were housed with pups during lactation. F_1_ offspring designated for the 2-year studies were initially housed 3 (males) or 5 (females) per cage after weaning, then separated as animals became larger according to the space requirements in the Guide for the Care and Use of Laboratory Animals.^193^ Feed and water were available ad libitum. Cages and racks were rotated every 2 weeks. Further details on animal maintenance are given in Table 3. Information on feed composition and contaminants is provided in Appendix K.

Groups of 62, 52, 52, and 62 time-mated female rats were administered DE-71 daily by gavage at doses of 0, 3, 15, and 50 mg DE-71/kg body weight, respectively, from GD 6 to weaning on PND 20. The vehicle was corn oil and control animals received the vehicle only. Body weights were taken daily and body weights from the previous day were used to calculate dosing volume (5 mL/kg). The day of delivery was defined as postnatal day (PND) 0. Female rats that did not deliver had a gross examination for evidence of pregnancy (e.g., presence of resorptions or fetuses). On PND 1 the number, sex distribution, and viability of pups were evaluated and pup body weights were recorded through lactation and at weaning. Body weight of pups on PND 1 was calculated from litter weights divided by number of pups. After PND 1, pup body weights were measured individually.

On PND 4, each litter was standardized to a maximum of eight pups, including four males and four females when possible. Litters with less than eight pups per litter or without at least two pups per sex were removed from the study, with one exception of a litter of seven in the 3 mg/kg group. Eight pups per litter were chosen to equalize lactational demands on dams.

Beginning on PND 12, each pup was dosed by oral gavage daily at the same dose level administered to its respective dam until weaning and dosed 5 days per week for the remainder of the study. Pup body weights were recorded on PNDs 1, 4, 7, 12, 15, 18, and 21. Dose volumes administered to pups were calculated using the most recent body weight (5 mL/kg). All offspring were weaned on a single day, when animals were between the ages of PND 21 to 23. The day of weaning was considered study day one for retained animals. At weaning, up to two male and two female offspring were randomly selected from each litter and allocated to the 2-year study. Groups of 60 males and 60 females (0 and 50 mg/kg) or 50 males and 50 females (3 and 15 mg/kg) were assigned to the 2-year study. Ten males and 10 females were randomly selected from litters of the 0 and 50 mg/kg groups for a 3-month interim evaluation. The study design is illustrated in Figure 4.

Figure 4

Study Design in the Perinatal and Postnatal Gavage Study of DE-71 in Wistar Han Rats

Abbreviations: GD = gestational day, PND = postnatal day, solid shading = direct exposure, hatched shading = indirect exposure

### Mouse Study Design

Groups of 50 male and 50 female mice were administered DE-71 in corn oil by gavage at doses of 0, 3, 30, or 100 mg DE-71/kg body weight 5 days per week for up to 105 weeks. Vehicle control animals received the corn oil vehicle alone. The dosing volume was 10 mL/kg.

Mice were quarantined for 12 days before the beginning of the studies. Five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. Mice were approximately 4 to 7 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix L). All test results were negative.

Male mice were housed individually and females were housed five per cage. Feed and water were available ad libitum. Cages and racks were rotated every 2 weeks. Further details of animal maintenance are given in Table 3. Information on feed composition and contaminants is provided in Appendix K.

### Clinical Examinations and Pathology

All rats were observed twice daily. For F_0_ rat dams, body weights were recorded on GD 5 through PND 20 and clinical observations were recorded daily on GD 6 through PND 21. For F_1_ rat offspring in the 2-year study, body weights were recorded on days 1 (first day after weaning), 4 (males), 5 (females), then weekly for the first 13 weeks, at 4-week intervals thereafter, and again at necropsy. Clinical findings were recorded at 4-week intervals.

Mice were observed twice daily. Body weights were recorded on days 1, 4 (males), 5 (females), then weekly for the first 13 weeks, at 4-week intervals thereafter until week 77, then at 2-week intervals and again at necropsy. Clinical findings were recorded at 4-week intervals until week 77 and at 2-week intervals thereafter.

Adipose, liver, plasma, and carcasses were collected for analysis of concentrations of BDE-47, BDE-99, and BDE-153. In rats, livers and carcasses from six male and six or seven female F_1_ offspring per dose group were collected after litter standardization on PND 4 following decapitation and exsanguination. Groups of six dams were randomly assigned to the tissue concentration study; on PND 21, adipose and livers from each dam and 1 pup/sex from their litters were collected per dose group. Samples of adipose, liver, and plasma (rats only) were collected at termination from up to 16 male and 16 female rats and mice per dose group. All samples were frozen at −70°C and shipped to the analytical chemistry laboratory. Details of analysis may be found in Appendix I.

Complete necropsies and microscopic examinations were performed on all 2-year rats and mice. At the 3-month interim evaluation in rats, the heart, right kidney, liver, lung, right testis, and thymus were weighed in the vehicle control and 50 mg/kg groups. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution, and testes and epididymis were fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. In the original evaluation of the uterus in rats, a cross section through each uterine horn, approximately 0.5 cm cranial to the cervix, was collected for histopathology review. For the residual evaluation, all remaining cervical, vaginal, and uterine tissue remnants were stored in 10% neutral buffered formalin, processed, and sectioned longitudinally. These evaluations were conducted for the 3-month interim and terminal kill groups of F_1_ female Wistar Han animals. Tissues examined microscopically are listed in Table 3.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent QA laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the adrenal gland, kidney, liver, mammary gland, pituitary gland, preputial gland, prostate gland, salivary gland, spleen, forestomach, thymus, thyroid gland, and uterus of rats and the adrenal gland, Harderian gland, small intestine, kidney, liver, mandibular lymph node, pancreas, pituitary gland, spleen, forestomach, testes, thymus, thyroid gland, and uterus of mice.

The QA report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^191^ and Boorman et al.^192^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^194^

### Study on the Relationship of the AhR to DE-71 Liver Tumor Formation

Formalin-fixed paraffin-embedded blocks of liver and kidney tissue from vehicle control and 50 mg/kg female rats were prepared at necropsy. Fresh-frozen control liver tissue was collected from five additional female rats and from one Sprague Dawley rat. Samples were shipped to ILS, Inc. (Research Triangle Park, NC), for DNA extraction and analyses of the aryl hydrocarbon receptor (AhR) genotypes. Further details may be found in Appendix M.

### Evaluation of Hras and Ctnnb1 Mutations in Hepatocellular Tumors

At necropsy, normal liver samples and hepatocellular tumors from vehicle control and DE-71-treated rats and mice were fixed in 10% neutral buffered formalin, transferred to 70% ethanol, and processed into paraffin blocks. The formalin-fixed paraffin-embedded normal liver tissue and liver tumors representative of spontaneous and DE-71-induced hepatocellular tumors were used for mutation analyses. Hepatocellular adenomas and carcinomas (n = 40) and hepatocellular carcinomas (n = 79) were used for mutation analyses in rats and mice, respectively. Further details may be found in Appendix N.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^195^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^196^ method for testing two groups for equality and Tarone’s^197^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented in Table A-1, Table A-4, Table B-1, Table B-4, Table C-1, Table C-4, Table D-1, Table D-4 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all nonneoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

The Poly-k test^198-200^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight.

This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^198^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^198^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice.^201^ Bailer and Portier^198^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^202^

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1 − P with the letter N added (e.g., P = 0.99 is presented as P = 0.01N). For neoplasms and nonneoplastic lesions detected at the 3-month interim evaluation, the Fisher exact test,^203^ a procedure based on the overall proportion of affected animals, was used.

In a second set of analyses for the rat study, mixed effects logistic regression was also used to account for potential litter effects.^204^ These models also incorporated the Poly-3 risk weights for each animal to adjust for survival. The primary tests in these models were for dose-related trends and pairwise comparisons of each dose group with the control group.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^205^ and Williams,^206,207^ or a t-test (3-month interim evaluation in the 2-year rat study). Pups per litter, pup survival during lactation, hematology, clinical chemistry, percent lipid, liver enzymes, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^208^ (as modified by Williams^209^) and Dunn.^210^ Jonckheere’s test^211^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^212^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the chi-square test.^213^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^214^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period.^215-217^ In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current mouse study. The historical control database includes six studies in Wistar Han rats, and only two of these (including the current study) are corn oil gavage studies. The study presented in this Technical Report is the only one that has an in utero and perinatal component.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^218^ In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of DE-71 and three polybrominated diphenyl ether congeners, BDE-47, BDE-99, and BDE-153 were assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium. DE-71 was also assessed for its ability to induce mutations in Escherichia coli, micronucleated erythrocytes in mouse bone marrow, and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^219,220^ The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^221^ and the somatic mutation theory of cancer.^222,223^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^224^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^225,226^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^227,228^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^229^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.