# Introduction

Figure 1

Pentabromodiphenyl Ether Mixture (DE-71 [Technical Grade]; CASRN 32534-81-9; Chemical Formula: C_12_H_5_Br_5_O; Molecular Weight: 564.7)

## Chemical and Physical Properties

Polybrominated diphenyl ether mixtures (PBDEs), which are flame retardant mixtures, have a common structure of a brominated diphenyl ether molecule with one to ten bromine atoms attached, and there are up to 209 possible congeners of PBDEs.^1^ This report focuses on DE-71, a technical grade pentabromodiphenyl ether mixture containing lower molecular weight PBDEs [e.g., 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47), 2,2′,4,4′,5-pentabromodiphenyl ether (BDE-99), and 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE-153)]. Other PBDE formulations such as the octaBDE formulation (heptaBDE and octaBDE congeners, with secondary contributions by hexaBDE and nonaBDE congeners), and the decaBDE formulations [2,2′,3,3′,4,4′,5,5′,6,6′-decabromodiphenyl ether (BDE-209), and small amounts of 2,2′,3,3′,4,4′,5,5′,6-nonabromodiphenyl ether (BDE-206), 2,2′,3,3′,4,4′,5,6,6′-nonabromodiphenyl ether (BDE-207), and 2,2′,3,3′,4,5,5′,6,6′-nonabromodiphenyl ether (BDE-208)]^2^ are not discussed in this report. DE-71, a viscous sticky brown liquid, is dominated (by weight) by penta congeners with secondary contributions by tetra and hexa congeners.^2^

PBDEs are lipophilic chemicals that bioaccumulate in the environment.^1,3-5^ The DE-71 flame retardant mixture used in the studies presented in this Technical Report had approximately 42% BDE-99, 36% BDE-47, 10% 2,2′,4,4′,6-pentabromodiphenyl ether (BDE-100), 4% 2,2′,4,4′,5,6′-hexabromodiphenyl ether (BDE-154), and 3% BDE-153 (Appendix J). Chemical and physical properties of these congeners are listed in Table 1 and structures are presented in Figure 2.

Table 1 Chemical and Physical Properties of Selected Polybrominated Diphenyl Ether Congeners Composing DE-71

| BDE-47^a^ | BDE-99^b^ | BDE-100^c^
Synonyms | Benzene,1,l′-oxybis [2,4-dibromo-]; 2,2′,4,4′-tetrabromodiphenyl ether | Benzene, l,2,4-tribromo-5-(2,4- dibromophenoxy)-;2,2′,4,4′,5-pentabromodiphenyl ether | 2,2′,4,4′,6-pentabromodiphenyl ether; 1,3,5-tribromo-2-(2,4-dibronphenoxy)-benzene
CASRN | 5436-43-1 | 60348-60-9 | 189084-64-8
Chemical formula | C_12_H_6_Br_4_O | ^C^ _ ^12^ _ ^H^ _5_ ^Br^ _5_ ^O^ | C_12_H_5_Br_5_O
Molecular weight | 485.8 | 564.7 | 564.7
Vapor pressure (Pa) at 25°C | 2.5 × 10^−4^ | 5 × 10^−5^ | 2.86 × 10^−5^
Melting point (°C) | 79–82 | 93 | 102 or 110
Solubility in water (µg/L) | 11 | 2.4 | 40
Henry’s law constant (Pa m^3^ mol^−1^) at 25°C | 0.85 | 0.60 | 0.069 or 0.384
Log octanol/water partition coefficient (K_OW_) at 25°C | 6.81 | 6.5–8.4 | 6.86
Log octanol/air partition coefficient (K_OA_) at 25°C | 10.5 | 11.3 | 11.13
| BDE-153^d^ | BDE-154^c^
Synonyms | Benzene, 1,l′-oxybis-2,4,5-tribromo-; 2,2′,4,4′,5,5′-hexabromodiphenyl ether | 2,2′,4,4′,5,6′-hexabromodiphenyl ether; 1,2,3-tribromo-2-(2,4,5-tribromophenoxy)-benzene
CASRN | 68631-49-2 | 207122-15-4
Chemical formula | C_12_H_4_Br_6_O | C_12_H_4_Br_6_O
Molecular weight | 643.6 | 643.6
Vapor pressure (Pa) at 25°C | 5.8 × 10^−6^ | 3.80 × 10^−6^
Melting point (°C) | 183 | 131–132.5
Solubility in water (µg/L) | 0.9 | 8.70 × 10^−4^
Henry’s law constant (Pa m^3^ mol^−1^) at 25°C | 0.26 | 0.24
Log octanol/water partition coefficient (K_OW_) at 25°C | 7.90 | 7.39
Log octanol/air partition coefficient (K_OA_) at 25°C | 11.9 | 11.92

^a^ USEPA, 2008a.^3^

^b^ USEPA, 2008b.^4^

^c^ Mackay et al. 2006.^8^

^d^ USEPA, 2008c.^5^

Figure 2

Chemical Structures of Selected Polybrominated Diphenyl Ethers in DE-71

## Production, Use, and Human Exposure

Lower molecular weight PBDEs (primarily pentaBDEs) were marketed as mixtures under several different trade names (e.g., DE-71, Bromkal 70-5, Tardex 50).^6^ PBDEs were used as additive flame retardants often in furniture materials.^1^ Additive flame retardants are mixed into products, but they are not covalently bound to the polymers in the commercial products, and thus, can leach out into the environment.^7^

The lower molecular weight PBDE congeners contained in DE-71 (e.g., BDE-47, BDE-99, and BDE-153) were used as flame retardants in polyester foams and may leach from the foams when they are deposited at waste dumps.^9-11^ Microorganisms may dehalogenate higher molecular weight PBDEs to lower molecular weight PBDEs.^12-14^ Photolytic debromination may also occur.^15,16^

PBDEs are present in water, wildlife (e.g., fish, seals, and birds) and in humans,^9-11,17^ and in various food products including meat, poultry, and fish.^18^ Total PBDE levels in fish caught in the United States can range up to 1,250 ng/g wet weight.^19^ PBDEs are found in everyday products including butter wrappers^20^ and plastic toys.^21^ The most prevalent PBDEs found in household dust are BDE-47, BDE-99, and BDE-153.^22^ Uptake of PBDEs by plants growing near electronic waste sites has been reported.^23^ Incineration of material containing PBDEs may result in the formation of brominated dioxins and furans and contribute to ambient air exposure to the PBDEs.^24^

In a limited survey, PBDEs were found in 39% of couches purchased prior to 2005, but in only 2% of couches purchased after 2005.^25^ Other studies also present evidence that levels of PBDEs in the environment may be decreasing.^26^ The potential for PBDE exposure, especially among the young, is a concern because of the widespread occurrence of these chemicals in the environment and in human tissues.^2,27^ Exposure to the fetus and infant may occur from mother’s milk, and children may be exposed to PBDEs adsorbed in house dust.^22,28-31^ Stapleton et al.^32^ found that flame retardants are often found on children’s hands, and hand to mouth behavior in children can be an important route of flame retardant exposure. BDE-47 is usually the most prevalent PBDE congener found in human tissue.^33-37^ The higher blood PBDE concentrations in children (up to two to fivefold higher than that of their parents exposed to the same indoor concentrations) is thought to be due to higher rates of dust ingestion,^38^ higher PBDE dietary intake due to higher food intake per kilogram of body weight, and high levels of PBDEs in human milk.^31^

The adult intake of total PBDEs (including higher molecular weight PBDEs such as BDE-209) in the United States is estimated to be 7.1 ng/kg body weight per day, resulting in a body burden of 31 ng/g lipid.^2^ Food is estimated to account for 10% of the total PBDE exposure in adults, and the remaining 90% of exposure is from household dust. Children’s PBDE intakes are estimated to be 47.2 ng/kg per day for ages 1 to 5, 13.0 ng/kg per day for ages 6 to 11, and 8.3 ng/kg per day for ages 12 to 19. Infant PBDE daily intakes were estimated to be up to 141 ng/kg per day in part due to ingestion of PBDEs from mother’s milk.

Levels of PBDEs in human serum/urine (including BDE-47, BDE-99, and BDE-153) are currently being followed as part of the National Health and Nutrition Examination Survey (NHANES).^39^ Concentrations of PBDEs in sera collected in 2006 were particularly high in certain occupational groups such as carpet installers (e.g., BDE-47 100 ng/g lipid in sera) and foam recyclers (e.g., 78 ng/g lipid in sera).^40^ PBDE levels were also found to be high in gymnasts (sera collected in 2012).^41^ Daily intake of total PBDEs near electronic waste sites may be higher than in the general population. In a recent study in Asia, the total daily intake of PBDEs near electronic waste sites was 1,671 ng/day for adults (approximately 24 ng/kg body weight for a 70 kg man) as well as a daily intake of up to 24 ng/day of BDE-47 in a toddler.^42^ Another study estimated that the total daily PBDE intake near electronic waste sites was 130 ng/kg body weight in adults, and 614 ng/kg body weight in children.^43^ Total daily adult median intakes of DE-71 constituents, BDE-47, BDE-99, and BDE-153 were estimated at 14.3, 6.2, and 12.5 ng/kg body weight per day, respectively, but could range up to 73 to 84 ng/kg body weight per day. Total daily intakes of BDE-47, BDE-99, and BDE-153 for children were 53, 25, and 51 ng/kg body weight per day, respectively (ranging up to 263, 164, and 291 ng/kg per day, respectively).^43^

An analysis of NHANES data compared PBDE concentrations in pooled sera collected from 2005 to 2006 and 2007 to 2008 versus PBDE levels in individual sera collected from 2003 to 2004 to determine if concentrations have changed over time; even though PBDEs started to be phased out in 2004, no reduction in PBDE sera concentrations were detected by 2008.^44^ The mean serum concentrations (ng/g lipid) for BDE-47, BDE-85, BDE-99, BDE-100, and BDE-153 in the 2007 to 2008 NHANES data for people 12 to 19 years of age were 35.9 ± 8.0, 0.8 ± 0.2, 8.5 ± 2.5, 6.7 ± 1.6, and 12.0 ± 3.3, respectively. The mean serum concentrations (ng/g lipid) for BDE-47, BDE-85, BDE-99, BDE-100, and BDE-153 in people greater than 60 years of age were 39.9 ± 10.6, 0.9 ± 0.2, 8.7 ± 2.7, 8.1 ± 2.3, and 13.4 ± 3.3, respectively.^44^

## Regulatory Status

The European Union banned the marketing and use of pentaBDE in 2003.^45^ The United States manufacturers of pentaBDEs voluntarily phased out their production in 2004, and various individual states have developed regulations banning the sale of products containing pentaBDE flame retardants.^2^

Based on evidence of long-range atmospheric transport, environmental persistence, and bioaccumulation in various species including humans, PBDE congeners were added to the United Nations Economic Commission for Europe lists of persistent organic pollutants protocol.^46^ The Stockholm Convention has initiated a global effort with more than 172 countries to manage the use and disposal of material containing persistent organic chemicals including the PBDEs.^47,48^

The Agency for Toxic Substances and Disease Registry^1^ has established minimal risk levels (MRLs) for pentaPBDEs. An MRL is an estimate of the daily human exposure to a hazardous substance that is likely to be without appreciable risk of adverse noncancer health effects over a specified duration of exposure. The pentaBDE acute (1 to 14 days) oral MRL is 0.03 mg/kg body weight per day based on endocrine disruption activity. The pentaBDE oral intermediate (14 to 364 days) MRL is 0.007 mg/kg based on liver toxicity in a 90-day oral exposure study in rats. In 2014, ATSDR began a rereview of the pentaBDE MRLs.

A reference dose (RfD) is the United States Environmental Protection Agency’s (USEPA) maximum acceptable oral dose of a toxic substance based upon critical toxic effects. RfDs for BDE-47, BDE-99, and BDE-153 are based on altered locomotor activity habituation in mice at 4 months of age following an acute oral dose of the PBDE congener on postnatal day 10.^3-5^ The RfD for BDE-47 of 1.17 × 10^−4^ mg/kg per day (0.1 μg/kg per day) is based upon a point of departure of 0.35 mg/kg for neurotoxicity in mice.^3,49^ The RfD for BDE-99 of 0.1 μg/kg per day was derived from a benchmark dose of 0.29 mg/kg per day, based on the effects of BDE-99 on spontaneous motor behavior in mice.^4,50,51^ The RfD for BDE-153 of 1.5 × 10^−4^ mg/kg day (0.2 μg/kg per day) was based on a no-observed-adverse-effect-level of 0.45 mg/kg for neurotoxicity in mice.^5,52^

The USEPA^53^ proposed to designate the processing of six PBDEs (tetraBDE, pentaBDE, hexaBDE, heptaBDE, octaBDE, and nonaBDE), or any combination of these chemical substances resulting from a chemical reaction, as a significant new use; designating manufacturing, importing, and processing of a seventh PBDE, decaBDE for any use that is not ongoing after December 31, 2013. Beginning January 2014, the state of California no longer required flame retardants to be incorporated into most furniture, or baby and infant products.^54^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Absorption, distribution, metabolism, and excretion studies have usually been done on individual PBDE congeners, not on the DE-71 mixture. The disposition and metabolism of several congeners in DE-71 has been reported in rodents.^55-66^ BDE-47, BDE-99, and BDE-153 are the most well studied of the congeners with some information also available for BDE-100 and BDE-154. However, very little information is available for other PBDE congeners in DE-71, which include two triBDEs (BDE-17 and BDE-28), a tetraBDE (BDE-66), a pentaBDE (BDE-85), a hexaBDE (BDE-138), and a heptaBDE (BDE-183), together contributing less than 4% of the total peak area. The disposition and metabolism data from these studies are in general agreement and some key studies are highlighted below.

Staskal et al.^65^ reported the effect of BDE-47 exposure in female C57BL/6 mice. Following a single oral dose (between 0.1 and 100 mg/kg) or an intratracheal dose (1 mg/kg), over 80% of the [^14^C]BDE-47 dose was absorbed whereas approximately 62% of the dose was absorbed following dermal application (1 mg/kg). Radioactivity was distributed to tissues with the proportion of dose reaching the tissues dependent on the lipid content; the highest dose was observed in adipose (8% to 14%), with liver, skin, and muscle containing up to 3%. Repeated exposure to 1 mg/kg [^14^C]BDE-47 for 10 days resulted in a higher concentration remaining in adipose tissue, suggesting its potential for bioaccumulation.^64^ Following a single oral dose, the radioactivity was rapidly excreted in urine and feces totaling 65% to 81% of the administered dose.^65^ The urinary excretion was dose-dependent with 40%, 38%, 33%, and 14% of 0.1, 1.0, 10, and 100 mg/kg excreted at the end of 5 days, with parent BDE-47 detected as the major peak in urine. BDE-47 was eliminated in female mice in a biphasic pattern with an estimated whole body terminal half-life of 23 days and estimated terminal half-lives for tissues of 6 to13 days.^65^

Disposition of multiple PBDE congeners was compared following a single 1 mg/kg intravenous dose of [^14^C]-labeled BDE-47 (2.1 µmol/kg), BDE-99 (1.9 µmol/kg), BDE-100 (µmol/kg), or BDE-153 (1.8 µmol/kg) in female C57BL/6 mice.^66^ Following administration, congeners were distributed with similar patterns to lipophilic tissues. The percent radioactivity in tissues examined 5 days following the dose administration were 26%, 39%, 55%, and 75% for BDE-47, BDE-99, BDE-100, and BDE-153, respectively, and were inversely related to excretion rates, demonstrating that the bromine substitution in these congeners played a role in disposition.

In a study where the disposition of BDE-47 was investigated in different stages of development in mice following gavage administration, the authors demonstrated that the pattern of disposition was similar, however, the concentration of BDE-47 was higher in pups compared to adults, suggesting the reduced capacity in pups to metabolize and excrete PBDEs.^63^

In a series of comparative studies, [14C]-labeled doses (0.1 to 1,000 µmol/kg; range of 0.05 to 640 mg/kg) of BDE-47, BDE-99, and BDE-153 were rapidly, but not completely, absorbed in male and female F344 rats and B6C3F1 mice following gavage administration.^55,61,62^ Of the three congeners, BDE-153 was the least absorbed (70% of the total dose in rats and mice) and BDE-99 was absorbed to the greatest extent (85% of the total dose in rats and mice). Similar to studies by Staskal et al.^63-66^ in mice, the radioactivity was distributed to all assayed tissues with the adipose tissue being the major depot for all three congeners; up to 40% of the total dose of BDE-47 was observed in female rats 24 hours after administration. Distribution of radioactivity to adipose and other tissues was dose proportional up to the highest doses administered for BDE-153 (100 µmol/kg) and BDE-47 and BDE-99 (1,000 µmol/kg). Most of the radioactivity in tissues consisted of parent material and was persistent over time, resulting in long elimination half-lives. These half-lives, likely representing elimination from lipid, are higher with increasing number of bromines (BDE-153>BDE-99>BDE-47) and generally followed log Kow measurements.^3,67^ Similar to earlier reported studies,^64^ the PBDEs accumulated in all assayed tissues following repeated dosing.^55,61,62^ The most prominent accumulation was observed in adipose, adrenal gland, skin, and thyroid gland following repeated doses of 0.1 and/or 1 µmol/kg BDE-47, BDE-99, or BDE-153.^62^ BDE-47 accumulated in the adipose tissue to the greatest extent when administered to male rats in an equimolar mixture (1 µmol/kg each) of the three congeners.^62^ Relative accumulation in the liver was greatest for BDE-153. Congener-specific differences in initial concentrations of radioactivity in tissues in the rat correlated primarily to differences in the extent of metabolism prior to deposition in lipid.^55,61,62^ Similar to observations by previous investigators, the major tissue depot for PBDE congeners in mice was adipose tissue; doses were persistent and accumulating in tissues.

Some species differences in the excretion of PBDE congeners have been reported in rodents. The most striking difference was in the amounts of radioactivity excreted in the urine of PBDE-treated animals.^55,60-62^ Following gavage administration of 30 µmol/kg of [14C]BDE-47 in Sprague Dawley rats, up to 0.5% of the dose was excreted in urine, whereas C57B1 mice excreted up to 20% of the administered dose in urine.^60^ Similarly, approximately 2% of a dose of 1 µmol/kg of BDE-47 or BDE-99 was excreted in the urine of rats within 24 hours after gavage administration, almost all as metabolites.^55,61^ In contrast, up to 40% of a BDE-47 dose or 10% of a BDE-99 dose (both 1 µmol/kg) was excreted unchanged in urine of mice. The difference was attributable to the affinity of the two congeners for a mouse-specific protein identified as the m-MUP-1 isoform.^66,68^ Consequently, the internal dose of BDE-47, and to a lesser extent BDE-99, was lower in mice than in rats receiving a comparable dose of either congener.^55,61^ BDE-153 had little apparent affinity for the carrier protein, as demonstrated by only up to 1% of the congener being excreted in urine of mice within 24 hours of dosing.^62^

The metabolism of the PBDE congeners in rodents appears to be similar.^55,60-62,69^ Following a single gavage dose, BDE-99 was metabolized to a greater extent than BDE-47 whereas BDE-153 was poorly metabolized.^55,62^ Repeated dosing resulted in increased metabolism of BDE-47 and BDE-99 but had little effect on BDE-153 metabolism. BDE-47 and BDE-99 appear to induce their own metabolism via increased expression of CYPs, and it is probable that concurrent exposure to BDE-153 contributes to this induction.^62,70^ BDE-47- and BDE-99-derived metabolites isolated from bile consisted mostly of hydroxylated and conjugated species arising through formation of arene oxides, with a loss of bromine in some cases (Figure 3). Other metabolism studies of BDE-47 and BDE-99 in rats showed similar results.^59,60,69,71,72^ A minor amount of BDE-47- and BDE-99-derived radioactivity was eliminated in urine of rats as catechols and conjugated tribromophenols, both arising from the cleavage of the ether linkage.^55,61,69^ Sufficient information on the metabolites of BDE-153 is not available in the literature.

Figure 3

Possible Pathways of Metabolism of Tetra-hexabromo Diphenyl Ethers in Rodents

Abbreviations: GST = glutathione transferases, P450s = cytochromes P450, SULT = sulfotransferases, UGT = UDP-glucuronosyltransferases, n = 2 or 3.

Adapted from Sanders et al.^61,62^; Chen et al.^55^; Staskal et al.^64^; Hakk et al.^57,58^

Some information on the disposition and metabolism of other PBDEs found in DE-71, such as BDE-100 and BDE-154, following gavage administration is available in the literature. The pentaBDE congener, BDE-100, was readily absorbed following oral administration of [14C]-labeled doses of 4.1 mg/kg to male Sprague Dawley rats.^57^ As with the congeners described above, the radiolabel was deposited into lipid and was persistent in tissues. Metabolites in bile and/or feces were identified as isomers of mono or dihydroxy tetraBDEs. Conjugated metabolites were suspected but were not confirmed. A second hexaBDE, BDE-154, in similar abundance to that of BDE-153 in DE-71, was rapidly absorbed and distributed to tissues following gavage administration of 1.9 mg/kg to male Sprague Dawley rats.^58^ BDE-154 was less bioaccumulative than BDE-153, and as with BDE-47 versus BDE-99, this observation appears to correlate to differences in the extent of metabolism. The dose was primarily excreted in feces, but in contrast to BDE-153, a large portion of the excreted radiolabel was in the form of metabolites, including multiple isomers of mono and dihydroxylated tetra, penta, and hexaBDEs.

Although pathways of metabolism, including hydroxylation, debromination, cleavage of the ether linkage, and conjugation (Figure 3), may be shared among these congeners, the number and substitution pattern of bromines on each phenyl ring influences the extent of metabolism and disposition and the potential for enzyme induction of the individual congeners. Several studies have shown that PBDEs have the potential to induce cytochrome P450s (CYPs).^55,62,70,73,74^ Studies conducted in male F344 rats by Sanders et al.^70^ showed that DE-71 and its individual congeners, BDE-47, BDE-99, and BDE-153 upregulated expression of CYP2B and CYP3B in a phenobarbital-like manner. The accompanying disposition and metabolism studies for BDE-47 and BDE-99 indicated that expression of the associated proteins increased, resulting in auto induction of metabolism (the congeners are inducers as well as substrates for the enzymes).^55,61^ In contrast, BDE-153 upregulated the genes to the greatest extent and with similar potency as PCB-153, but appeared to be a poor substrate for the CYPs.^62^

### Humans

Humans absorb specific PBDE congeners of DE-71 mixtures from the environment as evidenced by concentrations detected in tissues and fluids of populations living in highly populated as well as remote areas.^75-78^ As with rodents, the major depot of lower molecular weight PBDEs is in lipid, particularly in adipose tissue.^33^ These PDBEs are persistent in humans with congener-specific half-lives ranging from months to years.^2,27,79^ The PBDE congeners most often found in breast adipose tissue in California women include BDE-47, BDE-99, BDE-153, and BDE-154, and the mean levels of these congeners in adipose tissue were reported as 86, 35, 20, and 3 ng/g lipid, respectively.^80^ PBDE constituents of DE-71 were also found in maternal and cord blood^81-83^; median cord blood concentrations of BDE-47, BDE-99, and BDE-100 were reported to be 11.2, 3.2, and 1.4 ng/g lipid, respectively.^84^

PBDE congeners may be hydroxylated when incubated with human microsomes or hepatocytes.^85-89^ This activity appears to be mediated primarily by CYP2B6.^85,87^ Further, hydroxylated PBDEs attributable to exposure to tetra-hexaBDEs have been detected in human serum including that obtained from maternal and cord blood in pregnant women.^90,91^ Concentrations of hydroxylated BDE-47 and BDE-99 were higher in cord blood than in maternal blood in work conducted by Chen et al.^92^

BDE-47 and BDE-99, but not BDE-153, were metabolized to hydroxylated species by human microsomes^88^; a dihydroxylated metabolite and 2,4-dibromobenzene were detected after incubation with BDE-47. BDE-99 exposure yielded a dihydroxylated metabolite, 2,4,5-tribromophenol, and 1,3-dibromobenzene. The presence of tribromophenol and the dibromobenzenes in these studies indicated that, as in rodents, cleavage of the ether linkage of tetra and pentaBDEs is possible in humans. Additional hydroxylated metabolites for BDE-47 and BDE-99 have been described in human microsome and human hepatocyte studies.^85-87,89^ Comparative work conducted by Qiu et al.^69,91^ indicated differences in the profile of hydroxylated PBDE metabolites in humans and mice. For instance, following subcutaneous injection or oral administration of DE-71, the most abundant hydroxylated PBDE detected in plasma of mice was 4-OH-2,2′,3,4′-tetraBDE (indicating a bromine shift on BDE-47). In pregnant women, the hydroxlyated PBDEs found at the greatest concentration in blood (maternal and cord) were 5-OH BDE-47 and 5-OH BDE-99 with similar abundance. These two metabolites were not detected in DE-71-treated mice.

## Toxicity

### Experimental Animals

#### Thyroid and Liver Toxicity

Hydroxy-BDE-47 interfered with thyroxine (T_4_) for binding to the plasma transport protein transthyretin (TTR) (IC_50_, 0.18 μM).^93^ TTR binding activity was seen with BDE-47 (IC_50_ > 25 μM) but not with BDE-99.^93^ Other studies show that decreased circulating concentrations of T_4_ may be related to increased glucuronidation of T_4_ after PBDE exposure.^94^ Hydroxylated PBDEs inhibited deiodinase from converting T_4_ to triiodothyronine (T_3_).^95^ Hydroxylated PBDEs (e.g., hydroxyBDE-47) were more effective estrogen receptor agonists than the parent PBDE (e.g., BDE-47), but still had many-fold lower activity levels than estradiol.^96^ Meerts et al.^97^ compared the interaction of 17 PBDE congeners with T_4_ binding to TTR in an in vitro competitive binding assay, using human TTR and ^125^I-T_4_ as the displacement radioligand. Incubation of PBDEs with phenobarbital treated liver microsomes (mostly P450 2B enriched) in the presence of NADPH resulted in the formation of PBDE metabolites for use in the assay. PBDEs were able to compete with T_4_-TTR binding only after metabolic conversion by rat liver microsomes to hydroxylated PBDEs. The TTR binding activity of BDE-47 was greater than that of BDE-99.^97^

Hamers et al.^93^ also measured interaction of 19 PBDEs and other flame retardants with the AhR, androgen receptor (AR), progesterone receptor (PR), and estrogen receptor (ER), and if these substances inhibited estradiol sulfation by sulfotransferase. No AhR, AR, or PR agonist activity was noted for most of the chemicals tested (including BDE-47, BDE-99, and BDE-153) compared to the positive controls (2,3,7,8-tetrachlorodibenzo-p-dioxin, flutamide, or RU-486, respectively). Antagonist activity for BDEs (e.g., BDE-47) was found for the AhR (IC_50_ = 2.7 μM), AR (IC_50_ = 1 μM), and PR (IC_50_ > 15 μM) assays.

##### DE-71

DE-71 and its components (e.g., BDE-47) cause a number of toxic effects in rodents including alteration of thyroid homeostasis and liver toxicity.^1,3-5^

In a 14-day study, when male Charles River CD rats were administered 0, 50, 500, or 5,000 mg/kg DE-71 by oral gavage, decreased survival was observed in the 5,000 mg/kg group.^98^ This 14-day study was followed by a 28-day study in which male and female Charles River CD rats were exposed to DE-71 in the diet (0, 100, or 1,000 mg/kg).^98^ There were no treatment-related effects on survival or clinical signs. Liver weights were increased in 100 mg/kg females and 1,000 mg/kg males and females. Lesions included liver hypertrophy and thyroid gland hyperplasia in 100 and 1,000 mg/kg animals. In a 90-day DE-71 study in male and female CD Sprague Dawley rats administered 0, 2, 10, or 100 mg/kg by oral gavage, there were no treatment-related effects on survival or clinical signs; however, serum T_4_ concentrations were decreased, relative liver weights increased, and hepatocytomegaly and thyroid gland hyperplasia occurred in the 10 and 100 mg/kg groups.^98^

When DE-71 was administered at doses of 0, 1, 10, or 30 mg/kg by oral gavage to Long-Evans rat dams from gestational day (GD) 6 to postnatal day (PND) 21 there were no reported clinical signs and no effects on dam weight, litter size, sex ratio, or offspring viability or growth; pups did not receive direct dosing.^99^ There were decreases in serum T_4_ concentrations in the 30 mg/kg dams on GD 20 (48% decrease), in fetuses on GD 20 (at least 15% decrease), and in pups on PND 4 and PND 14 (50% and 64% maximal decreases in the 10 and 30 mg/kg groups). T_4_ rebounded by PND 36. No effect on serum T_4_ concentrations occurred at 1 mg/kg. There were no changes in serum T_3_ concentrations in dams. In 10 and 30 mg/kg pups on PNDs 4 and 14, ethoxyresorufin-O-deethylase (EROD; a marker of CYP1A1 activity) activity was increased up to 95-fold, pentoxyresorufin-O-dealkylase (PROD; a marker of CYP2B activity) activity was increased up to 26-fold, and uridine diphosphate glucuronosyl transferase (UDPGT) activity was increased up to 4.7-fold using T_4_ as the substrate for glucuronidation activities in hepatic microsomes. EROD and PROD activities were increased in 10 and 30 mg/kg dams and UDPGT activity was increased in the 30 mg/kg dams on PND 22. When 28-day-old female Long-Evans rats were administered DE-71 by oral gavage for 4 days (0.1 to 300 mg/kg) serum T_4_ was decreased a maximum of 80%.^74^ EROD and PROD liver enzyme concentration induction levels were increased up to 10- to 20-fold and up to 30- to 40-fold, respectively, in animals administered 10 mg/kg or greater. UDPGT activity was also increased. When male F344 rats were administered DE-71 (1.5, 15, or 150 mg/kg) orally on three consecutive days, liver CYP1A1, CYP2B, and CYP3A activities were increased in the 15 and 150 mg/kg groups.^70^ These three DE-71 rat studies^70,74,99^ did not include a pathology evaluation for target organ lesions.

When pregnant Long-Evans rats were administered DE-71 from GD 6 to PND 21 (0, 1.7, 10.2, or 30.6 mg/kg) serum T_4_ concentrations were decreased in the pups on PNDs 4 and 21.^100^ Liver mRNA for CYP1A1, CYP2B1, and CYP2B2, and EROD, PROD, and UDPGT activities were increased in the pups on PNDs 4 and 21. Hepatic efflux transporters Mdr1 (multidrug resistance), Mrp2 (multidrug resistance–associated protein), and Mrp3 and influx transporter Oatp1a4 mRNA expression increased in the pups on PNDs 4 and 21. All responses were reversed by PND 60.

##### BDE-47

After a 4-day exposure of C57BL/6 mice to BDE-47 (3, 10, or 100 mg/kg), serum T_4_ was decreased by 43% in 100 mg/kg mice, relative to controls, and liver (PROD) CYP2B concentrations, relative to controls, increased by 120%, 180%, and 480% in the 3, 10 and 100 mg/kg groups, respectively.^94^ Serum T_4_ was decreased in C57BL/6N mice after BDE-47 exposure (18 mg/kg for 14 days).^101^ Developmental exposure to low doses of BDE-47 resulted in changes in thyroid gland histology and morphology in rats.^102^

The BDE-47 upregulation of liver CYP2B (10 and 100 mg/kg) and CYP1A1 (100 mg/kg) after a 3-day exposure is thought to involve activation of both the constitutive activated/androstane receptor (CAR) (mouse and human) and pregnane X receptor (PXR) (human).^103^ This is based on the finding that BDE-47 increases CYP2B mRNA expression in wild mice but not in CAR knockout mice. In contrast, knocking out PXR in mice did not affect CYP2B mRNA expression related to BDE-47 exposure. However, in human primary hepatocytes, both CAR and PXR were involved in the PBDE effects on CYP2B concentrations.^103^ The authors of this work concluded that BDE-47 works primarily through the CAR receptor in mice, and through both the CAR and PXR receptors in humans.

The PBDEs (BDE-47, BDE-99, BDE-100, BDE-153, BDE-154, or BDE-183) did not induce EROD (a marker of CYP1A1 activity) in rodent hepatoma cell lines transfected with AhR.^104^ PBDEs (BDE-47,-BDE-99, BDE-100, BDE-153, BDE-154, BDE-183, or BDE-77) did not induce CYP1A1 in primary hepatocytes of the cynomolgus monkey (using EROD as a marker for CY1A).^105^

##### BDE-99

Liver CYP concentrations (1A1, 1A2, 2B1, and 2A2) were increased in Sprague Dawley rat pups on GD 20 when the dams were exposed to BDE-99 on GDs 6 to 19 (0, 0.5, 1, or 2 mg/kg).^106^ When dams were administered BDE-99 from GD 6 to PND 21 and their pups evaluated for spatial learning task in a water maze, the pups of exposed dams showed a delay in this learning task. Serum T_3_ was decreased by 14% and T_4_ was decreased by 25% in 2 mg/kg pups on PND 21.^107^ There was a decrease in genes in the AKT pathway in the liver of pups treated with BDE-99, suggesting that this PBDE induces changes in the metabolism of the pups.^108^

#### Immunotoxicity

PBDEs are reported to be immunotoxicants in rodents. When female C57Bl/6 mice were given a single oral dose of DE-71 (0.8 to 500 mg/kg) or a 14-day DE-71 exposure (250 to 1,000 mg/kg), there was a depression in an anti-sheep red blood cell response in the plaque forming cell response assay in the 1,000 mg/kg group in the 14-day exposure.^109^ There was also a treatment-related decrease in the thymus weight. There was no effect on natural killer cell activity in YAC-1 target cells.

When DE-71 was administered orally to B6C3F1 mice (0.5 to 100 mg/kg), natural killer cell activity was decreased at 100 mg/kg at the end of the treatment period. There were some decreases in splenic CD4+CD8+ cells.^110^

Recently NTP investigated the relative potency of a number of brominated dioxins and furans that are components of DE-71, with regard to their ability to suppress the humoral immune response.^111^ To assess the relative potencies of polybrominated dibenzo-p-dioxins/dibenzofurans, female B6C3F1/N mice received a single oral exposure to 2,3,7,8-tetrachlorodibenzo-p-dioxin (TCDD), 2,3,7,8-tetrabromodibenzo-furan (TBDF), 1,2,3,7,8-pentabromodibenzofuran (1PeBDF), or 2,3,4,7,8-pentabromodibenzofuran (4PeBDF). Inhibition of the IgM antibody forming cell response was measured 4 days following immunization with sheep red blood cells. The reference compound for these studies, TCDD, induced a significant reduction in the number of antigen specific antibody forming cells at doses of 0.1 μg/kg or greater. Exposure to the three dibenzofurans resulted in a reduction in the antibody response against sheep red blood cells, although to a lesser degree than TCDD. TBDF and 4PeBDF suppressed the humoral immune response at doses of 3 μg/kg or greater. 1PeBDF was less potent and suppressed the total number of antibody forming cells per spleen at doses of 30 μg/kg or greater. Taken together, these studies suggest that DE-71 and its components have potent and persistent effects on the humoral immune system. Other immune cells and processes may also be targeted to a lesser degree.

#### Neurotoxicity

##### DE-71

When 4-month-old C57BL/6 mice were administered 30 mg/kg DE-71 orally by gavage for 30 days, there was deposition of PBDE congeners (including BDE-47, BDE-99, and BDE-153) in the brains and reductions in striatal dopamine and dopamine handling, as well as reductions in the striatal dopamine transporter and VMAT2, and a significant locomotor deficit.^112^

##### BDE-47

When Sprague Dawley rats received a single oral dose (1, 5, or 10 mg/kg) of BDE-47 on PND 10, behavioral deficits in the Morris water maze were noted in all dosed groups.^113^ At 10 mg/kg, ultrastructural changes at 2 months of age were observed in the CA1 hippocampal neurons by electron microscopy. The endoplasmic reticulum and mitochondria appeared swollen and/or degranulated; and neurons had puffed periplast, dissolved cell organelles, and vacuolized mitochondria. At 2 months of age, mRNA levels for caspase 3 and caspase 12 were elevated in the hippocampus in 5 and 10 mg/kg males and females. At 10 mg/kg, mRNA levels for cytochrome C were elevated in males and mRNA levels for DAPK were decreased in females and elevated in males.

Evidence for decreased organ-to-body-weight ratios for thyroid gland and uterus and decreased T_4_ levels were seen in Sprague Dawley rats after a single oral dose (5 or 10 mg/kg) of BDE 47 on PND 10^114^. PBDE exposure to rats has also been shown to disrupt estrogen-regulating genes.^115^

Neurotoxic effects were seen in 10-day-old male NMRI mice administered a single oral dose of BDE-47 (0.7 or 10.5 mg/kg).^49^ At 2 and 4 months of age, the habituation pattern for locomotor activity in a novel environment was delayed in mice administered 10.5 mg/kg. At 5 months of age, no learning deficit was observed in the Morris water maze.

Neurotoxic effects were seen in male C57BL/6 mice administered a single 6.8 mg/kg oral dose of BDE-47 on PND 10.^116^ Hippocampal slices were prepared from the mice on PND 17 and field potentials in the CA1 hippocampal region demonstrated a deficit in long-term potentiation with BDE-47 exposure indicative of postsynaptic effects. Protein levels for the NMDA receptor subunit NR2B, AMPA receptor subunit GluR1, and phospho-alpha CaMKII were decreased in postsynaptic densities.

Male C57BL/6 mice administered a single oral dose of BDE-47 on PND 10 (1, 10, or 30 mg/kg) showed no changes in motor activity at 2 months of age; but at 4 months of age, the overall activity level was elevated in all dosed groups.^117^

PBDE neurotoxic effects occurring early may worsen as the animal ages, inducing persistent neurotoxic effects that are manifested later in life.^118^

##### BDE-99

Kuriyama et al.^119^ reported that when a single dose of BDE-99 (60 or 300 mg/kg) was given to pregnant Wistar rats on GD 6, increases in locomotor activity over a 24-hour time period on PND 34 for 300 mg/kg pups and on PND 71 for 60 and 300 mg/kg pups were observed. No changes were observed in developmental landmarks. Male offspring showed no impairment of sexual behavior. Serum T_4_ levels were decreased on PND 22.^120^

When Sprague Dawley rats received oral gavage doses of BDE-99 (0 or 2 mg/kg) from GD 6 to PND 21, maturation of negative geotaxis (position orientation) was delayed, and latency on the Morris water maze was longer in the dosed group.^121^ On PND 37, activities of superoxide dismutase and glutathione peroxidase were decreased in the hippocampus with no change observed in the cerebellum or cortex. Electron spin resonance spectra of spin adducts were increased in the hippocampus but not in the cerebellum or the cortex. Tissue levels of BDE-99 were similar across the three brain regions.

When male and female C57BL/6 mice were administered BDE-99 by oral gavage (0.4, 0.8, 4, 8, or 16 mg/kg) on PND 10, there were lower locomotor activity levels and a deficit in habituation at 4 to 16 mg/kg at 2 and 4 months of age.^50^ By 8 months of age, a lower activity level in the initial session was also observed at 0.8 mg/kg. A similar pattern was observed in female offspring. Further work by Viberg et al.^51,122^ showed decreases in nicotinic and muscarinic receptor binding in the hippocampus of adult mice exposed to BDE-99 (8 to 16 mg/kg) on PND 10.

When 10-day old male NMRI mice were given one oral dose of BDE-99 (0.8 or 12.0 mg/kg), locomotor activity level was initially lower and a deficit in habituation was observed in the 12 mg/kg dose group at 2 months of age.^49^ At 4 months of age, effects were seen in both dose groups. In the 12 mg/kg group, acquisition on the Morris water maze was not altered, but deficits were noted in performance when the mouse was required to learn on a new platform location.

When pregnant CD-1 mice received oral gavage doses of BDE-99 (0.6, 6, or 30 mg/kg) from GD 6 to PND 21 there were 15% to 20% decreases in litter size in the 6 and 30 mg/kg groups.^123^ No effects were observed on body weight, neurodevelopmental indices, ultrasonic vocalizations on PNDs 4, 8, or 12, or homing on PND 11. On PND 34, open-field activity was increased. On PND 60, habituation was diminished in the 0.6 and 6 mg/kg groups.^124,125^

BDE-99 caused adult neurotoxic effects when administered during the neonatal period coinciding with the brain growth spurt, affecting brain proteins involved with growth, differentiation, and synaptogenesis in the cortex and hippocampus (CAMKII, GAP-43, synaptophysin and tar).^126^ A review of in vitro test results shows that hydoxylated PBDEs can affect voltage-gated Ca^2+^ channels and, thus, have the potential to alter calcium homeostasis and induce changes in neurotransmitter release.^127^

##### BDE-153

When NMRI mice were administered BDE-153 orally (0, 0.45, 0.9, or 9 mg/kg) on PND 10 there was a disruption in spontaneous behavior indicated by decreased habituation and impaired learning and memory capabilities when tested in the Morris water maze (lowest-observed-effect-level of 0.9 mg/kg).^52^ A reduced density of nicotinic receptors in the hippocampus was observed at 6 months as well as decreases in locomotor activity habituation at 2, 4, and 6 months in the 9 mg/kg group. The Morris water maze test indicated learning but delayed performance in the 0.9 and 9.0 mg/kg groups.

### Humans

Human exposures to low molecular weight PBDEs have been associated with alterations in thyroid gland homeostasis with varying results among the studies reported. Different BDE congeners may have been measured and different segments of the population may have been studied in the studies described below. Increased ΣPBDE serum levels (the sum of 10 low molecular weight PBDEs measured) were associated with decreased thyroid stimulating hormone (TSH) levels (but no correlation was found for T_4_ levels) in pregnant mothers.^128^ In another study, BDE-153 was associated with decreased cord blood T_4_ levels.^129^ In contrast, in another study there were positive associations between increased PBDE serum levels (27 PBDE congeners measured) and increased serum T_4_ levels in pregnant women.^130^ The occurrence of total PBDEs, BDE-47, and hydroxylated PBDEs has been associated with increased levels of TSH in women living in California.^131^

In adult males, there is a reported association between increased T_4_ levels and increased BDE serum levels (BDE-47, BDE-99, BDE-100, and BDE-153).^132^ Elevated serum levels of TSH were seen in workers exposed to PBDEs (total serum BDEs in control 158/ng/g lipid vs 382 ng/g lipid in the “exposed” group; data not presented as individual BDE congener data) at electronic waste sites in China.^133^

## Reproductive and Developmental Toxicity

### Experimental Animals

DE-71 and congeners contained in DE-71 (e.g., BDE-47 and BDE-99) have been shown to cause reproductive and developmental toxicity.^6,134,135^ PBDEs may also cause reproductive toxicity in wildlife including fish, birds, and marine mammals.^136^

#### DE-71

In a DE-71 oral gavage study (0, 3, 30, or 60 mg/kg) in adult Wistar rats, males were exposed from PNDs 23 to 53 and females from PNDs 22 to 41.^137^ Liver to body weight ratios (at 30 and 60 mg/kg) were increased but no changes were seen in necropsy body weights. T_4_ levels were decreased by approximately 70% in females exposed to 30 and 60 mg/kg after the 20 day exposure. T_4_ levels were decreased approximately 85% and liver enzyme concentrations were increased in males exposed to 30 or 60 mg/kg for 31 days. Vaginal opening was delayed in rats exposed to 60 mg/kg (32.4 ± 4.2 days in vehicle controls versus 34.2 ± 7.3 days). Preputial separation was delayed in males by 1.7 and 2.1 days in the 30 and 60 mg/kg groups, respectively. Ventral prostate gland and seminal vesicle weights were significantly decreased in males at 60 mg/kg. Ovaries, uteri, testes, and epididymides were examined for treatment-related lesions after hematoxylin and eosin staining and none were found. However, there were treatment-related lesions in the thyroid gland consisting of decreased colloid area and increased follicular cell heights (indicative of the hypothyroid state) in 60 mg/kg females exposed for 20 days and 60 mg/kg males exposed for 31 days.

Stoker et al.^138^ examined competitive binding of DE-71, BDE-47, BDE-99, and BDE-100 with R1881 (also known as methyltrienolone, a synthetic androgen) for the androgen receptor in a rat ventral prostate cytosolic extract. DE-71 and BDE-100 both inhibited androgen receptor binding, with IC_50_s of approximately 5 μM. In addition, DE-71, BDE-100, and BDE-47 inhibited dihydrotestosterone-induced transcriptional activation.

When Long-Evans rat dams were administered DE-71 by gavage (0, 1.7, 10.2, or 30.6 mg/kg) from GD 6 to weaning (except for day of birth),^139^ there was a 5.5% (not statistically significant) decrease in anogenital distance on PND 7 in male pups from the 30.6 mg/kg group. Other findings in this dose group included an increase in the age of preputial separation attainment, and a 20% decrease in mean testosterone concentration on PND 60. In female pups, there was a reduction in mammary gland development on PND 21 in the 10.2 and 30.6 mg/kg groups.

Decreased epididymis, seminal vesicle, and prostate gland weights, as well as sperm head deformities and increased CYP17 levels were noted in male Wistar rats (7 weeks of age at start of dosing) exposed to DE-71 (0.27, 0.82, 2.47, 7.4, 22.2, 66.7, or 200 mg/kg) for 28 days; the bench mark dose for many of these effects was calculated to be 10 to 50 mg/kg.^140^

When Sprague Dawley rats were given a mixture of DE-71 and hexabromocylododecane (15:1, PBDE:HBCD) in the feed (estimated to deliver 0, 0.6, 20, or 60 mg/kg, assuming feed consumption of 80 g/kg body weight per day) 2 weeks prior to mating through GD 20, there was no effect on maternal health, litter size, or fetal viability, but the proportion of litters with fetuses that had anomalies increased (including soft tissue syndactyly and decreased ossification of the sixth sternebra) at all dose levels.^141^ The lowest dose in this study was estimated to deliver the amount of flame retardant a child would ingest, 100 mg/day.

#### BDE-47

In female offspring of Wistar rat dams administered one dose of BDE-47 (140 or 700 µg/kg) by oral gavage on GD 6 and evaluated on PND 38, there were decreases in ovarian follicle numbers and serum estradiol concentration in the 700 µg/kg group.^102^ There was no change in ovarian aromatase activity. On PND 100, degeneration of thyroid gland follicular epithelium was noted. No evidence of altered reproductive performance or teratology findings was seen when F_1_ females were mated to untreated males. When pregnant Wistar rats were given an intravenous injection of BDE-47 (0.002 or 0.2 mg/kg) on GD 15 and every fifth day until PND 20 (6 total injections), there were no effects on litter size, developmental landmarks, vaginal opening, testis descent or preputial separation.^142,143^ Locomotor activity was increased in all dosed groups on PND 20, but no effect was seen on motor coordination.^143^ The effects were observed in both male and female offspring. Total serum T_4_ levels were decreased on PND 27 in all dosed groups.^143^ Serum insulin-like growth factor 1 (IGF-1) levels were elevated on PND 27 in male offspring, but not in female offspring.^143^ After a bolus dose of glucose on PND 40 or PND 75, there were no BDE-47 related alterations in blood glucose levels.^143^

PBDE flame retardants have been reported to be ER agonists, but only at concentrations six magnitudes greater than that of the positive control, estradiol [e.g., BDE-47 (EC_50_ = 12 μM)].^93^ 6-Hydroxy-BDE-47 and BDE-47 inhibited sulfotransferase. A study using assays similar to those used by Hamers et al.^93^ showed that BDE-47 had agonist activity in the ER assay, but only at concentrations many-fold higher than that of estradiol.^144^

#### BDE-99

When Wistar rat dams were administered a single dose of BDE-99 (60 or 300 µg/kg in peanut oil) on GD 6, alterations in degenerative changes in mitochondria were noted in the ovaries of female offspring.^145^ Mating of the F_1_ females with untreated males resulted in an increased resorption rate in the dosed groups compared to controls. The same treatment protocol in male offspring showed reduced sperm and spermatid counts in the treated groups.^119^

In another study, Long-Evans rat dams were exposed to BDE-99 by subcutaneous injection (1 or 10 mg/kg) from GD 10 through 18.^115^ There were no effects on reproductive endpoints. At 120 days of age, uterine mRNA levels were extracted from female offspring, and estrogen target genes were determined by real-time polymerase chain reaction. Progesterone receptor transcript was down-regulated at both dose levels, and ERα, ERβ, and IGF-1 were upregulated at the lower dose.

When Long-Evans rat dams were exposed by subcutaneous injection to BDE-99 (1 or 10 mg/kg) from GD 10 through 18, there were decreases in the circulating sex steroids 17β-estradiol and testosterone in male offspring at weaning and in adulthood, reduction of anogenital distance, and feminization of sexually dimorphic behavior.^146^ Puberty onset was delayed at the higher dose in female offspring, and a slight acceleration in puberty onset was detected in low-dose males. The number of primordial/primary ovarian follicles was reduced in females at the lower dose, whereas the decline of secondary follicles was more pronounced at the higher dose.

Studies in the literature suggest that PBDEs weakly bind to the estrogen receptor. Other studies show that PBDE estrogenic activity may be due in part to the ability to interact with sulfotransferases, resulting in prolongation of estrogen in the circulation by inhibiting its conjugation and excretion.^5,147^

### Humans

The PBDE reproductive and developmental studies in humans reported in the literature were conducted on diverse study populations, and often did not provide enough data to quantify PBDE exposure or identify a no-effect level. Studies were often based on limited numbers of subjects.

PBDEs can pass through the placenta and may be found in umbilical cord plasma.^22,27,148^ BDE-28, BDE-47, and BDE-99 have been found in umbilical cord blood samples and BDE-47 was the most abundant congener (56 ng/g lipid).^149^ PBDE exposure to the infant may also occur from mother’s milk,^30,31^ and children may continue to be exposed to PBDEs from ingestion of house dust.^22,28,150^

Several studies suggest that in utero exposure to low molecular weight PBDEs may cause reproductive toxicity, alteration in hormone levels, or adverse effects on learning. Because of the structural similarity of PBDEs to the thyroid hormones, PBDEs (hydroxyl-PBDEs) bind to thyroid receptors α1 and β and may thus inhibit the release of TSH by the pituitary gland.^151^ This is of concern because maternal thyroid hormones play an essential role in fetal brain development.^152,153^ Hyperthyroidism during pregnancy has been linked to increased risk of miscarriage, premature birth, and intrauterine growth retardation.^154,155^

Total PBDE exposure and BDE-99 exposure have been associated with lower birth weight.^149,156^ A positive association between the amount of 12 congeners of PBDE in milk and lower birth weight, length, and head and chest circumference in newborns was reported (after adjusting for maternal age, prepregnant body mass index, and parity).^157^ PBDE exposure (BDE-47, BDE-99, BDE-100, and BDE-153) was associated with delayed time to pregnancy in a group of women enrolled in the Center for the Health Assessment of Mothers and Children of Salinas (CHAMACOS) study.^158^

Children exposed prenatally to PBDEs (BDE-47, BDE-99, BDE-100, BDE-153, and BDE-154) may have altered learning parameters when these endpoints are measured at 6 years of age (although the children may have been exposed to a number of other organohalogen compounds).^159^ In the CHAMACOS study, maternal PBDE levels (BDE-47, BDE-99, BDE-100, and BDE-153) were associated with impaired attention in children at 5 years of age, lower scores on an IQ test at 5 and 7 years of age, and poorer fine motor coordination at 5 and 7 years of age.^160^ Another study reported that children prenatally exposed to PBDEs [mother’s cord blood levels of BDE-47, median 11.2 ng/g lipid (maximum 613), BDE-99, median 3.2 ng/g lipid (maximum 20), or BDE-100, median 1.4 ng/g lipid (maximum 72)] scored lower on tests of mental and physical development at 12 through 48 and 72 months of age when including endpoints for verbal and performance IQ.^84^ Postnatal exposure to BDE-47 was related to an increased risk of symptoms on the attention deficit subscale of ADHD symptoms, but not to hyperactivity symptoms.^161^ The odds ratio for a low cognitive score was observed among children in Taiwan (8 to 12 months of age) from mothers with a higher PBDE exposure (as measured in cord blood).^162^ Newborns body mass index was lower in mothers with higher levels of PBDEs (BDE-28, BDE-47, BDE-99, BDE-100, and BDE-153) in a study conducted in Shanghai.^163^ Birth weights were lower for infants whose mothers had higher PBDE (BDE-47, BDE-99, BDE-100) serum levels (measured at the 26th week of pregnancy) in the CHAMACOS study.^164^

In a prospective birth cohort study, BDE-47 maternal serum concentration was measured at 16 weeks of gestation.^165^ There was an association between a 4.5 point decrease in IQ and hyperactivity scores in 5-year-olds (but not in children 1 to 3 years of age) whose mothers had BDE-47 levels 10-fold higher than the geometric mean of 20.1 ng/g lipid.

The concentration of PBDE (sum of BDE-47, BDE-153, BDE-99, BDE-100, BDE-28, BDE-66, and BDE-154) in breast milk was 4.16 ng/g fat in mothers of boys with cryptorchidism compared with 3.16 ng/g fat in mothers of boys without cryptorchidism.^166^ In this study, the concentrations of BDE-47, BDE-100, and BDE-154 were positively correlated with serum LH values. BDE-154 exposure as measured in maternal blood correlated with decreased FSH levels in boys at 3 months of age,^167^ and BDE-47 and BDE-100 exposures have been correlated with decreases in sperm quality.^168^

Data on the effects of PBDE exposure in men are limited. In one group of men in Massachusetts, an exposure to pentaBDEs (BDE-47, BDE-99, BDE-100) in dust above a mean level of approximately 2,000 ng/g was associated with a 3.6% increase in T_4_, a 5.4% increase in T_3_, a 17% increase in estradiol, a 16.8% increase in sex hormone binding globulin, and a 20% decrease in follicle stimulating hormone serum levels.^169^ In a study in men between the ages of 18 and 54, there was an association between increased PBDE (BDE-47, BDE-99, BDE-100) levels in house dust and a decrease in testosterone levels.^170^

## Carcinogenicity

### Experimental Animals

No studies were found in the literature that evaluated the carcinogenic potential of DE-71 in rodent models.

### Humans

No epidemiology studies reported in the literature provided a definitive understanding of the carcinogenic potential of PBDE exposures in humans. One Swedish case-control study found higher values of PBDEs (sum of BDE-47, BDE-99, and BDE-153) in blood samples from mothers of young men with testicular cancer than in age-matched controls.^171^ Study subjects were also exposed to other persistent organic chemicals and a definitive link between the cancer and PBDE exposure could not be made.

## Genetic Toxicity

There is little published genotoxicity data for DE-71. DE-71 (technical grade) was tested for mutagenicity in several strains of Salmonella typhimurium (TA100, TA98, TA1535, and TA1537) with and without hamster or rat liver S9 mix up to a high concentration of 10,000 µg/plate, and no mutagenic activity was observed in any strain.^172^ DE-71 (312 to 1,250 mg/kg per day) was administered to male B6C3F1 mice by gavage once daily for 3 days, and 24 hours after the third treatment, the frequency of micronucleated immature erythrocytes was determined in peripheral blood using flow cytometry and in bone marrow using slide-based data acquisition methods.^173^ No increases in the frequencies of micronucleated cells were seen in these mice in either bone marrow or peripheral blood samples. The only other information on the genotoxicity of DE-71 is from an industry study cited by the European Chemicals Bureau^174^ that reported negative results with DE-71 in a cytogenetic assay conducted in human lymphocytes (Existing Substances Regulation 793/93/EEC, 2000).

Three related bromodiphenyl ethers, BDE-47, BDE-99, and BDE-153, all of which are components of DE-71, have undergone in vitro testing in the comet assay and the micronucleus assay in human cell lines. Overall, the results of these assays in a variety of different cell lines indicate that BDE-47, in the absence of S9 metabolic activation enzymes, is capable of inducing DNA damage at non-cytotoxic doses, possibly by increasing the formation of reactive oxygen species.

In one study, human SK-N-MC neuroblastoma cells were exposed to BDE-47 at concentrations of 0, 5, 10, or 20 µM for 4 or 24 hours and DNA damage was assessed using the comet assay without S9 mix.^175^ A significant, dose-dependent increase in DNA damage was observed after 4 and 24 hours of exposure to BDE-47, with an approximately fivefold increase in DNA damage seen at the highest concentration in the 4-hour exposure study. Cell viability was approximately 90% or greater for all exposures.

In another study, human SH-SY5Y neuroblastoma cells were exposed to BDE-47 at concentrations of 1, 2, 4, or 8 µg/mL for 24 hours and assessed for DNA damage in the comet assay without S9 mix.^176^ A significant increase in DNA damage was detected only in cells exposed to 8 µg/mL BDE-47, a concentration that was cytotoxic to SH-SY5Y cells, with approximately 60% of cells surviving at that dose. In addition, increased production of reactive oxygen species was detected in cells exposed to 2, 4, or 8 µg/mL BDE-47, detected by the dichloro-dihydro-fluorescein diacetate (DCFH-DA) assay. A subsequent study by this same group reported exposing SH-SY5Y cells to 2, 4, or 8 μM BDE-47 or 5 μM BDE-153 for 24 hours and assessing them for DNA damage in the comet assay without S9 mix.^177^ BDE-153 produced a small but significant increase in DNA damage. BDE-47 (4 or 8 μM) produced small but significant increases in DNA damage. Coexposure of BDE-47 (8 μM) with BDE-153 (5 μM) was suggestive of an additive increase in DNA damage.

One additional report of comet assay results with SH-SY5Y cells exposed to BDE-47 (1, 5, or 10 µM for 24 hours) showed a significant increase in DNA damage at the high dose of 10 μM along with significant increases in 8-oxo-7,8-dihydroguanine, which were reduced by coexposure with 100 μM N-acetylcysteine, an antioxidant.^178^ Cell viability was not evaluated in these experiments. The experiments by Gao et al.^178^ were performed without S9 mix.

BDE-153, at a concentration of 5 µM for 24 hours, did not induce DNA damage in SH-SY5Y cells as measured by the comet assay and no additive or synergistic increases in DNA damage were seen with coexposure of SH-SY5Y cells to 5 µM BDE-153 and 10 µM BDE-47 compared to 10 μM BDE-47 alone,^178^ in contrast to the results reported by He et al.^177^

Human SH-SY5Y neuroblastoma cells were exposed to BDE-47 at concentrations of 1, 2, 4, or 8 µg/mL for 24 hours and assessed for chromosomal damage using the cytokinesis block micronucleus (CBMN) assay.^176^ Cells were exposed to 1, 2, or 4 µg/mL BDE-47 for 24 hours and 1,000 binucleated cells were scored per treatment for micronuclei. A small but statistically significant increase in the frequency of micronuclei was detected in cells exposed to 2 or 4 µg/mL BDE-47. In a second study, SH-SY5Y cells were exposed to 2, 4, or 8 µM BDE-47 for 24 hours and a small but significant increase in micronucleus frequency was reported for cells exposed to 4 or 8 µM BDE-47.^177^ A slight but significant increase in micronucleus frequency was reported for cells exposed to 5 µM BDE-153. Cells coexposed to 2, 4, or 8 µM BDE-47 and 5 µM BDE-153 exhibited greater frequencies of micronuclei than either BDE alone, but the increased micronucleus frequencies were not additive or synergistic.

Human MCF-7 breast carcinoma cells were exposed to BDE-47, BDE-99, or BDE-153 at concentrations of 0.01, 0.1, or 1 nM for 24 hours without S9 mix and were assessed for frequency of micronuclei using the CBMN assay.^179^ Small but significant increases in the frequencies of micronuclei were detected in cells exposed to 0.1 nM or 1 nM BDE-47 or 1 nM BDE-99. In cells exposed to 1 nM BDE-153, the micronucleus frequency was increased in one set of experiments but not in another.^179^

6-hydroxylated-BDE-47 and 6-methoxylated-BDE-47 are metabolites of BDE-47. The ability of these compounds to induce DNA damage was tested in human HepG2 hepatoma cells using the comet assay and the micronucleus assay.^180^ Cells were exposed for 24 hours to either compound at concentrations of 0.1, 0.2, 0.5, 1, 2, or 5 μM. Small but statistically significant increases in DNA damage were reported in the comet assay at concentrations of 1 μM and greater for both compounds. Both compounds also produced small but significant increases in the number of micronucleated cells per 1,000 cells. The formation of reactive oxygen species, as detected by the DCFH-DA assay, increased with exposure to 6-hydroxylated-BDE-47 (0.1, 0.5, and 2 μM) and 6-methoxylated-BDE-47 (2 μM).

BDE-47, 6-hydroxylated BDE-47, and BDE-99 were tested over a concentration range of 25 to 400 µg/L for ability to induce DNA damage in a differential cytotoxicity assay using wild-type chicken B-lymphoma DT40 cells and isogenic mutant clones deficient for various DNA repair genes (POLβ, XPA, RAD54, KU70, or REV3).^181^ The authors reported that BDE-47 demonstrated enhanced cytotoxicity in POLβ −/− and REV3 −/− clones, and this effect was more pronounced with 6-hydroxylated-BDE47. BDE-99 showed little evidence of cytotoxicity in DNA-repair deficient clones or wild-type DT40 cells. POLβ is a polymerase that is recruited to complete the base excision repair pathway, which is the primary pathway for removing oxidized bases from DNA, and REV3 is a translesion polymerase that allows bypass of chemically modified DNA bases, including oxidized bases. Ji et al.^181^ also showed that coexposing cells to BDE-47 or 6-OH-BDE-47 with N-acetylcarnitine, a scavenger of reactive oxygen species, reduced the cytotoxicity of both chemicals in wild-type and in POLβ −/− and REV3 −/− DT40 cells. These results suggest that BDE-47 and its metabolite, 6-hydroxy-BDE-47, induce DNA damage, possibly by generating reactive oxygen species.

Results of an in vivo comet assay in male rats revealed that the DNA of sperm was not damaged after dietary exposure for 70 days to a mixture of brominated flame retardants that contained DE-71 in addition to DE-79, decaBDE-209, and hexabromocyclododecane (0.02, 0.2, 2.0, or 20 mg/kg/day).^182^

## Study Rationale

The California Office of Environmental Health Hazard Assessment nominated individual PBDE congeners for toxicity and carcinogenicity study (e.g., BDE-47, BDE-99, and BDE-153) because they were considered a health risk and have been found in human and animal tissue in the United States. Because the individual PBDE congeners were not available in sufficient amounts, NTP conducted toxicity and carcinogenicity studies of DE-71 (a technical grade mixture that contained BDE-47, BDE-99, and BDE-153) in rats and mice to investigate the toxic and carcinogenic potential of the pentaPBDE formulation (DE-71).