# Appendix N Evaluation of Hras and Ctnnb1 Mutations in Hepatocellular Tumors from Wistar Han Rats and B6C3F1/N Mice Chronically Exposed to DE-71

## N.1 Introduction

Evaluation of genetic mutations in cancer genes from hepatocellular carcinomas that arise either spontaneously or due to chemical exposure can provide some insight into the mechanisms of chemical-induced carcinogenesis. Previous studies have shown that Ctnnb1 (beta-catenin) mutations and Hras mutations are common in liver cancers.^283-285^ Examination of genetic mutations in the hepatocellular tumors in rats and mice resulting from chronic DE-71 exposure might provide some understanding of DE-71-induced hepatocellular tumorigenesis.^286^

## N.2 Materials and Methods

### N.2.1 Animals and Tissue Sampling

Hepatocellular tumors as well as normal liver samples from rats and mice were obtained from the current DE-71 chronic bioassays. Male and female Wistar Han [Crl:WI(Han)] rats were administered 0, 3, 15, or 50 mg/kg body weight per day and male and female B6C3F1/N mice were administered 0, 3, 30, or 100 mg/kg per day by gavage 5 days per week for 2 years. At necropsy, hepatocellular tumors were fixed in 10% neutral buffered formalin for 18 to 24 hours, and then transferred to 70% ethanol and processed into paraffin blocks, sectioned, and stained with hematoxylin and eosin (H&E) for microscopic analysis. The formalin-fixed paraffin-embedded (FFPE) normal liver tissue and liver tumors representative of spontaneous and DE-71-induced hepatocellular tumors were used for mutation analyses. For rats, due to the paucity of hepatocellular carcinomas, both hepatocellular adenomas (n = 33) and carcinomas (n = 7) were used for mutation analysis. However, for mice, only hepatocellular carcinomas (n = 79) were used for mutation analysis. The hepatocellular tumors chosen for molecular biology analysis were based on their overall size and viability (minimal to no necrosis or hemorrhage observed microscopically) in order to maximize the amount and quality of DNA obtained from FFPE sections. DNA quality was measured using a NanoDrop^®^ spectrophotometer (Thermo Fischer Scientific, Inc., Wilmington, DE) to calculate the ratio of absorbances at 260 and 280 nm, and DNA samples with a purity range of 1.7 to 2.0 were used for analysis. Samples falling outside of this range were reisolated from FFPE sections until a suitable purity measurement was obtained, or were discarded.

### N.2.2 DNA Extraction, Polymerase Chain Reaction (PCR), Autosequencing, and Mutation Analysis

Hepatocellular tumors representing all DE-71-dosed groups (35 from Wistar Han rats and 62 from B6C3F1/N mice) and spontaneous hepatocellular tumors (5 from Wistar Han rats and 17 from B6C3F1/N mice) from vehicle controls were evaluated for hot-spot mutations in Hras and Ctnnb1 genes that are relevant in human hepatocellular carcinogenesis. In addition, age-matched non-tumor livers from rats (n = 10) and mice (n = 8) were also analyzed. FFPE sections at 10-micron thickness were collected into screw top tubes for DNA extraction. DNA was isolated from these FFPE-dissected tissue sections with a DNeasy^®^ Blood and Tissue Kit (QIAGEN, Valencia, CA). Amplification reactions were carried out by semi-nested PCR using primer sets designed for Hras and Ctnnb1 genes for rats (Table N-1) and mice (Table N-2). Controls lacking DNA were run with all sets of reactions. PCR products were purified using a QIAquick^®^ Gel Extraction Kit (QIAGEN). The purified PCR products were cycled with Terminal Ready Reaction Mix-BigDye^®^ (PerkinElmer Applied Biosystems, Foster City, CA), and the extension products were purified with DyeEx 2.0 Spin Kit (QIAGEN). The lyophilized PCR products were sequenced with an automatic sequencer (PerkinElmer Applied Biosystems ABI Model 3100). The resulting electropherograms were compared to identify mutations in hepatocellular adenomas and carcinomas that either arose spontaneously or were due to DE-71 administration. The mutations were confirmed by sequencing with both forward and reverse primers, and the positive mutations were verified by repeat analysis, starting from amplification of the original DNA extracts.

### N.2.3 Statistical Analysis of Mutation Incidences in Hepatocellular Tumors

To compare total mutation incidences in each dosed group to the incidences in the vehicle control groups, one-sided Fisher exact tests were used. Exact one-sided Cochran-Armitage trend tests were used to test for dose-related trends in the incidences of mutations across all dose groups.

## N.3 Results

Hras mutations in rodent hepatocellular carcinomas are commonly observed within codon 61.^284^ However, in this study, the rat hepatocellular tumors resulting from chronic DE-71 exposure demonstrated mutations exclusively within codon 60 [20% (7/35); Table N-3]. Interestingly, all the mutations were the same G to A transition (Gly to Asp). Ctnnb1 mutations on the other hand were fewer [11% (4/35)], more diverse, identified between codons 33 to 40, and consisted of transitions and transversions. No Hras or Ctnnb1 mutations were noted in the spontaneous hepatocellular adenomas in rats. There were no differences in the incidences of mutations between male and female rats (data not presented) and hence the combined data from both male and female rats are presented in Table N-3.

In the mouse hepatocellular carcinomas, the incidences of Hras mutations were low [10% (6/62)] and were located within codon 61 mainly C to A or A to T transversions (Table N-4). However, there were no significant differences in the incidences of Hras mutations or the mutation spectra between hepatocellular carcinomas occurring spontaneously or resulting from chronic treatment with DE-71. Conversely, statistically significant increased incidences of Ctnnb1 mutations were noted in mouse hepatocellular carcinomas resulting from chronic administration of DE-71. None of the hepatocellular carcinomas arising spontaneously harbored Ctnnb1 mutations. Ctnnb1 mutations in spontaneous hepatocellular carcinomas are very rare compared to Hras mutations (Table N-4). These mutations were present within codons 15 to 46 and contained a mixture of transitions and transversions. In addition, there was a deletion of codons 15 to 46 in one carcinoma. The spontaneous hepatocellular carcinomas did not harbor any mutations in Ctnnb1. There were no differences in the incidences of mutations between male and female mice (data not presented) and hence the combined data from both male and female mice are presented in Table N-4.

## N.4 Discussion

The Hras mutations in spontaneous and chemically induced rodent tumors are frequently localized within codon 61.^284^ The presence of a novel Hras mutation (G to A transition, Gly to Asp) exclusively within codon 60 in rat hepatocellular tumors resulting from chronic gavage administration of DE-71 in a dose dependent manner suggests a possible unique mutational signature for DE-71-induced hepatocellular tumorigenesis. Though mutations in codon 60 are uncommon, this mutation may have a functional significance for HRAS since it serves as a “pivot point” in the conformational change that occurs upon activation of p21^ras^ and it is located in the vicinity of hot-spot regions of codons 59, 61, and 62 that contain GDP/GTP binding domains.^287-289^ However, depending on the type of mutation and the resulting substituted amino acid, the functional consequences of codon 60 mutations may be different. For example, a codon 60 Gly to Cys mutation results in decreased GTPase activity of HRAS and hence an activating mutation^290^ whereas a Gly to Ala mutation abolishes the ability of HRAS to transform NIH 3T3 cells.^291^ In the current study, the codon 60 Gly to Asp mutation will likely result in alteration of HRAS since Asp is a large acidic amino acid compared to the relatively small Gly. Thus, a mutation in codon 60 may likely render mutant HRAS to cause persistent effector signaling even in the absence of extracellular stimuli and cause unperturbed MAPK signaling resulting in sustained hepatocellular proliferation. However, further experiments are needed to prove functional consequences of a codon 60 Gly to Asp mutation.

Statistically significant increased incidences of Ctnnb1 mutations were noted in mouse hepatocellular carcinomas resulting from chronic administration of DE-71. Though not statistically significant, the incidences of Hras mutations were decreased in hepatocellular carcinomas from 100 mg/kg mice. This pattern of increased incidences of Ctnnb1 mutations and decreased incidences of Hras mutations was also noted in hepatocellular carcinomas that resulted from chronic treatment with Ginkgo biloba extract.^284^ Aydinlik et al.^272^ demonstrated a high incidence of Ctnnb1 mutations in hepatocellular carcinomas that resulted from diethylnitrosamine initiation and phenobarbital promotion. However, in this study, Ctnnb1 mutations were absent in hepatocellular carcinomas that occurred in mice treated with only the initiating carcinogen (diethylnitrosamine) suggesting that initiated neoplastic hepatocytes harboring Ctnnb1 mutations had a growth advantage during the phenobarbital promotion.^272^ Using a similar protocol, Strathmann et al.,^292^ also demonstrated the unique selective pressure on Ctnnb1-mutated liver tumors after exposure to PCB153, a nondioxin-like tumor promoter.

PBDE components within DE-71 have been shown to be ligands for the CAR and PXR receptors.^70,74,103,106^ In addition, especially at high doses, treatment with DE-71 caused an increase in hepatic Cyp1a1 transcript levels, suggestive of a weak aryl hydrocarbon receptor activation potential for DE-71.^70^ DE-71 is nongenotoxic and may not directly cause genetic alterations resulting in mutations and initiating carcinogenesis. Due to the ability of DE-71 to activate multiple nuclear receptors and inhibit apoptosis, it may function as a highly efficient promoter of hepatocarcinogenesis.^272-274,293,294^ The high incidence of Ctnnb1 mutations in the mouse hepatocellular carcinomas is likely due to the promotion effects of DE-71 that induce a positive selective pressure on the initiated hepatocytes harboring Ctnnb1 mutations and result in high tumor incidence. On the other hand, metabolites of DE-71 including dihydroxylated BDEs may cause oxidative stress^88,106^ and subsequent DNA damage resulting in mutations in specific genes. Thus, the combination of DNA damage secondary to oxidative stress and the potent tumor promotion effects of DE-71 might have contributed to the DE-71 induced hepatocarcinogenesis.

Table N-1 Primers Used To Amplify the Hot-Spot Regions of Rat Hras and Ctnnb1 Genes

Exon | Codon | Primer | Strand | Sequence
2 | Hras-61 | RH61F1738 | Sense | 5′-TGATCCATCAGGGTATGAGAG-3′
| | RH61F1752 | Sense | 5′-ATGAGAGGTGCAAGGGTAG-3′
| | RH61R2300 | Antisense | 5′-TCAATGTAGGGGATGCCATAG-3′
| | RH61F1816 | Sense | 5′-GCTGTGTTCTTTTGCAGG-3′
| | RH61R1987 | Antisense | 5′-GACTTGGTGTTGTTGATGG-3′
2 | Ctnnb1-5-80 | RβCatF272 | Sense | 5′-ACATAATCAACAAGCCACCC-3′
| | RβCatF431 | Sense | 5′-ACTCAGGCAGCATTCTCAGTGCAT-3′
| | RβCatR725 | Antisense | 5′-GGAAGGTAACACAGAGAGTTGCTT-3′
| | RβCatR799 | Antisense | 5′-ATGTGAGACTCCGTTGCC-3′

Table N-2 Primers Used To Amplify the Hot-Spot Regions of Mouse Hras and Ctnnb1 Genes

Exon | Codon | Primer | Strand | Sequence
2 | Hras-61 | MH61OS | Sense | 5′-CCACTAAGCCTGTTGTGTTTTGCAG-3′
| | MAPH61S | Sense | 5′-GGACTCCTAGCGGAAACAGG-3′
| | MH61OA | Antisense | 5′-CTGTACTGATGGATGTCCTCGAAGGA-3′
| | MAPH61A | Antisense | 5′-GGTGTTGTTGATGGCAAATACA-3′
3 | Ctnnb1-5-55 | MbCat1F | Sense | 5′-TACAGGTAGCATTTTCAGTTCAC-3′
| | MbCat2R | Antisense | 5′-TAGCTTCCAAACACAAATGC-3′
| | MbCat8R | Antisense | 5′-ACATCTTCTTCCTCAGGGTTG-3′
| | MbCatF17130 | Sense | 5′-GATGGAGTTGGACATGGC-3′
| | MbCatOR17294 | Antisense | 5′-ACTTGGGAGGTGTCAACA-3′
| | MbCatIR17257 | Antisense | 5′-TTCTTCCTCAGGGTTGCC-3′

Table N-3 Summary of Hras and Ctnnb1 Mutations in Non-tumor Liver Tissue and Hepatocellular Adenomas and Carcinomas from Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

Tissue – DE-71 Dose (mg/kg) | Mutation Frequency | | Hras Cdn 60 | Ctnnb1
Tissue – DE-71 Dose (mg/kg) | Hras ^b^ | Ctnnb1 ^b^ | G[underlined: G]T to G[underlined: A]T | Cdn 33–40
Non-tumor Liver - 0 | 0/10 (0) | 0/10 (0) | 0 | 0
Hepatocellular Tumors^c^ - 0 | 0/5 (0) | 0/5 (0) | 0 | 0
- 3 | 1/3 (33) | 0/3 (0) | 1 | 0
- 15 | 1/12 (8) | 1/12 (8) | 1 | 1
- 50 | 5/20 (25) | 3/20 (15) | 5 | 3^d^
DE-71-treated combined | 7/35 (20) | 4/35 (11) | 7 | 4

^a^ Male and female Wistar Han rats were dosed with 0, 3, 15, or 50 mg DE-71 (mixture of polybrominated diphenyl ethers)/kg body weight by oral gavage for 2 years. Silent mutations are not included. Non-tumor Liver- 0 mg/kg (9 males + 1 female); Hepatocellular Tumors- 0 mg/kg (3 males + 2 females); 3 mg/kg (2 males + 1 female); 15 mg/kg (4 males + 8 females); 50 mg/kg (9 males + 11 females).

^b^ Number of tissues with mutations/number of tissues assayed (% with mutation).

^c^ Compared to mice, the hepatocellular carcinoma (HCC) incidence was lower in the rats and hence, hepatocellular adenomas (HCA) were also included in the mutation analysis. The rat HCA and HCC included in this study included: controls (5 HCA); 3 mg/kg (3 HCA); 15 mg/kg (11 HCA and 1 HCC); 50 mg/kg [14 HCA and 6 HCC (3 HCC had Hras mutations, 1 HCC had Ctnnb1 mutation)].

^d^ Double mutations in one tumor/animal.

Table N-4 Summary of Hras and Ctnnb1 Mutations in Non-tumor Liver Tissue and Hepatocellular Carcinomas from B6C3F1/N Mice in the Two-year Gavage Study of DE-71^a^

Tissue – DE-71 Dose (mg/kg) | Mutation Frequency | | Hras Cdn 61 (CAA) | | | Ctnnb1
Tissue – DE-71 Dose (mg/kg) | Hras ^b^ | Ctnnb1 ^b^ | AAA | CGA | CTA | Cdn 15–46
Non-tumor Liver - 0 | 0/8 (0) | 0/8 (0) | 0 | 0 | 0 | 0
Hepatocellular Carcinomas - 0 | 2/17 (12) | 0/17 (0)^##^ | 2 | 0 | 0 | 0
- 3 | 2/14 (14) | 3/14 (21) | 1 | 1 | 0 | 3
- 30 | 3/19 (16) | 1/19 (5) | 2 | 0 | 1 | 1
- 100 | 1/29 (3) | 9/29 (31)** | 1 | 0 | 0 | 9
Historical Spontaneous Hepatocellular Carcinomas^c^ | 276/513 (54) | 1/79 (1) | 167 | 80 | 29 | 1
DE-71-treated combined | 6/62 (10) | 13/62 (21)* | 4 | 1 | 1 | 13

* Significantly different (P < 0.05) from the spontaneous hepatocellular carcinomas (from vehicle control) by the Fisher exact test.

** P < 0.01.

^##^ Significant dose-related trend (P < 0.01) across the hepatocellular carcinoma groups by the Cochran-Armitage trend test.

^a^ Male and female B6C3F1/N mice were dosed with 0, 3, 30, or 100 mg DE-71 (mixture of polybrominated diphenyl ethers)/kg body weight by oral gavage for 2 years. Silent mutations are not included. Non-tumor Liver- 0 mg/kg (3 males + 5 females); Hepatocellular Carcinomas- 0 mg/kg (14 males + 3 females); 3 mg/kg (12 males + 2 females); 30 mg/kg (13 males + 6 females); 100 mg/kg (15 males + 14 females).

^b^ Number of tissues with mutations/number of tissues assayed (% with mutation).

^c^ Historical database for Hras and Ctnnb1 mutations in spontaneous hepatocellular carcinomas (Sills et al.^295^; Hayashi et al.^296^; unpublished data).