# Appendix M Study on the Relationship of the AhR to DE-71 Liver Tumor Formation in Wistar Han Rats

## M.1 Introduction

The aim of this study was to determine if a mutation in the aryl hydrocarbon receptor (AhR) genotype was related to DE-71-induced liver tumor formation in female Wistar Han [Crl:WI(Han)] rats. In the current 2-year studies of DE-71, there was clear evidence for liver tumor formation in male and female rats and mice.

The DE-71 test article had a small amount of polybrominated dibenzodioxins and furans (approximately 7 × 10^−6^% of the mixture; see Appendix J, Table J-4), and it was uncertain if these components could contribute to liver tumor formation via interaction with the AhR. The female rat was selected for study because, based on the original pathology results, high dose (50 mg/kg) female rats had more liver tumors than high dose male rats.

In the current 2-year study, Wistar Han rats were dosed with DE-71, a mixture of pentabromodiphenyl ethers (pentaBDEs). While pentaBDEs have low potential to interact with the AhR,^70^ there were small amounts of polybrominated dibenzodioxins and furans in the DE-71 mixture. While the polybrominated dibenzodioxins and furans have low toxic equivalency factors compared to 2,3,7,8-tetrachlorodibenzo-p-dioxin,^261^ they may have some potential to interact with the AhR and affect liver tumorigenesis by this mechanism.

It has been reported that Wistar Han rats show resistance to dioxin-induced hepatocarcinogenesis that may be related to an allelic mutation in the AhR in this strain of rat.^278^ According to Charles River Laboratories, about 50% of the Wistar Han rats used in the current 2-year study carry or are homozygous for mutation in the AhR allele (presumably at exon 10). An AhR mutation may alter receptor function and result in decreased dioxin-like effects (or polybrominated dibenzodioxins and furan effects) including induction of cancer by activation of the AhR.^252,253,279^

Two mutations have been found within the DNA sequence in the AhR that may account for the differences in susceptibilities to dioxin-like effects.^252^ One of the mutations is in exon 10 and causes a single amino acid change within the variable region of the AhR. The other mutation is in intron 10 and leads to use of cryptic splice sites to form mRNA transcripts that remove short amino acid sequences near the end of the transactivation domain. In this study, DNA sequences in intron 10 and exon 10 were compared with those of Sprague Dawley rats. Using analysis of genotype at exon 10, we tested the possibility that AhR mutations in the Wistar Han rat strain might have functional consequences for AhR activation and liver tumor occurrences. If a wild AhR is necessary for induction of liver tumors by DE-71, it would be expected that DE-71-induced liver tumors would only be seen in animals with the wild AhR genotype.

Therefore, the objective of this study was to compare the AhR genotype (at exon 10) to the DE-71-induced liver tumor incidence in high dose female rats to determine if liver tumor formation correlated with wild AhR genotype and conversely, if the absence of liver tumors correlated with mutant AhR genotype.

## M.2 Materials and Methods

### M.2.1 Animals and Tissue Specimens

All archival tissues were from the current 2-year study of DE-71 in Wistar Han rats. The NTP toxicogenomics faculty approved a plan for AhR genotyping of the livers of vehicle (corn oil) controls and 50 mg/kg female rats to determine if there was a correlation between AhR genotype and DE-71-induced liver tumor incidence as well as a non-target blocked tissue (e.g., kidney). Since liver and kidney tissues were only available from formalin-fixed paraffin-embedded (FFPE) blocks for DNA isolation, DNA extracted from a small number of fresh-frozen control liver samples was included to ensure extraction of high quality DNA for the genotyping assay for comparison. Five frozen archival Wistar Han livers were chosen from this study for which there was sufficient original tissue (50 mg) for DNA extraction.

### M.2.2 DNA Extraction

In order to perform the genotyping assay, one 20-micron section was taken from paraffin blocks of the liver of female vehicle controls and one 20-micron section was taken from the liver of 50 mg/kg female rats. In addition, to analyze a non-target tissue, similar sections were cut from the kidney, involving both vehicle control and high dose DE-71 kidneys. Paraffin sections from each block were placed in separate screw-top 1.5 mL tubes, centrifuged for 10 to 15 seconds, and stored at 4°C until delivery to ILS, Inc. (Research Triangle Park, NC), for DNA extraction and genotyping.

### M.2.3 Propagation and Purification of Authentic Standards

Plasmid controls were generated from genomic DNA (gDNA) and were extracted along with DNA from fresh-frozen tissue collected from five Wistar Han rats for each of the three genotypes (homozygous wild type, heterozygous, and homozygous mutant). Genotyped liver tissue from Wistar Han rats provided the gDNA template for the heterozygous and homozygous mutant controls while one genotyped Sprague Dawley rat fresh-frozen liver provided the gDNA template for the homozygous wild-type control.

### M.2.4 AhR Genotyping Assay

The AhR genotyping assay was a polymerase chain reaction (PCR)-based molecular beacon assay adapted from Pohjanvirta et al.^280^ The target amplicon and probes are listed in Table M1. Plasmids from Dr. Pohjanvirta for wild-type and mutant AhRs were obtained as standards for the genotyping assay. The gDNA templates were amplified using TaqMan^®^ Genotyping Master Mix (Life Technologies, Carlsbad, CA) according to manufacturer’s procedures and cycling conditions (95°C for 10 minutes, followed by 40 cycles of 95°C for 20 seconds, and 60°C for 1 minute) on the ViiA™ 7 Real-Time PCR System 4 (Life Technologies). Of the resultant 108 base pair PCR product, 1 µL was ligated into the pCR^TM^2.1 linear vector using the original TA Cloning^®^ Kit (Life Technologies) according to manufacturer’s procedures. The pCR^TM^2.1 plasmid containing the 108 base pair insert was transformed into One Shot^®^ MAX Efficiency^®^ DH5α™-T1^®^ Competent Cells (Life Technologies) according to manufacturer’s procedures. The transformed cells were then plated on LB agar plates containing ampicillin (Thermo Fisher Scientific, Inc., Waltham, MA) and incubated overnight at 37°C. After incubation, two colonies for each transformed plasmid were selected from the LB agar plates and incubated separately overnight at 37°C in LB broth containing ampicillin (Thermo Fisher Scientific, Inc.). The six resultant propagated plasmids were purified from the LB broth using the Quantum Prep^®^ Plasmid Midiprep Kit (Bio-Rad Laboratories, Hercules, CA) per manufacturer’s procedures. The resultant six purified plasmids (two plasmids per genotype) were assessed for quantity and ratio of absorbances at 260 and 280 nm using the NanoDrop^®^ ND-1000 spectrophotometer (Thermo Fischer Scientific, Inc.). Additionally, the plasmids were Sanger sequenced to confirm the incorporation of the 108 base pair amplicon with the presence or absence of each AhR single nucleotide polymorphism for which homozygous wild type was G/G, heterozygous type was G/A, and homozygous mutant was A/A.

## M.3 Results

The degraded quality of gDNA extracted from FFPE sections required the use of a nested PCR reaction in order to amplify a 200 base pair region of gDNA containing the AhR mutation of interest. The nested PCR product was then utilized as the template for both quantitative PCR (qPCR) and sequencing. The results of the qPCR and Sanger sequencing were combined to determine the AhR genotype for each sample.

The 118 liver FFPE samples yielded the following genotype totals: 26 (22.0%) homozygous wild-type G/G, 51 (43.2%) heterozygous G/A, 39 (33.1%) homozygous mutant A/A, and 2 (1.7%) undetermined. The 122 kidney FFPE samples yielded the following genotype totals: 21 (17.2%) homozygous wild-type G/G, 51 (41.8%) heterozygous G/A, 38 (31.1%) homozygous mutant A/A, and 12 (9.8%) undetermined.

A number of liver tumors occurred in female Wistar Han rats in the 2-year study ranging from adenomas to cholangiocarcinomas and carcinomas. A statistical analysis was performed for the relationship of genotype and number of animals in each liver tumor type (Table M-2). No significant difference was observed for any one genotype and hepatocellular tumors. When various tumors were combined such as adenomas and carcinomas or single and multiple tumors, no significant differences among the AhR genotypes (at exon 10) were observed.

## M.4 Discussion

DNA extraction was successfully performed from FFPE liver and kidney blocks from the current 2-year DE-71 study using commercial procedures optimized for retrieval of nucleic acids for amplification and sequencing analyses.^281^ Almost all liver FFPE tissues (60/60 vehicle controls; 58/60 dosed with DE-71) were able to be genotyped; only two samples (from animals dosed with DE-71) were unable to be analyzed for genotype because of poor gDNA sample quality. As indicated in Table M2, there was no statistically significant correlation between liver tumor incidences in the female rats administered DE-71 and the AhR genotype.

The incidences of different tumor types were compared between vehicle control and DE-71-treated rats. Statistical comparisons of incidences were performed for each tumor (e.g., hepatocellular adenoma) according to each genotype in vehicle control versus DE-71-treated tissues. Genotypes were homozygous wild-type (G/G), heterozygous (G/A), or homozygous mutant (A/A). In addition, tumor incidences of combined single or multiple tumor types such as single adenomas and multiple adenomas or after combined different tumor types such as adenomas and carcinomas were also compared. No differences were found in the number of tumor types or combinations of tumor types by AhR genotype in DE-71-dosed female rats.

The distribution of the AhR genotypes in this study shows that 22.0% were wild-type homozygous, 33.1% were mutant homozygous, and 43.2% were heterozygous. This suggests that DE-71-mediated liver tumor formation was independent of a fully functional AhR since over three-fourths of the Wistar rats in this study carried a mutant AhR allele.

Another possibility is that the level of AhR activation was inadequate to contribute to tumor formation during chronic exposure due to a low AhR affinity for the polybrominated diphenyl ethers (PBDEs) found in DE-71 or because of the absence or negligible amounts of dioxin-like contaminants in DE-71. Interestingly, Jiang et al.^282^ cloned variants of the AhR of the Wistar Han rat and found the expressed proteins did not vary in their ligand binding capacity from the wild-type AhR protein suggesting that the AhR variants were functionally normal. In addition, the AhR variants were not associated with TCDD-induced developmental toxicity measures in the study reported by these investigators. Overall, the data presented here suggest that under the conditions of the current 2-year study, the AhR genotype was not significantly associated with liver tumor formation after chronic DE-71 administration.

In summary, genotyping of female Wistar Han rats for an AhR mutation from paraffin archival samples did not show an association with the incidences of liver tumors after administration of DE-71 for 2 years.

## M.5 Acknowledgements

The authors are grateful to Dr. Raimo Pohjanvirta at the Department of Food Hygiene and Environmental Health, University of Helsinki, Helsinki, Finland, for supplying the cloned vectors containing wild-type and mutated AhR sequences.

Table M-1 Sequence and Primers for Amplification of Wild-Type and Mutant Aryl Hydrocarbon Receptors (AhR) in Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

108bp AhR Sequence
ACACAATAGACTACACGGAGATGCTTGGACCTACAAGGTTTATTCCCTGTAGAAAGCCCTTACCTTGCTTAGGAACGCCTGGGAGCCTGGAATCTCAGGGCTGTACTG
Rn4: Chr6:54,208,644–54,208,751
Reverse Complement (108bp)
CAGTACAGCCCTGAGATTCCAGGCTCCCAGGCGTTC[underlined: CTAAGCAAG][underlined: G][underlined: TAAGGGCT]TTCTACAGGGAATAAACCTTGTAGGTCCAAGCATCTCCGTGTAGTCTATTGTGT
Forward Primer: CAGTACAGCCCTGAGATTCCAG
Reverse Primer: ACACAATAGACTACACGGAGATGC (reverse complement)
Wild-Type (G) Probe: [VIC]-CTAAGCAAGGTAAGGGCT
Mutant (A) Probe: [FAM]-CTAAGCAAGATAAGGGCT

Table M-2 Summary of Liver Tumor Counts by Genotype in Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Tumor or Tumor Combination | Heterozygous G/A^a^ | Homozygous A/A^a^ | Homozygous G/G^a^ | P Value^b^
Hepatocellular Adenoma | 4 [51] | 3 [39] | 4 [26] | 0.516
Hepatocellular Adenoma, Multiple | 5 [51] | 1 [39] | 2 [26] | 0.409
Hepatocellular Carcinoma | 1 [51] | 2 [39] | 0 [26] | 0.600
Hepatocellular Carcinoma, Multiple | 1 [51] | 0 [39] | 1 [26] | 0.702
Hepatocholangiocarcinoma | 2 [51] | 1 [39] | 1 [26] | 1.000
Hepatocholangioma | 1 [51] | 0 [39] | 2 [26] | 0.162
Hepatocholangioma, Multiple | 0 [51] | 1 [39] | 0 [26] | 0.560
Cholangiocarcinoma | 0 [51] | 0 [39] | 1 [26] | 0.224
Cholangiocarcinoma, Multiple | 0 [51] | 0 [39] | 0 [26] | –^c^
Hepatocellular Adenoma + Hepatocellular Adenoma, Multiple | 9 [51] | 4 [39] | 6 [26] | 0.342
Hepatocellular Carcinoma + Hepatocellular Carcinoma, Multiple | 2 [51] | 2 [39] | 1 [26] | 1.000
Hepatocellular Adenoma + Hepatocellular Adenoma, Multiple + Hepatocellular Carcinoma + Hepatocellular Carcinoma, Multiple | 9 [51] | 5 [39] | 6 [26] | 0.512
Hepatocholangioma + Hepatocholangioma, Multiple | 1 [51] | 1 [39] | 2 [26] | 0.437
Cholangiocarcinoma + Cholangiocarcinoma, Multiple | 0 [51] | 0 [39] | 1 [26] | 0.224

^a^ Number of animals with tumor [total number of animals].

^b^ Fisher’s exact test used to compare genotype with number of animals.

^c^ Value of statistic cannot be computed.