# Appendix L Sentinel Animal Program

## L.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each animal and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and sent to BioReliance Corporation, Rockville, MD (3-month studies), or the Research Animal Diagnostic Laboratory (RADIL), University of Missouri, Columbia, MO (2-year studies), for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five males and five females at all timepoints, except blood was collected from only unmated female rats at arrival for the 2-year perinatal and postnatal gavage study.

Table L-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method/Test | Time of Collection
Rats
Three-month Study
ELISA
Mycoplasma arthritidis | Study Termination
Mycoplasma pulmonis | Study Termination
Pneumonia virus of mice (PVM) | Study Termination
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | Study Termination
Sendai | Study Termination
Immunofluorescence Assay
Parvo | Study Termination
Two-year Study
Multiplex Fluorescent Immunoassay
Kilham’s rat virus (KRV) | Arrival, 1, 6, 12, and 18 months, study termination
M. pulmonis | Arrival, 1, 6, 12, and 18 months, study termination
Parvo NS-1 | Arrival, 1, 6, 12, and 18 months, study termination
PVM | Arrival, 1, 6, 12, and 18 months, study termination
RCV/SDA | Arrival, 1, 6, 12, and 18 months, study termination
Rat minute virus (RMV) | Arrival, 1, 6, 12, and 18 months, study termination
Rat parvovirus (RPV) | Arrival, 1, 6, 12, and 18 months, study termination
Rat theilovirus (RTV) | Arrival, 1, 6, 12, and 18 months, study termination
Sendai | Arrival, 1, 6, 12, and 18 months, study termination
Theiler’s murine encephalomyelitis virus (TMEV) | Arrival, 1, 6, 12, and 18 months, study termination
Toolan’s H-1 virus | Arrival, 1, 6, 12, and 18 months, study termination
Mice
Three-month Study
ELISA
Ectromelia virus | Study Termination
Epizootic diarrhea of infant mice (EDIM) | Study Termination
Theiler’s murine encephalomyelitis virus – mouse poliovirus, strain GDVII (TMEV GDVII) | Study Termination
Lymphocytic choriomeningitis virus (LCMV) | Study Termination
Mouse adenoma virus-FL | Study Termination
Mouse hepatitis virus (MHV) | Study Termination
Mouse minute virus viral protein 2 (MMV VP2) | Study Termination
Mouse parvovirus viral protein 2 (MPV VP2) | Study Termination
Mycoplasma pulmonis | Study Termination
PVM | Study Termination
Reovirus | Study Termination
Sendai | Study Termination
Immunofluorescence Assay
Mouse cytomegalovirus (MCMV) | Study Termination
Ectromelia Virus | Study Termination
Two-year Study
Multiplex Fluorescent Immunoassay
Ectromelia virus | 1, 6, 12, and 18 months, study termination
EDIM | 1, 6, 12, and 18 months, study termination
LCMV | 1, 6, 12, and 18 months, study termination
M. pulmonis | 1, 6, 12, and 18 months, study termination
MHV | 1, 6, 12, and 18 months, study termination
Mouse norovirus (MNV) | 1, 6, 12, and 18 months, study termination
Parvo NS-1 | 1, 6, 12, and 18 months, study termination
MPV | 1, 6, 12, and 18 months, study termination
MMV | 1, 6, 12, and 18 months, study termination
PVM | 1, 6, 12, and 18 months, study termination
Reovirus | 1, 6, 12, and 18 months, study termination
TMEV GDVII | 1, 6, 12, and 18 months, study termination
Sendai | 1, 6, 12, and 18 months, study termination
Polymerase Chain Reaction
Helicobacter species | 18 months

## L.2 Results

All test results were negative.