# Appendix J Chemical Characterization and Dose Formulation Studies

## J.1 Procurement and Characterization

### J.1.1 DE-71

DE-71 was obtained from Great Lakes Chemical Corporation (El Dorado, AR) in two lots (2550OA30A and 1550OK07A). Lot 2550OA30A was used during the 3-month and 2-year studies; lot 1550OK07A was used for dose formulation development studies performed by the analytical chemistry laboratory at Battelle Columbus Operations (Columbus, OH) and was not used in any of the animal studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and by the study laboratory at Southern Research Institute (Birmingham, AL). Karl Fischer titration was performed by Galbraith Laboratories, Inc. (Knoxville, TN). Reports on analyses performed in support of the DE-71 studies are on file at the National Institute of Environmental Health Sciences.

Lot 2550OA30A of the test chemical, a viscous, sticky brown liquid, was identified as DE-71 by the analytical chemistry laboratory using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by the study laboratory using IR spectroscopy. IR spectra were consistent with the literature spectra^183^ and the structure of DE-71. Proton and carbon-13 NMR spectra were consistent with computer-calculated spectra and the structures for a polybrominated diphenyl ether mixture. Representative IR and proton NMR spectra are presented in Figure J-1 and Figure J-2.

For lot 2550OA30A, the moisture content was determined by Karl Fischer titration and the purity profile was determined by the analytical chemistry laboratory using gas chromatography (GC) with flame ionization detection (FID) by system A (Table J-1). The purity profile of the bulk chemical was also determined by the study laboratory using a similar GC/FID analysis (system B). In further analyses of the bulk chemical using GC coupled with mass spectrometry (MS) detection, the analytical chemistry laboratory confirmed the identity of the peaks observed in the purity profiles (using system C), and screened for the presence of polychlorinated (using system D) and polybrominated (using system E) dibenzodioxins and furans.

Karl Fischer titration indicated less than 0.1% water. GC/FID using system A (Table J-1) yielded a purity profile containing 16 reportable peaks, 11 of which were PBDEs tentatively identified by retention time matching to standards of PBDEs in chloroform obtained from Cambridge Isotope Laboratories, Inc. (CIL, Tewksbury, MA) (Table J-2). Six peaks in this profile contained areas exceeding 2% of the total peak area; BDE-99 (41.67%), BDE-47 (35.68%), BDE-100 (10.44%), BDE-154 (3.63%), BDE-153 (3.33%), and BDE-85 (2.03%). GC/FID by a similar system using a column with a thicker film (system B; Table J-1) yielded prolonged retention times, but very similar area percents for these six components. The identities of peaks in the GC/FID purity profile were confirmed by GC/MS using authentic PBDE standards for 11 peaks. The specific identity of an individual PBDE was based on the retention time and the mass spectrum of the standard to a peak in DE-71. It should be noted that other positional isomers with the same number of bromines might elute at the same retention time and would give the same mass spectrum. Therefore, the identity of the specific isomer should be considered tentative (Table J-2). Using polychlorinated analytical standards purchased from CIL and high resolution GC/MS by system D (Table J-1), samples of the bulk chemical were found to contain no polychlorinated dibenzodioxins or furans above the specified limits of quantitation (Table J-3). Polybrominated analytical standards obtained from CIL and high resolution GC/MS by system E (Table J-1) were used to determine that polybrominated dibenzodioxins and furans were present in the test article; concentrations of 2,3,7,8-TBDF, 1,2,3,7,8-PeBDF, 2,3,4,7,8-PeBDF, and co-eluting 1,2,3,4,7,8-HxBDF and 1,2,3,6,7,8-HxBDF were quantifiable (Table J-4). Taken together, these analyses indicated that the test article consisted of a mixture of approximately 54% pentabromodiphenyl ethers, 36% tetrabromodiphenyl ethers, and 7% hexabromodiphenyl ethers.

Stability studies of the bulk chemical were performed by the analytical chemistry laboratory using GC/FID by system A (Table J-1). These studies indicated that DE-71 was stable as a bulk chemical for 15 days when stored in sealed amber glass bottles at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature, protected from light, in sealed glass containers. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month and 2-year studies with GC/FID by system B and no degradation of the bulk chemical was detected.

### J.1.2 Corn Oil

Mazola corn oil was obtained in multiple lots from Red Diamond Foodservice, Inc. (Birmingham, AL), and Sam’s Club (Birmingham, AL) and was used as the vehicle in the 3-month and 2-year studies. Periodic analyses of the corn oil vehicle performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than 3 mEq/kg.

## J.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times during the 3-month studies and approximately every 4 weeks during the 2-year studies by mixing DE-71 with corn oil to give the required concentrations (Table J-5). Dose formulations were stored at approximately 5°C in amber glass containers sealed with Teflon^®^-lined lids for up to 46 days.

Stability studies of 0.05 mg/mL formulations were performed by the analytical chemistry laboratory using GC with electron capture detection (ECD) by system F (Table J-1). Stability was confirmed for at least 46 days for dose formulations stored in amber glass containers sealed with Teflon^®^-lined lids at temperatures up to 25°C and for 3 hours under simulated animal room conditions. An additional stability study was performed by the study laboratory on the 0.001 mg/mL dose formulation using GC/ECD by a system similar to system F, and stability was confirmed for at least 55 days for dose formulations stored in amber glass containers sealed with Teflon^®^-lined lids at 5°C and for 3 hours under simulated animal room conditions.

Periodic analyses of the dose formulations of DE-71 were conducted by the study laboratory using a system similar to system F. Determinations of the concentrations of DE-71 in corn oil were based on quantification of peak areas produced by the marker compound BDE-99. During the 3-month studies, the dose formulations were analyzed three times; all 15 formulations for rats and 14 of 15 for mice were within 10% of the target concentrations (Table J-6 and Table J-7). Animal room samples of these dose formulations were also analyzed; 11 of 15 for rats and 12 of 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 2 months (Table J-8 and Table J-9). Of the dose formulations analyzed and used during the studies, 38 of 39 for rats and all 36 for mice were within 10% of the target concentrations; 23 of 24 animal room samples for rats and 13 of 14 for mice were within 10% of the target concentrations.

Table J-1 Gas Chromatography Systems Used in the Gavage and Perinatal and Postnatal Gavage Studies of DE-71^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | Rtx^®^-5, 30 m × 0.25 mm, 0.25 µm film (Restek, Bellefonte, PA) | Helium at 3 mL/minute | 80°C for 1 minute, then 20°C/minute to 200°C, then 10°C/minute to 280°C, held for 10 minutes
System B
Flame ionization | Rtx^®^-5, 30 m × 0.25 mm, 1.0 µm film (Restek) | Helium at ~3 mL/minute | 80°C, then 20°C/minute to 200°C, then 10°C/minute to 300°C, held for 20 minutes
System C
Mass spectrometry with electron ionization (EI) (50 to 800 amu) | Rtx^®^-5, 30 m × 0.25 mm, 0.25 µm film (Restek) | Helium at 1 mL/minute | 80°C for 1 minute, then 20°C/minute to 200°C, then 10°C/minute to 280°C, held for 20 minutes
System D
Mass spectrometry with EI and selected ion recording (SIR) | DB-5, 60 m × 0.25 mm, 0.25 µm film (J&W Scientific, Folsom, CA) | Helium at 140 kPa | 140°C for 3 minutes, then 20°C/minute to 220°C, held for 16 minutes, then 5°C/minute to 235°C, held for 7 minutes, then 5°C/minute to 320°C, held for 10 minutes
System E
Mass spectrometry with EI and SIR | DB-5 MS, 30 m × 0.32 mm, 0.25 µm film (J&W Scientific) | Helium at 140 kPa | 130°C for 2.5 minutes, then 30°C/minute to 210°C, then 3°C/minute to 315°C, held for 25 minutes
System F
Electron capture | Rtx^®^-5, 30 m × 0.25 mm, 1.0 µm film (Restek) | Helium at ~3 mL/minute | 80°C, then 20°C/minute to 200°C, then 10°C/minute to 300°C, held for 10 minutes

^a^ The gas chromatographs were manufactured by Agilent Technologies, Inc. (Palo Alto, CA). The mass spectrometers were manufactured by Agilent Technologies, Inc. (system C) or VG Autospec (Manchester, UK; systems D and E).

Table J-2 Purity Profile of DE-71 Determined by Gas Chromatography with Flame Ionization Detection

Abbreviation | Name | CAS Number | Retention Time (minutes) | Total Area (%)
BDE-17 | 2,2′,4′-Tribromodiphenyl ether | 147217-75-2 | 10.66 | <0.10
BDE-28 | 2,4,4′-Tribromodiphenyl ether | 41318-75-6 | 10.91 | 0.29
– | Unknown A | – | 11.90 | 0.24
– | Unknown B | – | 12.48 | 0.64
BDE-47 | 2,2',4,4'-Tetrabromodiphenyl ether | 5436-43-1 | 12.86 | 35.68
BDE-66 | 2,3′,4,4′-Tetrabromodiphenyl ether | 189084-61-5 | 13.06 | 0.48
BDE-100 | 2,2′,4,4′,6-Pentabromodiphenyl ether | 189084-64-8 | 14.27 | 10.44
BDE-99 | 2,2′,4,4′,5-Pentabromodiphenyl ether | 60348-60-9 | 14.73 | 41.67
BDE-85 | 2,2′,3,4,4′-Pentabromodiphenyl ether | 182346-21-0 | 15.44 | 2.03
– | Unknown C | – | 15.57 | 0.21
BDE-154 | 2,2′,4,4′,5,6′-Hexabromodiphenyl ether | 207122-15-4 | 15.89 | 3.63
BDE-153 | 2,2′,4,4′,5,5′-Hexabromodiphenyl ether | 68631-49-2 | 16.61 | 3.33
– | Unknown D | – | 16.98 | 0.65
– | Unknown E | – | 17.21 | 0.16
BDE-138 | 2,2′,3,4,4′,5′-Hexabromodiphenyl ether | 182677-30-1 | 17.81 | 0.45
BDE-183 | 2,2′,3,4,4′,5′,6-Heptabromodiphenyl ether | 207122-16-5 | 19.62 | 0.12

Table J-3 Polychlorinated Dibenzodioxins and Furans in DE-71 Determined by Gas Chromatography with Mass Spectrometry Detection

Abbreviation | Name | CAS Number | LOQ^a^ (pg/g) | LOD^b^ (pg/g) | Method Blank (pg/g) | DE-71^c^ (pg/g) | DE-71^c^ (pg/g)
2,3,7,8-TCDD | 2,3,7,8-Tetrachlorodibenzo-p-dioxin | 1746-01-6 | 35 | 0.04 | ND | ND | ND
1,2,3,7,8-PeCDD | 1,2,3,7,8-Pentachlorodibenzo-p-dioxin | 40321-76-4 | 175 | 0.08 | ND | ND | ND
1,2,3,4,7,8-HxCDD | 1,2,3,4,7,8-Hexachlorodibenzo-p-dioxin | 39227-28-6 | 175 | 0.03 | ND | ND | ND
1,2,3,6,7,8-HxCDD | 1,2,3,6,7,8-Hexachlorodibenzo-p-dioxin | 57653-85-7 | 175 | 0.03 | ND | ND | ND
1,2,3,7,8,9-HxCDD | 1,2,3,7,8,9-Hexachlorodibenzo-p-dioxin | 19408-74-3 | 175 | 0.03 | ND | ND | ND
1,2,3,4,6,7,8-HpCDD | 1,2,3,4,6,7,8-Heptachlorodibenzo-p-dioxin | 35822-46-9 | 175 | 0.06 | ND | ND | ND
OCDD | Octachlorodibenzo-p-dioxin | 3268-87-9 | 350 | 0.02 | 10.1 | ND | ND
2,3,7,8-TCDF | 2,3,7,8-Tetrachlorodibenzofuran | 51207-31-9 | 35 | 0.04 | ND | ND | ND
1,2,3,7,8-PeCDF | 1,2,3,7,8-Pentachlorodibenzofuran | 57117-41-6 | 175 | 0.05 | ND | ND | ND
2,3,4,7,8-PeCDF | 2,3,4,7,8-Pentachlorodibenzofuran | 57117-31-4 | 175 | 0.04 | ND | ND | ND
1,2,3,4,7,8-HxCDF | 1,2,3,4,7,8-Hexachlorodibenzofuran | 70648-26-9 | 175 | 0.03 | 2.07 | ND | ND
1,2,3,6,7,8-HxCDF | 1,2,3,6,7,8-Hexachlorodibenzofuran | 57117-44-9 | 175 | 0.03 | ND | ND | ND
1,2,3,7,8,9-HxCDF | 1,2,3,7,8,9-Hexachlorodibenzofuran | 72918-21-9 | 175 | 0.03 | ND | ND | ND
2,3,4,6,7,8-HxCDF | 2,3,4,6,7,8-Hexachlorodibenzofuran | 60851-34-5 | 175 | 0.03 | ND | ND | ND
1,2,3,4,6,7,8-HpCDF | 1,2,3,4,6,7,8 Heptachlorodibenzofuran | 67562-39-4 | 175 | 0.35 | ND | ND | ND
1,2,3,4,7,8,9-HpCDF | 1,2,3,4,7,8,9-Heptachlorodibenzofuran | 55673-89-7 | 175 | 0.42 | ND | ND | ND
OCDF | Octachlorodibenzofuran | 39001-02-0 | 350 | 0.04 | 6.15 | ND | ND

LOQ = limit of quantitation; LOD = limit of detection; ND = not detected

^a^ Calculated based on standard levels specified in EPA Method 1613 relative to sample size and sample volume in a clean solvent standard.

^b^ Calculated at three times baseline noise in a spiked matrix standard representing optimum conditions. Individual LODs for each sample analyte vary depending on the noise level present in the region of the analyte.

^c^ Duplicate measurements.

Table J-4 Polybrominated Dibenzodioxins and Furans in DE-71 Determined by Gas Chromatography with Mass Spectrometry Detection

Abbreviation | Name | CAS Number | LOQ^a^ (pg/g) | LOD^b^ (pg/g) | Method Blank (pg/g) | DE-71^c^ (pg/g) | TEF^d^ | TEQ (pg/g)
2,3,7,8-TBDD | 2,3,7,8-Tetrabromodibenzo-p-dioxin | 50585-41-6 | 140 | 7.02 | 109.91 | 130 | 1 | 130
1,2,3,7,8-PeBDD | 1,2,3,7,8-Pentabromodibenzo-p-dioxin | 109333-34-8 | 1,750 | 118.95 | ND | 58 | 1 | 58
1,2,3,4,7,8-HxBDD and 1,2,3,6,7,8-HxBDD | 1,2,3,4,7,8-Hexabromodibenzo-p-dioxin and 1,2,3,6,7,8- Hexabromodibenzo-p-dioxin (coeluted) | Not found Not found | 3,500 | 30.20 | ND | 41 | 0.1 0.1 | 4.1
1,2,3,7,8,9-HxBDD | 1,2,3,7,8,9-Hexabromodibenzo-p-dioxin | Not found | 3,500 | 65.48 | ND | ND | 0.1
1,2,3,4,6,7,8-HpBDD | 1,2,3,4,6,7,8-Heptabromodibenzo-p-dioxin | Not found | NS | ND | ND | ND | 0.01
OBDD | Octabromodibenzo-p-dioxin | 2170-45-8 | 3,500 | 26.96 | ND | ND
2,3,7,8-TBDF | 2,3,7,8-Tetrabromodibenzofuran | 67733-57-7 | 1,400 | 144.47 | ND | 3,680^e^ | 0.1 | 368
1,2,3,7,8-PeBDF | 1,2,3,7,8-Pentabromodibenzofuran | 107555-93-1 | 7,000 | 955.08 | ND | 19,790^e^ | 0.03 | 594
2,3,4,7,8-PeBDF | 2,3,4,7,8-Pentabromodibenzofuran | 131166-92-2 | 7,000 | 893.01 | 23.4 | 5,381 | 0.3 | 1,614
1,2,3,4,7,8-HxBDF and 1,2,3,6,7,8-HxBDF | 1,2,3,4,7,8-Hexabromodibenzofuran and 1,2,3,6,7,8-Hexabromodibenzofuran (coeluted) | 129880-08-6 107555-94-2 | 5,600 | 34.72 | ND | 43,088^e^ | 0.1 0.1 | 4,309
2,3,4,6,7,8-HxBDF | 2,3,4,6,7,8-Hexabromodibenzofuran | 161880-50-8 | NS | ND | ND | ND | 0.1
1,2,3,7,8,9-HxBDF | 1,2,3,7,8,9-Hexabromodibenzofuran | 161880-49-5 | NS | ND | ND | ND
1,2,3,4,6,7,8-HpBDF | 1,2,3,4,6,7,8-Heptabromodibenzofuran | 107555-95-3 | 14,000 | 12.10 | ND | 535 | 0.1 | 54
1,2,3,4,7,8,9-HpBDF | 1,2,3,4,7,8,9-Heptabromodibenzofuran | 161880-51-9 | NS | ND | ND | ND | 0.1
OBDF | 1,2,3,4,6,7,8,9-Octabromodibenzofuran | 103582-29-2 | NS | | ND | ND
| | | | | TOTAL | 71,310 | 0.1 | 7,131

LOQ = limit of quantitation; LOD = limit of detection; TEF = toxic equivalency factor; TEQ = toxic equivalents [TEF × DE-71 component (pg/g)]; ND = not detected; NS = no standard available; NA = not available.

^a^ Calculated based on standard levels specified in EPA Method 1613 relative to sample size and sample volume in a clean solvent standard.

^b^ Calculated at three times baseline noise in a spiked matrix standard representing optimum conditions. Individual LODs for each sample analyte vary depending on the noise level present in the region of the analyte.

^c^ Averages of duplicate measurements are given.

^d^ van den Berg et al.^261^

^e^ Quantifiable, as value exceeds the LOQ.

Table J-5 Preparation and Storage of Dose Formulations in the Gavage and Perinatal and Postnatal Gavage Studies of DE-71

Three-month Studies | Two-year Studies
Preparation
Prior to making the dose formulations, a bottle of DE-71 was placed into a water bath at approximately 50°C for approximately 1 hour to reduce the viscosity of the test article. For the low concentration dose formulations, 1.00 g of warmed DE-71 was weighed into a beaker and dissolved into corn oil with warmed stirring. The solution was then quantitatively transferred to a 1 L volumetric flask, diluted with corn oil, and thoroughly mixed to prepare a 1 mg/mL stock solution. Using a positive displacement pipette, aliquots of the stock solution were transferred into appropriate volumetric flasks and diluted 1:1,000 with corn oil to achieve final dose formulation concentrations of 0.001 mg/mL (for mice) or 0.002 mg/mL (for rats). For the four highest concentration dose formulations, the appropriate amount of warmed DE-71 was weighed into a beaker, dissolved into corn oil with warmed stirring, quantitatively transferred to an appropriate volumetric flask, diluted to volume with corn oil, and stirred vigorously. The dose formulations were prepared four times. | Same as the four highest concentration dose formulations in the 3-month studies, except the corn oil was also warmed in a water bath to reduce viscosity and aid sampling. The dose formulations were prepared approximately every 4 weeks.
Chemical Lot Number
2550OA30A | 2550OA30A
Maximum Storage Time
46 days | 46 days
Storage Conditions
Stored in amber glass containers sealed with Teflon^®^-lined lids at approximately 5°C | Stored in amber glass containers sealed with Teflon^®^-lined lids at approximately 5°C
Study Laboratory
Southern Research Institute (Birmingham, AL) | Southern Research Institute (Birmingham, AL)

Table J-6 Results of Analyses of Dose Formulations Administered to F344/N Rats in the Three-month Gavage Study of DE-71

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
July 1, 2004 | July 2–3, 2004 | 1.00 | 0.942 | −6
| | 10.0 | 9.45 | −6
| | 20.0 | 18.7 | −7
| | 100 | 93.7 | −6
| August 16–17, 2004^b^ | 1.00 | 0.899 | −10
| | 10.0 | 9.07 | −9
| | 20.0 | 16.3 | −19
| | 100 | 92.2 | −8
July 8, 2004 | July 12–13, 2004 | 0.002 | 0.00199 | −1
| August 16–17, 2004^b^ | 0.002 | 0.00662 | +231
August 2, 2004 | August 5–6, 2004 | 0.002 | 0.00191 | −5
| | 1.00 | 0.940 | −6
| | 10.0 | 9.49 | −5
| | 20.0 | 19.3 | −4
| | 100 | 98.5 | −2
| September 14–15, 2004^b^ | 0.002 | 0.00172 | −15
| | 1.00 | 0.910 | −9
| | 10.0 | 9.08 | −9
| | 20.0 | 18.8 | −6
| | 100 | 93.7 | −6
October 4, 2004 | October 5–6, 2004 | 0.002 | 0.00189 | −6
| | 1.00 | 0.904 | −10
| | 10.0 | 9.03 | −10
| October 25–26, 2004^b^ | 0.002 | 0.00179 | −11
| | 1.00 | 0.950 | −5
| | 10.0 | 9.65 | −4
October 7, 2004 | October 8, 2004 | 20.0 | 18.5 | −8
| | 100 | 97.5 | −3
| October 25–26, 2004^b^ | 20.0 | 19.4 | −3
| | 100 | 96.2 | −4

^a^ Results of duplicate analyses. Dosing volume = 5 mL/kg; 0.002 mg/mL = 0.01 mg/kg, 1.00 mg/mL = 5 mg/kg, 10.0 mg/mL = 50 mg/kg, 20.0 mg/mL = 100 mg/kg, 100 mg/mL = 500 mg/kg.

^b^ Animal room samples.

Table J-7 Results of Analyses of Dose Formulations Administered to Mice in the Three-month Gavage Study of DE-71

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
July 1, 2004 | July 2–3, 2004 | 0.001 | 0.000919 | −8
| | 0.500 | 0.498 | 0
| | 5.00 | 4.66 | −7
| | 10.0 | 9.45 | −6
| August 16–17, 2004^b^ | 0.001 | 0.00102 | +2
| | 0.500 | 0.475 | −5
| | 5.00 | 4.07 | −19
| | 10.0 | 9.46 | −5
July 8, 2004 | July 12–13, 2004 | 50.0 | 51.8 | +4
| August 16–17, 2004^b^ | 50.0 | 43.0 | −14
August 2, 2004 | August 5–6, 2004 | 0.001 | 0.000970 | −3
| | 0.500 | 0.485 | −3
| | 5.00 | 4.75 | −5
| | 10.0 | 9.49 | −5
| | 50.0 | 49.1 | −2
| September 14–15, 2004^b^ | 0.001 | 0.000986 | −1
| | 0.500 | 0.483 | −3
| | 5.00 | 4.52 | −10
| | 10.0 | 9.12 | −9
| | 50.0 | 43.7 | −13
September 27, 2004 | September 29–30, 2004 | 5.00 | 4.46^c^ | −11
| October 25–26, 2004^b^ | 5.00 | 4.72 | −6
October 4, 2004 | October 5–6, 2004 | 0.001 | 0.001 | 0
| | 0.500 | 0.468 | −6
| | 10.0 | 9.03 | −10
| | 50.0 | 46.0 | −8
| October 25–26, 2004^b^ | 0.001 | 0.000969 | −3
| | 0.500 | 0.476 | −5
| | 10.0 | 9.81 | −2
| | 50.0 | 48.8 | −2

^a^ Results of duplicate analyses. Dosing volume = 10 mL/kg; 0.001 mg/mL = 0.01 mg/kg, 0.500 mg/mL = 5 mg/kg, 5.00 mg/mL = 50 mg/kg, 10.0 mg/mL = 100 mg/kg, 50.0 mg/mL = 500 mg/kg.

^b^ Animal room samples.

^c^ Formulation was outside the acceptable range of ±10% of target concentration, but used at NTP’s direction.

Table J-8 Results of Analyses of Dose Formulations Administered to Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Date Prepared^a^ | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^b^ (mg/mL) | Difference from Target (%)
July 10, 2008 | July 10–11, 2008 | 3.00 | 3.215 | +7
| | 10.0 | 9.84 | −2
| August 26–27, 2008^c^ | 3.00 | 2.90 | −3
| | 10.0 | 9.44 | −6
July 14, 2008 | July 14–15, 2008 | 0.600 | 0.584 | −3
| August 26–27, 2008^c^ | 0.600 | 0.608 | +1
August 12, 2008 | August 13–14, 2008 | 0.600 | 0.627 | +5
| September 23–24, 2008^c^ | 0.600 | 0.615 | +3
August 15, 2008 | August 15–16, 2008 | 3.00 | 2.93 | −2
| | 10.0 | 9.23 | −8
| September 23–24, 2008^c^ | 3.00 | 2.91 | −3
| | 10.0 | 8.88 | −11
October 6, 2008 | October 7–8, 2008 | 0.600 | 0.607 | +1
| | 3.00 | 3.17 | +6
| | 10.0 | 9.35 | −7
| November 18–19, 2008^c^ | 0.600 | 0.603 | +1
| | 3.00 | 2.91 | −3
| | 10.0 | 9.94 | −1
December 29, 2008 | December 30–31, 2008 | 3.00 | 2.93 | −2
January 5, 2009 | January 5–6, 2009 | 10.0 | 9.98 | 0
January 6, 2009 | January 6–7, 2009 | 0.600 | 0.622 | +4
February 23, 2009 | February 24–25, 2009 | 0.600 | 0.589 | −2
| | 3.00 | 2.74 | −9
March 2, 2009 | March 2–3, 2009 | 10.0 | 10.2 | +2
May 18, 2009 | May 19–20, 2009 | 0.600 | 0.609 | +2
| | 3.00 | 2.97 | −1
| | 10.0 | 9.72 | −3
| June 30–July 1, 2009^c^ | 0.600 | 0.617 | +3
| | 3.00 | 3.08 | +3
| | 10.0 | 9.53 | −5
July 14, 2009 | July 16–17, 2009 | 0.600 | 0.584 | −3
| | 3.00 | 2.94 | −2
| | 10.0 | 9.67 | −3
October 6, 2009 | October 7–8, 2009 | 0.600 | 0.598 | 0
| | 3.00 | 2.95 | −2
| | 10.0 | 9.47 | −5
December 1, 2009 | December 2–3, 2009 | 0.600 | 0.610 | +2
| | 3.00 | 3.01 | 0
| | 10.0 | 9.69 | −3
| January 12–13, 2010^c^ | 0.600 | 0.602 | 0
| | 3.00 | 3.01 | 0
| | 10.0 | 9.39 | −6
February 24, 2010 | February 25–26, 2010 | 0.600 | 0.602 | 0
| | 3.00 | 3.03 | +1
| | 10.0 | 9.61 | −4
| April 8–9, 2010^c^ | 0.600 | 0.615 | +3
| | 3.00 | 2.94 | −2
| | 10.0 | 9.77 | −2
April 20, 2010 | April 21–22, 2010 | 0.600 | 0.589 | −2
| | 3.00 | 2.97 | −1
| | 10.0 | 9.61 | −4
June 14, 2010 | June 15–16, 2010 | 0.600 | 0.665^d^ | +11
| | 3.00 | 2.97 | −1
| | 10.0 | 9.95 | −1
| July 27–28, 2010^c^ | 0.600 | 0.595 | −1
| | 3.00 | 2.91 | −3
| | 10.0 | 9.28 | −7
August 9, 2010 | August 12–13, 2010 | 0.600 | 0.618 | +3
| | 3.00 | 2.94 | −2
| | 10.0 | 9.77 | −2
| September 1–2, 2010^c^ | 0.600 | 0.610 | +2
| | 3.00 | 2.97 | −1
| | 10.0 | 9.97 | 0

^a^ Dose formulations prepared from July 10, 2008, to August 15, 2008, were used for dosing dams and pups; dose formulations prepared on August 12, 2008, and thereafter were used for dosing 2-year study rats.

^b^ Results of triplicate analyses. Dosing volume = 5 mL/kg; 0.600 mg/mL = 3 mg/kg, 3.00 mg/mL = 15 mg/kg, 10.0 mg/mL = 50 mg/kg.

^c^ Animal room samples.

^d^ Formulation was outside the acceptable range of ±10% of target concentration but was inadvertently used for dosing animals; the Study Director determined there was no effect on study outcome.

Table J-9 Results of Analyses of Dose Formulations Administered to Mice in the Two-year Gavage Study of DE-71

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
February 14, 2008 | February 14, 2008 | 0.30 | 0.272 | −9
| | 10.0 | 9.55 | −5
| March 10–11, 2008^b^ | 0.30 | 0.29778 | −1
| | 10.0 | 8.8791 | −11
February 21, 2008 | February 21–22, 2008 | 3.0 | 3.03 | +1
| March 10–11, 2008^b^ | 3.0 | 3.1169 | +4
February 26, 2008 | February 27–28, 2008 | 0.30 | 0.327 | +9
| | 3.0 | 3.08 | +3
| | 10.0 | 9.37 | −6
March 24, 2008 | March 25–26, 2008 | 0.30 | 0.295 | −2
| | 3.0 | 3.06 | +2
| | 10.0 | 9.22 | −8
| May 6–7, 2008^b^ | 0.30 | 0.31596 | +5
| | 3.0 | 3.1738 | +6
| | 10.0 | 9.8772 | −1
May 19, 2008 | May 20–21, 2008 | 3.0 | 3.189 | +6
| | 10.0 | 9.75 | −3
May 22, 2008 | May 22–23, 2008 | 0.30 | 0.302 | +1
August 12, 2008 | August 13–14, 2008 | 0.30 | 0.328 | +9
August 15, 2008 | August 15–16, 2008 | 3.0 | 2.93 | −2
| | 10.0 | 9.23 | −8
October 6, 2008 | October 7–8, 2008 | 0.30 | 0.314 | +5
| | 3.0 | 3.17 | +6
| | 10.0 | 9.35 | −7
| November 18–19, 2008^b^ | 0.30 | 0.31158 | +4
| | 3.0 | 3.0530 | +2
| | 10.0 | 10.569 | +6
December 29–30, 2008 | December 30–31, 2008 | 0.30 | 0.302 | +1
| | 3.0 | 2.93 | −2
January 5, 2009 | January 5–6, 2009 | 10.0 | 9.98 | 0
February 23, 2009 | February 24–25, 2009 | 0.30 | 0.299 | 0
| | 3.0 | 2.74 | −9
March 2, 2009 | March 2–3, 2009 | 10.0 | 10.17 | +2
May 18, 2009 | May 19–20, 2009 | 0.30 | 0.288 | −4
| | 3.0 | 2.97 | −1
| | 10.0 | 9.72 | −3
| June 30–July 1, 2009^b^ | 0.30 | 0.305 | +2
| | 3.0 | 3.045 | +2
| | 10.0 | 9.531 | −5
July 14, 2009 | July 16–17, 2009 | 0.30 | 0.317 | +6
| | 3.0 | 2.94 | −2
| | 10.0 | 9.67 | −3
October 6, 2009 | October 7–8, 2009 | 0.30 | 0.294 | −2
| | 3.0 | 2.95 | −2
| | 10.0 | 9.47 | −5
December 1, 2009 | December 2–3, 2009 | 0.30 | 0.325 | +8
| | 3.0 | 3.01 | 0
| | 10.0 | 9.69 | −3
| January 12–13, 2010^b^ | 0.30 | 0.310 | +3
| | 3.0 | 3.091 | +3

^a^ Results of triplicate analyses. Dosing volume = 10 mL/kg; 0.30 mg/mL = 3 mg/kg, 3.0 mg/mL = 30 mg/kg, 10.0 mg/mL = 100 mg/kg.

^b^ Animal room samples.

Figure J-1

Infrared Absorption Spectrum of DE-71

Figure J-2

Proton Nuclear Magnetic Resonance Spectrum of DE-71