# Appendix I Tissue Concentration Studies

## I.1 Materials and Methods

### I.1.1 Three-month Studies

Groups of 10 male and 10 female special study F344/N rats were randomly assigned to the tissue distribution study at the beginning of the 3-month study. Samples of adipose and liver were collected from vehicle control and each dosed group of special study male and female rats at day 25 and from 10 male and 10 female core study F344/N rats at week 14. Adipose samples were collected from vehicle control and each dosed group of male and female B6C3F1/N mice at week 14 (up to 10 animals/dose group).

All samples were frozen at −70°C and shipped to the analytical chemistry laboratory (Battelle Columbus Operations, Columbus, OH).

### I.1.2 Two-year Studies

In Wistar Han [Crl:WI(Han)] rats following perinatal exposure of dams, livers and carcasses from six male and six or seven female F_1_ pups from the vehicle control and each dosed group were collected after litter standardization on postnatal day (PND) 4 following decapitation and exsanguination. Groups of six F_0_ dams were randomly assigned to the tissue distribution study. On PND 21, adipose and livers from each dam and one pup/sex per litter were collected from all dose groups. Samples of adipose, liver, and plasma were collected at the end of the study from up to 15 F_1_ animals/sex per group from all dose groups.

Adipose and liver samples were collected from up to 16 male and 16 female B6C3F1/N mice per dose group at study termination, except that samples from 100 mg/kg male and female mice were collected at approximately 18 months.

All samples were frozen at −70°C and shipped to the analytical chemistry laboratory (Battelle Columbus Operations).

### I.1.3 Preparation of Plasma for Analysis

All samples were stored frozen at −70°C until analysis. After thawing at room temperature, a 100 µL aliquot of plasma was transferred into a tube along with the internal standard (100 µL of 11 µg PCB 118/mL toluene). For samples of less than 100 µL, blank plasma was added to bring the final volume to 100 µL. The tubes were mixed and placed in a sonicator for approximately 10 minutes and periodically shaken to remove plasma from the side of the tube. The tubes were subsequently placed on a sample rotator overnight (at 60 rpm), centrifuged for a minimum of 2 minutes at 1,000 rpm, and an aliquot of the supernatant was transferred to an auto injector vial for analysis.

### I.1.4 Preparation of Adipose, Liver, and PND 4 Pup Carcass for Analysis

All samples were stored frozen at −70°C until analysis. Prior to preparation, samples were allowed to thaw at room temperature. Adipose, liver, and PND 4 pup carcass were prepared and analyzed similarly to plasma with minor modifications. Pup carcass was homogenized in a 50 mL polypropylene tube for 5 minutes. The internal standard solution (100 µL of 55 µg PCB 118/mL toluene) and 3 mL of toluene were added to approximately 0.1 g of adipose, liver, or pup carcass homogenate and extraction was similar to that described above for plasma. An aliquot of the supernatant was transferred to an auto injector vial for analysis.

### I.1.5 Quantitation of BDE-47, BDE-99, and BDE-153

Selected polybrominated diphenyl ether (PBDE) congeners (BDE-47, BDE-99, and BDE-153) were quantified as described below using validated analytical methods. Authentic standards of BDE-47 (99.6%), BDE-99 (97.6%) and BDE-153 (99.5%) were obtained from Ceriliant Corporation (Round Rock, TX). All samples were analyzed on an Agilent 6890 gas chromatograph (Agilent, Santa Clara, CA) coupled to an electron capture detector. An RTX^®^-5 column (30 m × 0.25 mm, 1.0 µm film thickness) (Restek, Bellefonte, PA) was used with a helium carrier gas at a flow rate of 3 mL/minute. The oven temperature was held at 210°C for 2 minutes and then ramped to 330°C at 8°C/minute and held for 3 minutes. Injector and detector temperatures were 300°C and 320°C, respectively. One µL of each sample extract was analyzed in the splitless mode for plasma and in 1:1 split mode for other matrices.

All matrix calibration standards and quality control (QC) samples were treated and analyzed similar to the study samples. Calibration curves were run on adipose (0.900 to 120 µg/g), liver (0.900 to 120 µg/g), pup carcass (0.900 to 120 µg/g), and plasma (0.0875 to 15 µg/mL) with a minimum of six calibration standards and a calibration blank run before analysis of each set of samples. During the analysis of liver from the 3-month study an additional calibration curve covering the range 0.010 to 1.0 µg/mL was also run. The performance of the calibration curve was evaluated prior to the analysis of each sample set. A successful calibration was indicated by the following: correlation coefficient (r^2^) ≥ 0.98; relative standard deviation (RSD) ≤ ± 15% [except at experimental limit of quantitation (LOQs) where RSD ≤ ± 20%]; relative error (RE) ≤ ± 15% (except at experimental LOQ where RE ≤ ± 20%). The experimental LOQs for BDE-47, BDE-99, and BDE-153 were: plasma, 0.0875 µg/mL (except in one run where LOQ for BDE-153 was 0.188 µg/mL); adipose and pup carcass, 0.900 µg/g; and liver, 0.010 (low curve) or 0.900 (high curve) µg/g.

Data from study samples were considered valid if they were bracketed by valid QC sets. In general, for each sample set, method blanks and controls were bracketed by two QC sets, which consisted of a calibration blank and two concentrations of calibration standards (QC low and QC high), with six samples at each concentration. A QC set passed when the measured concentrations for QC standards were within 15% of their nominal values. If the QC standard failed, it was necessary to reanalyze the bracketed samples.

In addition, incurred sample reanalysis was conducted. During the analysis of rat liver samples from the 2-year study, incurred sample reanalysis did not pass all of the acceptance criteria mentioned above. Following an investigation, it was decided to analyze liver samples using up to four replicates when possible. The average value for the replicates was reported when applicable.

The concentration of each analyte was calculated using its individual response, the regression equation, sample weight, and dilution when applicable. Samples with responses greater than the highest calibration standard were diluted with the diluent to get a response within the range. The diluent was prepared similarly to samples but used blank matrix. The concentrations of BDE-43, BDE-99, and BDE-153 in adipose and liver (rats only) from the subchronic studies were expressed as µg/g matrix. The concentrations of BDE-43, BDE-99, and BDE-153 in plasma from the 2-year rat study were expressed as µg/mL plasma. The concentrations of BDE-43, BDE-99, and BDE-153 in adipose and liver from the 2-year studies were expressed as both µg/g matrix and µg/g lipid. The concentrations of BDE-43, BDE-99, and BDE-153 in pup carcass on PND 4 were expressed as µg/g carcass.

### I.1.6 Analysis of Adipose and Liver for Lipid Content

All samples were stored frozen at −70°C until analysis. Prior to analysis, samples were allowed to thaw at room temperature. An aliquot of approximately 10 mg of adipose or 50 mg of liver from each study animal was weighed into disposable hand-held homogenizer tubes. Triplicate aliquots were prepared when sufficient sample remained. Following the addition of 4 mL of 1:1 chloroform:methanol (v/v), samples were ground until visibly homogeneous and centrifuged for approximately 5 minutes at 3,000 rpm. The supernatant was transferred into a 5 mL volumetric flask. An additional 0.5 mL of extraction solution was added to each sample tube, and the contents were ground for an additional 30 seconds and centrifuged for 5 minutes at 300 rpm. The supernatant was combined with the first extract and the flask was filled to volume with extraction solution, sealed, and mixed. A 0.25 mL aliquot of each sample extract was evaporated to dryness using a dry block heater at approximately 100°C.

To each residue, 0.2 mL of concentrated sulfuric acid was added and the sample was mixed briefly and placed on the dry block heater at 100°C for 15 minutes. Samples were allowed to cool to room temperature and a vanillin reagent (2.5 mL of 1.2 mg vanillin/mL 68% aqueous phosphoric acid) was added to each hydrolysate. Tubes were vortexed for approximately 3 seconds, covered with an opaque box, and allowed to react for 30 minutes. A 0.2 mL aliquot of the resulting colored solution was pipetted into a 96-well plate, and the absorbance at 490 nm was measured using a DTX 880 Multimode Detector (Beckman Coulter, Inc., Brea, CA) at 25°C. Soybean oil was used as the standard for quantitation of lipids. Standards and blanks (extraction solvent) were carried through the sulfuric acid digestion and the vanillin reaction similar to the study samples. The lipid content of each sample was calculated as a percent of total tissue weight. The average lipid content was calculated for all samples where more than one replicate was analyzed.

Table I-1 Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose and Liver in F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
BDE-47 (µg/g)
Adipose
Day 25 | 0.44 ± 0.00 | 0.61 ± 0.07 | 63.82 ± 1.57 | 320.43 ± 6.32 | 604.67 ± 11.04 | 3,268.40 ± 107.68
Week 14 | 0.98 ± 0.04 | 1.81 ± 0.13 | 144.06 ± 3.27 | 596.78 ± 9.04 | 1,056.65 ± 19.45 | 4,849.10 ± 106.89
Liver
Day 25 | 0.01 ± 0.00 | 0.04 ± 0.00 | 2.73 ± 0.33 | 17.48 ± 2.25 | 30.96 ± 3.64 | 186.99 ± 14.40
Week 14 | 0.07 ± 0.01 | 0.09 ± 0.02 | 2.07 ± 0.15 | 8.85 ± 1.28 | 16.62 ± 1.88 | 80.87 ± 9.89
BDE-99 (µg/g)
Adipose
Day 25 | ND | 0.50 ± 0.05 | 36.29 ± 1.07 | 256.94 ± 4.95 | 560.33 ± 12.86 | 3,012.70 ± 132.59
Week 14 | 0.82 ± 0.03 | 1.50 ± 0.10 | 102.90 ± 2.82 | 574.49 ± 10.38 | 1,066.27 ± 18.00 | 4,867.30 ± 126.70
Liver
Day 25 | 0.01 ± 0.00 | 0.04 ± 0.00 | 2.12 ± 0.27 | 15.24 ± 2.34 | 27.90 ± 4.54 | 185.85 ± 19.62
Week 14 | 0.08 ± 0.01 | 0.08 ± 0.01 | 1.19 ± 0.21 | 3.79 ± 0.45 | 8.65 ± 0.86 | 58.25 ± 7.14
BDE-153 (µg/g)
Adipose
Day 25 | ND | ND | 7.59 ± 0.42 | 58.88 ± 1.60 | 136.24 ± 7.04 | 653.53 ± 52.46
Week 14 | ND | 0.45 ± 0.00 | 27.34 ± 0.66 | 210.13 ± 6.28 | 383.75 ± 9.51 | 1,649.50 ± 38.55
Liver
Day 25 | 0.01 ± 0.00 | 0.02 ± 0.00 | 1.60 ± 0.14 | 15.55 ± 1.87 | 28.12 ± 1.78 | 139.96 ± 9.76
Week 14 | 0.03 ± 0.00 | 0.03 ± 0.01 | 1.92 ± 0.28 | 17.23 ± 3.07 | 34.09 ± 4.55 | 112.10 ± 16.32
Female
n | 10 | 10 | 10 | 10 | 10 | 10
BDE-47 (µg/g)
Adipose
Day 25 | 0.44 ± 0.01 | 0.82 ± 0.05 | 80.24 ± 2.76 | 417.80 ± 21.02 | 721.14 ± 33.18^b^ | 4,157.40 ± 252.41
Week 14 | 1.15 ± 0.10 | 2.23 ± 0.09 | 180.03 ± 5.38 | 770.74 ± 15.00 | 1,363.80 ± 38.58 | 7,619.30 ± 252.15
Liver
Day 25 | 0.01 ± 0.00 | 0.04 ± 0.01 | 2.84 ± 0.13 | 22.75 ± 1.85 | 37.50 ± 4.13^b^ | 156.36 ± 14.87
Week 14 | 0.03 ± 0.01 | 0.06 ± 0.01 | 2.30 ± 0.19 | 11.54 ± 0.99 | 15.84 ± 1.51 | 158.65 ± 22.46
BDE-99 (µg/g)
Adipose
Day 25 | ND | 0.62 ± 0.04 | 48.22 ± 1.43 | 339.16 ± 17.30 | 657.59 ± 31.99^b^ | 4,054.40 ± 253.52
Week 14 | 1.00 ± 0.09 | 1.92 ± 0.09 | 118.30 ± 3.57 | 681.93 ± 14.11 | 1,314.00 ± 29.38 | 7,510.00 ± 255.13
Liver
Day 25 | 0.01 ± 0.00 | 0.04 ± 0.01 | 2.24 ± 0.18 | 21.07 ± 2.26 | 36.28 ± 5.13^b^ | 164.45 ± 19.94
Week 14 | 0.03 ± 0.01 | 0.05 ± 0.01 | 1.26 ± 0.08 | 5.23 ± 0.52 | 7.84 ± 0.83 | 131.56 ± 22.49
BDE-153 (µg/g)
Adipose
Day 25 | ND | ND | 9.97 ± 0.59 | 88.19 ± 3.98 | 183.52 ± 10.58^b^ | 1,021.26 ± 57.80
Week 14 | ND | 0.46 ± 0.01 | 27.21 ± 1.70 | 269.67 ± 10.98 | 601.63 ± 27.33 | 2,685.30 ± 114.75
Liver
Day 25 | 0.01 ± 0.00 | 0.02 ± 0.00 | 1.30 ± 0.04 | 15.70 ± 1.93 | 26.80 ± 1.78^b^ | 92.68 ± 5.60
Week 14 | 0.01 ± 0.00 | 0.02 ± 0.00 | 1.19 ± 0.11 | 16.88 ± 1.66 | 27.68 ± 2.54 | 148.29 ± 21.44

^a^ Data are presented as mean µg analyte/g tissue ± standard error. Values below the experimental limit of quantitation were replaced with ½ the limit of quantitation if there was at least one value in the group that was above the limit of quantitation. ND = all values were missing or below the limit of quantitation; BDE-47 = 2,2′,4,4′-tetrabromodiphenyl ether; BDE-99 = 2,2′,4,4′,5-pentabromodiphenyl ether; BDE-153 = 2,2′,4,4′,5,5′-hexabromodiphenyl ether.

^b^ n = 9.

Table I-2 Concentrations of Lipids and Selected Polybrominated Diphenyl Ether Congeners in Adipose and Liver in Wistar Han Rat Dams on PND 21 in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
n | 6 | 6 | 6 | 6
Lipid (%)
Adipose | 91.14 ± 1.64 | 94.60 ± 2.73 | 94.83 ± 2.05 | 94.59 ± 2.40
Liver | 6.39 ± 0.10 | 5.92 ± 0.19 | 6.17 ± 0.15 | 5.86 ± 0.12
BDE-47 (µg/g)
Adipose | ND | 40.2 ± 4.9 | 347.0 ± 41.8 | 925.7 ± 80.4
Adipose (lipid-adjusted) | ND | 43.1 ± 5.9 | 368.0 ± 44.9 | 974.1 ± 64.6
Liver | ND | ND | ND | 1.3 ± 0.2
Liver (lipid-adjusted) | ND | ND | ND | 21.8 ± 3.5
BDE-99 (µg/g)
Adipose | ND | 66.8 ± 6.4 | 501.8 ± 60.1 | 1,513.3 ± 186.9
Adipose (lipid-adjusted) | ND | 71.4 ± 7.9 | 535.3 ± 70.6 | 1,595.7 ± 183.3
Liver | ND | ND | ND | 1.1 ± 0.2
Liver (lipid-adjusted) | ND | ND | ND | 18.0 ± 3.7
BDE-153 (µg/g)
Adipose | ND | 11.0 ± 1.1 | 93.1 ± 16.5 | 304.8 ± 37.8
Adipose (lipid-adjusted) | ND | 11.6 ± 1.2 | 99.9 ± 19.5 | 322.9 ± 40.5
Liver | ND | ND | ND | 0.6 ± 0.1
Liver (lipid-adjusted) | ND | ND | ND | 9.5 ± 1.8

^a^ Data are presented as mean µg analyte/g matrix ± standard error. Values below the experimental limit of quantitation were replaced with ½ the limit of quantitation if there was at least one value in the group that was above the limit of quantitation. ND = all values were missing or below the limit of quantitation; BDE-47 = 2,2′,4,4′-tetrabromodiphenyl ether; BDE-99 = 2,2′,4,4′,5-pentabromodiphenyl ether; BDE-153 = 2,2′,4,4′,5,5′-hexabromodiphenyl ether.

Table I-3 Concentrations of Lipids and Selected Polybrominated Diphenyl Ether Congeners in Adipose, Liver, and Carcass in F_1_ Wistar Han Rat Pups in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Male
n | 6 | 6 | 6 | 6
Lipid (%)
PND 4
Liver | NS | NS | 9.82 ± 0.27 | 9.91 ± 0.82
PND 21
Adipose | 72.59 ± 3.38 | 67.57 ± 2.63^b^ | 74.86 ± 4.89^b^ | 77.61 ± 6.02^b^
Liver | 7.90 ± 0.22 | 8.22 ± 0.23 | 9.05 ± 0.25 | 10.49 ± 0.52
BDE-47 (µg/g)
PND 4
Liver | ND | 1.0 ± 0.3 | 7.5 ± 1.8 | 55.8 ± 21.7
Liver (lipid-adjusted) | ND | ND | 75.5 ± 16.5 | 686.3 ± 349.4
Carcass | ND | 4.5 ± 0.4 | 24.2 ± 4.0 | 58.2 ± 13.3
PND 21
Adipose | ND | 108.2 ± 12.6 | 403.8 ± 25.5 | 1,044.3 ± 103.1
Adipose (lipid-adjusted) | ND | 142.3 ± 23.1^b^ | 502.9 ± 51.2^b^ | 1,266.9 ± 202.5^b^
Liver | ND | ND | 2.1 ± 0.3 | 8.3 ± 1.7
Liver (lipid-adjusted) | ND | ND | 23.2 ± 2.7 | 79.6 ± 14.8
BDE-99 (µg/g)
PND 4
Liver | ND | 1.1 ± 0.2 | 7.8 ± 2.2 | 55.7 ± 19.1
Liver (lipid-adjusted) | ND | ND | 77.9 ± 20.1 | 657.1 ± 288.9
Carcass | ND | 3.8 ± 0.4 | 20.6 ± 3.4 | 52.2 ± 12.0
PND 21
Adipose | ND | 76.8 ± 9.1 | 294.0 ± 23.2 | 846.8 ± 96.7
Adipose (lipid-adjusted) | ND | 104.5 ± 18.^2b^ | 358.8 ± 41.7^b^ | 1,031.0 ± 184.7^b^
Liver | ND | ND | 0.6 ± 0.1 | 4.6 ± 1.3
Liver (lipid-adjusted) | ND | ND | 6.5 ± 1.4 | 43.5 ± 11.1
BDE-153 (µg/g)
PND 4
Liver | ND | ND | 3.1 ± 0.8 | 20.7 ± 6.5
Liver (lipid-adjusted) | ND | ND | 31.0 ± 6.9 | 240.9 ± 96.6
Carcass | ND | ND | 3.8 ± 0.6 | 10.1 ± 1.6
PND 21
Adipose | ND | 13.2 ± 1.7 | 65.8 ± 6.9 | 194.5 ± 22.9
Adipose (lipid-adjusted) | ND | 17.4 ± 3.5^b^ | 78.0 ± 8.9^b^ | 242.6 ± 24.8^b^
Liver | ND | ND | 1.3 ± 0.2 | 7.2 ± 1.2
Liver (lipid-adjusted) | ND | ND | 14.7 ± 2.4 | 68.8 ± 11.0
Female
n | 6 | 6 | 6 | 6
Lipid (%)
PND 4
Liver | NS | NS | 10.71 ± 0.87 | 10.80 ± 0.34^c^
PND 21
Adipose | 62.55 ± 2.07^d^ | 70.11 ± 2.73^b^ | 74.46 ± 2.35 | 74.65 ± 5.39^b^
Liver | 7.36 ± 0.21 | 7.43 ± 0.23 | 9.13 ± 0.40 | 11.28 ± 0.71
BDE-47 (µg/g)
PND 4
Liver | ND | 1.5 ± 0.4 | 8.8 ± 2.3 | 28.5 ± 6.8^c^
Liver (lipid-adjusted) | ND | ND | 90.0 ± 26.4 | 256.5 ± 56.4^c^
Carcass | ND | 5.5 ± 0.6 | 26.0 ± 2.5 | 60.2 ± 8.5^c^
PND 21
Adipose | ND | 92.1 ± 6.9 | 377.2 ± 15.0 | 922.5 ± 106.9
Adipose (lipid-adjusted) | ND | 139.6 ± 10.7^b^ | 508.6 ± 24.3 | 1,258.3 ± 107.3^b^
Liver | ND | ND | 1.9 ± 0.3 | 7.9 ± 0.8
Liver (lipid-adjusted) | ND | ND | 20.5 ± 3.0 | 70.4 ± 8.0
BDE-99 (µg/g)
PND 4
Liver | ND | 1.8 ± 0.5 | 9.1 ± 2.6 | 33.5 ± 8.2^c^
Liver (lipid-adjusted) | ND | ND | 93.7 ± 30.4 | 300.4 ± 66.9^c^
Carcass | ND | 5.0 ± 0.7 | 22.3 ± 2.3 | 55.1 ± 8.2^c^
PND 21
Adipose | ND | 67.8 ± 6.7 | 278.0 ± 14.3 | 713.5 ± 82.4
Adipose (lipid-adjusted) | ND | 102.2 ± 10.4^b^ | 373.8 ± 17.5 | 1,013.1 ± 71.8^b^
Liver | ND | ND | 0.5 ± 0.1 | 3.6 ± 0.3
Liver (lipid-adjusted) | ND | ND | 6.0 ± 1.0 | 31.9 ± 2.4
BDE-153 (µg/g)
PND 4
Liver | ND | 0.6 ± 0.1^d^ | 3.7 ± 1.0 | 14.4 ± 3.6^c^
Liver (lipid-adjusted) | ND | ND | 38.3 ± 12.1 | 129.9 ± 30.4^c^
Carcass | ND | 0.7 ± 0.2 | 4.1 ± 0.5 | 10.6 ± 1.2^c^
PND 21
Adipose | ND | 11.6 ± 0.9 | 65.9 ± 2.9 | 162.2 ± 9.2
Adipose (lipid-adjusted) | ND | 17.2 ± 1.3^b^ | 88.7 ± 3.7 | 237.9 ± 21.6^b^
Liver | ND | ND | 1.3 ± 0.2 | 6.6 ± 0.9
Liver (lipid-adjusted) | ND | ND | 14.0 ± 1.8 | 59.1 ± 8.7

^a^ Data are presented as mean µg analyte/g matrix ± standard error. Values below the experimental limit of quantitation were replaced with ½ the limit of quantitation if there was at least one value in the group that was above the limit of quantitation. ND = all values were missing or below the limit of quantitation; BDE-47 = 2,2′,4,4′-tetrabromodiphenyl ether; BDE-99 = 2,2′,4,4′,5-pentabromodiphenyl ether; BDE-153 = 2,2′,4,4′,5,5′-hexabromodiphenyl ether. NS = not sampled.

^b^ n = 4.

^c^ n = 7.

^d^ n = 5.

Table I-4 Concentrations of Lipids and Selected Polybrominated Diphenyl Ether Congeners in Adipose, Liver, and Plasma in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Male
n | 14 | 10 | 12 | 15
(lipid-adjusted) (%)
Adipose | 86.71 ± 1.89 | 87.69 ± 2.45 | 84.35 ± 3.18 | 101.20 ± 3.29
Liver | 5.08 ± 0.32 | 6.67 ± 0.61 | 6.98 ± 0.86 | 9.91 ± 1.24^b^
BDE-47 (µg/g)
Adipose | 0.6 ± 0.1 | 187.9 ± 7.5 | 470.6 ± 24.8 | 1,671.1 ± 344.8
Adipose (lipid-adjusted) | 0.8 ± 0.1 | 216.0 ± 11.5 | 564.6 ± 31.2 | 1,686.0 ± 372.7
Liver | ND | 4.1 ± 0.6 | 8.3 ± 1.1 | 50.9 ± 13.0
Liver (lipid-adjusted) | ND | 64.0 ± 9.3 | 122.6 ± 15.8 | 441.4 ± 76.9^b^
Plasma | ND | 0.44 ± 0.06 | 0.95 ± 0.08^c^ | 4.97 ± 0.43^c^
BDE-99 (µg/g)
Adipose | 0.7 ± 0.1 | 151.2 ± 5.9 | 461.5 ± 21.3 | 1,851.9 ± 416.6
Adipose (lipid-adjusted) | 0.8 ± 0.1 | 173.7 ± 8.7 | 553.6 ± 26.9 | 1,869.5 ± 449.2
Liver | ND | 2.0 ± 0.5 | 4.9 ± 0.7 | 40.6 ± 10.2
Liver (lipid-adjusted) | ND | 31.6 ± 7.4 | 71.6 ± 8.9 | 361.1 ± 66.7^b^
Plasma | ND | 0.22 ± 0.05 | 0.45 ± 0.05^c^ | 4.06 ± 0.54^c^
BDE-153 (µg/g)
Adipose | ND | 101.9 ± 5.3 | 447.8 ± 30.0 | 1,445.4 ± 227.5
Adipose (lipid-adjusted) | ND | 116.7 ± 6.2 | 538.0 ± 37.7 | 1,464.3 ± 246.7
Liver | ND | 1.8 ± 0.5 | 9.4 ± 1.6 | 47.4 ± 10.6
Liver (lipid-adjusted) | ND | 29.2 ± 7.9 | 132.7 ± 19.8 | 446.2 ± 60.5^b^
Plasma | ND | 0.20 ± 0.03 | 0.71 ± 0.06^c^ | 6.06 ± 1.40^c^
Female
n | 13 | 15 | 13 | 10
(lipid-adjusted) (%)
Adipose | 100.86 ± 3.61 | 99.18 ± 2.67 | 93.82 ± 2.49^d^ | 97.44 ± 2.69
Liver | 5.97 ± 0.28^d^ | 8.56 ± 1.30^e^ | 5.85 ± 0.19^f^ | 6.19 ± 0.36^g^
BDE-47 (µg/g)
Adipose | 0.7 ± 0.1 | 274.2 ± 21.8 | 744.0 ± 84.0 | 2,603.4 ± 542.8
Adipose (lipid-adjusted) | 0.7 ± 0.1 | 279.2 ± 22.7 | 817.3 ± 98.9^d^ | 2,619.5 ± 506.2
Liver | ND | 5.8 ± 1.6 | 11.3 ± 2.6 | 48.9 ± 12.8
Liver (lipid-adjusted) | ND | 59.8 ± 8.6^e^ | 164.6 ± 30.6^f^ | 819.3 ± 180.4^g^
Plasma | ND | 0.73 ± 0.10^f^ | 2.13 ± 0.42^c^ | 8.74 ± 1.78^d^
BDE-99 (µg/g)
Adipose | 0.7 ± 0.1 | 214.5 ± 18.8 | 742.1 ± 92.0 | 3,007.7 ± 671.1
Adipose (lipid-adjusted) | 0.8 ± 0.1 | 218.5 ± 19.1 | 815.3 ± 106.9^d^ | 3,017.8 ± 628.9
Liver | ND | 3.0 ± 1.1 | 7.5 ± 2.1 | 45.4 ± 12.4
Liver (lipid-adjusted) | ND | 25.3 ± 6.5^e^ | 102.3 ± 23.2^f^ | 767.6 ± 182.3^g^
Plasma | ND | 0.40 ± 0.06^f^ | 1.36 ± 0.32^c^ | 7.67 ± 1.86^d^
BDE-153 (µg/g)
Adipose | ND | 139.7 ± 15.5 | 675.7 ± 87.3 | 2,055.5 ± 226.2
Adipose (lipid-adjusted) | ND | 143.2 ± 17.3 | 734.8 ± 103.1^d^ | 2,093.5 ± 203.0
Liver | ND | 2.8 ± 0.8 | 10.0 ± 1.8 | 42.3 ± 8.8
Liver (lipid-adjusted) | ND | 28.4 ± 6.7^e^ | 152.4 ± 22.3^f^ | 730.1 ± 111.1^g^
Plasma | ND | 0.44 ± 0.09^f^ | 1.99 ± 0.39^c^ | 8.27 ± 0.83^d^

^a^ Data are presented as mean µg analyte/g matrix ± standard error. Values below the experimental limit of quantitation were replaced with ½ the limit of quantitation if there was at least one value in the group that was above the limit of quantitation. ND = all values were missing or below the limit of quantitation; BDE-47 = 2,2′,4,4′-tetrabromodiphenyl ether; BDE-99 = 2,2′,4,4′,5-pentabromodiphenyl ether; BDE-153 = 2,2′,4,4′,5,5′-hexabromodiphenyl ether.

^b^ n = 13.

^c^ n = 10.

^d^ n = 12.

^e^ n = 14.

^f^ n = 11.

^g^ n = 9.

Table I-5 Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 3
BDE-47 (µg/g) | ND | ND | 20.63 ± 0.87 | 206.89 ± 5.37 | 517.71 ± 12.64 | 6,168.00 ± 1,031.91
BDE-99 (µg/g) | 0.68 ± 0.09 | 1.50 ± 0.63 | 98.55 ± 3.15 | 587.83 ± 13.44 | 1,281.83 ± 58.03 | 10,588.0 ± 1,414.29
BDE-153 (µg/g) | 0.49 ± 0.04 | 0.62 ± 0.15 | 23.68 ± 1.15 | 273.37 ± 14.56 | 567.51 ± 44.33 | 9,796.00 ± 1,909.03
Female
n | 9 | 10 | 10 | 9 | 9 | 5
BDE-47 (µg/g) | 0.47 ± 0.02 | 0.49 ± 0.03 | 43.26 ± 2.37 | 356.08 ± 19.34 | 846.91 ± 49.51 | 4,196.80 ± 239.98
BDE-99 (µg/g) | 1.09 ± 0.18 | 1.59 ± 0.18 | 116.67 ± 8.41 | 616.96 ± 29.31 | 1,420.00 ± 98.15 | 6,729.20 ± 379.72
BDE-153 (µg/g) | 0.56 ± 0.09 | 0.85 ± 0.11 | 40.65 ± 5.83 | 343.88 ± 27.61 | 701.27 ± 91.36 | 3,936.00 ± 246.00

^a^ Data are presented as mean µg analyte/g adipose ± standard error. Values below the experimental limit of quantitation were replaced with ½ the limit of quantitation if there was at least one value in the group that was above the limit of quantitation. ND = all values were missing or below the limit of quantitation; BDE-47 = 2,2′,4,4′-tetrabromodiphenyl ether; BDE-99 = 2,2′,4,4′,5-pentabromodiphenyl ether; BDE-153 = 2,2′,4,4′,5,5′-hexabromodiphenyl ether.

Table I-6 Concentrations of Lipids and Selected Polybrominated Diphenyl Ether Congeners in Adipose and Liver in Mice in the Two-year Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Male
n | 9 | 4 | 0^b^ | 16
Lipid (%)
Adipose | 77.14 ± 5.94 | 75.50 ± 20.23 | – | 83.55 ± 3.19^c^
Liver | 6.78 ± 0.67^d^ | 6.17 ± 0.17^e^ | – | 5.55 ± 0.39^f^
BDE-47 (µg/g)
Adipose | 0.9 ± 0.5 | 22.6 ± 2.4 | – | 682.0 ± 64.4
Adipose (lipid-adjusted) | 1.3 ± 0.7 | 42.4 ± 15.6 | – | 850.3 ± 84.1^c^
Liver | ND | 0.8 ± 0.3 | – | 18.3 ± 2.7
Liver (lipid-adjusted) | ND | ND | – | 360.3 ± 61.3^f^
BDE-99 (µg/g)
Adipose | 3.1 ± 2.0 | 123.0 ± 15.6 | – | 1,601.3 ± 171.1
Adipose (lipid-adjusted) | 4.5 ± 3.0 | 223.7 ± 76.2 | – | 1,996.5 ± 190.4^c^
Liver | ND | 2.4 ± 0.8 | – | 32.9 ± 5.0
Liver (lipid-adjusted) | ND | 26.7 ± 9.6^e^ | – | 678.8 ± 148.5^f^
BDE-153 (µg/g)
Adipose | 1.2 ± 0.6 | 138.2 ± 27.1 | – | 11,031.9 ± 1,579.1
Adipose (lipid-adjusted) | 1.7 ± 1.0 | 231.7 ± 67.1 | – | 13,708.1 ± 2,188.0^c^
Liver | ND | 4.1 ± 1.1 | – | 339.5 ± 54.1
Liver (lipid-adjusted) | ND | 55.0 ± 21.0^e^ | – | 8,605.9 ± 3,030.5^f^
Female
n | 10 | 10 | 9 | 13
Lipid (%)
Adipose | 94.59 ± 4.00 | 91.52 ± 6.00 | 97.63 ± 10.20 | 81.25 ± 4.69
Liver | 7.41 ± 0.41^g^ | 7.83 ± 0.27^d^ | 8.90 ± 1.24^g^ | 7.22 ± 0.61^d^
BDE-47 (µg/g)
Adipose | 0.9 ± 0.2 | 49.1 ± 3.3 | 275.1 ± 33.6 | 1,015.9 ± 104.8
Adipose (lipid-adjusted) | 0.9 ± 0.2 | 57.5 ± 7.4 | 291.4 ± 39.4 | 1,293.0 ± 144.9
Liver | ND | 1.7 ± 0.3 | 12.5 ± 3.4 | 33.4 ± 6.0
Liver (lipid-adjusted) | ND | 21.4 ± 5.1^d^ | 193.1 ± 84.5^g^ | 388.9 ± 96.4^d^
BDE-99 (µg/g)
Adipose | 1.6 ± 0.3 | 119.8 ± 5.2 | 557.5 ± 60.8 | 2,114.2 ± 159.8
Adipose (lipid-adjusted) | 1.7 ± 0.3 | 137.3 ± 12.8 | 601.3 ± 74.7 | 2,707.5 ± 268.3
Liver | ND | 3.3 ± 0.5 | 20.4 ± 6.1 | 59.7 ± 10.8
Liver (lipid-adjusted) | ND | 40.6 ± 8.1^d^ | 332.0 ± 155.0^g^ | 674.7 ± 164.3^d^
BDE-153 (µg/g)
Adipose | ND | 113.3 ± 30.6 | 1,016.5 ± 239.0 | 5,766.8 ± 882.5
Adipose (lipid-adjusted) | ND | 127.1 ± 33.9 | 1,315.8 ± 519.5 | 7,793.4 ± 1,528.5
Liver | 0.6 ± 0.1 | 3.4 ± 0.4 | 53.2 ± 10.2 | 436.4 ± 189.7
Liver (lipid-adjusted) | 8.1 ± 1.8^g^ | 45.5 ± 7.2^d^ | 900.0 ± 318.4^g^ | 3,284.1 ± 856.0^d^

^a^ Data are presented as mean µg analyte/g tissue ± standard error. Values below the experimental limit of quantitation were replaced with ½ the limit of quantitation if there was at least one value in the group that was above the limit of quantitation. ND = all values were missing or below the limit of quantitation; BDE-47 = 2,2′,4,4′-tetrabromodiphenyl ether; BDE-99 = 2,2′,4,4′,5-pentabromodiphenyl ether; BDE-153 = 2,2′,4,4′,5,5′-hexabromodiphenyl ether.

^b^ Samples were not collected from 30 mg/kg males due to insufficient normal tissue.

^c^ n = 15.

^d^ n = 6.

^e^ n = 3.

^f^ n = 4.

^g^ n = 7.

Figure I-1

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in F344/N Rats on Day 25 in the Three-month Gavage Study of DE-71

Figure I-2

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in F344/N Rats at Week 14 in the Three-month Gavage Study of DE-71

Figure I-3

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Liver in F344/N Rats on Day 25 in the Three-month Gavage Study of DE-71

Figure I-4

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Liver in F344/N Rats at Week 14 in the Three-month Gavage Study of DE-71

Figure I-5

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in Wistar Han Rat Dams on PND 21 in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-6

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Liver in F_1_ Wistar Han Rat Pups on PND 4 in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-7

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in the Carcass of F_1_ Wistar Han Rat Pups on PND 4 in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-8

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in F_1_ Wistar Han Rat Pups on PND 21 in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-9

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Liver in F_1_ Wistar Han Rat Pups on PND 21 in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-10

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-11

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Liver in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-12

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Plasma in F_1_ Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Figure I-13

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in Mice in the Three-month Gavage Study of DE-71

Figure I-14

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Adipose in Mice in the Two-year Gavage Study of DE-71

Figure I-15

Concentrations of Selected Polybrominated Diphenyl Ether Congeners in Liver in Mice in the Two-year Gavage Study of DE-71