# Appendix H Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table H-1 Summary of Reproductive Tissue Evaluations for Male F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 50 mg/kg | 100 mg/kg | 500 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 316 ± 6 | 335 ± 7.9 | 318 ± 8 | 282 ± 12*
L. Cauda epididymis | 0.1289 ± 0.0050 | 0.1385 ± 0.0119^b^ | 0.1328 ± 0.0087 | 0.0724 ± 0.0047**
L. Epididymis | 0.4284 ± 0.0102 | 0.4485 ± 0.0168 | 0.4184 ± 0.0141 | 0.3135 ± 0.0128**
L. Testis | 1.4061 ± 0.0343 | 1.5028 ± 0.0337 | 1.4981 ± 0.0279 | 1.4818 ± 0.0291
Spermatid measurements
Spermatid heads (10^6^/testis) | 181.38 ± 3.90 | 186.38 ± 7.34 | 170.50 ± 5.90 | 164.88 ± 9.49
Spermatid heads (10^6^/g testis) | 152.48 ± 4.13 | 151.01 ± 6.13 | 137.20 ± 3.96* | 130.36 ± 6.20**
Epididymal spermatozoal measurements
Sperm motility (%) | 86.6 ± 0.7 | 86.5 ± 0.9 | 87.0 ± 0.6 | 82.7 ± 0.8**
Sperm (10^6^/cauda epididymis) | 78.3 ± 4.2 | 63.2 ± 8.9 | 81.3 ± 4.9 | 9.9 ± 1.1**
Sperm (10^6^/g cauda epididymis) | 608.5 ± 25.8 | 457.2 ± 77.4 | 591.2 ± 44.2 | 137.1 ± 14.6**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s (body weights) or Shirley’s (spermatid heads/g testis) test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ (cauda epididymis and epididymis weights) or Shirley’s (spermatid heads per testis and epididymal spermatozoal measurements) test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s (testis weights) or Dunn’s (spermatid heads/testis) test.

^b^ n = 9.

Table H-2 Estrous Cycle Characterization for Female F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 50 mg/kg | 100 mg/kg | 500 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 197 ± 3 | 189 ± 2 | 181 ± 3** | 169 ± 4**
Proportion of regular cycling females^b^ | 7/10 | 8/10 | 10/10* | 0/10
Estrous cycle length (days) | 5.8 ± 0.40 | 5.8 ± 0.29 | 5.3 ± 0.15 | –^c^
Estrous stages (% of cycle)
Diestrus | 61.7 | 60.0 | 56.7 | 100.0
Proestrus | 13.3 | 12.5 | 18.3 | 0.0
Estrus | 20.0 | 20.0 | 18.3 | 0.0
Metestrus | 5.0 | 7.5 | 6.7 | 0.0

* Significantly different (P ≤ 0.05) from the vehicle control group by the Chi-square test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated a significantly higher probability of extended diestrus in the 500 mg/kg group compared to the vehicle control group.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 10 of 10 animals.

Table H-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female F344/N Rats Administered DE-71 by Gavage for Three Months

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | <0.001
Overall Tests | 50 mg/kg vs. Vehicle Controls | 0.402 | –
Overall Tests | 100 mg/kg vs. Vehicle Controls | 0.004 | N
Overall Tests | 500 mg/kg vs. Vehicle Controls | <0.001 | –
Extended Estrus | Overall | 0.914
Extended Estrus | 50 mg/kg vs. Vehicle Controls | 0.595 | –
Extended Estrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Estrus | 500 mg/kg vs. Vehicle Controls | 0.601 | N
Extended Diestrus | Overall | <0.001
Extended Diestrus | 50 mg/kg vs. Vehicle Controls | 0.493 | N
Extended Diestrus | 100 mg/kg vs. Vehicle Controls | 0.004 | N
Extended Diestrus | 500 mg/kg vs. Vehicle Controls | <0.001 | –
Extended Metestrus | Overall | 1
Extended Metestrus | 50 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 50 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 50 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | Overall | 1
Skipped Diestrus | 50 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | 500 mg/kg vs. Vehicle Controls | 1 | –
Summary of Significant Groups
Overall Tests | 100 mg/kg vs. Vehicle Controls | 0.004 | N
Overall Tests | 500 mg/kg vs. Vehicle Controls | <0.001 | –
Extended Diestrus | 100 mg/kg vs. Vehicle Controls | 0.004 | N
Extended Diestrus | 500 mg/kg vs. Vehicle Controls | <0.001 | –

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Table H-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 5 mg/kg | 50 mg/kg | 100 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 39.3 ± 0.8 | 39.3 ± 1.0 | 37.3 ± 1.1 | 35.9 ± 0.7*
L. Cauda epididymis | 0.0274 ± 0.0011 | 0.0246 ± 0.0015 | 0.0237 ± 0.0015 | 0.0214 ± 0.0010**
L. Epididymis | 0.0560 ± 0.0019 | 0.0541 ± 0.0033 | 0.0554 ± 0.0028 | 0.0514 ± 0.0017
L. Testis | 0.1143 ± 0.0024 | 0.1149 ± 0.0018 | 0.1188 ± 0.0028 | 0.1112 ± 0.0021
Spermatid measurements
Spermatid heads (10^6^/testis) | 22.83 ± 0.77 | 23.39 ± 0.75 | 22.67 ± 0.58 | 23.10 ± 0.55
Spermatid heads (10^6^/g testis) | 221.67 ± 6.18 | 238.55 ± 9.18 | 218.16 ± 7.04 | 238.72 ± 4.68
Epididymal spermatozoal measurements
Sperm motility (%) | 88.5 ± 1.2 | 89.5 ± 0.2 | 88.7 ± 0.3 | 85.3 ± 0.8**
Sperm (10^6^/cauda epididymis) | 16.7 ± 0.8 | 15.8 ± 1.6 | 9.4 ± 2.4 | 12.1 ± 2.1
Sperm (10^6^/g cauda epididymis) | 614.1 ± 34.7 | 676.7 ± 86.4 | 425.9 ± 120.0 | 555.3 ± 92.1

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the vehicle control group by Williams’ (body weights) or Shirley’s (sperm motility) test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (epididymis and testis weights) or Dunn’s test (spermatid measurements, sperm/cauda epididymis, and sperm/g cauda epididymis).

Table H-5 Estrous Cycle Characterization for Female Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 5 mg/kg | 50 mg/kg | 100 mg/kg
Number weighed at necropsy | 9 | 10 | 9 | 9
Necropsy body wt (g) | 32.8 ± 0.5 | 29.5 ± 1.1* | 30.3 ± 1.0 | 31.0 ± 1.0
Proportion of regular cycling females^b^ | 6/8 | 9/10 | 7/9 | 8/9
Estrous cycle length (days) | 3.9 ± 0.25^c^ | 4.3 ± 0.18 | 4.4 ± 0.19 | 4.0 ± 0.12
Estrous stages (% of cycle)
Diestrus | 37.0 | 30.8 | 34.3 | 31.5
Proestrus | 4.6 | 4.2 | 1.9 | 0.0
Estrus | 40.7 | 45.0 | 43.5 | 46.3
Metestrus | 17.6 | 20.0 | 20.4 | 22.2

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunn’s test (estrous cycle length). Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated dosed females did not have extended estrus or diestrus.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle length was longer than 12 days or unclear in 1 of 9 animals.

Table H-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice Administered DE-71 by Gavage for Three Months

Stage | Comparison | P Value | Trend^a^
Overall Tests | Overall | 0.009
Overall Tests | 5 mg/kg vs. Vehicle Controls | 0.049 | N
Overall Tests | 50 mg/kg vs. Vehicle Controls | 0.339 | N
Overall Tests | 100 mg/kg vs. Vehicle Controls | 0.012 | N
Extended Estrus | Overall | 0.917
Extended Estrus | 5 mg/kg vs. Vehicle Controls | 0.604 | –
Extended Estrus | 50 mg/kg vs. Vehicle Controls | 0.995 | –
Extended Estrus | 100 mg/kg vs. Vehicle Controls | 0.603 | –
Extended Diestrus | Overall | 0.067
Extended Diestrus | 5 mg/kg vs. Vehicle Controls | 0.159 | N
Extended Diestrus | 50 mg/kg vs. Vehicle Controls | 0.213 | N
Extended Diestrus | 100 mg/kg vs. Vehicle Controls | 0.081 | N
Extended Metestrus | Overall | 1
Extended Metestrus | 5 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 50 mg/kg vs. Vehicle Controls | 1 | –
Extended Metestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | Overall | 1
Extended Proestrus | 5 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 50 mg/kg vs. Vehicle Controls | 1 | –
Extended Proestrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | Overall | 1
Skipped Estrus | 5 mg/kg vs. Vehicle Controls | 1 | –
Skipped Estrus | 50 mg/kg vs. Vehicle Controls | 0.92 | –
Skipped Estrus | 100 mg/kg vs. Vehicle Controls | 1 | –
Skipped Diestrus | Overall | 0.022
Skipped Diestrus | 5 mg/kg vs. Vehicle Controls | 0.064 | N
Skipped Diestrus | 50 mg/kg vs. Vehicle Controls | 0.079 | N
Skipped Diestrus | 100 mg/kg vs. Vehicle Controls | 0.079 | N
Summary of Significant Groups
Overall Tests | 5 mg/kg vs. Vehicle Controls | 0.049 | N
Overall Tests | 100 mg/kg vs. Vehicle Controls | 0.012 | N

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the vehicle control group.

Figure H-1

Vaginal Cytology Plots for Female F344/N Rats in the Three-month Gavage Study of DE-71

Abbreviations: D = diestrus, P = proestrus, E = estrus, M = metestrus

Figure H-2

Vaginal Cytology Plots for Female Mice in the Three-month Gavage Study of DE-71

Abbreviations: D = diestrus, P = proestrus, E = estrus, M = metestrus