# Appendix G Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table G-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 316 ± 6 | 335 ± 5 | 327 ± 6 | 330 ± 6 | 318 ± 8 | 272 ± 5**
Heart
Absolute | 0.76 ± 0.02 | 0.83 ± 0.01* | 0.81 ± 0.02 | 0.84 ± 0.02** | 0.82 ± 0.02 | 0.76 ± 0.02
Relative | 2.401 ± 0.026 | 2.489 ± 0.025 | 2.478 ± 0.025 | 2.552 ± 0.024** | 2.573 ± 0.033** | 2.801 ± 0.036**
R. Kidney
Absolute | 0.93 ± 0.02 | 0.99 ± 0.03 | 1.00 ± 0.03 | 1.07 ± 0.03** | 1.07 ± 0.03** | 1.08 ± 0.02**
Relative | 2.932 ± 0.023 | 2.942 ± 0.056 | 3.050 ± 0.054 | 3.240 ± 0.036** | 3.349 ± 0.027** | 3.958 ± 0.035**
Liver
Absolute | 10.09 ± 0.17 | 11.22 ± 0.33 | 12.13 ± 0.44** | 16.04 ± 0.52** | 17.42 ± 0.46** | 20.01 ± 0.58**
Relative | 31.940 ± 0.252 | 33.482 ± 0.536 | 37.037 ± 0.774** | 48.628 ± 1.130** | 54.787 ± 0.524** | 73.381 ± 1.224**
Lung
Absolute | 1.25 ± 0.06 | 1.46 ± 0.07 | 1.29 ± 0.05 | 1.29 ± 0.05 | 1.27 ± 0.04 | 1.05 ± 0.03**
Relative | 3.956 ± 0.202 | 4.370 ± 0.197 | 3.934 ± 0.128 | 3.908 ± 0.119 | 4.014 ± 0.155 | 3.842 ± 0.072
R. Testis
Absolute | 1.314 ± 0.031 | 1.344 ± 0.019 | 1.325 ± 0.012 | 1.372 ± 0.029 | 1.380 ± 0.021 | 1.354 ± 0.020
Relative | 4.158 ± 0.084 | 4.023 ± 0.062 | 4.065 ± 0.079 | 4.163 ± 0.051 | 4.352 ± 0.069 | 4.982 ± 0.084**
Thymus
Absolute | 0.230 ± 0.012 | 0.243 ± 0.014 | 0.241 ± 0.012 | 0.221 ± 0.011 | 0.245 ± 0.020 | 0.163 ± 0.014**
Relative | 0.727 ± 0.038 | 0.727 ± 0.041 | 0.739 ± 0.037 | 0.672 ± 0.038 | 0.772 ± 0.059 | 0.598 ± 0.048
Female
Necropsy body wt | 197 ± 3 | 191 ± 2 | 203 ± 4 | 189 ± 2 | 181 ± 3** | 169 ± 4**
Heart
Absolute | 0.53 ± 0.01 | 0.54 ± 0.01 | 0.54 ± 0.01 | 0.52 ± 0.01 | 0.52 ± 0.01 | 0.53 ± 0.01
Relative | 2.695 ± 0.056 | 2.835 ± 0.053 | 2.654 ± 0.038 | 2.741 ± 0.026 | 2.871 ± 0.046* | 3.147 ± 0.063**
R. Kidney
Absolute | 0.62 ± 0.01 | 0.65 ± 0.01 | 0.68 ± 0.01** | 0.68 ± 0.01** | 0.68 ± 0.02** | 0.79 ± 0.01**
Relative | 3.132 ± 0.047 | 3.378 ± 0.063* | 3.333 ± 0.050* | 3.617 ± 0.055** | 3.737 ± 0.048** | 4.716 ± 0.105**
Liver
Absolute | 5.56 ± 0.16 | 5.92 ± 0.10 | 6.47 ± 0.13** | 8.73 ± 0.16** | 9.85 ± 0.27** | 12.16 ± 0.35**
Relative | 28.191 ± 0.616 | 31.009 ± 0.599* | 31.891 ± 0.490** | 46.139 ± 0.590** | 54.511 ± 1.135** | 72.195 ± 1.448**
Lung
Absolute | 0.91 ± 0.03 | 0.93 ± 0.04 | 0.93 ± 0.02 | 0.88 ± 0.02 | 0.89 ± 0.06 | 0.77 ± 0.02**
Relative | 4.637 ± 0.172 | 4.900 ± 0.237 | 4.581 ± 0.132 | 4.656 ± 0.062 | 4.900 ± 0.328 | 4.598 ± 0.127
Thymus
Absolute | 0.226 ± 0.011 | 0.212 ± 0.009 | 0.209 ± 0.007 | 0.174 ± 0.009** | 0.152 ± 0.011** | 0.099 ± 0.009**
Relative | 1.149 ± 0.055 | 1.114 ± 0.051 | 1.032 ± 0.035 | 0.922 ± 0.051** | 0.836 ± 0.055** | 0.587 ± 0.050**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table G-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F_1_ Wistar Han Rats at the Three-month Interim Evaluation in the Two-year Perinatal and Postnatal Gavage Study^a^

| Vehicle Control | 50 mg/kg
n | 10 | 10
Male
Necropsy body wt | 403 ± 10 | 433 ± 16
Heart
Absolute | 1.02 ± 0.04 | 1.14 ± 0.05
Relative | 2.520 ± 0.073 | 2.631 ± 0.087
R. Kidney
Absolute | 1.29 ± 0.04 | 1.57 ± 0.08**
Relative | 3.198 ± 0.102 | 3.618 ± 0.113*
Liver
Absolute | 13.68 ± 0.39 | 19.53 ± 0.76**
Relative | 33.938 ± 0.702 | 45.180 ± 1.191**
Lung
Absolute | 1.57 ± 0.08 | 1.72 ± 0.11
Relative | 3.907 ± 0.183 | 4.039 ± 0.357
R. Testis
Absolute | 1.836 ± 0.069 | 2.168 ± 0.075**
Relative | 4.552 ± 0.132 | 5.011 ± 0.057**
Thymus
Absolute | 0.362 ± 0.022 | 0.399 ± 0.027
Relative | 0.895 ± 0.043 | 0.928 ± 0.060
Female
Necropsy body wt | 246 ± 4 | 213 ± 7**
Heart
Absolute | 0.74 ± 0.02 | 0.68 ± 0.02
Relative | 3.021 ± 0.059 | 3.207 ± 0.062*
R. Kidney
Absolute | 0.89 ± 0.02 | 0.84 ± 0.02
Relative | 3.636 ± 0.067 | 3.947 ± 0.056**
Liver
Absolute | 7.94 ± 0.18 | 9.28 ± 0.43*
Relative | 32.350 ± 0.579 | 43.369 ± 0.745**
Lung
Absolute | 1.18 ± 0.03^b^ | 1.04 ± 0.04**
Relative | 4.789 ± 0.105^b^ | 4.875 ± 0.127
Thymus
Absolute | 0.362 ± 0.020 | 0.264 ± 0.016**
Relative | 1.473 ± 0.071 | 1.239 ± 0.070*

* Significantly different (P ≤ 0.05) from the vehicle control group by a t-test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.

Table G-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 3
Necropsy body wt | 39.3 ± 0.8 | 38.8 ± 0.7 | 39.3 ± 1.0 | 37.3 ± 1.1 | 35.9 ± 0.7** | 28.6 ± 0.9**
Heart
Absolute | 0.13 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.11 ± 0.00**
Relative | 3.411 ± 0.090 | 3.562 ± 0.078 | 3.529 ± 0.093 | 3.582 ± 0.081 | 3.648 ± 0.055* | 3.966 ± 0.091**
R. Kidney
Absolute | 0.27 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.27 ± 0.01 | 0.26 ± 0.01 | 0.20 ± 0.01**
Relative | 6.784 ± 0.133 | 7.145 ± 0.175 | 7.067 ± 0.164 | 7.129 ± 0.148 | 7.245 ± 0.188 | 6.995 ± 0.056
Liver
Absolute | 1.38 ± 0.02 | 1.31 ± 0.05 | 1.50 ± 0.03 | 1.79 ± 0.08** | 2.18 ± 0.07** | 4.11 ± 0.02**
Relative | 35.024 ± 0.417 | 33.701 ± 1.195 | 38.207 ± 0.870 | 48.005 ± 1.761** | 60.684 ± 1.827** | 144.118 ± 4.508**
Lung
Absolute | 0.21 ± 0.02 | 0.19 ± 0.02 | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.16 ± 0.00
Relative | 5.306 ± 0.345 | 4.896 ± 0.402 | 4.687 ± 0.226 | 4.947 ± 0.269 | 4.897 ± 0.200 | 5.607 ± 0.189
R. Testis
Absolute | 0.115 ± 0.002 | 0.114 ± 0.002 | 0.116 ± 0.002 | 0.116 ± 0.002 | 0.112 ± 0.003 | 0.102 ± 0.007*
Relative | 2.931 ± 0.065 | 2.940 ± 0.056 | 2.969 ± 0.077 | 3.112 ± 0.071 | 3.102 ± 0.057 | 3.553 ± 0.184**
Thymus
Absolute | 0.037 ± 0.003 | 0.037 ± 0.001 | 0.034 ± 0.001 | 0.032 ± 0.002 | 0.037 ± 0.002 | 0.035 ± 0.001
Relative | 0.922 ± 0.068 | 0.949 ± 0.041 | 0.876 ± 0.029 | 0.875 ± 0.054 | 1.023 ± 0.044 | 1.240 ± 0.073**
Female
n | 9 | 10 | 10 | 9 | 9 | 5
Necropsy body wt | 32.8 ± 0.5 | 29.9 ± 0.6 | 29.5 ± 1.1* | 30.3 ± 1.0 | 31.0 ± 1.0 | 27.3 ± 0.3**
Heart
Absolute | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.11 ± 0.00 | 0.11 ± 0.00 | 0.12 ± 0.01 | 0.10 ± 0.00**
Relative | 3.596 ± 0.084 | 3.932 ± 0.103 | 3.849 ± 0.155 | 3.798 ± 0.083 | 3.813 ± 0.121 | 3.803 ± 0.072
R. Kidney
Absolute | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.01 | 0.17 ± 0.01
Relative | 4.954 ± 0.151 | 5.740 ± 0.162** | 5.323 ± 0.157** | 5.578 ± 0.111** | 5.436 ± 0.115** | 6.289 ± 0.190**
Liver
Absolute | 1.29 ± 0.20 | 1.10 ± 0.02 | 1.10 ± 0.03 | 1.51 ± 0.04 | 1.83 ± 0.05** | 3.74 ± 0.10**
Relative | 39.495 ± 6.272 | 36.887 ± 0.526 | 37.404 ± 0.887 | 50.224 ± 1.481* | 59.150 ± 1.078** | 137.002 ± 3.891**
Lung
Absolute | 0.19 ± 0.01^b^ | 0.19 ± 0.01 | 0.21 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.16 ± 0.01
Relative | 5.659 ± 0.290^b^ | 6.285 ± 0.303 | 7.143 ± 0.677 | 6.407 ± 0.271 | 5.855 ± 0.353 | 5.788 ± 0.328
Thymus
Absolute | 0.045 ± 0.003 | 0.043 ± 0.002 | 0.044 ± 0.002 | 0.046 ± 0.002 | 0.044 ± 0.002 | 0.040 ± 0.001
Relative | 1.380 ± 0.095 | 1.444 ± 0.085 | 1.522 ± 0.092 | 1.534 ± 0.053 | 1.422 ± 0.082 | 1.478 ± 0.045

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 8.