# Appendix F Clinical Pathology Results

Table F-1 Hematology and Clinical Chemistry Data for F344/N Rats in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
Hematology
n
Day 4 | 9 | 9 | 9 | 9 | 8 | 9
Day 25 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Automated hematocrit (%)
Day 4 | 51.4 ± 1.3 | 49.7 ± 1.1 | 49.9 ± 0.8 | 49.9 ± 0.7 | 49.8 ± 1.2 | 50.7 ± 1.0
Day 25 | 48.1 ± 0.6 | 48.6 ± 0.5 | 50.5 ± 0.8 | 48.5 ± 0.5 | 49.6 ± 0.9 | 48.0 ± 0.3
Week 14 | 44.8 ± 0.4 | 45.5 ± 0.5 | 44.4 ± 0.5 | 43.3 ± 0.4* | 43.6 ± 0.4* | 42.3 ± 0.4**
Manual hematocrit (%)
Day 4 | 50.7 ± 1.2 | 48.3 ± 1.0 | 49.0 ± 0.8 | 48.6 ± 0.7 | 48.6 ± 1.0 | 49.6 ± 1.0
Day 25 | 48.1 ± 0.5 | 48.6 ± 0.4 | 50.1 ± 0.7 | 48.3 ± 0.3 | 49.5 ± 0.8 | 48.0 ± 0.3
Week 14 | 44.3 ± 0.3 | 45.2 ± 0.4 | 43.7 ± 0.3 | 43.2 ± 0.4 | 43.6 ± 0.3 | 42.0 ± 0.4**
Hemoglobin (g/dL)
Day 4 | 16.7 ± 0.4 | 16.0 ± 0.3 | 16.1 ± 0.2 | 16.4 ± 0.3 | 16.3 ± 0.3 | 16.4 ± 0.3
Day 25 | 15.8 ± 0.1 | 16.3 ± 0.1 | 16.5 ± 0.2* | 16.1 ± 0.2 | 16.5 ± 0.3 | 15.8 ± 0.1
Week 14 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.1 ± 0.1 | 14.8 ± 0.1** | 14.7 ± 0.1** | 14.2 ± 0.1**
Erythrocytes (10^6^/μL)
Day 4 | 8.02 ± 0.19 | 7.78 ± 0.16 | 7.72 ± 0.12 | 7.82 ± 0.10 | 7.80 ± 0.20 | 8.02 ± 0.16
Day 25 | 7.92 ± 0.11 | 8.07 ± 0.10 | 8.26 ± 0.10 | 7.99 ± 0.09 | 8.21 ± 0.15 | 8.04 ± 0.06
Week 14 | 9.02 ± 0.06 | 9.11 ± 0.07 | 8.90 ± 0.07 | 8.80 ± 0.09 | 8.87 ± 0.06 | 8.87 ± 0.07
Reticulocytes (10^6^/μL)
Day 4 | 5.67 ± 0.31 | 5.48 ± 0.37 | 5.70 ± 0.37 | 5.13 ± 0.31 | 4.33 ± 0.40* | 3.59 ± 0.26**
Day 25 | 2.76 ± 0.12 | 2.81 ± 0.13 | 3.03 ± 0.18 | 2.84 ± 0.10 | 2.40 ± 0.14 | 2.00 ± 0.14**
Week 14 | 1.89 ± 0.06 | 2.03 ± 0.06 | 2.07 ± 0.06 | 1.95 ± 0.07 | 2.26 ± 0.04** | 2.30 ± 0.07**
Nucleated erythrocytes/100 leukocytes
Day 4 | 0.70 ± 0.20 | 0.70 ± 0.30 | 1.30 ± 0.20 | 0.80 ± 0.30 | 0.80 ± 0.20 | 1.00 ± 0.30
Day 25 | 0.10 ± 0.10 | 0.30 ± 0.20 | 0.10 ± 0.10 | 0.20 ± 0.10 | 0.20 ± 0.10 | 0.10 ± 0.10
Week 14 | 0.20 ± 0.10 | 0.30 ± 0.20 | 0.60 ± 0.30 | 0.50 ± 0.30 | 0.40 ± 0.20 | 0.60 ± 0.30
Mean cell volume (fL)
Day 4 | 64.1 ± 0.3 | 63.9 ± 0.5 | 64.7 ± 0.3 | 63.7 ± 0.2 | 63.9 ± 0.3 | 63.2 ± 0.2
Day 25 | 60.6 ± 0.2 | 60.2 ± 0.2 | 61.1 ± 0.4 | 60.8 ± 0.2 | 60.4 ± 0.3 | 59.8 ± 0.3
Week 14 | 49.7 ± 0.1 | 49.9 ± 0.3 | 49.8 ± 0.3 | 49.2 ± 0.2 | 49.1 ± 0.2* | 47.7 ± 0.2**
Mean cell hemoglobin (pg)
Day 4 | 20.8 ± 0.1 | 20.6 ± 0.1 | 20.9 ± 0.1 | 20.9 ± 0.2 | 20.9 ± 0.2 | 20.5 ± 0.1
Day 25 | 19.9 ± 0.1 | 20.2 ± 0.2 | 20.0 ± 0.1 | 20.1 ± 0.1 | 20.1 ± 0.2 | 19.7 ± 0.1
Week 14 | 17.1 ± 0.0 | 17.0 ± 0.1 | 17.0 ± 0.1 | 16.9 ± 0.1* | 16.6 ± 0.0** | 16.0 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 32.4 ± 0.2 | 32.3 ± 0.2 | 32.3 ± 0.1 | 32.8 ± 0.3 | 32.8 ± 0.2 | 32.5 ± 0.1
Day 25 | 32.8 ± 0.1 | 33.5 ± 0.2* | 32.8 ± 0.1 | 33.1 ± 0.1 | 33.3 ± 0.2 | 32.9 ± 0.1
Week 14 | 34.4 ± 0.1 | 34.0 ± 0.1 | 34.0 ± 0.2 | 34.2 ± 0.1 | 33.8 ± 0.1** | 33.5 ± 0.2**
Platelets (10^3^/μL)
Day 4 | 1,015.0 ± 33.4 | 1,008.7 ± 29.3 | 1,011.7 ± 35.9 | 1,048.3 ± 25.9 | 1,038.6 ± 38.6 | 924.2 ± 34.6
Day 25 | 828.7 ± 23.9 | 831.8 ± 34.3 | 847.5 ± 24.2 | 863.5 ± 14.5 | 830.4 ± 20.0 | 784.2 ± 21.0
Week 14 | 588.3 ± 16.1 | 595.1 ± 17.9 | 586.2 ± 18.9 | 623.5 ± 16.4 | 672.8 ± 11.9** | 633.7 ± 13.9**
Leukocytes (10^3^/μL)
Day 4 | 10.38 ± 0.43 | 9.26 ± 0.22 | 9.42 ± 0.30 | 8.98 ± 0.25* | 9.12 ± 0.39* | 7.88 ± 0.32**
Day 25 | 9.92 ± 0.33 | 9.53 ± 0.24 | 9.68 ± 0.30 | 8.72 ± 0.23** | 9.22 ± 0.40* | 8.07 ± 0.36**
Week 14 | 8.26 ± 0.16 | 8.31 ± 0.21 | 8.58 ± 0.29 | 8.55 ± 0.40 | 8.65 ± 0.24 | 7.42 ± 0.28
Segmented neutrophils (10^3^/μL)
Day 4 | 1.03 ± 0.04 | 1.03 ± 0.03 | 1.02 ± 0.05 | 1.04 ± 0.04 | 1.00 ± 0.06 | 1.09 ± 0.04
Day 25 | 0.95 ± 0.05 | 0.98 ± 0.04 | 1.10 ± 0.06 | 0.92 ± 0.03 | 0.90 ± 0.04 | 0.79 ± 0.04*
Week 14 | 1.16 ± 0.03 | 1.13 ± 0.05 | 1.25 ± 0.07 | 1.11 ± 0.05 | 1.06 ± 0.05 | 0.86 ± 0.03**
Lymphocytes (10^3^/μL)
Day 4 | 8.94 ± 0.41 | 7.87 ± 0.23 | 8.02 ± 0.26 | 7.58 ± 0.22* | 7.76 ± 0.32* | 6.37 ± 0.27**
Day 25 | 8.72 ± 0.30 | 8.28 ± 0.23 | 8.30 ± 0.27 | 7.58 ± 0.23** | 8.09 ± 0.40* | 7.03 ± 0.36**
Week 14 | 6.74 ± 0.14 | 6.82 ± 0.20 | 6.99 ± 0.26 | 7.09 ± 0.40 | 7.27 ± 0.25 | 6.24 ± 0.25
Monocytes (10^3^/μL)
Day 4 | 0.24 ± 0.02 | 0.22 ± 0.01 | 0.24 ± 0.02 | 0.21 ± 0.01 | 0.22 ± 0.02 | 0.26 ± 0.02
Day 25 | 0.11 ± 0.01 | 0.14 ± 0.01 | 0.14 ± 0.01 | 0.12 ± 0.01 | 0.12 ± 0.01 | 0.15 ± 0.01
Week 14 | 0.16 ± 0.01 | 0.16 ± 0.01 | 0.13 ± 0.01 | 0.14 ± 0.01 | 0.15 ± 0.01 | 0.17 ± 0.01
Basophils (10^3^/μL)
Day 4 | 0.031 ± 0.004 | 0.027 ± 0.003 | 0.024 ± 0.002 | 0.022 ± 0.003 | 0.024 ± 0.004 | 0.016 ± 0.002**
Day 25 | 0.027 ± 0.002 | 0.021 ± 0.002 | 0.025 ± 0.002 | 0.024 ± 0.003 | 0.024 ± 0.002 | 0.023 ± 0.002
Week 14 | 0.028 ± 0.002 | 0.029 ± 0.002 | 0.028 ± 0.003 | 0.039 ± 0.009 | 0.028 ± 0.002 | 0.024 ± 0.003
Eosinophils (10^3^/μL)
Day 4 | 0.04 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.01
Day 25 | 0.05 ± 0.00 | 0.04 ± 0.00 | 0.05 ± 0.01 | 0.03 ± 0.00** | 0.03 ± 0.00** | 0.02 ± 0.00**
Week 14 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.00 | 0.07 ± 0.01 | 0.05 ± 0.00** | 0.02 ± 0.00**
Large unstained cells (10^3^/μL)
Day 4 | 0.101 ± 0.009 | 0.080 ± 0.004 | 0.098 ± 0.011 | 0.091 ± 0.006 | 0.093 ± 0.008 | 0.104 ± 0.004
Day 25 | 0.065 ± 0.004 | 0.070 ± 0.006 | 0.067 ± 0.007 | 0.051 ± 0.005 | 0.065 ± 0.005 | 0.069 ± 0.007
Week 14 | 0.089 ± 0.010 | 0.089 ± 0.007 | 0.091 ± 0.008 | 0.108 ± 0.010 | 0.099 ± 0.012 | 0.106 ± 0.014
Clinical Chemistry
n
Day 4 | 9 | 9 | 9 | 9 | 9 | 9
Day 25 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 11.6 ± 0.4 | 12.2 ± 0.6 | 11.7 ± 0.2 | 11.3 ± 0.4 | 11.2 ± 0.6 | 12.2 ± 0.3
Day 25 | 13.8 ± 0.7 | 13.7 ± 0.6 | 13.2 ± 0.3 | 12.3 ± 0.5 | 13.4 ± 0.2 | 16.7 ± 0.5*
Week 14 | 14.7 ± 0.5 | 15.1 ± 0.3 | 14.2 ± 0.4 | 14.3 ± 0.5 | 14.9 ± 0.4 | 19.1 ± 0.5**
Creatinine (mg/dL)
Day 4 | 0.14 ± 0.02 | 0.13 ± 0.02 | 0.17 ± 0.02 | 0.14 ± 0.02 | 0.19 ± 0.01 | 0.20 ± 0.02*
Day 25 | 0.23 ± 0.02 | 0.20 ± 0.00 | 0.22 ± 0.01 | 0.24 ± 0.02 | 0.24 ± 0.02 | 0.25 ± 0.02
Week 14 | 0.30 ± 0.00 | 0.31 ± 0.02 | 0.30 ± 0.02 | 0.31 ± 0.01 | 0.33 ± 0.02 | 0.28 ± 0.01
Glucose (mg/dL)
Day 4 | 138 ± 3 | 136 ± 3 | 136 ± 4 | 130 ± 4 | 131 ± 4 | 109 ± 2**
Day 25 | 166 ± 4 | 148 ± 4** | 157 ± 5* | 140 ± 3** | 137 ± 4** | 128 ± 4**
Week 14 | 122 ± 3 | 141 ± 14 | 135 ± 8 | 119 ± 2 | 123 ± 5 | 114 ± 4
Total protein (g/dL)
Day 4 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.6 ± 0.1 | 5.7 ± 0.1 | 5.6 ± 0.1 | 5.5 ± 0.1
Day 25 | 5.9 ± 0.0 | 6.2 ± 0.0** | 6.3 ± 0.1** | 6.4 ± 0.1** | 6.6 ± 0.1** | 6.9 ± 0.1**
Week 14 | 6.8 ± 0.1 | 6.9 ± 0.1 | 6.8 ± 0.1 | 7.5 ± 0.1** | 7.7 ± 0.1** | 8.1 ± 0.1**
Albumin (g/dL)
Day 4 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.1 ± 0.1 | 4.0 ± 0.1 | 4.0 ± 0.0*
Day 25 | 4.4 ± 0.0 | 4.5 ± 0.0 | 4.6 ± 0.1* | 4.7 ± 0.0** | 4.7 ± 0.1** | 4.9 ± 0.1**
Week 14 | 4.7 ± 0.1 | 4.7 ± 0.1 | 4.7 ± 0.0 | 5.1 ± 0.1** | 5.2 ± 0.0** | 5.5 ± 0.0**
Cholesterol (mg/dL)
Day 4 | 105 ± 4 | 101 ± 3 | 106 ± 2 | 135 ± 3** | 148 ± 4** | 185 ± 6**
Day 25 | 77 ± 2 | 89 ± 2** | 89 ± 2** | 101 ± 1** | 112 ± 2** | 217 ± 3**
Week 14 | 88 ± 1 | 87 ± 2 | 83 ± 2 | 106 ± 3** | 117 ± 3** | 235 ± 5**
Alanine aminotransferase (IU/L)
Day 4 | 67 ± 4 | 68 ± 2 | 71 ± 2 | 69 ± 3 | 72 ± 4 | 94 ± 6**
Day 25 | 47 ± 1 | 50 ± 2 | 48 ± 2 | 52 ± 2 | 53 ± 2* | 109 ± 7**
Week 14 | 69 ± 4 | 71 ± 3 | 49 ± 2 | 42 ± 1** | 46 ± 2** | 79 ± 3
Alkaline phosphatase (IU/L)
Day 4 | 613 ± 20 | 605 ± 18 | 626 ± 13 | 594 ± 19 | 603 ± 16 | 615 ± 16
Day 25 | 391 ± 9 | 425 ± 8 | 427 ± 14 | 398 ± 13 | 369 ± 10 | 437 ± 15^b^
Week 14 | 226 ± 6 | 217 ± 4 | 204 ± 4 | 185 ± 2** | 178 ± 4** | 268 ± 5
Creatine kinase (IU/L)
Day 4 | 498 ± 36 | 571 ± 125 | 448 ± 34 | 468 ± 44 | 435 ± 47 | 416 ± 18
Day 25 | 372 ± 59 | 371 ± 42 | 359 ± 48 | 341 ± 42 | 355 ± 27 | 366 ± 41
Week 14 | 444 ± 33 | 443 ± 42 | 418 ± 46 | 456 ± 38 | 523 ± 60 | 349 ± 30
Sorbitol dehydrogenase (IU/L)
Day 4 | 6 ± 1 | 7 ± 2 | 7 ± 1 | 7 ± 1 | 10 ± 2* | 14 ± 1**
Day 25 | 14 ± 1 | 14 ± 1 | 13 ± 1^c^ | 15 ± 2 | 16 ± 1 | 28 ± 4*^b^
Week 14 | 18 ± 2^c^ | 15 ± 2^c^ | 13 ± 2 | 11 ± 1 | 15 ± 2 | 19 ± 3
Bile salts (µmol/L)
Day 4 | 20.3 ± 2.0 | 18.6 ± 1.4 | 21.5 ± 2.0 | 27.1 ± 1.2* | 31.9 ± 2.1** | 33.8 ± 1.6**
Day 25 | 21.1 ± 2.3 | 16.4 ± 0.7 | 22.8 ± 1.8 | 25.5 ± 1.5* | 32.7 ± 1.4** | 39.1 ± 2.2**
Week 14 | 15.5 ± 0.9 | 20.8 ± 2.2 | 22.3 ± 1.9* | 20.8 ± 0.9** | 27.0 ± 1.6** | 32.9 ± 1.6**
Total thyroxine (µg/dL)
Day 4 | 5.97 ± 0.34^d^ | 5.72 ± 0.12^d^ | 5.67 ± 0.29^d^ | 1.35 ± 0.10**^d^ | 0.87 ± 0.13**^d^ | 0.62 ± 0.11**^d^
Day 25 | 6.55 ± 0.26 | 6.54 ± 0.48 | 5.02 ± 0.31** | 1.33 ± 0.16** | 0.72 ± 0.10** | 0.48 ± 0.07**
Week 14 | 4.25 ± 0.20 | 4.53 ± 0.18 | 2.29 ± 0.16** | 0.50 ± 0.11** | 0.10 ± 0.05** | 0.46 ± 0.09**
Total triiodothyronine (ng/dL)
Day 25 | 100.9 ± 3.1 | 113.1 ± 7.6 | 90.8 ± 6.5 | 79.4 ± 4.1* | 80.0 ± 3.9 | 108.6 ± 3.9
Week 14 | 81.1 ± 4.5 | 75.7 ± 3.7 | 63.7 ± 5.6 | 77.9 ± 5.8 | 73.4 ± 5.3 | 120.7 ± 5.6
Thyroid stimulating hormone (ng/mL)
Day 4 | 5.70 ± 0.41d | 5.20 ± 0.40d | 5.04 ± 0.47d | 5.82 ± 0.55 | 5.10 ± 0.39d | 4.42 ± 0.39d
Day 25 | 3.66 ± 0.15 | 4.69 ± 0.38 | 5.16 ± 0.64 | 5.57 ± 0.66 | 6.55 ± 0.84** | 4.63 ± 0.60
Week 14 | 3.75 ± 0.33 | 3.61 ± 0.47 | 3.74 ± 0.46 | 4.62 ± 0.48 | 4.69 ± 0.57 | 6.19 ± 0.84*
Female
Hematology
n
Day 4 | 10 | 10 | 10 | 10 | 8 | 9
Day 25 | 10 | 10 | 10 | 10 | 9 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Automated hematocrit (%)
Day 4 | 50.4 ± 0.7 | 50.6 ± 0.6 | 51.1 ± 1.5 | 50.0 ± 1.0 | 50.4 ± 0.9 | 51.1 ± 0.6
Day 25 | 49.9 ± 0.6 | 51.4 ± 0.8 | 49.2 ± 1.5 | 50.0 ± 0.8 | 50.8 ± 1.3 | 48.0 ± 0.5
Week 14 | 43.3 ± 0.4 | 42.8 ± 0.3 | 42.5 ± 0.5 | 42.1 ± 0.4 | 40.3 ± 0.2** | 38.2 ± 0.3**
Manual hematocrit (%)
Day 4 | 49.0 ± 0.6 | 49.4 ± 0.7 | 50.2 ± 1.5 | 49.2 ± 1.1 | 48.7 ± 0.9 | 50.2 ± 0.7
Day 25 | 49.4 ± 0.5 | 50.6 ± 0.6 | 48.7 ± 1.4 | 49.2 ± 0.7 | 50.4 ± 1.1 | 47.8 ± 0.4
Week 14 | 43.0 ± 0.5 | 43.1 ± 0.3 | 42.9 ± 0.3 | 42.1 ± 0.5 | 40.7 ± 0.2** | 38.6 ± 0.4**
Hemoglobin (g/dL)
Day 4 | 16.2 ± 0.2 | 16.2 ± 0.1 | 16.4 ± 0.5 | 16.0 ± 0.3 | 16.0 ± 0.3 | 16.3 ± 0.2
Day 25 | 16.5 ± 0.2 | 17.0 ± 0.2 | 16.3 ± 0.5 | 16.5 ± 0.2 | 16.7 ± 0.4 | 15.6 ± 0.2*
Week 14 | 14.5 ± 0.1 | 14.4 ± 0.1 | 14.4 ± 0.1 | 14.3 ± 0.1 | 13.7 ± 0.1** | 12.8 ± 0.1**
Erythrocytes (10^6^/μL)
Day 4 | 8.08 ± 0.11 | 8.04 ± 0.07 | 8.10 ± 0.26 | 7.93 ± 0.15 | 8.06 ± 0.14 | 8.15 ± 0.11
Day 25 | 8.38 ± 0.11 | 8.57 ± 0.12 | 8.21 ± 0.26 | 8.35 ± 0.13 | 8.50 ± 0.18 | 8.12 ± 0.08
Week 14 | 8.46 ± 0.07 | 8.38 ± 0.07 | 8.31 ± 0.11 | 8.49 ± 0.08 | 8.32 ± 0.07 | 8.27 ± 0.08
Reticulocytes (10^6^/μL)
Day 4 | 3.30 ± 0.34 | 4.99 ± 0.48* | 4.21 ± 0.34 | 4.69 ± 0.43 | 4.71 ± 0.28* | 3.47 ± 0.19
Day 25 | 1.87 ± 0.05 | 1.71 ± 0.07 | 1.86 ± 0.10 | 1.72 ± 0.07 | 1.80 ± 0.10 | 1.28 ± 0.04**
Week 14 | 1.81 ± 0.06 | 1.89 ± 0.06 | 1.78 ± 0.04 | 1.92 ± 0.03 | 1.69 ± 0.03 | 2.03 ± 0.05
Nucleated erythrocytes/100 leukocytes
Day 4 | 0.80 ± 0.30 | 0.80 ± 0.40 | 0.30 ± 0.20 | 1.10 ± 0.30 | 0.60 ± 0.40 | 0.70 ± 0.30
Day 25 | 0.00 ± 0.00 | 0.10 ± 0.10 | 0.10 ± 0.10 | 0.10 ± 0.10 | 0.20 ± 0.10 | 0.20 ± 0.10
Week 14 | 0.40 ± 0.20 | 0.30 ± 0.20 | 0.20 ± 0.20 | 0.30 ± 0.20 | 0.30 ± 0.20 | 0.50 ± 0.20
Mean cell volume (fL)
Day 4 | 62.3 ± 0.2 | 62.9 ± 0.4 | 63.1 ± 0.4 | 63.0 ± 0.3 | 62.5 ± 0.3 | 62.8 ± 0.4
Day 25 | 59.6 ± 0.2 | 59.9 ± 0.3 | 60.0 ± 0.3 | 59.9 ± 0.2 | 59.8 ± 0.4 | 59.1 ± 0.2
Week 14 | 51.2 ± 0.2 | 51.2 ± 0.2 | 51.1 ± 0.2 | 49.6 ± 0.2** | 48.4 ± 0.2** | 46.2 ± 0.3**
Mean cell hemoglobin (pg)
Day 4 | 20.0 ± 0.1 | 20.1 ± 0.1 | 20.2 ± 0.1 | 20.2 ± 0.1 | 19.8 ± 0.1 | 20.0 ± 0.1
Day 25 | 19.6 ± 0.1 | 19.8 ± 0.1 | 19.9 ± 0.1 | 19.8 ± 0.1 | 19.6 ± 0.1 | 19.3 ± 0.1
Week 14 | 17.2 ± 0.0 | 17.2 ± 0.1 | 17.3 ± 0.1 | 16.8 ± 0.1** | 16.5 ± 0.1** | 15.5 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 32.2 ± 0.3 | 32.0 ± 0.3 | 32.1 ± 0.3 | 32.1 ± 0.2 | 31.8 ± 0.1 | 31.8 ± 0.2
Day 25 | 33.0 ± 0.2 | 33.1 ± 0.2 | 33.2 ± 0.1 | 33.0 ± 0.2 | 32.9 ± 0.2 | 32.6 ± 0.2
Week 14 | 33.6 ± 0.1 | 33.6 ± 0.2 | 33.9 ± 0.2 | 33.9 ± 0.2 | 34.0 ± 0.1* | 33.6 ± 0.1
Platelets (10^3^/μL)
Day 4 | 994.6 ± 62.3 | 1,096.4 ± 57.9 | 951.6 ± 29.8 | 1,048.6 ± 63.8 | 1,086.9 ± 52.1 | 881.1 ± 56.1
Day 25 | 703.9 ± 28.8 | 775.2 ± 31.8 | 785.4 ± 30.8 | 755.6 ± 20.8 | 788.1 ± 29.1 | 579.9 ± 19.0
Week 14 | 562.9 ± 13.4 | 568.9 ± 14.6 | 571.1 ± 21.8 | 594.5 ± 20.0 | 597.1 ± 23.4 | 504.4 ± 26.9
Leukocytes (10^3^/μL)
Day 4 | 10.90 ± 0.40 | 10.77 ± 0.43 | 11.16 ± 0.34 | 10.07 ± 0.31 | 10.29 ± 0.38 | 8.84 ± 0.30**
Day 25 | 9.32 ± 0.51 | 9.33 ± 0.45 | 9.53 ± 0.63 | 9.41 ± 0.44 | 9.76 ± 0.24 | 7.02 ± 0.41*
Week 14 | 7.42 ± 0.29 | 7.45 ± 0.37 | 6.63 ± 0.36 | 6.22 ± 0.21** | 6.10 ± 0.39* | 6.61 ± 0.28*
Segmented neutrophils (10^3^/μL)
Day 4 | 1.03 ± 0.06 | 1.08 ± 0.06 | 1.10 ± 0.06 | 0.95 ± 0.09 | 1.11 ± 0.07 | 0.92 ± 0.04
Day 25 | 1.00 ± 0.06 | 0.91 ± 0.05 | 0.93 ± 0.06 | 0.95 ± 0.09 | 0.93 ± 0.05 | 0.82 ± 0.06
Week 14 | 1.16 ± 0.10 | 1.05 ± 0.06 | 0.91 ± 0.07* | 0.81 ± 0.04** | 0.79 ± 0.08** | 0.77 ± 0.08**
Lymphocytes (10^3^/μL)
Day 4 | 9.48 ± 0.37 | 9.32 ± 0.36 | 9.67 ± 0.31 | 8.53 ± 0.27 | 8.79 ± 0.31 | 7.54 ± 0.27**
Day 25 | 8.06 ± 0.52 | 8.14 ± 0.41 | 8.31 ± 0.57 | 8.19 ± 0.38 | 8.52 ± 0.23 | 5.97 ± 0.36*
Week 14 | 5.94 ± 0.23 | 6.12 ± 0.35 | 5.44 ± 0.28 | 5.13 ± 0.18 | 5.06 ± 0.31 | 5.52 ± 0.21
Monocytes (10^3^/μL)
Day 4 | 0.20 ± 0.01 | 0.20 ± 0.02 | 0.21 ± 0.02 | 0.31 ± 0.10 | 0.24 ± 0.02 | 0.23 ± 0.02
Day 25 | 0.11 ± 0.01 | 0.14 ± 0.01 | 0.15 ± 0.01 | 0.14 ± 0.01 | 0.16 ± 0.01** | 0.13 ± 0.01
Week 14 | 0.14 ± 0.01 | 0.13 ± 0.01 | 0.13 ± 0.01 | 0.12 ± 0.01 | 0.12 ± 0.02 | 0.18 ± 0.01
Basophils (10^3^/μL)
Day 4 | 0.042 ± 0.004 | 0.036 ± 0.004 | 0.040 ± 0.004 | 0.032 ± 0.003 | 0.030 ± 0.003 | 0.033 ± 0.005
Day 25 | 0.027 ± 0.003 | 0.031 ± 0.003 | 0.029 ± 0.004 | 0.027 ± 0.003 | 0.029 ± 0.003 | 0.015 ± 0.004
Week 14 | 0.029 ± 0.003 | 0.027 ± 0.006 | 0.023 ± 0.003 | 0.026 ± 0.003 | 0.021 ± 0.004 | 0.033 ± 0.006
Eosinophils (10^3^/μL)
Day 4 | 0.05 ± 0.00 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.00 | 0.05 ± 0.01
Day 25 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.00 | 0.04 ± 0.00** | 0.04 ± 0.01** | 0.03 ± 0.00**
Week 14 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.00 | 0.04 ± 0.01** | 0.02 ± 0.00**
Large unstained cells (10^3^/μL)
Day 4 | 0.093 ± 0.008 | 0.081 ± 0.008 | 0.084 ± 0.006 | 0.205 ± 0.118 | 0.079 ± 0.007 | 0.076 ± 0.007
Day 25 | 0.059 ± 0.003 | 0.065 ± 0.006 | 0.070 ± 0.007 | 0.065 ± 0.005 | 0.077 ± 0.008 | 0.060 ± 0.006
Week 14 | 0.092 ± 0.008 | 0.072 ± 0.006 | 0.077 ± 0.008 | 0.084 ± 0.008 | 0.075 ± 0.008 | 0.093 ± 0.008
Clinical Chemistry
n
Day 4 | 3 | 3 | 3 | 4 | 6 | 2
Day 25 | 10 | 10 | 10 | 10 | 9 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 13.1 ± 1.0 | 13.9 ± 0.9 | 11.6 ± 1.2^e^ | 10.4 ± 0.9 | 11.6 ± 0.7 | 14.2 ± 0.9
Day 25 | 14.2 ± 0.5 | 15.0 ± 0.7 | 13.9 ± 0.7 | 12.9 ± 0.6 | 13.8 ± 0.3 | 15.8 ± 0.5
Week 14 | 13.0 ± 0.6 | 13.5 ± 0.7 | 13.2 ± 0.3 | 12.9 ± 0.5 | 13.9 ± 0.4 | 21.4 ± 0.9**
Creatinine (mg/dL)
Day 4 | 0.24 ± 0.02^c^ | 0.23 ± 0.02^f^ | 0.22 ± 0.02^c^ | 0.23 ± 0.02^d^ | 0.26 ± 0.03^f^ | 0.28 ± 0.01^d^
Day 25 | 0.24 ± 0.02 | 0.23 ± 0.02 | 0.20 ± 0.00 | 0.20 ± 0.01 | 0.27 ± 0.02 | 0.24 ± 0.02
Week 14 | 0.31 ± 0.02 | 0.30 ± 0.00^c^ | 0.28 ± 0.01 | 0.32 ± 0.01 | 0.28 ± 0.01 | 0.26 ± 0.02
Glucose (mg/dL)
Day 4 | 117 ± 2 | 126 ± 7 | 122 ± 10 | 119 ± 3 | 118 ± 4 | 107 ± 6
Day 25 | 149 ± 7 | 160 ± 8 | 148 ± 5 | 133 ± 4 | 131 ± 4 | 120 ± 2**
Week 14 | 124 ± 3 | 120 ± 2 | 117 ± 3 | 109 ± 2** | 109 ± 3** | 108 ± 3**
Total protein (g/dL)
Day 4 | 5.9 ± 0.1 | 5.7 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.3 | 5.7 ± 0.2 | 5.6 ± 0.2
Day 25 | 5.8 ± 0.1 | 5.9 ± 0.1 | 6.0 ± 0.1 | 6.4 ± 0.1** | 6.5 ± 0.1** | 7.0 ± 0.1**
Week 14 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1 | 7.4 ± 0.1** | 7.8 ± 0.1** | 7.2 ± 0.1**
Albumin (g/dL)
Day 4 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.3 ± 0.1 | 4.3 ± 0.2 | 4.2 ± 0.1 | 4.2 ± 0.1
Day 25 | 4.5 ± 0.1 | 4.6 ± 0.0 | 4.6 ± 0.1 | 4.8 ± 0.1** | 4.8 ± 0.0** | 5.0 ± 0.0**
Week 14 | 4.9 ± 0.1 | 4.8 ± 0.1 | 5.0 ± 0.1 | 5.4 ± 0.1** | 5.6 ± 0.0** | 5.1 ± 0.1**
Cholesterol (mg/dL)
Day 4 | 112 ± 6^c^ | 108 ± 4^c^ | 113 ± 3^c^ | 136 ± 3**^d^ | 147 ± 7**^b^ | 176 ± 4**^d^
Day 25 | 75 ± 2 | 82 ± 3* | 87 ± 3** | 117 ± 4** | 144 ± 4**^c^ | 244 ± 5**
Week 14 | 72 ± 2 | 74 ± 2 | 94 ± 3** | 145 ± 4** | 183 ± 9** | 310 ± 9**
Alanine aminotransferase (IU/L)
Day 4 | 61 ± 3^c^ | 61 ± 3^c^ | 58 ± 4^c^ | 65 ± 3^d^ | 69 ± 2*^f^ | 81 ± 4**^d^
Day 25 | 44 ± 2 | 49 ± 2 | 45 ± 2 | 42 ± 1 | 44 ± 2 | 78 ± 2**
Week 14 | 52 ± 3 | 52 ± 4 | 55 ± 6 | 35 ± 1* | 35 ± 1** | 147 ± 33
Alkaline phosphatase (IU/L)
Day 4 | 529 ± 14^b^ | 550 ± 21^g^ | 560 ± 13^c^ | 549 ± 23^b^ | 521 ± 55^e^ | 570 ± 25^h^
Day 25 | 328 ± 9 | 363 ± 10 | 352 ± 7 | 333 ± 11 | 313 ± 9 | 365 ± 9^i^
Week 14 | 193 ± 7 | 184 ± 6 | 182 ± 6 | 147 ± 7* | 137 ± 4** | 315 ± 12
Creatine kinase (IU/L)
Day 4 | 473 ± 136 | 448 ± 69 | 604 ± 78 | 727 ± 81 | 584 ± 72 | 399 ± 86
Day 25 | 423 ± 62 | 509 ± 50 | 435 ± 48 | 500 ± 64 | 421 ± 39 | 297 ± 39
Week 14 | 433 ± 48 | 337 ± 19 | 381 ± 41 | 406 ± 42 | 364 ± 33 | 322 ± 32
Sorbitol dehydrogenase (IU/L)
Day 4 | 4 ± 2^g^ | 1 ± 0^j^ | 3 ± 2^e^ | 4 ± 3^i^ | 2 ± 0^j^ | 5 ± 1^f^
Day 25 | 12 ± 3^c^ | 9 ± 3^f^ | 10 ± 2^g^ | 9 ± 3^b^ | 9 ± 3^b^ | 26 ± 3*^g^
Week 14 | 9 ± 2^c^ | 15 ± 2^c^ | 13 ± 3 | 19 ± 3** | 18 ± 1** | 31 ± 4**
Bile acids (µmol/L)
Day 4 | 16.2 ± 3.7 | 19.9 ± 2.8 | 16.4 ± 3.9 | 27.1 ± 4.9 | 26.4 ± 2.1 | 23.4 ± 0.2
Day 25 | 19.3 ± 1.9 | 25.4 ± 5.4 | 18.1 ± 1.9 | 25.0 ± 1.4* | 31.6 ± 1.8** | 32.3 ± 1.7**
Week 14 | 20.2 ± 6.0 | 16.8 ± 1.5 | 17.3 ± 0.6* | 20.9 ± 1.1** | 24.3 ± 0.9** | 32.2 ± 2.5**
Total thyroxine (µg/dL)
Day 4 | 4.88 ± 0.22^d^ | 4.90 ± 0.13^d^ | 4.12 ± 0.20*^d^ | 0.95 ± 0.12**^d^ | 0.57 ± 0.07**^d^ | 0.41 ± 0.08**^d^
Day 25 | 5.09 ± 0.17 | 4.89 ± 0.26 | 4.13 ± 0.25* | 1.02 ± 0.11** | 0.56 ± 0.14** | 0.30 ± 0.07**
Week 14 | 3.19 ± 0.24 | 3.36 ± 0.16 | 1.68 ± 0.12** | 0.41 ± 0.06** | 0.48 ± 0.09** | 0.50 ± 0.07**
Total triiodothyronine (ng/dL)
Day 25 | 94.1 ± 5.1 | 98.1 ± 3.4 | 91.5 ± 4.5 | 95.7 ± 4.1 | 98.7 ± 4.0 | 120.4 ± 4.6**
Week 14 | 79.0 ± 5.8 | 75.2 ± 4.1 | 62.6 ± 2.0 | 74.9 ± 4.1 | 83.6 ± 6.2 | 137.3 ± 5.7**
Thyroid stimulating hormone (ng/mL)
Day 4 | 4.57 ± 0.46^d^ | 4.08 ± 0.42^d^ | 5.80 ± 0.47^d^ | 4.51 ± 0.44^d^ | 4.55 ± 0.38^d^ | 3.61 ± 0.35^d^
Day 25 | 3.99 ± 0.26 | 3.96 ± 0.18 | 4.84 ± 0.32 | 5.27 ± 0.20** | 4.86 ± 0.43* | 5.56 ± 0.52*
Week 14 | 2.69 ± 0.20 | 2.95 ± 0.29 | 2.83 ± 0.28 | 3.40 ± 0.36 | 4.66 ± 0.72** | 4.32 ± 0.34**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 7.

^c^ n = 9.

^d^ n = 10.

^e^ n = 4.

^f^ n = 8.

^g^ n = 6.

^h^ n = 5.

^i^ n = 3.

^j^ n = 2.

Table F-2 Hematology Data for Mice in the Three-month Gavage Study of DE-71^a^

| Vehicle Control | 0.01 mg/kg | 5 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 3
Automated hematocrit (%) | 49.8 ± 0.8 | 48.7 ± 0.4 | 50.0 ± 0.4 | 48.8 ± 0.5 | 47.9 ± 0.4 | 43.6 ± 0.8**
Manual hematocrit (%) | 48.5 ± 0.7 | 48.1 ± 0.4 | 48.9 ± 0.3 | 48.1 ± 0.5 | 47.1 ± 0.5 | 43.5 ± 0.6**
Hemoglobin (g/dL) | 16.3 ± 0.2 | 16.0 ± 0.1 | 16.3 ± 0.1 | 16.1 ± 0.1 | 15.9 ± 0.1 | 14.3 ± 0.3*
Erythrocytes (10^6^/µL) | 10.41 ± 0.15 | 10.17 ± 0.10 | 10.38 ± 0.07 | 10.11 ± 0.10 | 9.93 ± 0.09* | 9.36 ± 0.21**
Reticulocytes (10^6^/µL) | 2.98 ± 0.02 | 2.82 ± 0.07 | 2.85 ± 0.07 | 2.69 ± 0.09** | 2.53 ± 0.04** | 2.97 ± 0.22*
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.10 ± 0.10 | 0.20 ± 0.10 | 0.00 ± 0.00 | 0.10 ± 0.10 | 0.30 ± 0.30
Mean cell volume (fL) | 47.8 ± 0.2 | 47.9 ± 0.2 | 48.2 ± 0.2 | 48.3 ± 0.4 | 48.2 ± 0.3 | 46.6 ± 0.2
Mean cell hemoglobin (pg) | 15.7 ± 0.1 | 15.8 ± 0.1 | 15.7 ± 0.1 | 16.0 ± 0.1 | 16.1 ± 0.1** | 15.3 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.8 ± 0.2 | 32.9 ± 0.1 | 32.7 ± 0.1 | 33.1 ± 0.2 | 33.3 ± 0.1* | 32.8 ± 0.1
Platelets (10^3^/µL) | 993.1 ± 38.2 | 1,046.1 ± 44.6 | 1,131.1 ± 43.0 | 1,193.5 ± 35.6** | 1,331.7 ± 40.0** | 1,090.0 ± 28.6*
Leukocytes (10^3^/µL) | 5.82 ± 0.65 | 6.45 ± 0.62 | 6.20 ± 0.57 | 6.01 ± 0.52 | 6.51 ± 0.67 | 7.76 ± 0.91
Segmented neutrophils (10^3^/µL) | 1.44 ± 0.27 | 0.98 ± 0.10 | 0.97 ± 0.12 | 1.36 ± 0.47 | 1.20 ± 0.22 | 2.75 ± 1.02
Lymphocytes (10^3^/µL) | 4.06 ± 0.68 | 5.08 ± 0.57 | 4.84 ± 0.44 | 4.32 ± 0.53 | 4.94 ± 0.66 | 4.57 ± 1.24
Monocytes (10^3^/µL) | 0.11 ± 0.02 | 0.12 ± 0.02 | 0.12 ± 0.02 | 0.10 ± 0.01 | 0.12 ± 0.02 | 0.21 ± 0.09
Basophils (10^3^/µL) | 0.026 ± 0.005 | 0.035 ± 0.007 | 0.029 ± 0.005 | 0.030 ± 0.004 | 0.031 ± 0.009 | 0.017 ± 0.009
Eosinophils (10^3^/µL) | 0.16 ± 0.02 | 0.19 ± 0.02 | 0.19 ± 0.02 | 0.17 ± 0.03 | 0.18 ± 0.03 | 0.12 ± 0.03
Large unstained cells | 0.035 ± 0.007 | 0.050 ± 0.009 | 0.049 ± 0.008 | 0.034 ± 0.006 | 0.044 ± 0.008 | 0.087 ± 0.015*
Female
n | 9 | 10 | 10 | 9 | 9 | 5
Automated hematocrit (%) | 48.9 ± 0.8 | 49.0 ± 0.5 | 49.5 ± 0.4 | 48.7 ± 0.5 | 48.1 ± 0.6 | 43.4 ± 0.7*
Manual hematocrit (%) | 48.5 ± 0.7 | 48.9 ± 0.3 | 49.4 ± 0.4 | 49.2 ± 0.4 | 48.4 ± 0.5 | 43.4 ± 0.7
Hemoglobin (g/dL) | 16.2 ± 0.2 | 16.2 ± 0.1 | 16.4 ± 0.1 | 16.3 ± 0.2 | 16.2 ± 0.2 | 14.6 ± 0.2*
Erythrocytes (10^6^/µL) | 10.24 ± 0.15 | 10.30 ± 0.09 | 10.39 ± 0.09 | 10.19 ± 0.11 | 10.05 ± 0.11 | 9.02 ± 0.12**
Reticulocytes (10^6^/µL) | 3.09 ± 0.11 | 3.06 ± 0.12 | 3.28 ± 0.15 | 2.63 ± 0.07** | 2.47 ± 0.13** | 2.08 ± 0.24**
Nucleated erythrocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.10 ± 0.10 | 0.00 ± 0.00 | 0.10 ± 0.10 | 0.00 ± 0.00
Mean cell volume (fL) | 47.8 ± 0.2 | 47.6 ± 0.2 | 47.6 ± 0.2 | 47.8 ± 0.2 | 47.9 ± 0.2 | 48.1 ± 0.5
Mean cell hemoglobin (pg) | 15.8 ± 0.1 | 15.8 ± 0.0 | 15.8 ± 0.1 | 16.0 ± 0.1 | 16.1 ± 0.1* | 16.2 ± 0.1*
Mean cell hemoglobin concentration (g/dL) | 33.2 ± 0.1 | 33.1 ± 0.2 | 33.1 ± 0.1 | 33.4 ± 0.1 | 33.6 ± 0.1 | 33.7 ± 0.2
Platelets (10^3^/µL) | 939.9 ± 52.4 | 937.9 ± 33.8 | 872.1 ± 25.6 | 997.8 ± 24.7 | 1,045.9 ± 51.8 | 1,129.4 ± 88.4
Leukocytes (10^3^/µL) | 4.04 ± 0.55 | 4.58 ± 0.31 | 4.74 ± 0.37 | 5.24 ± 0.50 | 4.79 ± 0.49 | 6.95 ± 0.97
Segmented neutrophils (10^3^/µL) | 0.57 ± 0.07 | 0.53 ± 0.07 | 0.58 ± 0.04 | 0.62 ± 0.11 | 0.57 ± 0.06 | 1.01 ± 0.17
Lymphocytes (10^3^/µL) | 3.21 ± 0.45 | 3.72 ± 0.30 | 3.83 ± 0.33 | 4.28 ± 0.39 | 3.95 ± 0.42 | 5.55 ± 0.77
Monocytes (10^3^/µL) | 0.06 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.19 ± 0.03**
Basophils (10^3^/µL) | 0.018 ± 0.004 | 0.014 ± 0.002 | 0.019 ± 0.004 | 0.022 ± 0.006 | 0.022 ± 0.008 | 0.024 ± 0.004
Eosinophils (10^3^/µL) | 0.16 ± 0.03 | 0.19 ± 0.03 | 0.19 ± 0.03 | 0.19 ± 0.04 | 0.12 ± 0.01 | 0.08 ± 0.02
Large unstained cells | 0.021 ± 0.005 | 0.029 ± 0.004 | 0.030 ± 0.005 | 0.039 ± 0.007 | 0.033 ± 0.006 | 0.102 ± 0.014**

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.