# Appendix E Genetic Toxicology

## E.1 Bacterial Mutagenicity Test Protocol

Bacterial mutagenicity was evaluated in DE-71 and three polybrominated diphenyl ethers, 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47), 2,2′,4,4′,5-pentabromodiphenyl ether (BDE-99), and 2,2′,4,4′,5,5′-hexabromodiphenyl ether (BDE-153). Testing was performed as reported by Zeiger et al.^172^ (DE-71) or Zeiger et al.^275^ (BDE-47, BDE-99, and BDE-153). Chemicals were sent to the laboratory as coded aliquots and incubated with the Salmonella typhimurium tester strains TA98, TA100, TA102, TA1535, and TA1537 or the Escherichia coli strain WP2 uvrA/pKM101, either in buffer or 10% S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine (S. typhimurium strains) or L-tryptophan (E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of test chemical. The high dose was limited to 10,000 µg/plate by design. No chemical-associated toxicity was observed in any test, though precipitation occurred at the higher doses of most trials.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine- or tryptophan-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

## E.2 Mouse Micronucleus Test Protocols

### E.2.1 Three-month Study

A detailed discussion of this assay is presented by MacGregor et al.^276^ At the end of the 3-month gavage study (Lot 2550OA30A), peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronucleated cells in 2,000 normochromatic erythrocytes (NCEs, mature erythrocytes) per animal. In addition, the percentage of polychromatic erythrocytes (PCEs, reticulocytes, immature erythrocytes) among a population of 1,000 erythrocytes in the peripheral blood was scored for each dose group as a measure of DE-71 associated bone marrow toxicity.

The results from the slide-based evaluation were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the slide-based micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups.

### E.2.2 Three-day Study

This study was conducted as described by Witt et al.^173^ DE-71 was supplied through the NTP Chemistry Support Contract (Battelle Columbus Laboratories, Columbus, OH) and sent to the testing laboratory (ILS, Inc., Research Triangle Park, NC) as coded aliquots. Adult male B6C3F1/N mice, five per treatment group, were administered DE-71, dissolved in corn oil, by gavage once daily for 3 consecutive days, and peripheral blood and bone marrow samples were obtained 24 hours after the third treatment. Following this same regimen, vehicle control animals received corn oil alone, and the positive control mice received cyclophosphamide at a daily dose of 50 mg/kg. For slide-based analysis of the bone marrow samples, air-dried smears of the contents flushed from the femurs were fixed in absolute methanol, stained with acridine orange, and coded before scoring; 2,000 uniformly stained PCEs were scored for induction of micronucleated cells in each animal. In addition, 500 erythrocytes (mature and immature) were scored to determine the percentage of PCEs among the total erythrocyte population in the bone marrow as a measure of DE-71 associated bone marrow toxicity.

For data collected through flow cytometric methods, blood samples were processed immediately upon collection as described in the MicroFlow^®^ BASIC Kits from Litron Laboratories (Rochester, NY). The kits contain all the supplies and reagents necessary to process blood samples. Briefly, a 60 to 120 μL blood sample was collected from the vena cava after euthanasia, diluted in sodium heparin solution, and fixed in ultracold methanol. Fixed blood samples were immediately placed into a −80°C freezer for storage until flow cytometric analysis was conducted. A FACSCalibur flow cytometer (Becton Dickinson, San Jose, CA) was used to carry out the analyses. PCEs were identified by the presence of an active transferrin receptor (CD71+) on the cell surface; mature erythrocytes were identified as CD71-negative. For each animal, 10,000 to 20,000 CD71+ red blood cells were scored for the presence of micronuclei; approximately 10^6^ total erythrocytes were counted to determine percent PCEs in blood as a measure of DE-71-associated bone marrow toxicity.

Slide-based evaluations of NCEs and PCEs were conducted as described for NCEs in the 3-month study. Based on prior experience with the large number of cells scored using flow cytometric scoring techniques,^277^ it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the vehicle control group depend on whether the variances among the groups are equal. NTP uses Levene’s test at α = 0.05 to test for equal variances among the treatment groups. In the case of equal variances, linear regression was used to test for a linear trend with dose and Williams’ test^206,207^ was used to test for pairwise differences between each treatment group and the vehicle control group. In the case of unequal variances, Jonckheere’s test^211^ was used to test for linear trend, and pairwise comparisons of each dosed group with the vehicle control group were tested using Dunn’s test.^210^ To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P ≤ 0.025.

Factors that must be considered in analyzing micronucleus test data include number of animals per dose group (a minimum of three is required), dose levels and number of doses administered, route of administration, cell type analyzed, sample time (interval between last dosing and harvesting of cells for analysis), frequencies of micronucleated cells in the negative and positive controls, and the results of the statistical analyses. The final conclusion for a micronucleus test is determined by considering the results of statistical analyses, the reproducibility of any observed effects, and the magnitude and biological significance of those effects.

## E.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.

## E.4 Results

DE-71 was tested for mutagenic activity in bacteria in three independent studies at three separate laboratories using a total of six different bacterial tester strains (S. typhimurium TA98, TA100, TA102, TA1535, TA1537, and E. coli WP2 uvrA/pKM101) with and without 10% rat or hamster liver metabolic activation enzymes (S9). The study conducted by SITEK Research Laboratories used the same lot of DE-71 (2550OA30A) that was used in the 2-year gavage studies. No evidence of mutagenicity was observed^172^ (Table E-1 and Table E-2). In all three studies, dose levels ranged up to 10,000 µg/plate in the absence of observable toxicity, although precipitation occurred in one of the three studies at 1,000 µg/plate and above.

Three related test articles, BDE-47, BDE-99, and BDE-153 were tested for mutagenic activity in three bacterial tester strains (S. typhimurium TA98, TA100, and TA102) with and without rat liver S9 mix, and no evidence of mutagenicity was observed with any of the three test articles in any of the tests that were conducted (Table E-3, Table E-4, and Table E-5).

In vivo, no increases in the frequencies of micronucleated NCEs were observed in peripheral blood samples from male or female mice in the 3-month gavage study of DE-71 (0.01 to 500 mg/kg; Table E-6). Five mice were examined in each dose group except in the 500 mg/kg group only three male mice were available. In a second micronucleus study conducted in male B6C3F1/N mice, no increases in the frequencies of PCEs or NCEs were seen in peripheral blood samples following administration of DE-71 (312.5 to 1,250 mg/kg) by gavage once daily for 3 days; blood samples were evaluated using flow cytometric methods^173^ (Table E-7). In these same mice, slide-based data acquisition methods were used to evaluate bone marrow smears for induction of micronucleated PCEs and results were consistent with the results from blood samples (Table E-8). In none of the micronucleus tests conducted with DE-71 were significant alterations in the percentage PCEs seen over the dose range tested, suggesting that DE-71 did not induce toxicity in the bone marrow of treated mice. In the 3-day gavage study evaluated using flow cytometric methods, the trend test for percent PCEs gave a significant P value (0.023), but pairwise comparison of the top dose to the vehicle control group was not significant; thus, the small increase detected by flow cytometry (but not by slide scoring in the bone marrow) was not considered to be significant.

Table E-1 Mutagenicity of DE-71 in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% hamster S9 | With 10% hamster S9 | With 10% rat S9 | | With 10% rat S9
Study performed at SRI International
TA100
| 0 | 121 ± 6 | 113 ± 7 | 116 ± 9 | 116 ± 7 | 101 ± 8 | | 108 ± 4
| 100 | 98 ± 4 | 107 ± 9 | 108 ± 7 | 122 ± 19 | 120 ± 10 | | 102 ± 6
| 333 | 87 ± 5 | 104 ± 9 | 100 ± 8 | 111 ± 2 | 110 ± 9 | | 104 ± 6
| 1,000 | 86 ± 6 | 102 ± 11 | 109 ± 13 | 99 ± 5 | 111 ± 9 | | 111 ± 9
| 3,333 | 98 ± 7 | 101 ± 5 | 109 ± 4 | 108 ± 8 | 124 ± 8 | | 98 ± 1
| 10,000 | 101 ± 14 | 99 ± 10 | 123 ± 5 | 89 ± 11 | 116 ± 5 | | 115 ± 13
Trial summary | | Negative | Negative | Negative | Negative | Negative | | Negative
Positive control^b^ | | 481 ± 25 | 397 ± 12 | 1,419 ± 38 | 1,834 ± 92 | 372 ± 34 | | 1,836 ± 102
TA98
| 0 | 15 ± 1 | 21 ± 3 | 33 ± 5 | 38 ± 3 | 25 ± 4 | | 28 ± 5
| 100 | 16 ± 1 | 19 ± 3 | 36 ± 4 | 35 ± 3 | 33 ± 3 | | 29 ± 5
| 333 | 15 ± 2 | 20 ± 5 | 33 ± 3 | 35 ± 3 | 23 ± 1 | | 24 ± 4
| 1,000 | 13 ± 1 | 18 ± 2 | 30 ± 4 | 30 ± 1 | 24 ± 4 | | 31 ± 2
| 3,333 | 18 ± 2 | 18 ± 4 | 30 ± 3 | 28 ± 5 | 24 ± 1 | | 26 ± 2
| 10,000 | 25 ± 5 | 17 ± 3 | 21 ± 3 | 32 ± 2 | 21 ± 1 | | 28 ± 5
Trial summary | | Negative | Negative | Negative | Negative | Negative | | Negative
Positive control | | 620 ± 55 | 378 ± 12 | 1,278 ± 63 | 1,551 ± 2 | 418 ± 14 | | 1,522 ± 83
TA1535
| 0 | 28 ± 2 | 30 ± 3 | 10 ± 3 | 10 ± 2 | 6 ± 1 | | 9 ± 2
| 100 | 19 ± 2 | 24 ± 4 | 8 ± 2 | 7 ± 2 | 9 ± 2 | | 7 ± 0
| 333 | 18 ± 2 | 25 ± 4 | 8 ± 1 | 12 ± 2 | 8 ± 1 | | 10 ± 1
| 1,000 | 19 ± 1 | 31 ± 3 | 8 ± 0 | 13 ± 1 | 6 ± 1 | | 9 ± 2
| 3,333 | 25 ± 1 | 16 ± 1 | 8 ± 1 | 11 ± 2 | 11 ± 3 | | 8 ± 2
| 10,000 | 27 ± 4 | 14 ± 3 | 7 ± 1 | 8 ± 2 | 9 ± 1 | | 6 ± 2
Trial summary | | Negative | Negative | Negative | Negative | Negative | | Negative
Positive control | | 427 ± 12 | 472 ± 34 | 382 ± 19 | 586 ± 12 | 132 ± 4 | | 489 ± 17
TA1537
| 0 | 5 ± 2 | 8 ± 3 | 5 ± 1 | 7 ± 1 | 7 ± 1 | | 7 ± 1
| 100 | 5 ± 0 | 4 ± 1 | 7 ± 3 | 9 ± 2 | 7 ± 2 | | 8 ± 1
| 333 | 4 ± 1 | 6 ± 2 | 7 ± 1 | 10 ± 1 | 7 ± 1 | | 8 ± 1
| 1,000 | 2 ± 0 | 4 ± 0 | 8 ± 0 | 9 ± 1 | 9 ± 1 | | 9 ± 0
| 3,333 | 9 ± 1 | 4 ± 1 | 8 ± 1 | 8 ± 1 | 6 ± 1 | | 8 ± 1
| 10,000 | 6 ± 2 | 8 ± 2 | 5 ± 1 | 7 ± 1 | 6 ± 2 | | 4 ± 0
Trial summary | | Negative | Negative | Negative | Negative | Negative | | Negative
Positive control | | 222 ± 11 | 283 ± 43 | 519 ± 11 | 268 ± 14 | 123 ± 4 | | 251 ± 20
Study performed at BioReliance Corporation
TA102
| 0 | 307 ± 24 | 329 ± 26 | | | | 347 ± 28 | 221 ± 13
| 100 | 1,219 ± 890 | 296 ± 11 | | | | 397 ± 27 | 224 ± 36
| 333 | 303 ± 3 | 209 ± 25 | | | | 396 ± 7 | 155 ± 17
| 1,000 | 302 ± 10^c^ | 325 ± 9^c^ | | | | 310 ± 12^c^ | 233 ± 7^c^
| 3,333 | 308 ± 13^c^ | 302 ± 39^c^ | | | | 339 ± 7^c^ | 325 ± 14^c^
| 10,000 | 328 ± 16^c^ | 272 ± 17^c^ | | | | 355 ± 6^c^ | 333 ± 16^c^
Trial summary | | Negative | Negative | | | | Negative | Equivocal
Positive control | | 1,003 ± 3 | 1,324 ± 26 | | | | 1,434 ± 84 | 845 ± 22
TA100
| 0 | 184 ± 7 | | | | | 182 ± 9
| 100 | 227 ± 12 | | | | | 180 ± 6
| 333 | 186 ± 19 | | | | | 180 ± 1
| 1,000 | 208 ± 25^c^ | | | | | 178 ± 3^c^
| 3,333 | 203 ± 9^c^ | | | | | 180 ± 8^c^
| 10,000 | 236 ± 18^c^ | | | | | 184 ± 10^c^
Trial summary | | Negative | | | | | Negative
Positive control | | 689 ± 45 | | | | | 693 ± 22
TA98
| 0 | 15 ± 3 | | | | | 20 ± 2
| 100 | 14 ± 1 | | | | | 22 ± 2
| 333 | 10 ± 1 | | | | | 20 ± 3
| 1,000 | 12 ± 0^c^ | | | | | 21 ± 1^c^
| 3,333 | 11 ± 2^c^ | | | | | 17 ± 1^c^
| 10,000 | 11 ± 0^c^ | | | | | 19 ± 2^c^
Trial summary | | Negative | | | | | Negative
Positive control | | 112 ± 9 | | | | | 245 ± 11

^a^ Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol and these data are presented by Zeiger et al.^172^ 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), 4-nitro-o-phenylenediamine (TA98), and cumene hydroperoxide (TA102). The positive control for metabolic activation with all strains was 2-aminoanthracene, except sterigmatocystin was used for TA102.

^c^ Precipitate on plate.

Table E-2 Mutagenicity of DE-71 in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% rat S9 | With 10% rat S9
TA100
| 0 | 68 ± 8 | 70 ± 3 | 90 ± 7 | 68 ± 3
| 1,000 | 53 ± 2 | 57 ± 9 | 82 ± 4 | 66 ± 2
| 2,500 | 63 ± 3 | 58 ± 5 | 72 ± 1 | 73 ± 6
| 5,000 | 69 ± 2 | 68 ± 4 | 85 ± 4 | 73 ± 3
| 7,500 | 70 ± 3 | 65 ± 2 | 70 ± 5 | 72 ± 6
| 10,000 | 75 ± 8 | 76 ± 1 | 82 ± 9 | 66 ± 1
Trial summary | | Negative | Negative | Negative | Negative
Positive control^b^ | | 557 ± 8 | 554 ± 3 | 868 ± 76 | 1,101 ± 49
TA98
| 0 | 27 ± 2 | 20 ± 2 | 31 ± 3 | 24 ± 2
| 1,000 | 18 ± 2 | 20 ± 5 | 31 ± 2 | 27 ± 3
| 2,500 | 17 ± 3 | 21 ± 2 | 30 ± 3 | 36 ± 3
| 5,000 | 19 ± 3 | 26 ± 5 | 24 ± 3 | 32 ± 2
| 7,500 | 22 ± 5 | 33 ± 2 | 23 ± 2 | 27 ± 3
| 10,000 | 22 ± 2 | 33 ± 8 | 23 ± 1 | 38 ± 3
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 514 ± 13 | 648 ± 26 | 1,416 ± 42 | 1,071 ± 42
Escherichia coli WP2 uvrA/pKM101 (analogous to TA102)
| 0 | 143 ± 5 | 167 ± 13 | 195 ± 12 | 211 ± 3
| 1,000 | 152 ± 9 | 163 ± 3 | 211 ± 13 | 219 ± 5
| 2,500 | 160 ± 6 | 181 ± 8 | 226 ± 10 | 254 ± 1
| 5,000 | 118 ± 4 | 193 ± 8 | 166 ± 8 | 254 ± 13
| 7,500 | 120 ± 1 | 210 ± 8 | 151 ± 6 | 261 ± 5
| 10,000 | 120 ± 8 | 249 ± 5 | 142 ± 15 | 266 ± 18
Trial summary | | Negative | Negative | Negative | Negative
Positive control | | 1,654 ± 53 | 1,913 ± 40 | 996 ± 15 | 1,046 ± 74

^a^ Study was performed at SITEK Research Laboratories using lot 2550OA30A. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 2-nitrofluorene (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table E-3 Mutagenicity of 2,2′,4,4′-Tetrabromodiphenyl Ether (BDE-47) in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% rat S9
TA102
| 0 | 223 ± 9 | 262 ± 6 | 285 ± 18
| 100 | 136 ± 68^b^ | 225 ± 5 | 276 ± 9
| 333 | 71 ± 71^b^ | 248 ± 3 | 273 ± 13
| 1,000 | 216 ± 12^c^ | 264 ± 3^c^ | 303 ± 5^c^
| 3,333 | 213 ± 6^c^ | 268 ± 5^c^ | 287 ± 1^c^
| 10,000 | 171 ± 22^c^ | 258 ± 6^c^ | 276 ± 6^c^
Trial summary | | Negative | Negative | Negative
Positive control^d^ | | 1,405 ± 66 | 1,053 ± 7 | 1,346 ± 71
TA100
| 0 | 169 ± 15 | | 149 ± 7
| 100 | 186 ± 10 | | 118 ± 8
| 333 | 172 ± 12 | | 116 ± 7
| 1,000 | 209 ± 11^c^ | | 130 ± 1^c^
| 3,333 | 202 ± 8^c^ | | 121 ± 5^c^
| 10,000 | 146 ± 8^c^ | | 121 ± 10^c^
Trial summary | | Negative | | Negative
Positive control | | 589 ± 19 | | 700 ± 48
TA98
| 0 | 18 ± 0^e^ | | 22 ± 3
| 100 | 14 ± 2 | | 23 ± 2
| 333 | 18 ± 1 | | 19 ± 1
| 1,000 | 13 ± 1^c^ | | 15 ± 1^c^
| 3,333 | 11 ± 1^c^ | | 14 ± 2^c^
| 10,000 | 10 ± 2^c^ | | 18 ± 1^c^
Trial summary | | Negative | | Negative
Positive control | | 124 ± 9 | | 273 ± 13

^a^ Study was performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^275^ 0 μg/plate was the solvent control.

^b^ Slightly toxic.

^c^ Precipitate on plate.

^d^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and cumene hydroperoxide (TA102). The positive control for metabolic activation with all strains was 2-aminoanthracene, except sterigmatocystin was used for TA102.

^e^ Contamination.

Table E-4 Mutagenicity of 2,2′,4,4′,5-Pentabromodiphenyl Ether (BDE-99) in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% rat S9
TA102
| 0 | 224 ± 23^b^ | 269 ± 15 | 306 ± 15
| 100 | Toxic | 264 ± 9 | 243 ± 16
| 333 | 194 ± 17^c^ | 252 ± 13 | 265 ± 15
| 1,000 | 175 ± 4^c^ | 231 ± 16^c^ | 301 ± 4^c^
| 3,333 | 200 ± 9^c^ | 197 ± 23^c^ | 283 ± 15^c^
| 10,000 | 132 ± 2^c^ | 258 ± 8^c^ | 379 ± 19^c^
Trial summary | | Negative | Negative | Negative
Positive control^d^ | | 906 ± 89 | 992 ± 41 | 1,218 ± 42
TA100
| 0 | 178 ± 7 | | 200 ± 6
| 100 | 168 ± 3 | | 183 ± 11
| 333 | 173 ± 6 | | 184 ± 2
| 1,000 | 170 ± 4^c^ | | 188 ± 13^c^
| 3,333 | 170 ± 2^c^ | | 187 ± 12^c^
| 10,000 | 139 ± 27^c^ | | 147 ± 11^c^
Trial summary | | Negative | | Negative
Positive control | | 681 ± 45 | | 752 ± 17
TA98
| 0 | 18 ± 2 | | 28 ± 1
| 100 | 14 ± 4 | | 22 ± 1
| 333 | 14 ± 2 | | 21 ± 4
| 1,000 | 13 ± 1^c^ | | 23 ± 2^c^
| 3,333 | 11 ± 1^c^ | | 24 ± 3^c^
| 10,000 | 7 ± 0^c^ | | 13 ± 1^c^
Trial summary | | Negative | | Negative
Positive control | | 120 ± 13 | | 250 ± 22

^a^ Study was performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^275^ 0 μg/plate was the solvent control.

^b^ Slightly toxic.

^c^ Precipitate on plate.

^d^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and cumene hydroperoxide (TA102). The positive control for metabolic activation with all strains was 2-aminoanthracene, except sterigmatocystin was used for TA102.

Table E-5 Mutagenicity of 2,2′,4,4′,5,5′-Hexabromodiphenyl Ether (BDE-153) in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 10% rat S9
TA102
| 0 | 307 ± 17 | 329 ± 11
| 100 | 284 ± 10 | 348 ± 24
| 333 | 331 ± 3 | 341 ± 5
| 1,000 | 320 ± 11 | 351 ± 38^b^
| 3,333 | 289 ± 6^b^ | 394 ± 7^b^
| 5,000 | 269 ± 24^b^ | 373 ± 27^b^
Trial summary | | Negative | Negative
Positive control^c^ | | 785 ± 21 | 1,404 ± 104
TA100
| 0 | 178 ± 7 | 191 ± 10
| 100 | 203 ± 6 | 182 ± 7
| 333 | 188 ± 3^b^ | 186 ± 7^b^
| 1,000 | 235 ± 17^b^ | 212 ± 3^b^
| 3,333 | 178 ± 5^b^ | 232 ± 27^b^
| 5,000 | 167 ± 14^b^ | 186 ± 43^b^
Trial summary | | Negative | Negative
Positive control | | 686 ± 41 | 644 ± 24
TA98
| 0 | 16 ± 2 | 18 ± 1
| 100 | 14 ± 2 | 19 ± 2
| 333 | 11 ± 3^b^ | 18 ± 1^b^
| 1,000 | 11 ± 1^b^ | 16 ± 3^b^
| 3,333 | 9 ± 1^b^ | 13 ± 1^b^
| 5,000 | 11 ± 2^b^ | 16 ± 3^b^
Trial summary | | Negative | Negative
Positive control | | 102 ± 4 | 223 ± 4

^a^ Study was performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^275^ 0 μg/plate was the solvent control.

^b^ Precipitate on plate.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and cumene hydroperoxide (TA102). The positive control for metabolic activation with all strains was 2-aminoanthracene, except sterigmatocystin was used for TA102.

Table E-6 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Administered DE-71 by Gavage for Three Months^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Corn oil^d^ | 0 | 5 | 1.90 ± 0.40 | | 2.360 ± 0.19
DE-71 | 0.01 | 5 | 2.10 ± 0.53 | 0.3758 | 2.480 ± 0.26
| 5 | 5 | 1.80 ± 0.46 | 0.5654 | 2.540 ± 0.23
| 50 | 5 | 1.80 ± 0.34 | 0.5654 | 2.300 ± 0.19
| 100 | 5 | 2.30 ± 0.37 | 0.2683 | 2.940 ± 0.34
| 500 | 3 | 1.83 ± 0.73 | 0.5376 | 2.133 ± 0.39
| | | P = 0.537^e^
Female
Corn oil^d^ | 0 | 5 | 1.30 ± 0.20 | | 2.840 ± 0.12
DE-71 | 0.01 | 5 | 1.60 ± 0.33 | 0.2886 | 3.140 ± 0.38
| 5 | 5 | 1.50 ± 0.32 | 0.3526 | 3.040 ± 0.43
| 50 | 5 | 1.20 ± 0.46 | 0.5793 | 2.360 ± 0.40
| 100 | 5 | 0.80 ± 0.20 | 0.8625 | 2.260 ± 0.12
| 500 | 5 | 1.40 ± 0.48 | 0.4236 | 1.980 ± 0.14
| | | P = 0.510^e^

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^276^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; exposed group values are significant at P ≤ 0.005.

^d^ Vehicle control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.

Table E-7 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male Mice Administered DE-71 by Gavage for Three Days^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/ 1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/ 1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Corn oil^d^ | 0 | 5 | 2.59 ± 0.20 | | 1.57 ± 0.04 | | 1.736 ± 0.09
DE-71 | 312.5 | 5 | 2.16 ± 0.10 | 0.8731 | 1.53 ± 0.04 | 0.6358 | 1.565 ± 0.12 | 0.3789
| 625 | 5 | 2.21 ± 0.12 | 0.9286 | 1.59 ± 0.06 | 0.4287 | 1.518 ± 0.19 | 0.2654
| 1,250 | 5 | 2.33 ± 0.19 | 0.9447 | 1.60 ± 0.01 | 0.4297 | 1.325 ± 0.13 | 0.0396
| | | P = 0.767^e^ | | P = 0.223^e^ | | P = 0.023^e^
Cyclophosphamide^f^ | 50 | | 32.56 ± 1.58 | <0.0001 | 2.03 ± 0.05 | <0.0001 | 0.175 ± 0.01 | <0.0001

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^173^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group; dosed group values are significant at P ≤ 0.025 by Williams’ test; positive control values are significant at P ≤ 0.05.

^d^ Vehicle control.

^e^ Dose-related trend; significant at P ≤ 0.025 by Jonckheere’s test.

^f^ Positive control.

Table E-8 Induction of Micronuclei in Bone Marrow Polychromatic Erythrocytes of Male Mice Administered DE-71 by Gavage for Three Days^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | PCEs^b^ (%)
Corn oil^d^ | 0 | 5 | 2.00 ± 0.42 | | 68.00 ± 2.56
DE-71 | 312.5 | 5 | 1.50 ± 0.32 | 0.8012 | 72.50 ± 1.92
| 625 | 5 | 1.90 ± 0.37 | 0.5637 | 71.60 ± 5.03
| 1,250 | 5 | 2.10 ± 0.19 | 0.4379 | 66.80 ± 4.83
| | | P = 0.327^e^
Cyclophosphamide^f^ | 50 | 5 | 33.70 ± 4.14 | <0.0001 | 31.60 ± 4.62

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^173^ PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.008; positive control values are significant at P ≤ 0.05.

^d^ Vehicle control.

^e^ Significance of micronucleated PCEs/1,000 PCEs tested by the one-tailed trend test; significant at P ≤ 0.025.

^f^ Positive control.