# Appendix D Summary of Lesions in Female Mice in the Two-year Gavage Study of DE-71

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | 1 | – | 1 | –
Moribund | 10 | 10 | 9 | 46
Natural deaths | 6 | 5 | 3 | 4
Survivors
Terminal kill | 33 | 35 | 37 | –
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (49)
Gallbladder | (44) | (44) | (47) | (45)
Intestine large, cecum | (46) | (45) | (47) | (47)
Intestine large, colon | (47) | (45) | (47) | (47)
Intestine large, rectum | (47) | (46) | (47) | (47)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Intestine small, duodenum | (46) | (45) | (47) | (47)
Intestine small, ileum | (46) | (45) | (47) | (47)
Intestine small, jejunum | (46) | (45) | (47) | (47)
Carcinoma | – | – | 1 (2%) | –
Liver | (50) | (49) | (50) | (49)
Hemangioma | – | 1 (2%) | – | –
Hemangiosarcoma | – | – | 1 (2%) | –
Hepatocellular adenoma | 5 (10%) | 5 (10%) | 11 (22%) | 4 (8%)
Hepatocellular adenoma, multiple | – | 2 (4%) | 21 (42%) | 42 (86%)
Hepatocellular carcinoma | 4 (8%) | 1 (2%) | 5 (10%) | 19 (39%)
Hepatocellular carcinoma, multiple | – | 1 (2%) | 1 (2%) | 8 (16%)
Serosa, fibrosarcoma, metastatic, skin | 1 (2%) | – | – | –
Mesentery | (11) | (26) | (12) | (5)
Fibrosarcoma, metastatic, skin | 1 (9%) | – | – | –
Oral mucosa | (0) | (1) | (0) | (0)
Pancreas | (50) | (48) | (50) | (50)
Fibrosarcoma, metastatic, skin | 1 (2%) | – | – | –
Salivary glands | (50) | (50) | (50) | (48)
Fibrosarcoma, metastatic, skin | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (49)
Hepatocellular carcinoma, metastatic, liver | – | – | – | 1 (2%)
Squamous cell papilloma | – | 3 (6%) | 1 (2%) | 2 (4%)
Stomach, glandular | (49) | (47) | (47) | (48)
Cardiovascular System
Blood vessel | (47) | (49) | (50) | (49)
Heart | (50) | (50) | (50) | (49)
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (47)
Adenoma | – | – | 1 (2%) | –
Fibrosarcoma, metastatic, skin | 1 (2%) | – | – | –
Capsule, adenoma | – | – | 1 (2%) | –
Adrenal medulla | (49) | (50) | (48) | (48)
Pheochromocytoma benign | – | – | 1 (2%) | –
Pheochromocytoma malignant | – | – | – | 1 (2%)
Islets, pancreatic | (50) | (48) | (50) | (50)
Adenoma | 1 (2%) | – | 2 (4%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Parathyroid gland | (44) | (48) | (47) | (47)
Pituitary gland | (50) | (47) | (46) | (45)
Pars distalis, adenoma | 5 (10%) | 5 (11%) | 8 (17%) | –
Pars intermedia, adenoma | – | 2 (4%) | – | –
Thyroid gland | (50) | (49) | (48) | (47)
C-cell, adenoma | 1 (2%) | – | – | –
Follicular cell, adenoma | 1 (2%) | – | – | –
Follicular cell, carcinoma | – | 1 (2%) | – | –
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Tissue NOS | (1) | (2) | (0) | (1)
Genital System
Clitoral gland | (49) | (49) | (50) | (50)
Ovary | (48) | (49) | (50) | (48)
Cystadenoma | 2 (4%) | 1 (2%) | 3 (6%) | –
Granulosa cell tumor benign | 1 (2%) | – | – | –
Granulosa cell tumor malignant | – | – | – | 1 (2%)
Uterus | (50) | (50) | (50) | (49)
Adenoma | 1 (2%) | – | – | –
Hemangioma | 1 (2%) | – | – | –
Polyp stromal | – | 2 (4%) | 3 (6%) | –
Bilateral, polyp stromal | – | – | 1 (2%) | –
Vagina | (0) | (1) | (0) | (0)
Squamous cell carcinoma | – | 1 (100%) | – | –
Hematopoietic System
Bone marrow | (49) | (50) | (50) | (49)
Rhabdomyosarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Lymph node | (9) | (17) | (12) | (4)
Lymph node, mandibular | (48) | (50) | (50) | (45)
Lymph node, mesenteric | (48) | (45) | (49) | (48)
Spleen | (50) | (47) | (48) | (48)
Capsule, fibrosarcoma, metastatic, skin | 1 (2%) | – | – | –
Thymus | (48) | (45) | (46) | (46)
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Skin | (50) | (50) | (50) | (50)
Mast cell tumor benign | – | – | – | 1 (2%)
Lip, mast cell tumor benign | – | – | – | 1 (2%)
Subcutaneous tissue, fibrosarcoma | 1 (2%) | 1 (2%) | – | –
Subcutaneous tissue, fibrous histiocytoma, multiple | – | 1 (2%) | – | –
Subcutaneous tissue, rhabdomyosarcoma, metastatic, skeletal muscle | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (49) | (50) | (50) | (50)
Maxilla, rhabdomyosarcoma, metastatic, skeletal muscle | 1 (2%) | – | – | –
Skeletal muscle | (2) | (3) | (4) | (1)
Rhabdomyosarcoma | 1 (50%) | 2 (67%) | 2 (50%) | –
Nervous System
Brain | (50) | (50) | (50) | (49)
Peripheral nerve | (1) | (1) | (1) | (1)
Spinal cord | (1) | (1) | (3) | (1)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 1 (2%) | 5 (10%) | 3 (6%) | –
Alveolar/bronchiolar carcinoma | – | 1 (2%) | 1 (2%) | –
Fibrosarcoma, metastatic, skin | 1 (2%) | – | – | –
Granulosa cell tumor malignant, metastatic, ovary | – | – | – | 1 (2%)
Hepatocellular carcinoma, metastatic, liver | 2 (4%) | 1 (2%) | – | 1 (2%)
Mediastinum, fibrosarcoma, metastatic, skin | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (48)
Pleura | (0) | (0) | (1) | (0)
Trachea | (50) | (50) | (50) | (47)
Special Senses System
Eye | (47) | (45) | (47) | (48)
Harderian gland | (50) | (49) | (50) | (49)
Adenoma | 9 (18%) | 1 (2%) | 4 (8%) | 2 (4%)
Carcinoma | 1 (2%) | 1 (2%) | 1 (2%) | –
Urinary System
Kidney | (50) | (50) | (49) | (48)
Urinary bladder | (49) | (50) | (49) | (48)
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Lymphoma malignant | 7 (14%) | 6 (12%) | 6 (12%) | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 34 | 30 | 41 | 49
Total primary neoplasms | 44 | 46 | 79 | 83
Total animals with benign neoplasms | 24 | 20 | 38 | 46
Total benign neoplasms | 28 | 27 | 60 | 52
Total animals with malignant neoplasms | 16 | 15 | 15 | 31
Total malignant neoplasms | 16 | 19 | 19 | 31
Total animals with metastatic neoplasms | 4 | 1 | 1 | 3
Total metastatic neoplasms | 13 | 1 | 3 | 3

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Primary Neoplasms in Female Mice in the Two-year Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Harderian Gland: Adenoma
Overall rate^a^ | 9/50 (18%) | 1/50 (2%) | 4/50 (8%) | 2/50 (4%)
Adjusted rate^b^ | 20.7% | 2.3% | 8.7% | 9.6%
Terminal rate^c^ | 8/33 (24%) | 1/35 (3%) | 3/37 (8%) | 0/0 (0%)
First incidence (days) | 656 | 729 (T) | 677 | 542
Poly-3 test^d^ | P = 0.379N | P = 0.007N | P = 0.095N | P = 0.251N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 10/50 (20%) | 2/50 (4%) | 5/50 (10%) | 2/50 (4%)
Adjusted rate | 23.0% | 4.5% | 10.9% | 9.6%
Terminal rate | 9/33 (27%) | 1/35 (3%) | 4/37 (11%) | 0/0 (0%)
First incidence (days) | 656 | 684 | 677 | 542
Poly-3 test | P = 0.315N | P = 0.011N | P = 0.105N | P = 0.197N
Liver: Hepatocellular Adenoma
Overall rate | 5/50 (10%) | 7/49 (14%) | 32/50 (64%) | 46/49 (94%)
Adjusted rate | 11.6% | 16.0% | 68.0% | 97.9%
Terminal rate | 5/33 (15%) | 7/35 (20%) | 26/37 (70%) | 0/0 (0%)
First incidence (days) | 729 (T) | 729 (T) | 563 | 432
Poly-3 test | P < 0.001 | P = 0.385 | P < 0.001 | P < 0.001
Liver: Hepatocellular Carcinoma
Overall rate | 4/50 (8%) | 2/49 (4%) | 6/50 (12%) | 27/49 (55%)
Adjusted rate | 9.2% | 4.6% | 13.0% | 75.5%
Terminal rate | 3/33 (9%) | 1/35 (3%) | 4/37 (11%) | 0/0 (0%)
First incidence (days) | 696 | 712 | 598 | 432
Poly-3 test | P < 0.001 | P = 0.333N | P = 0.411 | P < 0.001
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 8/50 (16%) | 8/49 (16%) | 33/50 (66%) | 47/49 (96%)
Adjusted rate | 18.4% | 18.3% | 69.5% | 98.8%
Terminal rate | 7/33 (21%) | 7/35 (20%) | 26/37 (70%) | 0/0 (0%)
First incidence (days) | 696 | 712 | 563 | 432
Poly-3 test | P < 0.001 | P = 0.602N | P < 0.001 | P < 0.001
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 1/50 (2%) | 5/50 (10%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 2.3% | 11.2% | 6.5% | 0.0%
Terminal rate | 1/33 (3%) | 3/35 (9%) | 2/37 (5%) | 0/0 (0%)
First incidence (days) | 729 (T) | 687 | 677 | –^e^
Poly-3 test | P = 0.309N | P = 0.108 | P = 0.327 | P = 0.638N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 1/50 (2%) | 6/50 (12%) | 4/50 (8%) | 0/50 (0%)
Adjusted rate | 2.3% | 13.4% | 8.7% | 0.0%
Terminal rate | 1/33 (3%) | 4/35 (11%) | 3/37 (8%) | 0/0 (0%)
First incidence (days) | 729 (T) | 687 | 677 | –
Poly-3 test | P = 0.322N | P = 0.061 | P = 0.197 | P = 0.638N
Ovary: Cystadenoma
Overall rate | 2/48 (4%) | 1/49 (2%) | 3/50 (6%) | 0/48 (0%)
Adjusted rate | 4.9% | 2.3% | 6.6% | 0.0%
Terminal rate | 2/31 (7%) | 1/34 (3%) | 3/37 (8%) | 0/0 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | –
Poly-3 test | P = 0.540N | P = 0.482N | P = 0.546 | P = 0.429N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 5/50 (10%) | 5/47 (11%) | 8/46 (17%) | 0/45 (0%)
Adjusted rate | 11.6% | 11.6% | 18.4% | 0.0%
Terminal rate | 5/33 (15%) | 5/35 (14%) | 7/36 (19%) | 0/0 (0%)
First incidence (days) | 729 (T) | 729 (T) | 563 | –
Poly-3 test | P = 0.408N | P = 0.629 | P = 0.277 | P = 0.196N
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 0/50 (0%) | 3/50 (6%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 0.0% | 6.7% | 2.2% | 9.6%
Terminal rate | 0/33 (0%) | 2/35 (6%) | 1/37 (3%) | 0/0 (0%)
First incidence (days) | – | 690 | 729 (T) | 542
Poly-3 test | P = 0.279 | P = 0.124 | P = 0.511 | P = 0.121
Uterus: Stromal Polyp
Overall rate | 0/50 (0%) | 2/50 (4%) | 4/50 (8%) | 0/50 (0%)
Adjusted rate | 0.0% | 4.5% | 8.8% | 0.0%
Terminal rate | 0/33 (0%) | 2/35 (6%) | 3/37 (8%) | 0/0 (0%)
First incidence (days) | – | 729 (T) | 726 | –
Poly-3 test | P = 0.409 | P = 0.243 | P = 0.067 | –^f^
All Organs: Histiocytic Sarcoma
Overall rate | 1/50 (2%) | 3/50 (6%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 2.3% | 6.5% | 2.2% | 4.9%
Terminal rate | 1/33 (3%) | 0/35 (0%) | 1/37 (3%) | 0/0 (0%)
First incidence (days) | 729 (T) | 522 | 729 (T) | 459
Poly-3 test | P = 0.537N | P = 0.327 | P = 0.748N | P = 0.575
All Organs: Malignant Lymphoma
Overall rate | 7/50 (14%) | 6/50 (12%) | 6/50 (12%) | 1/50 (2%)
Adjusted rate | 15.8% | 13.3% | 13.1% | 4.9%
Terminal rate | 3/33 (9%) | 5/35 (14%) | 6/37 (16%) | 0/0 (0%)
First incidence (days) | 593 | 421 | 729 (T) | 496
Poly-3 test | P = 0.232N | P = 0.483N | P = 0.476N | P = 0.234N
All Organs: Benign Neoplasms
Overall rate | 24/50 (48%) | 20/50 (40%) | 38/50 (76%) | 46/50 (92%)
Adjusted rate | 54.6% | 44.6% | 80.4% | 97.7%
Terminal rate | 22/33 (67%) | 17/35 (49%) | 30/37 (81%) | 0/0 (0%)
First incidence (days) | 601 | 687 | 563 | 432
Poly-3 test | P < 0.001 | P = 0.228N | P = 0.005 | P < 0.001
All Organs: Malignant Neoplasms
Overall rate | 16/50 (32%) | 15/50 (30%) | 15/50 (30%) | 31/50 (62%)
Adjusted rate | 35.4% | 31.6% | 31.9% | 80.5%
Terminal rate | 9/33 (27%) | 7/35 (20%) | 11/37 (30%) | 0/0 (0%)
First incidence (days) | 589 | 421 | 563 | 432
Poly-3 test | P < 0.001 | P = 0.436N | P = 0.446N | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 34/50 (68%) | 30/50 (60%) | 41/50 (82%) | 49/50 (98%)
Adjusted rate | 74.4% | 62.8% | 85.9% | 99.7%
Terminal rate | 26/33 (79%) | 20/35 (57%) | 32/37 (87%) | 0/0 (0%)
First incidence (days) | 589 | 421 | 563 | 432
Poly-3 test | P < 0.001 | P = 0.156N | P = 0.118 | P < 0.001

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver, lung, ovary, and pituitary gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table D-3 Historical Incidence of Liver Neoplasms in Control Female B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatocellular Adenoma or Hepatocellular Carcinoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (February 2008) | 5/50 | 4/50 | 8/50
Ginkgo biloba extract (March 2005) | 17/50 | 9/50 | 20/50
Indole-3-carbinol (April 2007) | 7/50 | 6/50 | 12/50
Kava kava extract (August 2004) | 8/50 | 3/50 | 10/50
N,N-dimethyl-p-toluidine (October 2004) | 17/50 | 6/50 | 20/50
Tetrabromobisphenol A (August 2007) | 13/50 | 2/50 | 15/50
Total (%) | 67/300 (22.3%) | 30/300 (10.0%) | 85/300 (28.3%)
Mean ± standard deviation | 22.3% ± 10.5% | 10.0% ± 5.1% | 28.3% ± 10.2%
Range | 10%–34% | 4%–18% | 16%–40%
Overall Historical Incidence: All Routes
Total (%) | 272/698 (39.0%) | 112/698 (16.1%) | 320/698 (45.9%)
Mean ± standard deviation | 39.1% ± 21.9% | 16.1% ± 8.1% | 45.9% ± 21.9%
Range | 10%–78% | 4%–34% | 16%–82%
| Hepatoblastoma | Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (February 2008) | 0/50 | 8/50
Ginkgo biloba extract (March 2005) | 1/50 | 20/50
Indole-3-carbinol (April 2007) | 0/50 | 12/50
Kava kava extract (August 2004) | 0/50 | 10/50
N,N-dimethyl-p-toluidine (October 2004) | 0/50 | 20/50
Tetrabromobisphenol A (August 2007) | 0/50 | 15/50
Total (%) | 1/300 (0.3%) | 85/300 (28.3%)
Mean ± standard deviation | 0.3% ± 0.8% | 28.3% ± 10.2%
Range | 0%–2% | 16%–40%
Overall Historical Incidence: All Routes
Total (%) | 4/698 (0.6%) | 320/698 (45.9%)
Mean ± standard deviation | 0.6% ± 0.9% | 45.9% ± 21.9%
Range | 0%–2% | 16%–82%

^a^ Data as of November 2014.

Table D-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | 1 | – | 1 | –
Moribund | 10 | 10 | 9 | 46
Natural deaths | 6 | 5 | 3 | 4
Survivors
Terminal kill | 33 | 35 | 37 | –
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (49)
Foreign body | – | – | 1 (2%) | –
Inflammation, granulomatous | – | – | – | 1 (2%)
Inflammation, acute | – | – | 1 (2%) | –
Inflammation, chronic | – | 1 (2%) | – | –
Necrosis | 1 (2%) | – | – | –
Muscularis, degeneration | 1 (2%) | 1 (2%) | 2 (4%) | 3 (6%)
Gallbladder | (44) | (44) | (47) | (45)
Intestine large, cecum | (46) | (45) | (47) | (47)
Intestine large, colon | (47) | (45) | (47) | (47)
Intestine large, rectum | (47) | (46) | (47) | (47)
Diverticulum | – | – | 1 (2%) | –
Edema | – | 1 (2%) | – | –
Intestine small, duodenum | (46) | (45) | (47) | (47)
Intestine small, ileum | (46) | (45) | (47) | (47)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Ulcer | 1 (2%) | – | – | –
Intestine small, jejunum | (46) | (45) | (47) | (47)
Inflammation, acute | – | – | 1 (2%) | –
Liver | (50) | (49) | (50) | (49)
Basophilic focus | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Clear cell focus | – | 3 (6%) | 2 (4%) | 2 (4%)
Eosinophilic focus | 3 (6%) | 1 (2%) | 15 (30%) | 8 (16%)
Eosinophilic focus, multiple | – | 1 (2%) | 1 (2%) | 7 (14%)
Fatty change | 18 (36%) | 18 (37%) | 39 (78%) | 20 (41%)
Fibrosis | 1 (2%) | 1 (2%) | – | –
Hematopoietic cell proliferation | 13 (26%) | 15 (31%) | 8 (16%) | 13 (27%)
Hemorrhage | 4 (8%) | 1 (2%) | 4 (8%) | 5 (10%)
Inflammation, acute | – | – | – | 1 (2%)
Inflammation, chronic | 32 (64%) | 33 (67%) | 34 (68%) | 32 (65%)
Mixed cell focus | – | 2 (4%) | – | 1 (2%)
Necrosis, focal | 1 (2%) | 1 (2%) | 4 (8%) | 3 (6%)
Tension lipidosis | 3 (6%) | 2 (4%) | 2 (4%) | –
Centrilobular, mineralization | – | – | 1 (2%) | –
Centrilobular, necrosis | – | – | 2 (4%) | –
Centrilobular, hepatocyte, hypertrophy | – | 7 (14%) | 45 (90%) | 47 (96%)
Hepatocyte, cytoplasmic alteration | – | – | 1 (2%) | –
Kupffer cell, pigmentation | 3 (6%) | 10 (20%) | 24 (48%) | 27 (55%)
Midzonal, necrosis | – | – | 1 (2%) | –
Mesentery | (11) | (26) | (12) | (5)
Accessory spleen | – | 1 (4%) | – | –
Cyst | – | 1 (4%) | – | –
Inflammation, chronic | – | 1 (4%) | – | –
Inflammation, chronic active | 1 (9%) | – | – | –
Mineralization | – | 1 (4%) | – | –
Fat, necrosis | 10 (91%) | 22 (85%) | 12 (100%) | 3 (60%)
Oral mucosa | (0) | (1) | (0) | (0)
Pancreas | (50) | (48) | (50) | (50)
Atrophy | 6 (12%) | 8 (17%) | 5 (10%) | –
Cyst | 1 (2%) | 3 (6%) | 3 (6%) | –
Fibrosis | – | 1 (2%) | 1 (2%) | –
Inflammation, chronic | 29 (58%) | 31 (65%) | 31 (62%) | 22 (44%)
Inflammation, chronic active | – | 1 (2%) | – | –
Mineralization, chronic | – | – | 1 (2%) | –
Necrosis | 1 (2%) | 1 (2%) | – | 1 (2%)
Duct, cyst | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (50) | (48)
Atrophy | 1 (2%) | – | 1 (2%) | –
Infiltration cellular, mononuclear cell | 32 (64%) | 37 (74%) | 30 (60%) | 26 (54%)
Mineralization | 1 (2%) | 5 (10%) | 5 (10%) | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (50) | (50) | (49)
Angiectasis, focal | – | – | – | 1 (2%)
Cyst | 1 (2%) | – | 1 (2%) | –
Edema | 1 (2%) | – | – | –
Erosion | – | 1 (2%) | 2 (4%) | 3 (6%)
Hemorrhage | 1 (2%) | – | – | –
Infiltration cellular, mast cell | – | – | 1 (2%) | –
Inflammation | 5 (10%) | 3 (6%) | 5 (10%) | 6 (12%)
Inflammation, acute | – | – | – | 1 (2%)
Inflammation, chronic | 2 (4%) | – | – | –
Mineralization | – | 1 (2%) | – | –
Ulcer | 5 (10%) | 3 (6%) | 1 (2%) | 1 (2%)
Epithelium, hyperplasia | 9 (18%) | 5 (10%) | 6 (12%) | 16 (33%)
Stomach, glandular | (49) | (47) | (47) | (48)
Erosion | 1 (2%) | – | – | 1 (2%)
Inflammation, acute | 1 (2%) | 1 (2%) | 1 (2%) | –
Mineralization | 5 (10%) | 6 (13%) | 6 (13%) | 1 (2%)
Ulcer | – | 1 (2%) | 1 (2%) | –
Epithelium, vacuolization cytoplasmic | 1 (2%) | – | – | –
Glands, ectasia, focal | 4 (8%) | 3 (6%) | 4 (9%) | 1 (2%)
Cardiovascular System
Blood vessel | (47) | (49) | (50) | (49)
Inflammation | 1 (2%) | – | – | –
Mineralization | 1 (2%) | – | 1 (2%) | –
Heart | (50) | (50) | (50) | (49)
Cardiomyopathy | 4 (8%) | 8 (16%) | 5 (10%) | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation, chronic | – | 1 (2%) | – | –
Mineralization | 1 (2%) | 4 (8%) | 2 (4%) | 1 (2%)
Necrosis, multifocal | – | – | 1 (2%) | –
Thrombosis | – | – | 1 (2%) | –
Valve, thrombosis | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (47)
Accessory adrenal cortical nodule | 5 (10%) | 5 (10%) | 1 (2%) | 3 (6%)
Degeneration, fatty | 3 (6%) | 2 (4%) | 3 (6%) | –
Hematopoietic cell proliferation | – | 2 (4%) | 2 (4%) | 1 (2%)
Hemorrhage | 1 (2%) | – | – | 2 (4%)
Hyperplasia | 1 (2%) | – | 4 (8%) | –
Hyperplasia, focal | – | 1 (2%) | – | –
Hypertrophy, focal | 7 (14%) | 4 (8%) | 9 (18%) | 2 (4%)
Hypertrophy, diffuse | – | – | 4 (8%) | 8 (17%)
Capsule, cyst | – | – | – | 1 (2%)
Capsule, hyperplasia | 49 (98%) | 50 (100%) | 47 (96%) | 47 (100%)
Adrenal medulla | (49) | (50) | (48) | (48)
Hyperplasia | 1 (2%) | – | 1 (2%) | –
Pigmentation | – | 1 (2%) | – | –
Islets, pancreatic | (50) | (48) | (50) | (50)
Hyperplasia | 3 (6%) | 3 (6%) | 2 (4%) | 1 (2%)
Parathyroid gland | (44) | (48) | (47) | (47)
Cyst | 2 (5%) | 1 (2%) | 1 (2%) | –
Hyperplasia | – | – | 1 (2%) | –
Pituitary gland | (50) | (47) | (46) | (45)
Pars distalis, angiectasis | – | 1 (2%) | 1 (2%) | –
Pars distalis, cyst | 2 (4%) | – | 1 (2%) | –
Pars distalis, hyperplasia | 9 (18%) | 13 (28%) | 13 (28%) | 10 (22%)
Rathke’s cleft, cyst | 1 (2%) | – | – | 1 (2%)
Thyroid gland | (50) | (49) | (48) | (47)
Infiltration cellular, mononuclear cell | – | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | 1 (2%) | – | –
Follicle, cyst | 2 (4%) | 1 (2%) | – | –
Follicle, degeneration | 34 (68%) | 28 (57%) | 26 (54%) | 11 (23%)
Follicle, degeneration, focal | – | 1 (2%) | – | –
Follicle, hypertrophy | 24 (48%) | 31 (63%) | 37 (77%) | 42 (89%)
Follicular cell, hyperplasia | – | – | – | 1 (2%)
General Body System
Peritoneum | (0) | (0) | (0) | (1)
Tissue NOS | (1) | (2) | (0) | (1)
Abscess, chronic | – | – | – | 1 (100%)
Fibrosis | – | 1 (50%) | – | –
Foreign body | – | – | – | 1 (100%)
Inflammation, chronic | – | 1 (50%) | – | –
Mineralization | – | 1 (50%) | – | –
Fat, fibrosis | – | 1 (50%) | – | –
Fat, inflammation, chronic active | – | 1 (50%) | – | –
Fat, necrosis | – | 1 (50%) | – | –
Genital System
Clitoral gland | (49) | (49) | (50) | (50)
Cyst | 1 (2%) | – | – | –
Inflammation, acute | 1 (2%) | – | – | –
Inflammation, chronic active | 5 (10%) | 13 (27%) | 8 (16%) | 18 (36%)
Ovary | (48) | (49) | (50) | (48)
Abscess, chronic active | 1 (2%) | – | – | –
Angiectasis | 1 (2%) | – | 1 (2%) | –
Atrophy | – | – | – | 1 (2%)
Cyst | 13 (27%) | 13 (27%) | 6 (12%) | 7 (15%)
Thrombosis | – | – | 1 (2%) | –
Uterus | (50) | (50) | (50) | (49)
Angiectasis | 1 (2%) | – | – | –
Cyst | 2 (4%) | – | – | –
Edema | 1 (2%) | – | – | –
Hemorrhage | 1 (2%) | 2 (4%) | – | –
Hyperplasia, cystic | 45 (90%) | 47 (94%) | 46 (92%) | 43 (88%)
Inflammation, histiocytic | 1 (2%) | – | – | –
Inflammation, acute | 1 (2%) | – | 1 (2%) | –
Necrosis | 1 (2%) | – | 1 (2%) | –
Thrombosis | 1 (2%) | – | – | –
Serosa, cyst | – | – | – | 1 (2%)
Vagina | (0) | (1) | (0) | (0)
Hematopoietic System
Bone marrow | (49) | (50) | (50) | (49)
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Myeloid cell, hyperplasia | 1 (2%) | 3 (6%) | 1 (2%) | –
Lymph node | (9) | (17) | (12) | (4)
Ectasia | 3 (33%) | 6 (35%) | 4 (33%) | –
Hemorrhage | 3 (33%) | 5 (29%) | 3 (25%) | –
Hyperplasia, lymphoid | – | 2 (12%) | – | 1 (25%)
Pigmentation | 3 (33%) | 5 (29%) | 5 (42%) | –
Iliac, ectasia | – | – | 1 (8%) | –
Iliac, hemorrhage | – | 1 (6%) | 1 (8%) | –
Iliac, hyperplasia, lymphoid | 1 (11%) | – | 1 (8%) | –
Iliac, hyperplasia, plasma cell | – | – | 1 (8%) | –
Lumbar, pigmentation | – | – | 1 (8%) | –
Pancreatic, hyperplasia, lymphoid | – | 1 (6%) | – | –
Renal, hematopoietic cell proliferation | – | 1 (6%) | – | –
Renal, hyperplasia, lymphoid | – | – | 1 (8%) | –
Renal, pigmentation | – | 1 (6%) | 1 (8%) | –
Lymph node, mandibular | (48) | (50) | (50) | (45)
Atrophy | 1 (2%) | – | – | –
Ectasia | 1 (2%) | – | – | –
Fibrosis | 1 (2%) | – | – | –
Hematopoietic cell proliferation | – | – | – | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 3 (6%) | 3 (6%) | 2 (4%) | –
Hyperplasia, plasma cell | 1 (2%) | 1 (2%) | – | –
Infiltration cellular, mast cell | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | – | – | –
Pigmentation | 36 (75%) | 39 (78%) | 41 (82%) | 38 (84%)
Lymph node, mesenteric | (48) | (45) | (49) | (48)
Atrophy | 1 (2%) | – | 1 (2%) | 1 (2%)
Ectasia | – | 1 (2%) | 3 (6%) | –
Hemorrhage | – | 2 (4%) | – | –
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 1 (2%) | –
Hyperplasia, plasma cell | 1 (2%) | – | – | –
Necrosis, lymphoid | – | – | – | 2 (4%)
Pigmentation | – | – | – | 2 (4%)
Spleen | (50) | (47) | (48) | (48)
Accessory spleen | – | 1 (2%) | – | –
Atrophy | 1 (2%) | – | – | –
Hematopoietic cell proliferation | 15 (30%) | 10 (21%) | 11 (23%) | 24 (50%)
Necrosis | 1 (2%) | – | – | –
Pigmentation | 35 (70%) | 26 (55%) | 28 (58%) | 31 (65%)
Lymphoid follicle, atrophy | 2 (4%) | 1 (2%) | 3 (6%) | 1 (2%)
Lymphoid follicle, hyperplasia | 12 (24%) | 20 (43%) | 7 (15%) | 21 (44%)
Lymphoid follicle, hyperplasia, plasma cell | 1 (2%) | – | – | –
Lymphoid follicle, hyperplasia, focal | 2 (4%) | – | – | –
Thymus | (48) | (45) | (46) | (46)
Atrophy | 25 (52%) | 22 (49%) | 26 (57%) | 13 (28%)
Cyst | 8 (17%) | 6 (13%) | 6 (13%) | 2 (4%)
Hyperplasia, lymphoid | 16 (33%) | 16 (36%) | 9 (20%) | 10 (22%)
Mineralization | 1 (2%) | – | – | –
Necrosis, lymphoid | 2 (4%) | 1 (2%) | 1 (2%) | –
Integumentary System
Mammary gland | (50) | (50) | (50) | (50)
Galactocele | 30 (60%) | 28 (56%) | 32 (64%) | 31 (62%)
Hyperplasia | 3 (6%) | – | 5 (10%) | –
Inflammation, chronic | 1 (2%) | 2 (4%) | 3 (6%) | 1 (2%)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | 2 (4%) | – | – | –
Edema | – | 2 (4%) | 1 (2%) | –
Fibrosis | 1 (2%) | – | 2 (4%) | –
Foreign body | 1 (2%) | 1 (2%) | 1 (2%) | –
Hemorrhage | 1 (2%) | 2 (4%) | – | –
Hyperkeratosis | 1 (2%) | 1 (2%) | – | –
Infiltration cellular, mast cell | – | 1 (2%) | – | –
Inflammation, granulomatous | 1 (2%) | 1 (2%) | – | –
Inflammation, acute | 2 (4%) | 4 (8%) | 3 (6%) | –
Inflammation, chronic | 6 (12%) | 8 (16%) | 10 (20%) | 8 (16%)
Inflammation, chronic active | 2 (4%) | 2 (4%) | 3 (6%) | 2 (4%)
Mineralization | – | 2 (4%) | 2 (4%) | 1 (2%)
Necrosis, fatty, focal | – | – | – | 1 (2%)
Ulcer | 4 (8%) | 4 (8%) | 6 (12%) | –
Epidermis, hyperplasia | – | – | 1 (2%) | –
Epidermis, tail, hyperkeratosis | 1 (2%) | – | 2 (4%) | –
Epidermis, tail, hyperplasia | 1 (2%) | 4 (8%) | 3 (6%) | –
Hair follicle, atrophy, focal | – | – | – | 1 (2%)
Hair follicle, inflammation, chronic active | – | – | – | 1 (2%)
Lip, foreign body | – | 1 (2%) | – | –
Lip, inflammation, chronic | 1 (2%) | 1 (2%) | – | –
Lip, inflammation, chronic active | – | 1 (2%) | – | –
Subcutaneous tissue, fibrosis | – | 1 (2%) | – | –
Musculoskeletal System
Bone | (49) | (50) | (50) | (50)
Fibro-osseous lesion | 43 (88%) | 46 (92%) | 49 (98%) | 43 (86%)
Tail, callus | 1 (2%) | – | 2 (4%) | 1 (2%)
Tail, developmental malformation | – | – | 1 (2%) | –
Vertebra, callus | – | – | 1 (2%) | –
Skeletal muscle | (2) | (3) | (4) | (1)
Fibrosis | – | – | 1 (25%) | –
Hemorrhage | – | – | 2 (50%) | –
Inflammation, chronic | – | – | 1 (25%) | –
Mineralization | – | – | 1 (25%) | –
Necrosis | – | – | 1 (25%) | –
Regeneration | – | – | 1 (25%) | –
Nervous System
Brain | (50) | (50) | (50) | (49)
Compression | 1 (2%) | 2 (4%) | 1 (2%) | –
Developmental malformation | – | – | – | 1 (2%)
Hemorrhage | 3 (6%) | 1 (2%) | 3 (6%) | 1 (2%)
Infiltration cellular, mononuclear cell | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Necrosis | – | – | 1 (2%) | –
Pigmentation | – | – | 1 (2%) | –
Meninges, inflammation, chronic | 1 (2%) | – | – | –
Peripheral nerve | (1) | (1) | (1) | (1)
Degeneration | 1 (100%) | – | 1 (100%) | –
Sciatic, degeneration | – | 1 (100%) | – | –
Spinal cord | (1) | (1) | (3) | (1)
Degeneration | – | – | 2 (67%) | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Congestion | 2 (4%) | 1 (2%) | 1 (2%) | –
Cyst | – | – | 1 (2%) | –
Edema | – | – | – | 1 (2%)
Fibrosis | 1 (2%) | – | – | –
Foreign body | – | – | 1 (2%) | –
Hemorrhage | 12 (24%) | 3 (6%) | 1 (2%) | 7 (14%)
Infiltration cellular, histiocyte | 4 (8%) | 2 (4%) | 2 (4%) | 1 (2%)
Inflammation, granulomatous | – | – | – | 1 (2%)
Inflammation, acute | – | – | 1 (2%) | –
Metaplasia, osseous | 2 (4%) | – | – | 2 (4%)
Mineralization | 3 (6%) | 2 (4%) | 3 (6%) | –
Thrombosis | 1 (2%) | – | 1 (2%) | 1 (2%)
Alveolar epithelium, hyperplasia | – | – | 1 (2%) | –
Alveolus, infiltration cellular, histiocyte | – | – | – | 1 (2%)
Nose | (50) | (50) | (50) | (48)
Foreign body | 4 (8%) | 3 (6%) | 3 (6%) | 3 (6%)
Inflammation, acute | 6 (12%) | 6 (12%) | 4 (8%) | 10 (21%)
Mineralization | – | – | – | 1 (2%)
Pleura | (0) | (0) | (1) | (0)
Inflammation, suppurative | – | – | 1 (100%) | –
Trachea | (50) | (50) | (50) | (47)
Special Senses System
Eye | (47) | (45) | (47) | (48)
Atrophy | – | 1 (2%) | – | –
Cornea, inflammation, acute | – | – | 1 (2%) | –
Harderian gland | (50) | (49) | (50) | (49)
Hyperplasia | 1 (2%) | 2 (4%) | 2 (4%) | 1 (2%)
Inflammation, chronic | – | 1 (2%) | – | –
Urinary System
Kidney | (50) | (50) | (49) | (48)
Infarct | – | – | 1 (2%) | 1 (2%)
Infiltration cellular, mononuclear cell | 38 (76%) | 44 (88%) | 43 (88%) | 45 (94%)
Metaplasia, osseous | – | – | 1 (2%) | 1 (2%)
Mineralization | 7 (14%) | 5 (10%) | 5 (10%) | 1 (2%)
Nephropathy | 14 (28%) | 9 (18%) | 9 (18%) | 3 (6%)
Artery, inflammation, chronic | 1 (2%) | – | – | –
Interstitium, inflammation, chronic | 1 (2%) | – | – | 2 (4%)
Papilla, necrosis | – | 2 (4%) | – | –
Pelvis, inflammation, chronic | – | – | – | 1 (2%)
Renal tubule, accumulation, hyaline droplet | 2 (4%) | 1 (2%) | – | 1 (2%)
Renal tubule, atrophy | – | 1 (2%) | 1 (2%) | –
Renal tubule, cyst | – | – | – | 1 (2%)
Renal tubule, degeneration | – | 1 (2%) | 1 (2%) | –
Renal tubule, dilatation | 31 (62%) | 23 (46%) | 34 (69%) | 43 (90%)
Renal tubule, necrosis | – | – | 1 (2%) | –
Renal tubule, regeneration | – | – | 1 (2%) | –
Renal tubule, vacuolization cytoplasmic | – | – | 1 (2%) | –
Urinary bladder | (49) | (50) | (49) | (48)
Hyperplasia, lymphoid | 1 (2%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.