# Appendix C Summary of Lesions in Male Mice in the Two-year Gavage Study of DE-71

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | 1 | – | – | 2
Moribund | 15 | 7 | 14 | 36
Natural deaths | 5 | 10 | 5 | 12
Survivors
Terminal kill | 29 | 33 | 31
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Gallbladder | (43) | (42) | (41) | (31)
Intestine large, cecum | (46) | (43) | (45) | (45)
Intestine large, colon | (48) | (44) | (46) | (46)
Intestine large, rectum | (48) | (46) | (46) | (46)
Intestine small, duodenum | (46) | (43) | (47) | (44)
Intestine small, ileum | (45) | (41) | (44) | (43)
Intestine small, jejunum | (46) | (42) | (44) | (46)
Adenoma | – | – | – | 1 (2%)
Carcinoma | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Hepatoblastoma | 1 (2%) | 1 (2%) | 12 (24%) | 5 (10%)
Hepatoblastoma, multiple | – | – | 4 (8%) | –
Hepatocellular adenoma | 13 (26%) | 12 (24%) | 4 (8%) | 7 (14%)
Hepatocellular adenoma, multiple | 10 (20%) | 23 (46%) | 45 (90%) | 33 (66%)
Hepatocellular carcinoma | 14 (28%) | 13 (26%) | 13 (26%) | 10 (20%)
Hepatocellular carcinoma, multiple | 4 (8%) | 2 (4%) | 17 (34%) | 35 (70%)
Hepatocholangiocarcinoma | – | 1 (2%) | – | –
Mesentery | (12) | (3) | (9) | (5)
Hepatoblastoma, metastatic, liver | – | – | 2 (22%) | –
Hepatocellular carcinoma, metastatic, liver | 1 (8%) | – | 1 (11%) | –
Pancreas | (50) | (50) | (50) | (50)
Salivary glands | (50) | (50) | (50) | (50)
Carcinoma | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Squamous cell papilloma | 2 (4%) | 1 (2%) | 2 (4%) | 3 (6%)
Stomach, glandular | (50) | (48) | (48) | (50)
Tongue | (0) | (0) | (0) | (1)
Tooth | (2) | (1) | (0) | (1)
Cardiovascular System
Blood vessel | (50) | (49) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (48)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | – | –
Capsule, adenoma | – | 1 (2%) | 1 (2%) | –
Adrenal medulla | (50) | (50) | (50) | (48)
Pheochromocytoma benign | 1 (2%) | – | – | –
Islets, pancreatic | (50) | (50) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Parathyroid gland | (48) | (43) | (49) | (44)
Adenoma | – | 1 (2%) | – | –
Pituitary gland | (47) | (43) | (43) | (44)
Pars distalis, adenoma | – | 1 (2%) | – | –
Thyroid gland | (50) | (49) | (50) | (49)
Follicular cell, adenoma | 1 (2%) | 1 (2%) | 2 (4%) | –
General Body System
Tissue NOS | (2) | (1) | (0) | (1)
Genital System
Coagulating gland | (1) | (0) | (1) | (0)
Hepatoblastoma, metastatic, liver | – | – | 1 (100%) | –
Epididymis | (50) | (50) | (50) | (50)
Granular cell tumor benign | – | – | 1 (2%) | –
Hepatoblastoma, metastatic, liver | – | – | 1 (2%) | –
Penis | (1) | (0) | (1) | (0)
Preputial gland | (50) | (50) | (50) | (50)
Prostate | (50) | (50) | (50) | (50)
Seminal vesicle | (50) | (50) | (49) | (49)
Testes | (50) | (50) | (50) | (49)
Interstitial cell, adenoma | 1 (2%) | – | 1 (2%) | –
Rete testes, adenoma | 1 (2%) | – | – | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Hemangiosarcoma | – | 1 (2%) | – | –
Cranium, carcinoma, metastatic, Zymbal’s gland | 1 (2%) | – | – | –
Lymph node | (5) | (4) | (4) | (1)
Fat, hemangiosarcoma | – | 1 (25%) | – | –
Mediastinal, hepatocholangiocarcinoma, metastatic, liver | – | 1 (25%) | – | –
Thoracic, hepatocholangiocarcinoma, metastatic, liver | – | 1 (25%) | – | –
Lymph node, mandibular | (50) | (49) | (49) | (46)
Lymph node, mesenteric | (49) | (47) | (46) | (47)
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | 1 (2%) | –
Spleen | (50) | (47) | (47) | (47)
Hemangiosarcoma | 1 (2%) | 1 (2%) | – | –
Thymus | (40) | (41) | (40) | (39)
Integumentary System
Mammary gland | (2) | (2) | (1) | (4)
Skin | (50) | (50) | (50) | (50)
Lipoma | 1 (2%) | – | – | –
Schwannoma malignant | – | – | 1 (2%) | –
Lip, mast cell tumor benign | – | – | 1 (2%) | –
Subcutaneous tissue, lipoma | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (49) | (50) | (50) | (49)
Skeletal muscle | (2) | (2) | (0) | (0)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (50%) | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Peripheral nerve | (2) | (1) | (1) | (0)
Spinal cord | (1) | (1) | (1) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | 5 (10%) | 4 (8%) | 3 (6%) | 1 (2%)
Alveolar/bronchiolar adenoma, multiple | – | 2 (4%) | – | –
Alveolar/bronchiolar carcinoma | 4 (8%) | 3 (6%) | 1 (2%) | –
Alveolar/bronchiolar carcinoma, multiple | 1 (2%) | 3 (6%) | – | –
Carcinoma, metastatic, Zymbal’s gland | 1 (2%) | – | – | –
Hepatoblastoma, metastatic, liver | – | – | 2 (4%) | –
Hepatocellular carcinoma, metastatic, liver | (12%) | 2 (4%) | 4 (8%) | 4 (8%)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Nose | (50) | (48) | (50) | (50)
Pleura | (0) | (1) | (0) | (0)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (100%) | – | –
Trachea | (47) | (48) | (49) | (47)
Special Senses System
Eye | (49) | (47) | (47) | (46)
Harderian gland | (50) | (49) | (50) | (50)
Adenoma | 5 (10%) | 6 (12%) | 3 (6%) | –
Carcinoma | 1 (2%) | – | – | –
Zymbal’s gland | (1) | (0) | (0) | (0)
Carcinoma | 1 (100%) | – | – | –
Urinary System
Kidney | (50) | (50) | (49) | (50)
Hepatocholangiocarcinoma, metastatic, liver | – | 1 (2%) | – | –
Renal tubule, adenoma | – | 1 (2%) | – | –
Renal tubule, carcinoma | – | 1 (2%) | 1 (2%) | –
Urethra | (0) | (4) | (3) | (0)
Urinary bladder | (50) | (49) | (48) | (48)
Hepatoblastoma, metastatic, liver | – | – | 1 (2%) | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (50)
Histiocytic sarcoma | 1 (2%) | 1 (2%) | – | –
Lymphoma malignant | 5 (10%) | 7 (14%) | 1 (2%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 40 | 46 | 49 | 48
Total primary neoplasms | 75 | 89 | 113 | 96
Total animals with benign neoplasms | 30 | 39 | 49 | 41
Total benign neoplasms | 42 | 53 | 63 | 45
Total animals with malignant neoplasms | 27 | 25 | 37 | 45
Total malignant neoplasms | 33 | 36 | 50 | 51
Total animals with metastatic neoplasms | 7 | 3 | 7 | 4
Total metastatic neoplasms | 11 | 9 | 13 | 4

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Primary Neoplasms in Male Mice in the Two-year Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Harderian Gland: Adenoma
Overall rate^a^ | 5/50 (10%) | 6/50 (12%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate^b^ | 12.4% | 13.8% | 6.7% | 0.0%
Terminal rate^c^ | 4/29 (14%) | 6/33 (18%) | 1/31 (3%) | 0/0 (0%)
First incidence (days) | 684 | 729 (T) | 618 | –^e^
Poly-3 test^d^ | P = 0.078N | P = 0.554 | P = 0.300N | P = 0.175N
Harderian Gland: Adenoma or Carcinoma
Overall rate | 6/50 (12%) | 6/50 (12%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 14.9% | 13.8% | 6.7% | 0.0%
Terminal rate | 5/29 (17%) | 6/33 (18%) | 1/31 (3%) | 0/0 (0%)
First incidence (days) | 684 | 729 (T) | 618 | –
Poly-3 test | P = 0.057N | P = 0.567N | P = 0.192N | P = 0.131N
Liver: Hepatocellular Adenoma
Overall rate | 23/50 (46%) | 35/50 (70%) | 49/50 (98%) | 40/50 (80%)
Adjusted rate | 53.2% | 72.9% | 98.8% | 93.5%
Terminal rate | 15/29 (52%) | 25/33 (76%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 491 | 428 | 431 | 451
Poly-3 test | P < 0.001 | P = 0.034 | P < 0.001 | P < 0.001
Liver: Hepatocellular Carcinoma
Overall rate | 18/50 (36%) | 15/50 (30%) | 30/50 (60%) | 45/50 (90%)
Adjusted rate | 40.7% | 33.0% | 65.2% | 97.7%
Terminal rate | 8/29 (28%) | 9/33 (27%) | 21/31 (68%) | 0/0 (0%)
First incidence (days) | 491 | 540 | 453 | 451
Poly-3 test | P < 0.001 | P = 0.293N | P = 0.013 | P < 0.001
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 31/50 (62%) | 40/50 (80%)^f^ | 49/50 (98%) | 47/50 (94%)
Adjusted rate | 68.1% | 81.6% | 98.8% | 99.5%
Terminal rate | 18/29 (62%) | 26/33 (79%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 491 | 428 | 431 | 451
Poly-3 test | P < 0.001 | P = 0.092 | P < 0.001 | P < 0.001
Liver: Hepatoblastoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 16/50 (32%) | 5/50 (10%)
Adjusted rate | 2.5% | 2.3% | 35.0% | 23.4%
Terminal rate | 1/29 (3%) | 1/33 (3%) | 9/31 (29%) | 0/0 (0%)
First incidence (days) | 729 (T) | 729 (T) | 453 | 477
Poly-3 test | P < 0.001 | P = 0.743N | P < 0.001 | P = 0.020
Liver: Hepatocellular Carcinoma or Hepatoblastoma
Overall rate | 18/50 (36%) | 15/50 (30%) | 36/50 (72%) | 45/50 (90%)
Adjusted rate | 40.7% | 33.0% | 76.8% | 97.7%
Terminal rate | 8/29 (28%) | 9/33 (27%) | 25/31 (81%) | 0/0 (0%)
First incidence (days) | 491 | 540 | 453 | 451
Poly-3 test | P < 0.001 | P = 0.293N | P < 0.001 | P < 0.001
Liver: Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma
Overall rate | 31/50 (62%) | 40/50 (80%)^f^ | 49/50 (98%) | 47/50 (94%)
Adjusted rate | 68.1% | 81.6% | 98.8% | 99.5%
Terminal rate | 18/29 (62%) | 26/33 (79%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 491 | 428 | 431 | 451
Poly-3 test | P < 0.001 | P = 0.092 | P < 0.001 | P < 0.001
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 5/50 (10%) | 6/50 (12%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 12.4% | 13.7% | 6.8% | 5.3%
Terminal rate | 4/29 (14%) | 5/33 (15%) | 3/31 (10%) | 0/0 (0%)
First incidence (days) | 639 | 557 | 729 (T) | 543
Poly-3 test | P = 0.177N | P = 0.560 | P = 0.309N | P = 0.371N
Lung: Alveolar/bronchiolar Carcinoma
Overall rate | 5/50 (10%) | 6/50 (12%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 12.3% | 13.8% | 2.3% | 0.0%
Terminal rate | 4/29 (14%) | 6/33 (18%) | 1/31 (3%) | 0/0 (0%)
First incidence (days) | 568 | 729 (T) | 729 (T) | –
Poly-3 test | P = 0.029N | P = 0.548 | P = 0.083N | P = 0.177N
Lung: Alveolar/bronchiolar Adenoma or Carcinoma
Overall rate | 10/50 (20%) | 12/50 (24%) | 4/50 (8%) | 1/50 (2%)
Adjusted rate | 24.5% | 27.3% | 9.1% | 5.3%
Terminal rate | 8/29 (28%) | 11/33 (33%) | 4/31 (13%) | 0/0 (0%)
First incidence (days) | 568 | 557 | 729 (T) | 543
Poly-3 test | P = 0.013N | P = 0.480 | P = 0.051N | P = 0.103N
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 2/50 (4%) | 1/50 (2%) | 2/50 (4%) | 3/50 (6%)
Adjusted rate | 5.0% | 2.3% | 4.6% | 15.0%
Terminal rate | 2/29 (7%) | 0/33 (0%) | 2/31 (7%) | 0/0 (0%)
First incidence (days) | 729 (T) | 692 | 729 (T) | 492
Poly-3 test | P = 0.109 | P = 0.471N | P = 0.660N | P = 0.229
All Organs: Malignant Lymphoma
Overall rate | 5/50 (10%) | 7/50 (14%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 12.4% | 16.1% | 2.2% | 0.0%
Terminal rate | 4/29 (14%) | 7/33 (21%) | 0/31 (0%) | 0/0 (0%)
First incidence (days) | 680 | 729 (T) | 431 | –
Poly-3 test | P = 0.020N | P = 0.433 | P = 0.078N | P = 0.175N
All Organs: Benign Neoplasms
Overall rate | 30/50 (60%) | 39/50 (78%) | 49/50 (98%) | 41/50 (82%)
Adjusted rate | 67.9% | 81.2% | 98.8% | 94.1%
Terminal rate | 21/29 (72%) | 29/33 (88%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 298 | 428 | 431 | 442
Poly-3 test | P < 0.001 | P = 0.094 | P < 0.001 | P < 0.001
All Organs: Malignant Neoplasms
Overall rate | 27/50 (54%) | 25/50 (50%) | 37/50 (74%) | 45/50 (90%)
Adjusted rate | 59.5% | 54.7% | 77.6% | 97.7%
Terminal rate | 14/29 (48%) | 18/33 (55%) | 25/31 (81%) | 0/0 (0%)
First incidence (days) | 491 | 540 | 431 | 451
Poly-3 test | P < 0.001 | P = 0.400N | P = 0.041 | P < 0.001
All Organs: Benign or Malignant Neoplasms
Overall rate | 40/50 (80%) | 46/50 (92%) | 49/50 (98%) | 48/50 (96%)
Adjusted rate | 84.0% | 93.9% | 98.8% | 100.0%
Terminal rate | 23/29 (79%) | 32/33 (97%) | 31/31 (100%) | 0/0 (0%)
First incidence (days) | 298 | 428 | 431 | 442
Poly-3 test | P = 0.005 | P = 0.096 | P = 0.007 | P = 0.003

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for liver and lung; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ A single incidence of hepatocholangiocarcinoma occurred in an animal that also had an adenoma.

Table C-3 Historical Incidence of Liver Neoplasms in Control Male B6C3F1/N Mice^a^

Study (Study Start) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatocellular Adenoma or Hepatocellular Carcinoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (February 2008) | 23/50 | 18/50 | 31/50
Ginkgo biloba extract (March 2005) | 31/50 | 22/50 | 39/50
Indole-3-carbinol (April 2007) | 26/50 | 12/50 | 35/50
Kava extract (August 2004) | 27/50 | 20/50 | 38/50
N,N-dimethyl-p-toluidine (October 2004) | 29/50 | 22/50 | 38/50
Tetrabromobisphenol A (August 2007) | 32/50 | 11/50 | 39/50
Total (%) | 168/300 (56%) | 105/300 (35.0%) | 220/300 (73.3%)
Mean ± standard deviation | 56.0% ± 6.7% | 35.0% ± 9.8% | 73.3% ± 6.3%
Range | 46%–64% | 22%–44% | 62%–78%
Overall Historical Incidence: All Routes
Total (%) | 437/700 (62.4%) | 262/700 (37.4%) | 541/700 (77.3%)
Mean ± standard deviation | 62.4% ± 10.5% | 37.4% ± 11.2% | 77.3% ± 8.3%
Range | 46%–78% | 22%–52% | 62%–90%
| Hepatoblastoma | Hepatocellular Adenoma, Hepatocellular Carcinoma, or Hepatoblastoma | Hepatocholangio-carcinoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (February 2008) | 1/50 | 31/50 | 0/50
Ginkgo biloba extract (March 2005) | 3/50 | 39/50 | 0/50
Indole-3-carbinol (April 2007) | 3/50 | 36/50 | 0/50
Kava extract (August 2004) | 0/50 | 38/50 | 4/50
N,N-dimethyl-p-toluidine (October 2004) | 1/50 | 38/50 | 0/50
Tetrabromobisphenol A (August 2007) | 2/50 | 39/50 | 0/50
Total (%) | 10/300 (3.3%) | 221/300 (73.7%) | 4/300 (1.3%)
Mean ± standard deviation | 3.3% ± 2.4% | 73.7% ± 6.1% | 1.3 ± 3.3%
Range | 0%–6% | 62%–78% | 0%–8%
Overall Historical Incidence: All Routes
Total (%) | 34/700 (4.9%) | 545/700 (77.9%) | 9/700 (1.3%)
Mean ± standard deviation | 4.9% ± 3.7% | 77.9% ± 8.3% | 1.3% ± 2.4%
Range | 0%–12% | 62%–90% | 0%–8%

^a^ Data as of November 2014.

Table C-4 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 30 mg/kg | 100 mg/kg
Disposition Summary
Animals initially in study | 50 | 50 | 50 | 50
Early deaths
Accidental deaths | 1 | – | – | 2
Moribund | 15 | 7 | 14 | 36
Natural deaths | 5 | 10 | 5 | 12
Survivors
Terminal kill | 29 | 33 | 31 | –
Animals examined microscopically | 50 | 50 | 50 | 50
Alimentary System
Esophagus | (50) | (50) | (50) | (50)
Foreign body | – | – | – | 1 (2%)
Inflammation, acute | 1 (2%) | – | – | 2 (4%)
Inflammation, chronic | – | 1 (2%) | – | –
Mineralization | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | 2 (4%)
Muscularis, degeneration | – | 2 (4%) | 2 (4%) | –
Gallbladder | (43) | (42) | (41) | (31)
Cyst | – | – | 1 (2%) | –
Intestine large, cecum | (46) | (43) | (45) | (45)
Lymphoid tissue, necrosis | 1 (2%) | – | – | –
Intestine large, colon | (48) | (44) | (46) | (46)
Intestine large, rectum | (48) | (46) | (46) | (46)
Serosa, fibrosis | – | 1 (2%) | – | –
Intestine small, duodenum | (46) | (43) | (47) | (44)
Infiltration cellular, plasma cell | – | – | 1 (2%) | –
Inflammation | – | – | 1 (2%) | –
Intestine small, ileum | (45) | (41) | (44) | (43)
Intestine small, jejunum | (46) | (42) | (44) | (46)
Peyer’s patch, hyperplasia | – | 1 (2%) | – | –
Serosa, fibrosis | – | – | – | 1 (2%)
Liver | (50) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | –
Basophilic focus | 6 (12%) | 2 (4%) | – | 5 (10%)
Basophilic focus, multiple | – | 1 (2%) | 1 (2%) | –
Clear cell focus | 10 (20%) | 6 (12%) | 17 (34%) | 7 (14%)
Clear cell focus, multiple | – | 7 (14%) | 3 (6%) | –
Congestion | – | 1 (2%) | – | –
Depletion glycogen | 1 (2%) | 1 (2%) | – | –
Eosinophilic focus | 14 (28%) | 12 (24%) | 4 (8%) | 10 (20%)
Eosinophilic focus, multiple | 1 (2%) | 10 (20%) | 6 (12%) | 1 (2%)
Fatty change | 17 (34%) | 25 (50%) | 17 (34%) | 5 (10%)
Hematopoietic cell proliferation | 10 (20%) | 5 (10%) | 1 (2%) | 3 (6%)
Hemorrhage | 3 (6%) | 1 (2%) | 1 (2%) | 2 (4%)
Inflammation, chronic | 13 (26%) | 19 (38%) | 22 (44%) | 12 (24%)
Mineralization | 1 (2%) | – | – | –
Mixed cell focus | 2 (4%) | 4 (8%) | – | 1 (2%)
Mixed cell focus, multiple | – | 1 (2%) | – | –
Necrosis, focal | 2 (4%) | 2 (4%) | 16 (32%) | 2 (4%)
Tension lipidosis | 1 (2%) | – | – | –
Bile duct, cyst | 1 (2%) | – | – | –
Centrilobular, hepatocyte, hypertrophy | – | 28 (56%) | 46 (92%) | 48 (96%)
Hepatocyte, mitotic alteration | – | 1 (2%) | – | –
Hepatocyte, necrosis | – | – | – | 1 (2%)
Kupffer cell, pigmentation | 5 (10%) | 15 (30%) | 33 (66%) | 25 (50%)
Mesentery | (12) | (3) | (9) | (5)
Hemorrhage | 1 (8%) | – | – | –
Inflammation, chronic | 1 (8%) | – | – | 1 (20%)
Artery, inflammation, chronic active | – | – | 2 (22%) | 2 (40%)
Artery, thrombosis | 1 (8%) | – | – | –
Fat, necrosis | 8 (67%) | 3 (100%) | 6 (67%) | 2 (40%)
Pancreas | (50) | (50) | (50) | (50)
Atrophy | 10 (20%) | 14 (28%) | 7 (14%) | –
Cyst | 1 (2%) | 4 (8%) | – | –
Degeneration | – | – | – | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Hypertrophy, focal | 1 (2%) | – | – | –
Inflammation, granulomatous, focal | – | 1 (2%) | – | –
Inflammation, acute | – | 1 (2%) | – | –
Inflammation, chronic | 12 (24%) | 17 (34%) | 19 (38%) | 8 (16%)
Inflammation, chronic active | 2 (4%) | – | – | –
Mineralization | – | 2 (4%) | – | –
Necrosis | – | 2 (4%) | – | –
Acinus, hyperplasia, focal | – | – | 1 (2%) | –
Artery, inflammation, chronic active | – | 1 (2%) | – | –
Artery, mineralization | – | 1 (2%) | – | –
Artery, necrosis | – | 1 (2%) | – | –
Salivary glands | (50) | (50) | (50) | (50)
Atrophy | 2 (4%) | – | – | –
Cyst | 1 (2%) | – | – | –
Hyperplasia, lymphoid | – | – | – | 1 (2%)
Infiltration cellular, mononuclear cell | 31 (62%) | 38 (76%) | 30 (60%) | 21 (42%)
Inflammation, granulomatous | 1 (2%) | – | – | –
Inflammation, acute | – | 1 (2%) | – | –
Mineralization | – | 5 (10%) | 4 (8%) | 1 (2%)
Necrosis | – | 1 (2%) | – | –
Vacuolization cytoplasmic, macrovesicular | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (50) | (50) | (50)
Cyst | – | 1 (2%) | – | –
Edema | – | – | 2 (4%) | –
Erosion | 4 (8%) | 5 (10%) | 9 (18%) | 3 (6%)
Fibrosis | 2 (4%) | – | – | –
Foreign body | – | – | 2 (4%) | –
Inflammation | 18 (36%) | 18 (36%) | 34 (68%) | 19 (38%)
Mineralization | 1 (2%) | – | – | 1 (2%)
Necrosis | 1 (2%) | – | 1 (2%) | –
Ulcer | 9 (18%) | 8 (16%) | 14 (28%) | 11 (22%)
Epithelium, hyperplasia | 26 (52%) | 19 (38%) | 40 (80%) | 29 (58%)
Serosa, fibrosis | – | – | 1 (2%) | –
Stomach, glandular | (50) | (48) | (48) | (50)
Dilatation | – | – | 1 (2%) | –
Edema | – | – | 1 (2%) | –
Erosion | – | – | 1 (2%) | 2 (4%)
Fibrosis | – | 1 (2%) | – | –
Hemorrhage | – | – | – | 1 (2%)
Inflammation | 1 (2%) | 1 (2%) | 2 (4%) | –
Inflammation, acute | 1 (2%) | 1 (2%) | – | –
Mineralization | 4 (8%) | 5 (10%) | 6 (13%) | 2 (4%)
Necrosis | – | – | 1 (2%) | –
Ulcer | 1 (2%) | – | 2 (4%) | 1 (2%)
Glands, ectasia, focal | – | 1 (2%) | 2 (4%) | –
Serosa, fibrosis | – | – | 1 (2%) | –
Tongue | (0) | (0) | (0) | (1)
Angiectasis | – | – | – | 1 (100%)
Tooth | (2) | (1) | (0) | (1)
Inflammation, acute | 1 (50%) | – | – | 1 (100%)
Inflammation, chronic active | 1 (50%) | – | – | –
Malformation | – | 1 (100%) | – | –
Necrosis | 1 (50%) | – | – | –
Cardiovascular System
Blood vessel | (50) | (49) | (50) | (50)
Heart | (50) | (50) | (50) | (50)
Cardiomyopathy | 8 (16%) | 10 (20%) | 7 (14%) | 1 (2%)
Inflammation, acute | – | 1 (2%) | – | –
Mineralization | 1 (2%) | – | 5 (10%) | 5 (10%)
Thrombosis | – | 1 (2%) | – | –
Artery, inflammation, chronic active | 1 (2%) | – | – | –
Artery, mineralization | – | – | 1 (2%) | –
Endocrine System
Adrenal cortex | (50) | (50) | (49) | (48)
Accessory adrenal cortical nodule | 2 (4%) | 2 (4%) | 7 (14%) | 1 (2%)
Degeneration, fatty | 1 (2%) | – | 1 (2%) | 2 (4%)
Hyperplasia | – | – | 1 (2%) | –
Hypertrophy, focal | 10 (20%) | 10 (20%) | 5 (10%) | 3 (6%)
Hypertrophy, diffuse | 1 (2%) | – | 3 (6%) | 20 (42%)
Vacuolization cytoplasmic | 1 (2%) | – | 1 (2%) | 1 (2%)
Capsule, fibrosis | – | – | – | 1 (2%)
Capsule, hemorrhage | – | – | – | 1 (2%)
Capsule, hyperplasia | 42 (84%) | 41 (82%) | 47 (96%) | 41 (85%)
Adrenal medulla | (50) | (50) | (50) | (48)
Hyperplasia | – | 1 (2%) | – | 1 (2%)
Islets, pancreatic | (50) | (50) | (50) | (50)
Hyperplasia | 32 (64%) | 25 (50%) | 21 (42%) | 6 (12%)
Parathyroid gland | (48) | (43) | (49) | (44)
Cyst | 3 (6%) | 1 (2%) | 5 (10%) | –
Pituitary gland | (47) | (43) | (43) | (44)
Pars distalis, angiectasis | 1 (2%) | – | – | –
Pars distalis, cyst | 2 (4%) | 2 (5%) | – | 1 (2%)
Pars distalis, hyperplasia, focal | – | 1 (2%) | 4 (9%) | 1 (2%)
Thyroid gland | (50) | (49) | (50) | (49)
Hypertrophy | – | 1 (2%) | – | –
Mineralization | 1 (2%) | – | – | –
C-cell, hyperplasia | – | – | 1 (2%) | –
Follicle, cyst | – | – | 1 (2%) | 1 (2%)
Follicle, degeneration | 21 (42%) | 19 (39%) | 12 (24%) | 6 (12%)
Follicle, degeneration, focal | – | 1 (2%) | – | –
Follicle, hypertrophy | 25 (50%) | 35 (71%) | 41 (82%) | 45 (92%)
General Body System
Tissue NOS | (2) | (1) | (0) | (1)
Abdominal, fibrosis | – | 1 (100%) | – | –
Fat, necrosis | – | 1 (100%) | – | –
Genital System
Coagulating gland | (1) | (0) | (1) | (0)
Cyst | 1 (100%) | – | – | –
Epididymis | (50) | (50) | (50) | (50)
Fibrosis | – | – | – | 1 (2%)
Granuloma sperm | 1 (2%) | – | 1 (2%) | –
Inflammation, granulomatous | 1 (2%) | – | – | –
Inflammation, chronic | 21 (42%) | 28 (56%) | 24 (48%) | 7 (14%)
Inflammation, chronic active | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | –
Artery, inflammation | 1 (2%) | – | – | –
Penis | (1) | (0) | (1) | (0)
Concretion | 1 (100%) | – | – | –
Inflammation, acute | 1 (100%) | – | – | –
Preputial gland | (50) | (50) | (50) | (50)
Cyst | 9 (18%) | 16 (32%) | 14 (28%) | 3 (6%)
Ectasia | – | 1 (2%) | – | –
Fibrosis | – | 1 (2%) | – | –
Inflammation, acute | 2 (4%) | – | – | 1 (2%)
Inflammation, chronic | 24 (48%) | 28 (56%) | 25 (50%) | 5 (10%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | 3 (6%) | –
Necrosis | – | – | 1 (2%) | –
Prostate | (50) | (50) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | –
Inflammation, granulomatous | – | – | – | 1 (2%)
Inflammation, acute | 4 (8%) | 2 (4%) | 1 (2%) | –
Inflammation, chronic | 27 (54%) | 33 (66%) | 30 (60%) | 15 (30%)
Inflammation, chronic active | – | 1 (2%) | – | –
Necrosis | – | 1 (2%) | – | –
Epithelium, hyperplasia | 3 (6%) | – | 1 (2%) | –
Seminal vesicle | (50) | (50) | (49) | (49)
Atrophy | – | – | 1 (2%) | –
Dilatation | – | 1 (2%) | – | –
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Inflammation, acute | 2 (4%) | 1 (2%) | – | –
Inflammation, chronic | 3 (6%) | 7 (14%) | 8 (16%) | –
Testes | (50) | (50) | (50) | (49)
Abnormal residual body | – | 1 (2%) | 1 (2%) | 1 (2%)
Angiectasis | – | – | – | 1 (2%)
Giant cell | 2 (4%) | – | 4 (8%) | 2 (4%)
Germinal epithelium, atrophy | 11 (22%) | 8 (16%) | 20 (40%) | 13 (27%)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (50)
Myeloid cell, hyperplasia | 2 (4%) | – | – | –
Lymph node | (5) | (4) | (4) | (1)
Hyperplasia, lymphoid | 1 (20%) | – | – | –
Pigmentation | 2 (40%) | – | 2 (50%) | –
Iliac, hyperplasia, lymphoid | – | 1 (25%) | – | –
Inguinal, hyperplasia, lymphoid | – | – | – | 1 (100%)
Inguinal, pigmentation | – | – | 1 (25%) | –
Lymph node, mandibular | (50) | (49) | (49) | (46)
Atrophy | 1 (2%) | – | 1 (2%) | –
Hemorrhage | 2 (4%) | 3 (6%) | – | –
Hyperplasia, lymphoid | – | 1 (2%) | – | –
Hyperplasia, plasma cell | 1 (2%) | – | – | –
Infiltration cellular, polymorphonuclear | 1 (2%) | 1 (2%) | – | –
Necrosis, lymphoid | 1 (2%) | – | – | –
Pigmentation | 45 (90%) | 48 (98%) | 46 (94%) | 44 (96%)
Lymph node, mesenteric | (49) | (47) | (46) | (47)
Angiectasis | – | – | 1 (2%) | –
Atrophy | – | – | – | 3 (6%)
Congestion | 1 (2%) | – | 3 (7%) | –
Ectasia | 1 (2%) | 1 (2%) | 1 (2%) | 2 (4%)
Hematopoietic cell proliferation | 1 (2%) | – | 1 (2%) | –
Hemorrhage | 3 (6%) | 7 (15%) | 7 (15%) | 8 (17%)
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Hyperplasia, plasma cell | – | – | 1 (2%) | –
Infiltration cellular, polymorphonuclear | 1 (2%) | 1 (2%) | – | 1 (2%)
Necrosis, lymphoid | – | 1 (2%) | – | –
Pigmentation | 1 (2%) | – | 2 (4%) | 4 (9%)
Spleen | (50) | (47) | (47) | (47)
Atrophy | 1 (2%) | – | – | –
Hematopoietic cell proliferation | 14 (28%) | 10 (21%) | 13 (28%) | 25 (53%)
Infiltration cellular, eosinophil | – | – | – | 1 (2%)
Pigmentation | 13 (26%) | 12 (26%) | 2 (4%) | 2 (4%)
Capsule, fibrosis, focal | – | 1 (2%) | – | –
Capsule, inflammation, granulomatous, focal | – | 1 (2%) | – | –
Lymphoid follicle, atrophy | 1 (2%) | 2 (4%) | 3 (6%) | 4 (9%)
Lymphoid follicle, hyperplasia | 11 (22%) | 7 (15%) | 9 (19%) | 5 (11%)
Thymus | (40) | (41) | (40) | (39)
Atrophy | 26 (65%) | 28 (68%) | 23 (58%) | 23 (59%)
Cyst | 14 (35%) | 12 (29%) | 13 (33%) | 3 (8%)
Hemorrhage | – | – | – | 1 (3%)
Hyperplasia, lymphoid | 1 (3%) | 2 (5%) | 3 (8%) | 1 (3%)
Infiltration cellular, histiocyte | – | – | 1 (3%) | 1 (3%)
Inflammation, granulomatous, focal | – | – | 1 (3%) | –
Necrosis, lymphoid | – | 6 (15%) | 3 (8%) | 3 (8%)
Integumentary System
Mammary gland | (2) | (2) | (1) | (4)
Skin | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | – | – | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | 1 (2%)
Fibrosis, focal | – | – | 1 (2%) | –
Foreign body | – | – | – | 1 (2%)
Hemorrhage | – | – | – | 1 (2%)
Hyperkeratosis | 1 (2%) | 3 (6%) | – | 1 (2%)
Inflammation, acute | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Inflammation, chronic | 2 (4%) | 3 (6%) | – | 2 (4%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | 1 (2%)
Mineralization | – | – | 2 (4%) | –
Thrombosis | – | – | – | 1 (2%)
Ulcer | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Epidermis, hyperplasia | 1 (2%) | 1 (2%) | – | –
Epidermis, tail, hyperplasia | – | – | – | 2 (4%)
Lip, inflammation, acute | 2 (4%) | 1 (2%) | – | –
Prepuce, inflammation, acute | – | – | 2 (4%) | –
Subcutaneous tissue, angiectasis, focal | – | 1 (2%) | – | –
Subcutaneous tissue, cyst | – | – | 1 (2%) | –
Subcutaneous tissue, inflammation, chronic | 1 (2%) | – | – | –
Subcutaneous tissue, necrosis | 1 (2%) | – | – | –
Musculoskeletal System
Bone | (49) | (50) | (50) | (49)
Fibro-osseous lesion | 2 (4%) | 1 (2%) | – | –
Tail, callus | – | 2 (4%) | – | 1 (2%)
Tail, developmental malformation | 1 (2%) | 3 (6%) | – | –
Vertebra, callus | 2 (4%) | – | – | –
Skeletal muscle | (2) | (2) | (0) | (0)
Fibrosis | 2 (100%) | – | – | –
Hemorrhage | 2 (100%) | – | – | –
Inflammation, chronic | 2 (100%) | – | – | –
Regeneration | 1 (50%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (50)
Cyst epithelial inclusion | – | – | – | 1 (2%)
Hemorrhage | 6 (12%) | 2 (4%) | 2 (4%) | 5 (10%)
Infiltration cellular, mononuclear cell | – | 2 (4%) | – | –
Inflammation, acute | – | – | – | 1 (2%)
Metaplasia, osseous | – | 1 (2%) | – | –
Necrosis | – | – | 1 (2%) | –
Meninges, inflammation, acute | – | 1 (2%) | – | –
Meninges, inflammation, chronic | 1 (2%) | – | – | –
Meninges, thrombosis | – | 1 (2%) | – | –
Peripheral nerve | (2) | (1) | (1) | (0)
Degeneration | 2 (100%) | 1 (100%) | 1 (100%) | –
Hemorrhage | 1 (50%) | – | – | –
Spinal cord | (1) | (1) | (1) | (0)
Degeneration | – | – | 1 (100%) | –
Hemorrhage | – | – | 1 (100%) | –
Respiratory System
Lung | (50) | (50) | (50) | (50)
Congestion | 1 (2%) | – | – | 2 (4%)
Fibrosis | – | – | 1 (2%) | –
Foreign body | – | – | – | 1 (2%)
Hemorrhage | 10 (20%) | 6 (12%) | 6 (12%) | 3 (6%)
Hyperplasia | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | 8 (16%) | 11 (22%) | 5 (10%) | 1 (2%)
Inflammation, acute | 2 (4%) | 1 (2%) | – | 1 (2%)
Inflammation, chronic | 1 (2%) | – | – | 1 (2%)
Metaplasia, osseous | – | – | – | 1 (2%)
Mineralization | 1 (2%) | 2 (4%) | 3 (6%) | 2 (4%)
Thrombosis | 3 (6%) | – | – | –
Alveolar epithelium, hyperplasia | 2 (4%) | 6 (12%) | 1 (2%) | –
Alveolar epithelium, hypertrophy | – | – | – | 1 (2%)
Alveolus, infiltration cellular, histiocyte | – | – | 1 (2%) | –
Nose | (50) | (48) | (50) | (50)
Foreign body | 4 (8%) | 7 (15%) | 7 (14%) | 5 (10%)
Fungus | 1 (2%) | – | 2 (4%) | –
Hemorrhage | – | – | 1 (2%) | –
Inflammation, acute | 9 (18%) | 12 (25%) | 19 (38%) | 6 (12%)
Mineralization | 2 (4%) | 2 (4%) | 2 (4%) | –
Glands, fibrosis | 1 (2%) | – | – | –
Pleura | (0) | (1) | (0) | (0)
Trachea | (47) | (48) | (49) | (47)
Hemorrhage | – | 1 (2%) | – | –
Special Senses System
Eye | (49) | (47) | (47) | (46)
Atrophy | 1 (2%) | – | – | –
Cataract | – | – | 1 (2%) | –
Anterior chamber, edema | 1 (2%) | – | – | –
Anterior chamber, infiltration cellular, polymorphonuclear | 1 (2%) | – | – | –
Anterior chamber, necrosis | 1 (2%) | – | – | –
Cornea, fibrosis | 1 (2%) | – | – | –
Cornea, inflammation | 1 (2%) | – | – | –
Cornea, inflammation, acute | 1 (2%) | – | 1 (2%) | –
Cornea, inflammation, chronic active | 1 (2%) | 1 (2%) | – | –
Cornea, necrosis | 1 (2%) | – | 1 (2%) | –
Cornea, epithelium, hyperplasia | 1 (2%) | – | – | –
Nerve, degeneration | 1 (2%) | – | – | –
Nerve, inflammation, acute | 1 (2%) | – | – | –
Retrobulbar, inflammation, acute | – | – | 1 (2%) | –
Harderian gland | (50) | (49) | (50) | (50)
Atrophy | 1 (2%) | – | – | –
Fibrosis | 1 (2%) | – | – | –
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia | 1 (2%) | 2 (4%) | 1 (2%) | –
Hyperplasia, focal | 1 (2%) | – | – | –
Inflammation, acute | 1 (2%) | – | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Necrosis | 1 (2%) | – | – | –
Zymbal’s gland | (1) | (0) | (0) | (0)
Urinary System
Kidney | (50) | (50) | (49) | (50)
Casts protein | – | 1 (2%) | – | –
Congestion | 1 (2%) | – | – | –
Hydronephrosis | – | 1 (2%) | – | –
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | –
Infarct | 2 (4%) | 1 (2%) | 5 (10%) | –
Infarct, multiple | 1 (2%) | – | – | –
Infiltration cellular, mononuclear cell | 35 (70%) | 41 (82%) | 39 (80%) | 26 (52%)
Inflammation | – | – | 1 (2%) | –
Inflammation, acute | 1 (2%) | 1 (2%) | – | –
Metaplasia, osseous | 2 (4%) | 2 (4%) | 1 (2%) | –
Mineralization | 36 (72%) | 32 (64%) | 24 (49%) | 6 (12%)
Nephropathy | 38 (76%) | 45 (90%) | 37 (76%) | 9 (18%)
Artery, perirenal tissue, inflammation | 1 (2%) | – | – | –
Interstitium, inflammation | 1 (2%) | – | – | –
Interstitium, inflammation, chronic | 2 (4%) | 1 (2%) | 1 (2%) | –
Papilla, inflammation, acute | 1 (2%) | 2 (4%) | – | –
Papilla, necrosis | 4 (8%) | 6 (12%) | 2 (4%) | –
Papilla, pelvis, inflammation, acute | – | – | 1 (2%) | –
Papilla, renal tubule, necrosis | – | 1 (2%) | – | –
Pelvis, inflammation, acute | 1 (2%) | – | – | –
Pelvis, inflammation, chronic | 1 (2%) | – | – | –
Renal tubule, cyst | 1 (2%) | 2 (4%) | 1 (2%) | –
Renal tubule, cyst, multiple | 1 (2%) | – | – | –
Renal tubule, degeneration | 3 (6%) | – | 2 (4%) | –
Renal tubule, dilatation | 14 (28%) | 14 (28%) | 15 (31%) | 9 (18%)
Renal tubule, hyperplasia | – | 1 (2%) | – | –
Renal tubule, pigmentation | 1 (2%) | – | 3 (6%) | –
Transitional epithelium, hyperplasia | 1 (2%) | – | – | –
Urethra | (0) | (4) | (3) | (0)
Angiectasis | – | 1 (25%) | 1 (33%) | –
Hemorrhage | – | – | 1 (33%) | –
Inflammation, acute | – | 2 (50%) | 2 (67%) | –
Necrosis | – | 1 (25%) | 1 (33%) | –
Bulbourethral gland, cyst | – | 1 (25%) | – | –
Bulbourethral gland, hemorrhage | – | – | 1 (33%) | –
Bulbourethral gland, inflammation | – | 1 (25%) | – | –
Bulbourethral gland, necrosis | – | 2 (50%) | 1 (33%) | –
Urinary bladder | (50) | (49) | (48) | (48)
Fibrosis | – | 1 (2%) | – | –
Hemorrhage | 2 (4%) | 1 (2%) | 1 (2%) | –
Hyperplasia, lymphoid | – | – | 1 (2%) | –
Inflammation, acute | 2 (4%) | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | –
Necrosis | 1 (2%) | 3 (6%) | 3 (6%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.