# Appendix B Summary of Lesions in F_1_ Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Table B-1 Summary of the Incidence of Neoplasms in F_1_ Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | 2 | 1 | – | –
Moribund | 8 | 10 | 13 | 11
Natural deaths | 3 | – | 4 | 10
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 36 | 39 | 33 | 28
Other | – | – | – | 1
Animals examined microscopically | 60 | 50 | 50 | 59
Systems Examined at Three Months with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (49)
Intestine large, cecum | (48) | (49) | (47) | (40)
Intestine large, colon | (48) | (49) | (50) | (46)
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Intestine large, rectum | (49) | (49) | (49) | (45)
Intestine small, duodenum | (47) | (49) | (47) | (42)
Leiomyosarcoma | – | 1 (2%) | – | –
Intestine small, ileum | (47) | (49) | (48) | (41)
Intestine small, jejunum | (46) | (49) | (47) | (42)
Leiomyoma | – | 1 (2%) | 1 (2%) | –
Liver | (50) | (49) | (50) | (47)
Adenocarcinoma, metastatic, uterus | – | – | 2 (4%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Cholangiocarcinoma | – | – | – | 1 (2%)
Cholangiocarcinoma, multiple | – | – | – | 1 (2%)
Hepatocellular adenoma | 2 (4%) | 2 (4%) | 6 (12%) | 8 (17%)
Hepatocellular adenoma, multiple | 1 (2%) | – | 2 (4%) | 8 (17%)
Hepatocellular carcinoma | – | – | 1 (2%) | 3 (6%)
Hepatocellular carcinoma, multiple | – | – | – | 3 (6%)
Hepatocholangiocarcinoma | – | – | – | 1 (2%)
Hepatocholangioma | – | – | – | 5 (11%)
Hepatocholangioma, multiple | – | – | – | 3 (6%)
Mesentery | (10) | (7) | (9) | (6)
Adenocarcinoma, metastatic, uterus | – | – | 3 (33%) | –
Granulosa cell tumor malignant, metastatic, ovary | 1 (10%) | – | – | –
Schwannoma malignant | – | – | 1 (11%) | –
Oral mucosa | (0) | (0) | (1) | (1)
Squamous cell carcinoma | – | – | 1 (100%) | –
Pancreas | (50) | (49) | (49) | (47)
Adenocarcinoma, metastatic, uterus | – | – | 3 (6%) | –
Carcinoma | – | – | – | 1 (2%)
Salivary glands | (50) | (50) | (49) | (45)
Parotid gland, adenocarcinoma | – | – | – | 1 (2%)
Sublingual gland, adenocarcinoma | 1 (2%) | – | – | –
Stomach, forestomach | (50) | (49) | (50) | (48)
Adenocarcinoma, metastatic, uterus | – | – | 2 (4%) | –
Squamous cell papilloma | – | – | 1 (2%) | –
Stomach, glandular | (49) | (49) | (50) | (46)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (1) | (0) | (3) | (3)
Heart | (50) | (50) | (50) | (48)
Endocardium, schwannoma benign | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (46)
Adenocarcinoma, metastatic, uterus | – | – | 2 (4%) | –
Adenoma | 1 (2%) | – | – | –
Adrenal medulla | (50) | (50) | (50) | (47)
Pheochromocytoma benign | 1 (2%) | 1 (2%) | 1 (2%) | –
Pheochromocytoma complex | 1 (2%) | – | 1 (2%) | –
Pheochromocytoma malignant | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (49) | (49) | (47)
Adenoma | – | 1 (2%) | – | –
Parathyroid gland | (49) | (47) | (49) | (46)
Adenoma | 1 (2%) | 1 (2%) | – | –
Pituitary gland | (50) | (49) | (50) | (47)
Pars distalis, adenoma | 21 (42%) | 20 (41%) | 23 (46%) | 20 (43%)
Pars distalis, adenoma, multiple | 2 (4%) | – | – | 1 (2%)
Pars intermedia, adenoma | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Thyroid gland | (45) | (49) | (47) | (42)
C-cell, adenoma | 6 (13%) | 3 (6%) | 7 (15%) | 2 (5%)
C-cell, adenoma, multiple | 1 (2%) | 3 (6%) | 3 (6%) | 2 (5%)
Follicular cell, adenoma | 1 (2%) | 3 (6%) | 3 (6%) | 1 (2%)
General Body System
Tissue NOS | (3) | (2) | (4) | (2)
Adenocarcinoma, metastatic, uterus | – | – | 2 (50%) | –
Abdominal, carcinoma, metastatic, pancreas | – | – | – | 1 (50%)
Genital System
Clitoral gland | (49) | (49) | (50) | (47)
Ovary | (50) | (49) | (50) | (46)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Cystadenoma | – | 1 (2%) | 1 (2%) | 2 (4%)
Granulosa cell tumor benign | 1 (2%) | 3 (6%) | 1 (2%) | 2 (4%)
Granulosa cell tumor malignant | 1 (2%) | – | – | –
Leiomyosarcoma | – | 1 (2%) | – | –
Luteoma | – | 1 (2%) | – | –
Schwannoma malignant, metastatic, mesentery | – | – | 1 (2%) | –
Uterus | (50) | (49) | (50) | (47)
Adenocarcinoma | – | 1 (2%) | 3 (6%) | 2 (4%)
Adenocarcinoma, multiple | 1 (2%) | – | – | –
Adenoma | 1 (2%) | – | 1 (2%) | –
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Granular cell tumor benign | – | – | 1 (2%) | –
Leiomyoma | – | 1 (2%) | – | –
Malignant mixed Müllerian tumor | 1 (2%) | – | – | –
Polyp stromal | 3 (6%) | 5 (10%) | 6 (12%) | 5 (11%)
Polyp stromal, multiple | – | 1 (2%) | 1 (2%) | –
Sarcoma stromal | – | – | 1 (2%) | –
Schwannoma malignant | – | – | 2 (4%) | 1 (2%)
Cervix, granular cell tumor benign | 1 (2%) | – | – | –
Cervix, polyp stromal | – | – | – | 1 (2%)
Cervix, schwannoma malignant | 1 (2%) | – | – | –
Vagina | (1) | (1) | (2) | (2)
Granular cell tumor benign | – | 1 (100%) | – | –
Granular cell tumor benign, multiple | – | – | – | 1 (50%)
Polyp, multiple | – | – | – | 1 (50%)
Sarcoma stromal, metastatic, uterus | – | – | 1 (50%) | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (50%) | –
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (46)
Lymph node | (10) | (5) | (6) | (9)
Mediastinal, adenocarcinoma, metastatic, uterus | – | – | 1 (17%) | –
Lymph node, mandibular | (50) | (50) | (50) | (48)
Adenocarcinoma, metastatic, salivary glands | – | – | – | 1 (2%)
Lymph node, mesenteric | (50) | (49) | (50) | (46)
Hemangiosarcoma | 2 (4%) | – | – | –
Spleen | (50) | (49) | (50) | (45)
Adenocarcinoma, metastatic, uterus | – | – | 1 (2%) | –
Thymus | (50) | (49) | (48) | (46)
Thymoma benign | – | – | – | 1 (2%)
Integumentary System
Mammary gland | (50) | (49) | (50) | (48)
Carcinoma | 1 (2%) | 1 (2%) | 2 (4%) | 3 (6%)
Carcinoma, multiple | – | – | – | 1 (2%)
Fibroadenoma | 8 (16%) | 7 (14%) | 10 (20%) | 6 (13%)
Fibroadenoma, multiple | 1 (2%) | 3 (6%) | 2 (4%) | 3 (6%)
Skin | (50) | (50) | (50) | (49)
Basal cell adenoma | 1 (2%) | – | – | –
Osteosarcoma, metastatic, bone | 1 (2%) | – | – | –
Schwannoma malignant | – | 1 (2%) | – | –
Squamous cell papilloma | – | – | 1 (2%) | 2 (4%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (49)
Femur, osteosarcoma | 1 (2%) | – | – | –
Skeletal muscle | (1) | (0) | (0) | (0)
Granulosa cell tumor malignant, metastatic, ovary | 1 (100%) | – | – | –
Nervous System
Brain | (50) | (50) | (50) | (49)
Glioma malignant | – | – | 1 (2%) | –
Peripheral nerve | (0) | (0) | (1) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (49)
Adenocarcinoma, metastatic, uterus | – | – | 2 (4%) | 1 (2%)
Carcinoma, metastatic, pancreas | – | – | – | 1 (2%)
Malignant mixed Müllerian tumor, metastatic, uterus | 1 (2%) | – | – | –
Schwannoma malignant, metastatic, uterus | – | – | 1 (2%) | –
Nose | (50) | (50) | (50) | (47)
Chondroma | 1 (2%) | – | – | –
Trachea | (47) | (50) | (50) | (47)
Special Senses System
Ear | (1) | (0) | (0) | (0)
Eye | (50) | (49) | (47) | (45)
Harderian gland | (49) | (50) | (50) | (49)
Urinary System
Kidney | (50) | (50) | (49) | (47)
Ureter | (1) | (0) | (0) | (1)
Urinary bladder | (50) | (49) | (49) | (45)
Adenocarcinoma, metastatic, uterus | – | – | 2 (4%) | –
Systemic Lesions
Multiple organs^b^ | (50) | (50) | (50) | (49)
Histiocytic sarcoma | – | – | 1 (2%) | 1 (2%)
Leukemia granulocytic | – | – | 2 (4%) | –
Lymphoma malignant | – | 3 (6%) | – | –
Neoplasm Summary
Total animals with primary neoplasms^c^
2-Year study | 40 | 38 | 46 | 44
Total primary neoplasms
2-Year study | 65 | 68 | 90 | 94
Total animals with benign neoplasms
2-Year study | 37 | 35 | 41 | 43
Total benign neoplasms
2-Year study | 55 | 60 | 73 | 75
Total animals with malignant neoplasms
2-Year study | 10 | 8 | 13 | 16
Total malignant neoplasms
2-Year study | 10 | 8 | 17 | 19
Total animals with metastatic neoplasms
2-Year study | 3 | – | 7 | 3
Total metastatic neoplasms
2-Year study | 4 | – | 26 | 9

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Primary Neoplasms in F_1_ Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Adrenal Medulla: Pheochromocytoma Benign, Complex, or Malignant
Overall rate^a^ | 2/50 (4%) | 1/50 (2%) | 3/50 (6%) | 0/47 (0%)
Adjusted rate^b^ | 4.6% | 2.2% | 6.8% | 0.0%
Terminal rate^c^ | 2/37 (5%) | 1/39 (3%) | 1/33 (3%) | 0/28 (0%)
First incidence (days) | 729 (T) | 729 (T) | 614 | –^e^
Poly-3 test^d^ | P = 0.291N | P = 0.476N | P = 0.510 | P = 0.274N
Liver: Cholangiocarcinoma
Overall rate | 0/50 (0%) | 0/49 (0%) | 0/50 (0%) | 2/47 (4%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 5.4%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 0/33 (0%) | 2/28 (7%)
First incidence (days) | – | – | – | 729 (T)
Poly-3 test | P = 0.030 | –^f^ | – | P = 0.203
Liver: Hepatocholangioma
Overall rate | 0/50 (0%) | 0/49 (0%) | 0/50 (0%) | 8/47 (17%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 21.5%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 0/33 (0%) | 7/28 (25%)
First incidence (days) | – | – | – | 619
Poly-3 test | P < 0.001 | – | – | P < 0.001
Liver: Hepatocellular Adenoma
Overall rate | 3/50 (6%) | 2/49 (4%) | 8/50 (16%) | 16/47 (34%)
Adjusted rate | 6.9% | 4.4% | 18.2% | 41.4%
Terminal rate | 3/37 (8%) | 2/39 (5%) | 6/33 (18%) | 11/28 (39%)
First incidence (days) | 729 (T) | 729 (T) | 656 | 490
Poly-3 test | P < 0.001 | P = 0.476N | P = 0.103 | P < 0.001
Liver: Hepatocellular Carcinoma
Overall rate | 0/50 (0%) | 0/49 (0%) | 1/50 (2%) | 6/47 (13%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 16.2%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 0/33 (0%) | 5/28 (18%)
First incidence (days) | – | – | 686 | 677
Poly-3 test | P < 0.001 | – | P = 0.503 | P = 0.008
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 3/50 (6%) | 2/49 (4%) | 8/50 (16%) | 17/47 (36%)
Adjusted rate | 6.9% | 4.4% | 18.2% | 44.0%
Terminal rate | 3/37 (8%) | 2/39 (5%) | 6/33 (18%) | 12/28 (43%)
First incidence (days) | 729 (T) | 729 (T) | 656 | 490
Poly-3 test | P < 0.001 | P = 0.476N | P = 0.103 | P < 0.001
Liver: Hepatocholangioma, Hepatocellular Adenoma, or Hepatocellular Carcinoma
Overall rate | 3/50 (6%) | 2/49 (4%) | 8/50 (16%) | 21/47 (45%)
Adjusted rate | 6.9% | 4.4% | 18.2% | 53.8%
Terminal rate | 3/37 (8%) | 2/39 (5%) | 6/33 (18%) | 15/28 (54%)
First incidence (days) | 729 (T) | 729 (T) | 656 | 490
Poly-3 test | P < 0.001 | P = 0.476N | P = 0.103 | P < 0.001
Mammary Gland: Fibroadenoma
Overall rate | 9/50 (18%) | 10/50 (20%) | 12/50 (24%) | 9/49 (18%)
Adjusted rate | 20.5% | 21.4% | 27.1% | 22.4%
Terminal rate | 8/37 (22%) | 9/39 (23%) | 10/33 (30%) | 4/28 (14%)
First incidence (days) | 508 | 585 | 610 | 537
Poly-3 test | P = 0.491 | P = 0.562 | P = 0.317 | P = 0.521
Mammary Gland: Carcinoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 2/50 (4%) | 4/49 (8%)
Adjusted rate | 2.3% | 2.2% | 4.6% | 10.3%
Terminal rate | 1/37 (3%) | 0/39 (0%) | 0/33 (0%) | 2/28 (7%)
First incidence (days) | 729 (T) | 658 | 676 | 597
Poly-3 test | P = 0.052 | P = 0.744N | P = 0.506 | P = 0.148
Mammary Gland: Fibroadenoma or Carcinoma
Overall rate | 10/50 (20%) | 11/50 (22%) | 14/50 (28%) | 13/49 (27%)
Adjusted rate | 22.8% | 23.4% | 31.4% | 32.0%
Terminal rate | 9/37 (24%) | 9/39 (23%) | 10/33 (30%) | 6/28 (21%)
First incidence (days) | 508 | 585 | 610 | 537
Poly-3 test | P = 0.189 | P = 0.572 | P = 0.251 | P = 0.241
Ovary: Benign Granulosa Cell Tumor
Overall rate | 1/50 (2%) | 3/49 (6%) | 1/50 (2%) | 2/46 (4%)
Adjusted rate | 2.3% | 6.6% | 2.3% | 5.5%
Terminal rate | 1/37 (3%) | 2/39 (5%) | 0/33 (0%) | 2/28 (7%)
First incidence (days) | 729 (T) | 651 | 676 | 729 (T)
Poly-3 test | P = 0.524 | P = 0.327 | P = 0.757N | P = 0.442
Ovary: Benign or Malignant Granulosa Cell Tumor
Overall rate | 2/50 (4%) | 3/49 (6%) | 1/50 (2%) | 2/46 (4%)
Adjusted rate | 4.6% | 6.6% | 2.3% | 5.5%
Terminal rate | 2/37 (5%) | 2/39 (5%) | 0/33 (0%) | 2/28 (7%)
First incidence (days) | 729 (T) | 651 | 676 | 729 (T)
Poly-3 test | P = 0.612N | P = 0.527 | P = 0.495N | P = 0.633
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 23/50 (46%) | 20/49 (41%) | 23/50 (46%) | 21/47 (45%)
Adjusted rate | 50.9% | 41.8% | 48.3% | 50.5%
Terminal rate | 18/37 (49%) | 14/38 (37%) | 13/33 (39%) | 9/28 (32%)
First incidence (days) | 445 | 358 | 368 | 396
Poly-3 test | P = 0.389 | P = 0.250N | P = 0.480N | P = 0.568N
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 1/45 (2%) | 3/49 (6%) | 3/47 (6%) | 1/42 (2%)
Adjusted rate | 2.5% | 6.6% | 7.3% | 2.9%
Terminal rate | 1/36 (3%) | 3/39 (8%) | 3/33 (9%) | 0/28 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | 553
Poly-3 test | P = 0.494N | P = 0.345 | P = 0.310 | P = 0.724
Thyroid Gland (C-Cell): Adenoma
Overall rate | 7/45 (16%) | 6/49 (12%) | 10/47 (21%) | 4/42 (10%)
Adjusted rate | 17.0% | 13.1% | 24.2% | 11.7%
Terminal rate | 6/36 (17%) | 5/39 (13%) | 10/33 (30%) | 4/28 (14%)
First incidence (days) | 592 | 694 | 729 (T) | 729 (T)
Poly-3 test | P = 0.411N | P = 0.422N | P = 0.295 | P = 0.378N
Uterus (Original and Residual Evaluations): Adenoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 1/49 (2%)
Adjusted rate | 2.3% | 2.2% | 6.8% | 2.6%
Terminal rate | 0/37 (0%) | 1/39 (3%) | 2/33 (6%) | 0/28 (0%)
Poly-3 test | P = 0.597 | P = 0.749N | P = 0.306 | P = 0.732
Uterus (Original Evaluation): Carcinoma
Overall rate | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 2/49 (4%)
Adjusted rate | 2.3% | 2.2% | 6.8% | 5.2%
Terminal rate | 0/37 (0%) | 1/39 (3%) | 1/33 (3%) | 2/28 (7%)
First incidence (days) | 592 | 729 (T) | 686 | 729 (T)
Poly-3 test | P = 0.332 | P = 0.748N | P = 0.307 | P = 0.456
Uterus (Residual Evaluation): Carcinoma
Overall rate | 2/50 (4%) | 0/50 (0%) | 4/50 (8%) | 3/49 (6%)
Adjusted rate | 4.5% | 0.0% | 9.1% | 7.8%
Terminal rate | 0/37 (0%) | 0/39 (0%) | 1/33 (3%) | 3/28 (11%)
First incidence (days) | 508 | – | 676 | 729 (T)
Poly-3 test | P = 0.172 | P = 0.228N | P = 0.335 | P = 0.436
Uterus (Original and Residual Evaluations): Carcinoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 4/50 (8%) | 4/49 (8%)
Adjusted rate | 4.5% | 2.2% | 9.1% | 10.4%
Terminal rate | 0/37 (0%) | 1/39 (3%) | 1/33 (3%) | 4/28 (14%)
First incidence (days) | 508 | 729 (T) | 676 | 729 (T)
Poly-3 test | P = 0.118 | P = 0.485N | P = 0.335 | P = 0.274
Uterus (Original Evaluation): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 4/50 (8%) | 2/49 (4%)
Adjusted rate | 4.5% | 2.2% | 9.0% | 5.2%
Terminal rate | 0/37 (0%) | 1/39 (3%) | 1/33 (3%) | 2/28 (7%)
First incidence (days) | 508 | 729 (T) | 614 | 729 (T)
Poly-3 test | P = 0.450 | P = 0.485N | P = 0.337 | P = 0.642
Uterus (Residual Evaluation): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 1/50 (2%) | 6/50 (12%) | 4/49 (8%)
Adjusted rate | 4.5% | 2.2% | 13.6% | 10.4%
Terminal rate | 0/37 (0%) | 1/39 (3%) | 3/33 (9%) | 3/28 (11%)
First incidence (days) | 508 | 729 (T) | 676 | 686
Poly-3 test | P = 0.135 | P = 0.485N | P = 0.131 | P = 0.275
Uterus (Original and Residual Evaluations): Adenoma or Carcinoma
Overall rate | 2/50 (4%) | 2/50 (4%) | 7/50 (14%) | 5/49 (10%)
Adjusted rate | 4.5% | 4.3% | 15.7% | 12.9%
Terminal rate | 0/37 (0%) | 2/39 (5%) | 3/33 (9%) | 4/28 (14%)
First incidence (days) | 508 | 729 (T) | 614 | 686
Poly-3 test | P = 0.100 | P = 0.678N | P = 0.079 | P = 0.163
Uterus (Original Evaluation): Stromal Polyp
Overall rate | 3/50 (6%) | 6/50 (12%) | 7/50 (14%) | 5/49 (10%)
Adjusted rate | 6.9% | 12.8% | 15.9% | 12.8%
Terminal rate | 2/37 (5%) | 5/39 (13%) | 6/33 (18%) | 4/28 (14%)
First incidence (days) | 592 | 585 | 655 | 553
Poly-3 test | P = 0.388 | P = 0.277 | P = 0.158 | P = 0.296
Uterus (Residual Evaluation): Stromal Polyp
Overall rate | 3/50 (6%) | 10/50 (20%) | 6/50 (12%) | 7/49 (14%)
Adjusted rate | 6.9% | 21.5% | 13.5% | 17.8%
Terminal rate | 2/37 (5%) | 8/39 (21%) | 4/33 (12%) | 5/28 (18%)
First incidence (days) | 592 | 694 | 614 | 553
Poly-3 test | P = 0.351 | P = 0.045 | P = 0.249 | P = 0.117
Uterus (Original and Residual Evaluations): Stromal Polyp
Overall rate | 4/50 (8%) | 12/50 (24%) | 11/50 (22%) | 9/49 (18%)
Adjusted rate | 9.2% | 25.5% | 24.8% | 22.8%
Terminal rate | 3/37 (8%) | 9/39 (23%) | 9/33 (27%) | 7/28 (25%)
First incidence (days) | 592 | 585 | 614 | 553
Poly-3 test | P = 0.283 | P = 0.037 | P = 0.045 | P = 0.077
Uterus (Original Evaluation): Stromal Polyp or Stromal Sarcoma
Overall rate | 3/50 (6%) | 6/50 (12%) | 8/50 (16%) | 5/49 (10%)
Adjusted rate | 6.9% | 12.8% | 18.2% | 12.8%
Terminal rate | 2/37 (5%) | 5/39 (13%) | 7/33 (21%) | 4/28 (14%)
First incidence (days) | 592 | 585 | 655 | 553
Poly-3 test | P = 0.390 | P = 0.277 | P = 0.099 | P = 0.296
Uterus (Residual Evaluation): Stromal Polyp or Stromal Sarcoma
Overall rate | 3/50 (6%) | 10/50 (20%) | 7/50 (14%) | 7/49 (14%)
Adjusted rate | 6.9% | 21.5% | 15.8% | 17.8%
Terminal rate | 2/37 (5%) | 8/39 (21%) | 5/33 (15%) | 5/28 (18%)
First incidence (days) | 592 | 694 | 614 | 553
Poly-3 test | P = 0.354 | P = 0.045 | P = 0.162 | P = 0.117
Uterus (Original and Residual Evaluations): Stromal Polyp or Stromal Sarcoma
Overall rate | 4/50 (8%) | 12/50 (24%) | 12/50 (24%) | 9/49 (18%)
Adjusted rate | 9.2% | 25.5% | 27.1% | 22.8%
Terminal rate | 3/37 (8%) | 9/39 (23%) | 10/33 (30%) | 7/28 (25%)
First incidence (days) | 592 | 585 | 614 | 553
Poly-3 test | P = 0.284 | P = 0.037 | P = 0.026 | P = 0.077
All Organs: Malignant Lymphoma
Overall rate | 0/50 (0%) | 3/50 (6%) | 0/50 (0%) | 0/49 (0%)
Adjusted rate | 0.0% | 6.4% | 0.0% | 0.0%
Terminal rate | 0/37 (0%) | 1/39 (3%) | 0/33 (0%) | 0/28 (0%)
First incidence (days) | – | 651 | – | –
Poly-3 test | P = 0.239N | P = 0.133 | – | –
All Organs: Benign Neoplasms
Overall rate | 37/50 (74%) | 35/50 (70%) | 41/50 (82%) | 43/49 (88%)
Adjusted rate | 78.9% | 70.8% | 84.3% | 95.8%
Terminal rate | 29/37 (78%) | 27/39 (69%) | 28/33 (85%) | 27/28 (96%)
First incidence (days) | 445 | 358 | 368 | 396
Poly-3 test | P = 0.002 | P = 0.246N | P = 0.334 | P = 0.012
All Organs: Malignant Neoplasms
Overall rate | 10/50 (20%) | 8/50 (16%) | 13/50 (26%) | 16/49 (33%)
Adjusted rate | 22.5% | 16.8% | 27.8% | 39.5%
Terminal rate | 7/37 (19%) | 3/39 (8%) | 3/33 (9%) | 10/28 (36%)
First incidence (days) | 585 | 585 | 508 | 385
Poly-3 test | P = 0.014 | P = 0.337N | P = 0.365 | P = 0.069
All Organs: Benign or Malignant Neoplasms
Overall rate | 40/50 (80%) | 38/50 (76%) | 46/50 (92%) | 44/49 (90%)
Adjusted rate | 83.8% | 76.4% | 92.0% | 96.2%
Terminal rate | 30/37 (81%) | 28/39 (72%) | 29/33 (88%) | 27/28 (96%)
First incidence (days) | 445 | 358 | 368 | 385
Poly-3 test | P = 0.007 | P = 0.255N | P = 0.171 | P = 0.043

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for adrenal ^g^land, liver, ovary, pituitary gland, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table B-3 Historical Incidence of Liver Neoplasms in Control Female Wistar Han Rats^a^

Study (Study Start) | Cholangiocarcinoma | Hepatocholangioma | Hepatocellular Adenoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (August 2008) | 0/50 | 0/50 | 3/50
Tetrabromobisphenol A (July 2007) | 0/50 | 0/50 | 1/50
Total (%) | 0/100 | 0/100 | 4/100 (4.0%)
Mean ± standard deviation | – | – | 4.0% ± 2.8%
Range | – | – | 2%–6%
Overall Historical Incidence: All Routes
Total (%) | 0/300 | 0/300 | 6/300
Mean ± standard deviation | – | – | 2.0% ± 2.2%
Range | – | – | 0%–6%
| Hepatocellular Carcinoma | Hepatocellular Adenoma or Hepatocellular Carcinoma | Hepatocholangioma, Hepatocellular Adenoma, or Hepatocellular Carcinoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (August 2008) | 0/50 | 3/50 | 3/50
Tetrabromobisphenol A (July 2007) | 0/50 | 1/50 | 1/50
Total (%) | 0/100 | 4/100 (4.0%) | 4/100 (4.0%)
Mean ± standard deviation | – | 4.0% ± 2.8% | 4.0% ± 2.8%
Range | – | 2%–6% | 2%–6%
Overall Historical Incidence: All Routes
Total (%) | 0/300 | 6/300 | 6/300
Mean ± standard deviation | – | 2.0% ± 2.2% | 2.0% ± 2.2%
Range | – | 0%–6% | 0%–6%

^a^ Data as of November 2014.

Table B-4 Historical Incidence of Uterus Neoplasms in Control Female Wistar Han Rats^a^

Study (Study Start) | Stromal Polyp | Stromal Sarcoma | Stromal Polyp or Stromal Sarcoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (August 2008) | 3/50 | 0/50 | 3/50
Tetrabromobisphenol A (July 2007) | 2/50 | 0/50 | 2/50
Total (%) | 5/100 (5.0%) | 0/100 | 5/100 (5.0%)
Mean ± standard deviation | 5.0% ± 1.4% | – | 5.0% ± 1.4%
Range | 4%–6% | – | 4%–6%
Overall Historical Incidence: All Routes (Original Evaluation)
Total (%) | 13/194 | 3/194 | 15/194
Mean ± standard deviation | 6.7% ± 2.5% | 1.6% ± 1.9% | 7.8% ± 3.5%
Range | 4%–10% | 0%–4% | 4%–12%
Overall Historical Incidence: All Routes (Residual Evaluation)
Total (%) | 20/194 | 2/194 | 22/194
Mean ± standard deviation | 10.3% ± 2.9% | 1.1% ± 1.2% | 11.4% ± 3.7%
Range | 6%–12% | 0%–2% | 6%–14%
Overall Historical Incidence: All Routes (Original and Residual Evaluations)
Total (%) | 27/194 | 3/194 | 29/194
Mean ± standard deviation | 14.0% ± 5.2% | 1.6% ± 1.9% | 15.1% ± 6.3%
Range | 8%–20% | 0%–4% | 8%–22%

^a^ Data as of May 2015.

Table B-5 Summary of the Incidence of Nonneoplastic Lesions in F_1_ Female Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | | | 10
Early deaths
Accidental deaths | 2 | 1 | – | –
Moribund | 8 | 10 | 13 | 11
Natural deaths | 3 | – | 4 | 10
Survivors
Died last week of study | 1 | – | – | –
Terminal kill | 36 | 39 | 33 | 28
Other | – | – | – | 1
Animals examined microscopically | 60 | 50 | 50 | 59
Three-month Interim Evaluation
Alimentary System
Esophagus | (10) | | | (10)
Intestine large, cecum | (10) | | | (10)
Intestine large, colon | (10) | | | (10)
Intestine large, rectum | (10) | | | (10)
Intestine small, duodenum | (10) | | | (10)
Intestine small, ileum | (10) | | | (10)
Intestine small, jejunum | (10) | | | (10)
Liver | (9) | | | (10)
Fatty change | – | | | 3 (30%)
Hepatocyte, hypertrophy | – | | | 10 (100%)
Oral mucosa | (1) | | | (0)
Pancreas | (10) | | | (10)
Atrophy | 1 (10%) | | | –
Salivary glands | (10) | | | (10)
Stomach, forestomach | (10) | | | (10)
Stomach, glandular | (10) | | | (10)
Endocrine System
Adrenal cortex | (10) | | | (10)
Accessory adrenal cortical nodule | 3 (30%) | | | 2 (20%)
Adrenal medulla | (9) | | | (10)
Islets, pancreatic | (10) | | | (10)
Parathyroid gland | (10) | | | (10)
Pituitary gland | (10) | | | (10)
Thyroid gland | (10) | | | (10)
Follicle, hypertrophy | 1 (10%) | | | 5 (50%)
Genital System
Clitoral gland | (10) | | | (10)
Inflammation, chronic | 7 (70%) | | | 6 (60%)
Inflammation, chronic active | – | | | 1 (10%)
Ovary | (10) | | | (10)
Uterus | (10) | | | (10)
Hematopoietic System
Bone marrow | (10) | | | (10)
Lymph node | (2) | | | (2)
Pigmentation | 1 (50%) | | | –
Popliteal, pigmentation | – | | | 2 (100%)
Lymph node, mandibular | (10) | | | (10)
Hyperplasia, lymphoid | 1 (10%) | | | –
Lymph node, mesenteric | (10) | | | (10)
Spleen | (10) | | | (10)
Hematopoietic cell proliferation | – | | | 1 (10%)
Pigmentation | – | | | 1 (10%)
Thymus | (10) | | | (10)
Respiratory System
Lung | (10) | | | (10)
Inflammation, chronic | – | | | 2 (20%)
Metaplasia, osseous | – | | | 1 (10%)
Nose | (10) | | | (10)
Trachea | (10) | | | (10)
Systems Examined at Three Months with No Lesions Observed
Cardiovascular System
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (50) | (50) | (50) | (49)
Hyperkeratosis | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | –
Intestine large, cecum | (48) | (49) | (47) | (40)
Intestine large, colon | (48) | (49) | (50) | (46)
Intestine large, rectum | (49) | (49) | (49) | (45)
Degeneration, fatty, focal | – | 1 (2%) | – | –
Intestine small, duodenum | (47) | (49) | (47) | (42)
Epithelium, vacuolization cytoplasmic | – | 1 (2%) | – | –
Intestine small, ileum | (47) | (49) | (48) | (41)
Intestine small, jejunum | (46) | (49) | (47) | (42)
Liver | (50) | (49) | (50) | (47)
Angiectasis | 1 (2%) | – | 4 (8%) | 2 (4%)
Basophilic focus | 2 (4%) | 4 (8%) | 7 (14%) | 5 (11%)
Basophilic focus, multiple | 42 (84%) | 39 (80%) | 33 (66%) | 28 (60%)
Cholangiofibrosis | – | – | – | 3 (6%)
Clear cell focus | 2 (4%) | 3 (6%) | 1 (2%) | –
Clear cell focus, multiple | 33 (66%) | 18 (37%) | 25 (50%) | 31 (66%)
Congestion | 3 (6%) | – | – | 1 (2%)
Cyst | – | – | 1 (2%) | –
Eosinophilic focus | 5 (10%) | 5 (10%) | 10 (20%) | 12 (26%)
Eosinophilic focus, multiple | – | 2 (4%) | 11 (22%) | 19 (40%)
Fatty change | 15 (30%) | 12 (24%) | 28 (56%) | 39 (83%)
Fibrosis | – | – | 1 (2%) | –
Hematopoietic cell proliferation | 4 (8%) | 1 (2%) | – | –
Hepatodiaphragmatic nodule | 4 (8%) | 5 (10%) | – | 1 (2%)
Hyperplasia, nodular | – | – | 2 (4%) | 7 (15%)
Inflammation, granulomatous | 1 (2%) | – | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Mixed cell focus | – | 1 (2%) | – | –
Pigmentation | 1 (2%) | 2 (4%) | 1 (2%) | –
Bile duct, cyst | 1 (2%) | 2 (4%) | 4 (8%) | 6 (13%)
Bile duct, cyst, multiple | 1 (2%) | – | 1 (2%) | 1 (2%)
Bile duct, fibrosis | 1 (2%) | – | – | –
Bile duct, hyperplasia | 16 (32%) | 20 (41%) | 16 (32%) | 14 (30%)
Bile duct, inflammation, chronic active | – | – | – | 1 (2%)
Hepatocyte, degeneration | – | – | 1 (2%) | –
Hepatocyte, hypertrophy | – | 48 (98%) | 49 (98%) | 45 (96%)
Hepatocyte, mitosis | – | – | 1 (2%) | –
Hepatocyte, necrosis | 4 (8%) | 2 (4%) | 1 (2%) | 8 (17%)
Oval cell, hyperplasia | 1 (2%) | 3 (6%) | 3 (6%) | 10 (21%)
Serosa, inflammation, acute | 1 (2%) | – | – | –
Mesentery | (10) | (7) | (9) | (6)
Congestion | 1 (10%) | – | – | –
Inflammation, granulomatous, chronic active | – | 1 (14%) | – | –
Inflammation, chronic | 1 (10%) | – | – | –
Fat, necrosis | 8 (80%) | 6 (86%) | 5 (56%) | 6 (100%)
Oral mucosa | (0) | (0) | (1) | (1)
Pancreas | (50) | (49) | (49) | (47)
Atrophy | 3 (6%) | 3 (6%) | 3 (6%) | 5 (11%)
Inflammation, granulomatous, chronic | – | 1 (2%) | – | –
Inflammation, chronic | 3 (6%) | – | 1 (2%) | –
Salivary glands | (50) | (50) | (49) | (45)
Cyst | 1 (2%) | – | – | –
Inflammation, chronic | 1 (2%) | – | 1 (2%) | –
Duct, degeneration, hyaline | – | 1 (2%) | – | –
Duct, parotid gland, inflammation, acute | 1 (2%) | 2 (4%) | 4 (8%) | 1 (2%)
Duct, submandibular gland, inflammation, acute | 1 (2%) | – | – | –
Parotid gland, atrophy | 4 (8%) | 4 (8%) | 4 (8%) | 5 (11%)
Parotid gland, basophilic focus | – | – | – | 1 (2%)
Parotid gland, inflammation | – | 1 (2%) | – | –
Parotid gland, inflammation, acute | – | – | 1 (2%) | –
Parotid gland, inflammation, chronic | 1 (2%) | – | – | –
Parotid gland, necrosis | – | – | – | 1 (2%)
Parotid gland, vacuolization cytoplasmic | 6 (12%) | 9 (18%) | 7 (14%) | 2 (4%)
Sublingual gland, ectopic tissue | – | – | 1 (2%) | 1 (2%)
Sublingual gland, vacuolization cytoplasmic | – | 1 (2%) | – | –
Submandibular gland, ectopic tissue | – | | – | 1 (2%)
Submandibular gland, inflammation, acute | – | 1 (2%) | – | –
Submandibular gland, inflammation, chronic | – | – | – | 1 (2%)
Submandibular gland, necrosis | – | 1 (2%) | – | –
Stomach, forestomach | (50) | (49) | (50) | (48)
Edema | 1 (2%) | 1 (2%) | 2 (4%) | –
Foreign body | 1 (2%) | – | – | –
Hyperkeratosis | 4 (8%) | 6 (12%) | 7 (14%) | 4 (8%)
Inflammation, acute | – | 3 (6%) | 1 (2%) | –
Inflammation, chronic | 1 (2%) | – | 3 (6%) | 2 (4%)
Inflammation, chronic active | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%)
Mineralization | – | 2 (4%) | 3 (6%) | 1 (2%)
Ulcer | 2 (4%) | 4 (8%) | 3 (6%) | 3 (6%)
Epithelium, hyperplasia | 5 (10%) | 6 (12%) | 6 (12%) | 4 (8%)
Stomach, glandular | (49) | (49) | (50) | (46)
Erosion | – | – | 1 (2%) | –
Inflammation, acute | – | 1 (2%) | 2 (4%) | –
Inflammation, chronic | – | – | – | 1 (2%)
Mineralization | 9 (18%) | 11 (22%) | 14 (28%) | 7 (15%)
Necrosis | – | – | 1 (2%) | –
Ulcer | – | 1 (2%) | 1 (2%) | 1 (2%)
Tooth | (1) | (0) | (0) | (0)
Inflammation, chronic | 1 (100%) | – | – | –
Cardiovascular System
Blood vessel | (1) | (0) | (3) | (3)
Inflammation, acute | 1 (100%) | – | – | –
Heart | (50) | (50) | (50) | (48)
Cardiomyopathy | 12 (24%) | 8 (16%) | 10 (20%) | 4 (8%)
Inflammation, chronic | 1 (2%) | – | – | –
Epicardium, inflammation, chronic | – | 1 (2%) | – | –
Epicardium, inflammation, chronic active | 1 (2%) | – | – | –
Endocrine System
Adrenal cortex | (50) | (49) | (50) | (46)
Accessory adrenal cortical nodule, multifocal | – | 1 (2%) | – | –
Angiectasis | 45 (90%) | 44 (90%) | 44 (88%) | 34 (74%)
Hematopoietic cell proliferation | 1 (2%) | – | 3 (6%) | 1 (2%)
Hemorrhage | 1 (2%) | – | – | –
Hyperplasia, focal | 8 (16%) | 6 (12%) | 12 (24%) | 19 (41%)
Hypertrophy, focal | 13 (26%) | 9 (18%) | 12 (24%) | 14 (30%)
Necrosis | – | 1 (2%) | – | –
Vacuolization cytoplasmic | 5 (10%) | 5 (10%) | 7 (14%) | 9 (20%)
Adrenal medulla | (50) | (50) | (50) | (47)
Hyperplasia, focal | – | – | 1 (2%) | –
Islets, pancreatic | (50) | (49) | (49) | (47)
Hyperplasia | 1 (2%) | – | – | –
Hypertrophy | 1 (2%) | – | – | –
Pigmentation, hemosiderin | 1 (2%) | – | – | –
Parathyroid gland | (49) | (47) | (49) | (46)
Pituitary gland | (50) | (49) | (50) | (47)
Pigmentation, hemosiderin | – | – | 2 (4%)
Pars distalis, cyst | 3 (6%) | – | – | 1 (2%)
Pars distalis, cyst, multiple | – | 1 (2%) | 3 (6%) | –
Pars distalis, hyperplasia, focal | 14 (28%) | 9 (18%) | 17 (34%) | 9 (19%)
Pars distalis, vacuolization cytoplasmic | – | – | – | 1 (2%)
Pars intermedia, hyperplasia, focal | – | 1 (2%) | – | 1 (2%)
Pars intermedia, hypertrophy | – | 1 (2%) | – | –
Pars nervosa, cyst, multiple | – | – | 1 (2%) | –
Pars nervosa, inflammation, chronic | 1 (2%) | – | 1 (2%) | 1 (2%)
Thyroid gland | (45) | (49) | (47) | (42)
Mineralization | – | – | – | 1 (2%)
C-cell, hyperplasia | 45 (100%) | 48 (98%) | 46 (98%) | 38 (90%)
Follicle, cyst | 2 (4%) | – | 2 (4%) | –
Follicle, cyst, multiple | 1 (2%) | – | – | –
Follicle, hypertrophy | 8 (18%) | 17 (35%) | 22 (47%) | 35 (83%)
Follicular cell, hyperplasia | 1 (2%) | 5 (10%) | 4 (9%) | 6 (14%)
Follicular cell, hypertrophy | – | – | 1 (2%) | –
General Body System
Tissue NOS | (3) | (2) | (4) | (2)
Abscess | 1 (33%) | – | – | –
Fibrosis | – | – | 1 (25%) | 1 (50%)
Inflammation, suppurative, chronic active | – | 1 (50%) | – | –
Inflammation, acute | 1 (33%) | – | – | –
Inflammation, chronic active | 1 (33%) | – | – | –
Genital System
Clitoral gland | (49) | (49) | (50) | (47)
Inflammation, chronic | 1 (2%) | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | – | – | 1 (2%) | 2 (4%)
Duct, cyst | 2 (4%) | 4 (8%) | 3 (6%) | 3 (6%)
Duct, cyst, multiple | – | 1 (2%) | – | –
Ovary | (50) | (49) | (50) | (46)
Atrophy | 1 (2%) | 3 (6%) | 1 (2%) | 2 (4%)
Cyst | 5 (10%) | 5 (10%) | 8 (16%) | 8 (17%)
Cyst, multiple | – | – | 1 (2%) | –
Hyperplasia, tubulostromal | – | 4 (8%) | 3 (6%) | 1 (2%)
Follicle, cyst | 4 (8%) | 2 (4%) | 3 (6%) | 5 (11%)
Follicle, cyst, multiple | 2 (4%) | 1 (2%) | – | 1 (2%)
Granulosa cell, hyperplasia, multifocal | – | – | – | 1 (2%)
Uterus | (50) | (49) | (50) | (47)
Adenomyosis | – | 1 (2%) | – | –
Angiectasis | 1 (2%) | – | – | –
Cyst | – | 1 (2%) | – | –
Cyst, squamous | – | – | – | 1 (2%)
Decidual reaction | – | – | 1 (2%) | 1 (2%)
Dilatation | – | – | 1 (2%) | 1 (2%)
Hemorrhage | 1 (2%) | – | 1 (2%) | –
Hyperplasia, atypical | 3 (6%) | 1 (2%) | 2 (4%) | –
Inflammation, chronic | 1 (2%) | – | – | –
Inflammation, chronic active | – | 1 (2%) | – | –
Metaplasia, squamous | – | – | 1 (2%) | 4 (9%)
Cervix, hyperkeratosis | – | – | 1 (2%) | –
Cervix, hyperplasia, squamous | – | – | – | 2 (4%)
Endometrium, hyperplasia, cystic | 15 (30%) | 9 (18%) | 17 (34%) | 14 (30%)
Myometrium, degeneration, mucoid | – | – | 1 (2%) | –
Serosa, cyst | – | – | 1 (2%) | –
Serosa, inflammation, acute | 1 (2%) | – | – | –
Vagina | (1) | (1) | (2) | (2)
Hematopoietic System
Bone marrow | (50) | (50) | (50) | (46)
Fibrosis | – | – | – | 1 (2%)
Myeloid cell, hyperplasia | 6 (12%) | 4 (8%) | 7 (14%) | 11 (24%)
Lymph node | (10) | (5) | (6) | (9)
Pigmentation, hemosiderin | 1 (10%) | – | – | –
Axillary, ectasia | 1 (10%) | – | – | –
Axillary, hyperplasia, lymphoid | 1 (10%) | – | – | –
Axillary, pigmentation | 1 (10%) | – | – | –
Iliac, hyperplasia, lymphoid | – | – | – | 1 (11%)
Inguinal, pigmentation | 2 (20%) | – | 2 (33%) | –
Mediastinal, ectasia | – | 1 (20%) | 1 (17%) | –
Mediastinal, hemorrhage | 2 (20%) | 1 (20%) | – | 1 (11%)
Mediastinal, hyperplasia, lymphoid | – | – | – | 1 (11%)
Mediastinal, hyperplasia, plasma cell | – | – | 1 (17%) | –
Mediastinal, inflammation, granulomatous, chronic active | – | 1 (20%) | – | –
Mediastinal, pigmentation | – | – | 1 (17%) | –
Mediastinal, pigmentation, hemosiderin | 3 (30%) | 2 (40%) | 1 (17%) | 4 (44%)
Pancreatic, hemorrhage | 1 (10%) | – | – | –
Pancreatic, pigmentation, hemosiderin | 1 (10%) | – | – | 1 (11%)
Popliteal, hemorrhage | – | – | – | 1 (11%)
Popliteal, hyperplasia, lymphoid | – | – | – | 1 (11%)
Popliteal, pigmentation | – | 1 (20%) | – | 3 (33%)
Lymph node, mandibular | (50) | (50) | (50) | (48)
Ectasia | 4 (8%) | 2 (4%) | 4 (8%) | 1 (2%)
Hemorrhage | 2 (4%) | – | – | –
Hyperplasia, lymphoid | – | – | – | 2 (4%)
Hyperplasia, plasma cell | – | – | – | 1 (2%)
Necrosis | 1 (2%) | – | – | –
Pigmentation, hemosiderin | – | 1 (2%) | – | –
Lymph node, mesenteric | (50) | (49) | (50) | (46)
Ectasia | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%)
Hemorrhage | 1 (2%) | 4 (8%) | 3 (6%) | 1 (2%)
Hyperplasia, lymphoid | 1 (2%) | – | – | –
Infiltration cellular, histiocyte | 1 (2%) | – | – | –
Inflammation, acute | 1 (2%) | – | – | –
Pigmentation, hemosiderin | 1 (2%) | 1 (2%) | 1 (2%) | –
Spleen | (50) | (49) | (50) | (45)
Accessory spleen | 1 (2%) | 1 (2%) | – | –
Angiectasis | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 27 (54%) | 24 (49%) | 19 (38%) | 17 (38%)
Hemorrhage | – | 1 (2%) | 1 (2%) | –
Pigmentation | 31 (62%) | 31 (63%) | 32 (64%) | 27 (60%)
Capsule, fibrosis, focal | 1 (2%) | – | – | –
Lymphoid follicle, atrophy | – | 2 (4%) | 3 (6%) | 1 (2%)
Thymus | (50) | (49) | (48) | (46)
Atrophy | 10 (20%) | 7 (14%) | 18 (38%) | 9 (20%)
Cyst | – | – | – | 1 (2%)
Hemorrhage | 4 (8%) | 6 (12%) | 5 (10%) | 1 (2%)
Integumentary System
Mammary gland | (50) | (49) | (50) | (48)
Degeneration, fatty | 1 (2%) | – | – | –
Fibrosis | – | – | 2 (4%) | –
Galactocele | 2 (4%) | – | 3 (6%) | 3 (6%)
Hyperplasia | 26 (52%) | 28 (57%) | 24 (48%) | 19 (40%)
Inflammation, granulomatous | – | – | 1 (2%) | –
Inflammation, chronic active | – | – | – | 1 (2%)
Duct, cyst | 1 (2%) | | 1 (2%) | –
Duct, dilatation | 16 (32%) | 19 (39%) | 13 (26%) | 6 (13%)
Duct, inflammation, acute | – | – | – | 1 (2%)
Skin | (50) | (50) | (50) | (49)
Fibrosis | 1 (2%) | – | – | –
Hyperkeratosis | 1 (2%) | – | 2 (4%) | –
Inflammation, acute | – | – | 2 (4%) | –
Inflammation, chronic | – | 1 (2%) | 1 (2%) | –
Inflammation, chronic active | – | 1 (2%) | – | 1 (2%)
Ulcer | 1 (2%) | – | 2 (4%) | 1 (2%)
Epidermis, hyperplasia | – | 1 (2%) | 1 (2%) | 2 (4%)
Musculoskeletal System
Bone | (50) | (50) | (50) | (49)
Skeletal muscle | (1) | (0) | (0) | (0)
Nervous System
Brain | (50) | (50) | (50) | (49)
Compression | 8 (16%) | 9 (18%) | 11 (22%) | 13 (27%)
Cyst | 1 (2%) | – | – | –
Hemorrhage, multifocal | – | – | 1 (2%) | –
Peripheral nerve | (0) | (0) | (1) | (0)
Respiratory System
Lung | (50) | (50) | (50) | (49)
Infiltration cellular, histiocyte | 25 (50%) | 23 (46%) | 22 (44%) | 30 (61%)
Inflammation, acute | – | – | – | 1 (2%)
Inflammation, chronic | 1 (2%) | – | – | 1 (2%)
Mineralization | – | – | 1 (2%) | 1 (2%)
Alveolar epithelium, hyperplasia | 1 (2%) | 3 (6%) | 1 (2%) | –
Serosa, inflammation, acute | 1 (2%) | – | – | –
Nose | (50) | (50) | (50) | (47)
Inflammation, acute | – | 1 (2%) | 1 (2%) | 1 (2%)
Trachea | (47) | (50) | (50) | (47)
Inflammation, chronic | – | 1 (2%) | 1 (2%) | –
Special Senses System
Ear | (1) | (0) | (0) | (0)
Eye | (50) | (49) | (47) | (45)
Developmental malformation | – | 1 (2%) | – | –
Mineralization | 1 (2%) | – | – | –
Retina, atrophy | 9 (18%) | 3 (6%) | 9 (19%) | 10 (22%)
Harderian gland | (49) | (50) | (50) | (49)
Urinary System
Kidney | (50) | (50) | (49) | (47)
Calculus gross observation | 1 (2%) | – | – | –
Casts protein | 2 (4%) | – | – | 2 (4%)
Cyst | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Cyst, multiple | 1 (2%) | – | – | 1 (2%)
Hydronephrosis | 1 (2%) | 1 (2%) | 1 (2%) | 6 (13%)
Inflammation, chronic | 2 (4%) | – | 1 (2%) | –
Inflammation, chronic active | – | – | 1 (2%) | –
Nephropathy | 13 (26%) | 8 (16%) | 17 (35%) | 15 (32%)
Pigmentation | – | 1 (2%) | 3 (6%) | 4 (9%)
Pelvis, inflammation, acute | 1 (2%) | – | – | –
Pelvis, inflammation, chronic active | 16 (32%) | 10 (20%) | 6 (12%) | 3 (6%)
Pelvis, mineralization | 31 (62%) | 29 (58%) | 23 (47%) | 19 (40%)
Renal tubule, dilatation | – | – | 1 (2%) | –
Transitional epithelium, hyperplasia | 3 (6%) | 4 (8%) | 1 (2%) | 2 (4%)
Ureter | (1) | (0) | (0) | (1)
Inflammation, chronic | – | – | – | 1 (100%)
Mineralization | – | – | – | 1 (100%)
Transitional epithelium, hyperplasia | 1 (100%) | – | – | –
Urinary bladder | (50) | (49) | (49) | (45)
Inflammation, chronic | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | – | –
Transitional epithelium, hyperplasia | 1 (2%) | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.