# Appendix A Summary of Lesions in F_1_ Male Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

Table A-1 Summary of the Incidence of Neoplasms in F_1_ Male Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | 1 | 1 | – | 1
Moribund | 8 | 7 | 10 | 12
Natural deaths | 4 | 7 | 2 | 12
Survivors
Terminal kill | 36 | 35 | 38 | 25
Other | 1 | – | – | –
Animals examined microscopically | 59 | 50 | 50 | 60
Systems Examined at Three Months with No Neoplasms Observed
Alimentary System
Cardiovascular System
Endocrine System
General Body System
Genital System
Hematopoietic System
Integumentary System
Musculoskeletal System
Nervous System
Respiratory System
Special Senses System
Urinary System
Two-year Study
Alimentary System
Esophagus | (49) | (50) | (50) | (50)
Squamous cell papilloma | – | – | 1 (2%) | –
Intestine large, cecum | (46) | (43) | (49) | (43)
Intestine large, colon | (48) | (45) | (50) | (48)
Intestine large, rectum | (48) | (46) | (49) | (47)
Intestine small, duodenum | (46) | (45) | (49) | (46)
Fibroma | 1 (2%) | – | – | –
Intestine small, ileum | (45) | (43) | (49) | (42)
Intestine small, jejunum | (45) | (44) | (50) | (46)
Fibroma | – | – | – | 1 (2%)
Liver | (49) | (50) | (50) | (50)
Hepatocellular adenoma | 3 (6%) | 2 (4%) | 4 (8%) | 7 (14%)
Hepatocellular adenoma, multiple | – | – | – | 1 (2%)
Hepatocellular carcinoma | – | – | – | 2 (4%)
Hepatocholangioma | – | – | – | 2 (4%)
Mesentery | (12) | (6) | (13) | (10)
Lipoma | 1 (8%) | – | – | –
Oral mucosa | (1) | (0) | (0) | (0)
Pancreas | (46) | (47) | (50) | (49)
Adenoma | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%)
Adenoma, multiple | – | – | 1 (2%) | –
Salivary glands | (46) | (48) | (50) | (50)
Parotid gland, adenoma | 1 (2%) | – | 1 (2%) | –
Parotid gland, carcinoma | – | – | 1 (2%) | –
Stomach, forestomach | (49) | (50) | (50) | (50)
Fibrosarcoma | 1 (2%) | – | – | –
Leiomyosarcoma | – | – | – | 1 (2%)
Squamous cell papilloma | 1 (2%) | – | – | –
Squamous cell papilloma, multiple | – | – | 1 (2%) | –
Stomach, glandular | (48) | (46) | (50) | (49)
Fibrosarcoma | 1 (2%) | – | – | –
Tongue | (0) | (1) | (0) | (0)
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (0) | (2) | (0) | (0)
Heart | (49) | (50) | (50) | (50)
Endocrine System
Adrenal cortex | (49) | (49) | (50) | (49)
Carcinoma | 1 (2%) | – | – | 1 (2%)
Adrenal medulla | (49) | (48) | (50) | (49)
Pheochromocytoma benign | – | – | 1 (2%) | –
Pheochromocytoma complex | – | 1 (2%) | – | –
Pheochromocytoma malignant | 1 (2%) | – | – | –
Islets, pancreatic | (49) | (49) | (50) | (50)
Adenoma | 4 (8%) | 2 (4%) | 2 (4%) | 1 (2%)
Carcinoma | 2 (4%) | – | 1 (2%) | –
Parathyroid gland | (47) | (49) | (50) | (50)
Adenoma | 1 (2%) | – | – | –
Adenoma, multiple | 1 (2%) | – | – | –
Pituitary gland | (49) | (49) | (50) | (50)
Craniopharyngioma | – | 1 (2%) | – | –
Ganglioneuroma | – | 1 (2%) | – | –
Glioma malignant, metastatic, brain | 1 (2%) | – | 1 (2%) | –
Pars distalis, adenoma | 19 (39%) | 12 (24%) | 21 (42%) | 34 (68%)
Pars distalis, adenoma, multiple | – | – | 1 (2%) | 1 (2%)
Pars intermedia, adenoma | – | 2 (4%) | – | –
Thyroid gland | (45) | (45) | (48) | (46)
C-cell, adenoma | 11 (24%) | 12 (27%) | 10 (21%) | 6 (13%)
C-cell, adenoma, multiple | – | – | 1 (2%) | –
C-cell, carcinoma | – | – | – | 1 (2%)
Follicular cell, adenoma | 1 (2%) | 3 (7%) | 2 (4%) | 6 (13%)
Follicular cell, carcinoma | – | 2 (4%) | 1 (2%) | –
General Body System
Tissue NOS | (3) | (3) | (2) | (1)
Schwannoma malignant | – | 1 (33%) | 1 (50%) | –
Genital System
Epididymis | (49) | (50) | (50) | (50)
Preputial gland | (49) | (49) | (50) | (50)
Carcinoma | 1 (2%) | – | – | –
Prostate | (49) | (50) | (50) | (50)
Adenoma | – | – | 1 (2%) | –
Seminal vesicle | (49) | (46) | (50) | (49)
Testes | (49) | (49) | (50) | (50)
Interstitial cell, adenoma | 2 (4%) | 4 (8%) | 2 (4%) | 4 (8%)
Hematopoietic System
Bone marrow | (49) | (48) | (50) | (50)
Lymph node | (2) | (6) | (5) | (6)
Lymph node, mandibular | (48) | (49) | (50) | (50)
Lymph node, mesenteric | (49) | (49) | (50) | (50)
Hemangioma | 1 (2%) | – | 2 (4%) | 1 (2%)
Hemangiosarcoma | 7 (14%) | 2 (4%) | 3 (6%) | 4 (8%)
Spleen | (47) | (46) | (50) | (49)
Hemangiosarcoma | 1 (2%) | – | – | 1 (2%)
Thymus | (45) | (49) | (49) | (50)
Thymoma benign | – | – | 1 (2%) | –
Thymoma malignant | – | – | 1 (2%) | –
Integumentary System
Mammary gland | (33) | (38) | (39) | (41)
Fibroadenoma | – | – | 3 (8%) | –
Fibroma | – | 1 (3%) | – | –
Skin | (49) | (49) | (50) | (50)
Basal cell adenoma | 1 (2%) | 1 (2%) | 1 (2%) | –
Fibroma | 1 (2%) | 3 (6%) | 1 (2%) | –
Fibrosarcoma | – | 1 (2%) | – | 1 (2%)
Hamartoma | – | 1 (2%) | – | –
Hemangiosarcoma | – | 1 (2%) | – | –
Keratoacanthoma | 2 (4%) | – | 1 (2%) | –
Lipoma | – | – | 1 (2%) | –
Schwannoma malignant | – | 1 (2%) | 1 (2%) | 2 (4%)
Squamous cell papilloma | – | 1 (2%) | – | 2 (4%)
Pinna, squamous cell papilloma | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (49) | (50) | (50) | (50)
Skeletal muscle | (1) | (2) | (4) | (0)
Hemangiosarcoma | 1 (100%) | – | – | –
Nervous System
Brain | (49) | (50) | (50) | (50)
Glioma malignant | 1 (2%) | – | 2 (4%) | –
Granular cell tumor benign | 1 (2%) | – | – | 1 (2%)
Meninges, granular cell tumor benign | – | – | 1 (2%) | 2 (4%)
Meninges, hemangioma | – | 1 (2%) | – | –
Peripheral nerve | (2) | (1) | (3) | (0)
Spinal cord | (2) | (1) | (3) | (0)
Respiratory System
Lung | (49) | (50) | (50) | (50)
Alveolar/bronchiolar adenoma | – | 3 (6%) | – | –
Carcinoma, metastatic, adrenal cortex | – | – | – | 1 (2%)
Osteosarcoma, metastatic, lung | – | – | 1 (2%) | –
Schwannoma malignant, metastatic, skin | – | 1 (2%) | – | –
Thymoma malignant, metastatic, thymus | – | – | 1 (2%) | –
Nose | (49) | (49) | (50) | (50)
Fibrosarcoma | – | – | – | 1 (2%)
Respiratory epithelium, adenoma | – | 1 (2%) | – | –
Trachea | (49) | (46) | (50) | (49)
Special Senses System
Eye | (46) | (46) | (50) | (45)
Harderian gland | (49) | (49) | (50) | (50)
Lacrimal gland | (0) | (0) | (1) | (2)
Zymbal’s gland | (0) | (0) | (0) | (1)
Carcinoma | – | – | – | 1 (100%)
Urinary System
Kidney | (49) | (46) | (50) | (50)
Lipoma | – | – | – | 1 (2%)
Ureter | (1) | (0) | (0) | (0)
Urinary bladder | (49) | (48) | (50) | (50)
Leiomyoma | – | – | – | 1 (2%)
Systemic Lesions
Multiple organs^b^ | (49) | (50) | (50) | (50)
Histiocytic sarcoma | – | 2 (4%) | 1 (2%) | –
Leukemia | 1 (2%) | – | – | –
Lymphoma malignant | – | 4 (8%) | 1 (2%) | –
Mesothelioma malignant | – | 1 (2%) | – | 1 (2%)
Neoplasm Summary
Total animals with primary neoplasms^c^
2-Year study | 36 | 39 | 44 | 47
Total primary neoplasms
2-Year study | 71 | 68 | 76 | 88
Total animals with benign neoplasms
2-Year study | 33 | 34 | 40 | 45
Total benign neoplasms
2-Year study | 53 | 52 | 63 | 72
Total animals with malignant neoplasms
2-Year study | 13 | 14 | 10 | 12
Total malignant neoplasms
2-Year study | 18 | 16 | 13 | 16
Total animals with metastatic neoplasms
2-Year study | 1 | 1 | 3 | 1
Total metastatic neoplasms
2-Year study | 1 | 1 | 3 | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Primary Neoplasms in F_1_ Male Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Brain: Granular Cell Tumor Benign
Overall rate^a^ | 1/49 (2%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate^b^ | 2.4% | 0.0% | 2.3% | 7.5%
Terminal rate^c^ | 0/36 (0%) | 0/35 (0%) | 1/38 (3%) | 1/25 (4%)
First incidence (days) | 669 | –^e^ | 729 (T) | 558
Poly-3 test^d^ | P = 0.071 | P = 0.504N | P = 0.757N | P = 0.285
Liver: Hepatocellular Adenoma
Overall rate | 3/49 (6%) | 2/50 (4%) | 4/50 (8%) | 8/50 (16%)
Adjusted rate | 7.1% | 4.8% | 9.2% | 19.8%
Terminal rate | 3/36 (8%) | 1/35 (3%) | 4/38 (11%) | 3/25 (12%)
First incidence (days) | 729 (T) | 658 | 729 (T) | 595
Poly-3 test | P = 0.016 | P = 0.503N | P = 0.512 | P = 0.081
Liver: Hepatocellular Adenoma or Carcinoma
Overall rate | 3/49 (6%) | 2/50 (4%) | 4/50 (8%) | 9/50 (18%)
Adjusted rate | 7.1% | 4.8% | 9.2% | 22.3%
Terminal rate | 3/36 (8%) | 1/35 (3%) | 4/38 (11%) | 4/25 (16%)
First incidence (days) | 729 (T) | 658 | 729 (T) | 595
Poly-3 test | P = 0.006 | P = 0.503N | P = 0.512 | P = 0.047
Liver: Hepatocholangioma, Hepatocellular Adenoma, or Hepatocellular Carcinoma
Overall rate | 3/49 (6%) | 2/50 (4%) | 4/50 (8%) | 11/50 (22%)
Adjusted rate | 7.1% | 4.8% | 9.2% | 27.2%
Terminal rate | 3/36 (8%) | 1/35 (3%) | 4/38 (11%) | 5/25 (20%)
First incidence (days) | 729 (T) | 658 | 729 (T) | 595
Poly-3 test | P < 0.001 | P = 0.503N | P = 0.512 | P = 0.014
Lung: Alveolar/bronchiolar Adenoma
Overall rate | 0/49 (0%) | 3/50 (6%) | 0/50 (0%) | 0/50 (0%)
Adjusted rate | 0.0% | 7.2% | 0.0% | 0.0%
Terminal rate | 0/36 (0%) | 3/35 (9%) | 0/38 (0%) | 0/25 (0%)
First incidence (days) | – | 729 (T) | – | –
Poly-3 test | P = 0.249N | P = 0.116 | –^f^ | –
Mammary Gland: Fibroadenoma
Overall rate | 0/49 (0%) | 0/50 (0%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 0.0% | 0.0% | 6.9% | 0.0%
Terminal rate | 0/36 (0%) | 0/35 (0%) | 3/38 (8%) | 0/25 (0%)
First incidence (days) | – | – | 729 (T) | –
Poly-3 test | P = 0.667N | – | P = 0.122 | –
Mammary Gland: Fibroma or Fibroadenoma
Overall rate | 0/49 (0%) | 1/50 (2%) | 3/50 (6%) | 0/50 (0%)
Adjusted rate | 0.0% | 2.4% | 6.9% | 0.0%
Terminal rate | 0/36 (0%) | 0/35 (0%) | 3/38 (8%) | 0/25 (0%)
First incidence (days) | – | 592 | 729 (T) | –
Poly-3 test | P = 0.515N | P = 0.500 | P = 0.122 | –
Mesenteric Lymph Node: Hemangiosarcoma
Overall rate | 7/49 (14%) | 2/50 (4%) | 3/50 (6%) | 4/50 (8%)
Adjusted rate | 16.1% | 4.8% | 6.9% | 10.2%
Terminal rate | 5/36 (14%) | 2/35 (6%) | 3/38 (8%) | 3/25 (12%)
First incidence (days) | 515 | 729 (T) | 729 (T) | 701
Poly-3 test | P = 0.516N | P = 0.087N | P = 0.157N | P = 0.318N
Pancreas: Adenoma
Overall rate | 1/46 (2%) | 1/47 (2%) | 3/50 (6%) | 1/49 (2%)
Adjusted rate | 2.4% | 2.5% | 6.9% | 2.6%
Terminal rate | 0/36 (0%) | 1/35 (3%) | 3/38 (8%) | 1/25 (4%)
First incidence (days) | 620 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.636 | P = 0.754 | P = 0.325 | P = 0.746
Pancreatic Islets: Adenoma
Overall rate | 4/49 (8%) | 2/49 (4%) | 2/50 (4%) | 1/50 (2%)
Adjusted rate | 9.4% | 4.9% | 4.6% | 2.5%
Terminal rate | 3/36 (8%) | 2/35 (6%) | 2/38 (5%) | 1/25 (4%)
First incidence (days) | 630 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.215N | P = 0.354N | P = 0.331N | P = 0.204N
Pancreatic Islets: Adenoma or Carcinoma
Overall rate | 6/49 (12%) | 2/49 (4%) | 3/50 (6%) | 1/50 (2%)
Adjusted rate | 14.0% | 4.9% | 6.9% | 2.5%
Terminal rate | 5/36 (14%) | 2/35 (6%) | 2/38 (5%) | 1/25 (4%)
First incidence (days) | 630 | 729 (T) | 595 | 729 (T)
Poly-3 test | P = 0.111N | P = 0.144N | P = 0.229N | P = 0.069N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 19/49 (39%) | 12/49 (24%) | 22/50 (44%) | 35/50 (70%)
Adjusted rate | 40.7% | 28.1% | 47.4% | 71.7%
Terminal rate | 10/36 (28%) | 7/35 (20%) | 16/38 (42%) | 13/25 (52%)
First incidence (days) | 508 | 485 | 436 | 351
Poly-3 test | P < 0.001 | P = 0.152N | P = 0.328 | P < 0.001
Skin: Squamous Cell Papilloma, Keratoacanthoma, or Basal Cell Adenoma
Overall rate | 3/49 (6%) | 2/50 (4%) | 3/50 (6%) | 2/50 (4%)
Adjusted rate | 7.0% | 4.8% | 6.9% | 5.1%
Terminal rate | 2/36 (6%) | 2/35 (6%) | 3/38 (8%) | 2/25 (8%)
First incidence (days) | 574 | 729 (T) | 729 (T) | 729 (T)
Poly-3 test | P = 0.528N | P = 0.511N | P = 0.658N | P = 0.540N
Skin: Fibroma
Overall rate | 1/49 (2%) | 3/50 (6%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 2.4% | 7.2% | 2.3% | 0.0%
Terminal rate | 1/36 (3%) | 3/35 (9%) | 1/38 (3%) | 0/25 (0%)
First incidence (days) | 729 (T) | 729 (T) | 729 (T) | –
Poly-3 test | P = 0.177N | P = 0.300 | P = 0.756N | P = 0.515N
Skin: Fibroma or Fibrosarcoma
Overall rate | 1/49 (2%) | 4/50 (8%) | 1/50 (2%) | 1/50 (2%)
Adjusted rate | 2.4% | 9.5% | 2.3% | 2.5%
Terminal rate | 1/36 (3%) | 3/35 (9%) | 1/38 (3%) | 1/25 (4%)
First incidence (days) | 729 (T) | 585 | 729 (T) | 729 (T)
Poly-3 test | P = 0.345N | P = 0.178 | P = 0.756N | P = 0.744
Testes: Adenoma
Overall rate | 2/49 (4%) | 4/49 (8%) | 2/50 (4%) | 4/50 (8%)
Adjusted rate | 4.7% | 9.6% | 4.6% | 10.0%
Terminal rate | 1/36 (3%) | 3/35 (9%) | 2/38 (5%) | 2/25 (8%)
First incidence (days) | 620 | 585 | 729 (T) | 610
Poly-3 test | P = 0.346 | P = 0.324 | P = 0.690N | P = 0.305
Thyroid Gland (Follicular Cell): Adenoma
Overall rate | 1/45 (2%) | 3/45 (7%) | 2/48 (4%) | 6/46 (13%)
Adjusted rate | 2.5% | 7.6% | 4.7% | 16.1%
Terminal rate | 1/36 (3%) | 2/35 (6%) | 2/38 (5%) | 4/25 (16%)
First incidence (days) | 729 (T) | 647 | 729 (T) | 609
Poly-3 test | P = 0.028 | P = 0.297 | P = 0.518 | P = 0.042
Thyroid Gland (Follicular Cell): Adenoma or Carcinoma
Overall rate | 1/45 (2%) | 5/45 (11%) | 3/48 (6%) | 6/46 (13%)
Adjusted rate | 2.5% | 12.6% | 7.0% | 16.1%
Terminal rate | 1/36 (3%) | 4/35 (11%) | 3/38 (8%) | 4/25 (16%)
First incidence (days) | 729 (T) | 647 | 729 (T) | 609
Poly-3 test | P = 0.089 | P = 0.095 | P = 0.324 | P = 0.042
Thyroid Gland (C-Cell): Adenoma
Overall rate | 11/45 (24%) | 12/45 (27%) | 11/48 (23%) | 6/46 (13%)
Adjusted rate | 27.1% | 29.5% | 25.2% | 16.3%
Terminal rate | 11/36 (31%) | 9/35 (26%) | 9/38 (24%) | 5/25 (20%)
First incidence (days) | 729 (T) | 485 | 592 | 698
Poly-3 test | P = 0.116N | P = 0.503 | P = 0.521N | P = 0.190N
Thyroid Gland (C-Cell): Adenoma or Carcinoma
Overall rate | 11/45 (24%) | 12/45 (27%) | 11/48 (23%) | 7/46 (15%)
Adjusted rate | 27.1% | 29.5% | 25.2% | 19.0%
Terminal rate | 11/36 (31%) | 9/35 (26%) | 9/38 (24%) | 6/25 (24%)
First incidence (days) | 729 (T) | 485 | 592 | 698
Poly-3 test | P = 0.190N | P = 0.503 | P = 0.521N | P = 0.282N
All Organs: Hemangiosarcoma
Overall rate | 8/49 (16%) | 3/50 (6%) | 3/50 (6%) | 5/50 (10%)
Adjusted rate | 18.4% | 7.2% | 6.9% | 12.5%
Terminal rate | 6/36 (17%) | 3/35 (9%) | 3/38 (8%) | 3/25 (12%)
First incidence (days) | 515 | 729 (T) | 729 (T) | 595
Poly-3 test | P = 0.524N | P = 0.109N | P = 0.098N | P = 0.332N
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 9/49 (18%) | 4/50 (8%) | 5/50 (10%) | 6/50 (12%)
Adjusted rate | 20.7% | 9.6% | 11.4% | 15.1%
Terminal rate | 7/36 (19%) | 4/35 (11%) | 4/38 (11%) | 4/25 (16%)
First incidence (days) | 515 | 729 (T) | 476 | 595
Poly-3 test | P = 0.528N | P = 0.127N | P = 0.183N | P = 0.349N
All Organs: Malignant Lymphoma
Overall rate | 0/49 (0%) | 4/50 (8%) | 1/50 (2%) | 0/50 (0%)
Adjusted rate | 0.0% | 9.4% | 2.3% | 0.0%
Terminal rate | 0/36 (0%) | 2/35 (6%) | 1/38 (3%) | 0/25 (0%)
First incidence (days) | – | 549 | 729 (T) | –
Poly-3 test | P = 0.195N | P = 0.060 | P = 0.504 | –
All Organs: Benign Neoplasms
Overall rate | 33/49 (67%) | 34/50 (68%) | 40/50 (80%) | 45/50 (90%)
Adjusted rate | 70.3% | 74.8% | 83.9% | 91.7%
Terminal rate | 23/36 (64%) | 26/35 (74%) | 32/38 (84%) | 21/25 (84%)
First incidence (days) | 508 | 301 | 436 | 351
Poly-3 test | P = 0.004 | P = 0.404 | P = 0.088 | P = 0.006
All Organs: Malignant Neoplasms
Overall rate | 13/49 (27%) | 14/50 (28%) | 11/50 (22%) | 12/50 (24%)
Adjusted rate | 29.8% | 31.5% | 23.8% | 28.9%
Terminal rate | 10/36 (28%) | 8/35 (23%) | 6/38 (16%) | 6/25 (24%)
First incidence (days) | 515 | 465 | 289 | 310
Poly-3 test | P = 0.491N | P = 0.522 | P = 0.344N | P = 0.559N
All Organs: Benign or Malignant Neoplasms
Overall rate | 36/49 (73%) | 39/50 (78%) | 44/50 (88%) | 47/50 (94%)
Adjusted rate | 76.7% | 82.3% | 88% | 94%
Terminal rate | 26/36 (72%) | 27/35 (77%) | 32/38 (84%) | 22/25 (88%)
First incidence (days) | 508 | 301 | 289 | 310
Poly-3 test | P = 0.015 | P = 0.339 | P = 0.116 | P = 0.015

(T) Terminal kill.

^a^ Number of neoplasm-bearing animals/number of animals examined. Denominator is number of animals examined microscopically for brain, liver, lung, pancreas, pancreatic islets, pituitary gland, testes, and thyroid gland; for other tissues, denominator is number of animals necropsied.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at terminal kill.

^d^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A negative trend or a lower incidence in a dose group is indicated by N.

^e^ Not applicable; no neoplasms in animal group.

^f^ Value of statistic cannot be computed.

Table A-3 Historical Incidence of Liver Neoplasms in Control Male Wistar Han Rats^a^

Study (Study Start) | Hepatocholangioma | Hepatocellular Adenoma | Hepatocellular Carcinoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (August 2008) | 0/49 | 3/49 | 0/49
Tetrabromobisphenol A (July 2007) | 0/50 | 0/50 | 0/50
Total (%) | 0/99 | 3/99 (3.0%) | 0/99
Mean ± standard deviation | – | 3.1% ± 4.3% | –
Range | – | 0%–6% | –
Overall Historical Incidence: All Routes
Total (%) | 0/299 | 4/299 (1.3%) | 0/299
Mean ± standard deviation | – | 1.4% ± 2.5% | –
Range | – | 0%–6% | –
| Hepatocellular Adenoma or Hepatocellular Carcinoma | Hepatocholangioma, Hepatocellular Adenoma, or Hepatocellular Carcinoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (August 2008) | 3/49 | 3/49
Tetrabromobisphenol A (July 2007) | 0/50 | 0/50
Total (%) | 3/99 (3.0%) | 3/99 (3.0%)
Mean ± standard deviation | 3.1% ± 4.3% | 3.1% ± 4.3%
Range | 0%–6% | 0%–6%
Overall Historical Incidence: All Routes
Total (%) | 4/299 (1.3%) | 4/299 (1.3%)
Mean ± standard deviation | 1.4% ± 2.5% | 1.4% ± 2.5%
Range | 0%–6% | 0%–6%

^a^ Data as of November 2014.

Table A-4 Historical Incidence of Thyroid Gland Neoplasms in Control Male Wistar Han Rats^a^

Study (Study Start) | Follicular Cell Adenoma | Follicular Cell Carcinoma | Follicular Cell Adenoma or Follicular Cell Carcinoma
Historical Incidence: Corn Oil Gavage Studies
DE-71 (August 2008) | 1/45 | 0/45 | 1/45
Tetrabromobisphenol A (July 2007) | 3/50 | 0/50 | 3/50
Total (%) | 4/95 (4.2%) | 0/95 | 4/95 (4.2%)
Mean ± standard deviation | 4.1% ± 2.7% | – | 4.1% ± 2.7%
Range | 2%–6% | – | 2%–6%
Overall Historical Incidence: All Routes
Total (%) | 5/295 (1.7%) | 0/295 | 5/295 (1.7%)
Mean ± standard deviation | 1.7% ± 2.4% | – | 1.7% ± 2.4%
Range | 0%–6% | – | 0%–6%

^a^ Data as of November 2014.

Table A-5 Historical Incidence of Pituitary Gland (Pars Distalis) Adenoma in Control Male Wistar Han Rats^a^

Study (Study Start) | Incidence in Controls
Historical Incidence: Corn Oil Gavage Studies
DE-71 (August 2008) | 19/49
Tetrabromobisphenol A (July 2007) | 21/50
Total (%) | 40/99 (40.4%)
Mean ± standard deviation | 40.4% ± 2.3%
Range | 39%–42%
Overall Historical Incidence: All Routes
Total (%) | 101/298 (33.9%)
Mean ± standard deviation | 33.9% ± 5.7%
Range | 28%–42%

^a^ Data as of November 2014.

Table A-6 Summary of the Incidence of Nonneoplastic Lesions in F_1_ Male Wistar Han Rats in the Two-year Perinatal and Postnatal Gavage Study of DE-71^a^

| Vehicle Control | 3 mg/kg | 15 mg/kg | 50 mg/kg
Disposition Summary
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation | 10 | – | – | 10
Early deaths
Accidental deaths | 1 | 1 | – | 1
Moribund | 8 | 7 | 10 | 12
Natural deaths | 4 | 7 | 2 | 12
Survivors
Terminal kill | 36 | 35 | 38 | 25
Other | 1 | – | – | –
Animals examined microscopically | 59 | 50 | 50 | 60
Three-month Interim Evaluation
Alimentary System
Esophagus | (10) | | | (10)
Intestine large, cecum | (10) | | | (10)
Intestine large, colon | (10) | | | (10)
Intestine large, rectum | (10) | | | (10)
Intestine small, duodenum | (10) | | | (10)
Intestine small, ileum | (10) | | | (10)
Intestine small, jejunum | (10) | | | (10)
Liver | (10) | | | (10)
Fatty change | 2 (20%) | | | 8 (80%)
Hepatocyte, hypertrophy | – | | | 10 (100%)
Mesentery | (0) | | | (1)
Fibrosis, focal | – | | | 1 (100%)
Oral mucosa | (0) | | | (1)
Pancreas | (10) | | | (10)
Atrophy | 1 (10%) | | | 2 (20%)
Salivary glands | (10) | | | (10)
Stomach, forestomach | (10) | | | (10)
Stomach, glandular | (10) | | | (10)
Cardiovascular System
Blood vessel | (0) | | | (1)
Heart | (10) | | | (10)
Cardiomyopathy | 1 (10%) | | | –
Endocrine System
Adrenal cortex | (10) | | | (10)
Accessory adrenal cortical nodule | 1 (10%) | | | 2 (20%)
Vacuolization cytoplasmic | 1 (10%) | | | 1 (10%)
Adrenal medulla | (10) | | | (10)
Vacuolization cytoplasmic | – | | | 1 (10%)
Islets, pancreatic | (10) | | | (10)
Parathyroid gland | (10) | | | (10)
Pituitary gland | (10) | | | (9)
Thyroid gland | (10) | | | (10)
Follicle, hypertrophy | – | | | 4 (40%)
Genital System
Epididymis | (10) | | | (10)
Preputial gland | (10) | | | (10)
Inflammation, chronic | 9 (90%) | | | 8 (80%)
Prostate | (10) | | | (10)
Inflammation, chronic | 2 (20%) | | | 3 (30%)
Seminal vesicle | (10) | | | (10)
Testes | (10) | | | (10)
Hematopoietic System
Bone marrow | (10) | | | (10)
Lymph node | (1) | | | (1)
Pigmentation | – | | | 1 (100%)
Lymph node, mandibular | (10) | | | (10)
Lymph node, mesenteric | (10) | | | (10)
Spleen | (10) | | | (10)
Thymus | (10) | | | (10)
Respiratory System
Lung | (10) | | | (10)
Inflammation, chronic | 2 (20%) | | | 4 (40%)
Metaplasia, osseous | – | | | 1 (10%)
Alveolus, infiltration cellular, histiocyte | – | | | 1 (10%)
Nose | (10) | | | (10)
Trachea | (10) | | | (10)
Urinary System
Kidney | (10) | | | (10)
Casts protein | – | | | 1 (10%)
Hydronephrosis | 1 (10%) | | | 3 (30%)
Inflammation, chronic | 1 (10%) | | | –
Renal tubule, vacuolization cytoplasmic | – | | | 1 (10%)
Urinary bladder | (10) | | | (10)
Systems Examined at Three Months with No Lesions Observed
General Body System
Integumentary System
Musculoskeletal System
Nervous System
Special Senses System
Two-year Study
Alimentary System
Esophagus | (49) | (50) | (50) | (50)
Hyperkeratosis | 1 (2%) | 1 (2%) | – | –
Inflammation, acute | – | – | – | 1 (2%)
Ulcer | – | – | – | 1 (2%)
Muscularis, degeneration | – | 1 (2%) | – | –
Muscularis, hemorrhage | – | 1 (2%) | – | –
Periesophageal tissue, inflammation, granulomatous, chronic | 1 (2%) | – | – | –
Intestine large, cecum | (46) | (43) | (49) | (43)
Inflammation, chronic | – | 1 (2%) | – | –
Intestine large, colon | (48) | (45) | (50) | (48)
Inflammation, chronic | – | 1 (2%) | – | –
Intestine large, rectum | (48) | (46) | (49) | (47)
Inflammation, acute | – | – | – | 2 (4%)
Intestine small, duodenum | (46) | (45) | (49) | (46)
Inflammation, acute | – | – | – | 1 (2%)
Epithelium, vacuolization cytoplasmic | 1 (2%) | – | – | –
Intestine small, ileum | (45) | (43) | (49) | (42)
Inflammation, focal, chronic active | – | – | 1 (2%) | –
Peyer’s patch, hyperplasia | – | – | 1 (2%) | –
Intestine small, jejunum | (45) | (44) | (50) | (46)
Ulcer | – | 1 (2%) | – | –
Epithelium, vacuolization cytoplasmic | 1 (2%) | – | – | –
Peyer’s patch, hyperplasia | – | – | 1 (2%) | –
Liver | (49) | (50) | (50) | (50)
Angiectasis | – | – | 1 (2%) | 1 (2%)
Basophilic focus | 8 (16%) | 4 (8%) | 3 (6%) | 7 (14%)
Basophilic focus, multiple | 8 (16%) | 17 (34%) | 8 (16%) | 4 (8%)
Cholangiofibrosis | – | – | 1 (2%) | 1 (2%)
Clear cell focus | 1 (2%) | 1 (2%) | – | 2 (4%)
Clear cell focus, multiple | 38 (78%) | 36 (72%) | 35 (70%) | 27 (54%)
Congestion | 4 (8%) | 3 (6%) | – | 2 (4%)
Degeneration, cystic | – | – | 1 (2%) | 1 (2%)
Eosinophilic focus | 3 (6%) | 2 (4%) | 10 (20%) | 7 (14%)
Eosinophilic focus, multiple | – | 1 (2%) | 2 (4%) | 8 (16%)
Fatty change | 32 (65%) | 37 (74%) | 48 (96%) | 48 (96%)
Fibrosis | 1 (2%) | – | – | 1 (2%)
Hematopoietic cell proliferation | – | – | 1 (2%) | –
Hemorrhage | 2 (4%) | – | 1 (2%) | –
Hepatodiaphragmatic nodule | – | 1 (2%) | – | 1 (2%)
Hyperplasia, nodular | – | – | 3 (6%) | –
Inflammation, chronic | 1 (2%) | 2 (4%) | – | 5 (10%)
Mixed cell focus | 2 (4%) | 2 (4%) | – | 2 (4%)
Mixed cell focus, multiple | – | 1 (2%) | 1 (2%) | 2 (4%)
Pigmentation | – | – | 1 (2%) | 6 (12%)
Thrombosis | 1 (2%) | – | – | –
Artery, degeneration | – | – | 1 (2%) | –
Artery, inflammation, chronic | – | – | – | 1 (2%)
Bile duct, cyst | – | – | – | 1 (2%)
Bile duct, hyperplasia | 16 (33%) | 17 (34%) | 16 (32%) | 16 (32%)
Hepatocyte, hypertrophy | 1 (2%) | 44 (88%) | 50 (100%) | 50 (100%)
Hepatocyte, necrosis | 4 (8%) | 2 (4%) | 1 (2%) | 5 (10%)
Oval cell, hyperplasia | – | – | 2 (4%) | 3 (6%)
Mesentery | (12) | (6) | (13) | (10)
Hemorrhage | 2 (17%) | 1 (17%) | – | 1 (10%)
Inflammation, chronic | – | – | 1 (8%) | –
Fat, necrosis | 9 (75%) | 5 (83%) | 11 (85%) | 9 (90%)
Oral mucosa | (1) | (0) | (0) | (0)
Pancreas | (46) | (47) | (50) | (49)
Atrophy | 3 (7%) | 5 (11%) | 7 (14%) | 1 (2%)
Basophilic focus | – | – | 1 (2%) | –
Basophilic focus, multiple | – | – | – | 1 (2%)
Hyperplasia | – | 1 (2%) | 2 (4%) | 1 (2%)
Inflammation, acute | – | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Pigmentation, hemosiderin | 1 (2%) | – | – | –
Duct, cyst | – | 1 (2%) | – | –
Duct, cyst, multiple | – | – | 2 (4%) | –
Salivary glands | (46) | (48) | (50) | (50)
Duct, parotid gland, cyst | – | 1 (2%) | 2 (4%) | –
Duct, parotid gland, inflammation, acute | 1 (2%) | 1 (2%) | – | 4 (8%)
Duct, submandibular gland, inflammation, acute | – | – | – | 1 (2%)
Parotid gland, atrophy | 2 (4%) | 2 (4%) | 4 (8%) | 13 (26%)
Parotid gland, basophilic focus | – | – | – | 1 (2%)
Parotid gland, hyperplasia, focal | 1 (2%) | – | – | –
Parotid gland, inflammation, chronic | 1 (2%) | 1 (2%) | 1 (2%) | –
Parotid gland, vacuolization cytoplasmic | 4 (9%) | 4 (8%) | 7 (14%) | 17 (34%)
Sublingual gland, atrophy | – | – | – | 1 (2%)
Sublingual gland, vacuolization cytoplasmic | – | – | – | 1 (2%)
Submandibular gland, inflammation, acute | – | – | – | 1 (2%)
Submandibular gland, inflammation, chronic | – | 1 (2%) | – | –
Submandibular gland, vacuolization cytoplasmic | – | – | – | 1 (2%)
Stomach, forestomach | (49) | (50) | (50) | (50)
Edema | – | 1 (2%) | – | 2 (4%)
Erosion | 1 (2%) | 1 (2%) | – | –
Hyperkeratosis | 9 (18%) | 5 (10%) | 5 (10%) | 17 (34%)
Inflammation, acute | 1 (2%) | 2 (4%) | 1 (2%) | 4 (8%)
Inflammation, chronic | 3 (6%) | 1 (2%) | 2 (4%) | 4 (8%)
Inflammation, chronic active | 3 (6%) | 2 (4%) | 2 (4%) | 3 (6%)
Ulcer | 3 (6%) | 1 (2%) | 3 (6%) | 5 (10%)
Epithelium, hyperplasia | 8 (16%) | 6 (12%) | 5 (10%) | 17 (34%)
Stomach, glandular | (48) | (46) | (50) | (49)
Cyst | – | – | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | –
Inflammation, multifocal, chronic | – | 1 (2%) | – | –
Inflammation, acute | – | – | 1 (2%) | 2 (4%)
Inflammation, chronic | – | – | – | 1 (2%)
Mineralization | 7 (15%) | 3 (7%) | 5 (10%) | 2 (4%)
Tongue | (0) | (1) | (0) | (0)
Infiltration cellular | – | 1 (100%) | – | –
Tooth | (1) | (0) | (0) | (0)
Cardiovascular System
Blood vessel | (0) | (2) | (0) | (0)
Angiectasis | – | 1 (50%) | – | –
Heart | (49) | (50) | (50) | (50)
Cardiomyopathy | 33 (67%) | 32 (64%) | 34 (68%) | 29 (58%)
Inflammation, acute | – | – | – | 1 (2%)
Necrosis, multifocal | – | – | – | 1 (2%)
Pigmentation, hemosiderin | – | – | – | 1 (2%)
Thrombosis | – | – | – | 1 (2%)
Endocardium, hyperplasia | – | 1 (2%) | – | –
Epicardium, inflammation, granulomatous | 1 (2%) | – | – | –
Epicardium, inflammation, chronic | – | – | – | 1 (2%)
Pericardium, inflammation, granulomatous | – | – | – | 1 (2%)
Pericardium, necrosis | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (49) | (49) | (50) | (49)
Accessory adrenal cortical nodule | – | – | – | 1 (2%)
Angiectasis | 13 (27%) | 17 (35%) | 15 (30%) | 18 (37%)
Degeneration, cystic | 1 (2%) | – | – | –
Hyperplasia, focal | 13 (27%) | 10 (20%) | 18 (36%) | 16 (33%)
Hypertrophy, focal | 9 (18%) | 11 (22%) | 7 (14%) | 8 (16%)
Necrosis, focal | – | – | – | 1 (2%)
Vacuolization cytoplasmic | 12 (24%) | 9 (18%) | 10 (20%) | 17 (35%)
Adrenal medulla | (49) | (48) | (50) | (49)
Infiltration cellular, eosinophil | – | 1 (2%) | – | –
Islets, pancreatic | (49) | (49) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | 1 (2%)
Parathyroid gland | (47) | (49) | (50) | (50)
Cyst | – | 2 (4%) | – | 1 (2%)
Cyst, multiple | 1 (2%) | – | – | –
Hyperplasia, focal | – | 1 (2%) | 2 (4%) | –
Pituitary gland | (49) | (49) | (50) | (50)
Pars distalis, cyst | 3 (6%) | 3 (6%) | 4 (8%) | 4 (8%)
Pars distalis, cyst, multiple | 1 (2%) | – | 1 (2%) | –
Pars distalis, hyperplasia, focal | 15 (31%) | 11 (22%) | 13 (26%) | 8 (16%)
Pars intermedia, cyst | – | – | 1 (2%) | –
Pars intermedia, hemorrhage | 1 (2%) | – | – | –
Pars intermedia, hyperplasia, focal | 2 (4%) | – | 1 (2%) | –
Pars nervosa, inflammation, chronic | 2 (4%) | – | – | 2 (4%)
Thyroid gland | (45) | (45) | (48) | (46)
Cyst | 1 (2%) | 1 (2%) | – | –
Mineralization | – | – | 1 (2%) | –
C-cell, hyperplasia | 44 (98%) | 41 (91%) | 47 (98%) | 44 (96%)
Follicle, hypertrophy | 1 (2%) | 26 (58%) | 34 (71%) | 23 (50%)
Follicular cell, hyperplasia | 8 (18%) | 5 (11%) | 5 (10%) | 7 (15%)
General Body System
Tissue NOS | (3) | (3) | (2) | (1)
Fibrosis | 1 (33%) | – | 1 (50%) | 1 (100%)
Inflammation, chronic active | 1 (33%) | – | – | –
Fat, necrosis | – | 1 (33%) | – | –
Genital System
Epididymis | (49) | (50) | (50) | (50)
Inflammation, chronic | – | – | – | 3 (6%)
Vacuolization cytoplasmic | 1 (2%) | – | – | –
Bilateral, granuloma sperm | – | 1 (2%) | – | –
Preputial gland | (49) | (49) | (50) | (50)
Inflammation, granulomatous, chronic | 1 (2%) | – | – | –
Inflammation, chronic | 3 (6%) | 2 (4%) | – | 2 (4%)
Inflammation, chronic active | – | 4 (8%) | 6 (12%) | 2 (4%)
Mineralization | 1 (2%) | – | – | –
Duct, ectasia | 2 (4%) | 2 (4%) | 5 (10%) | 15 (30%)
Prostate | (49) | (50) | (50) | (50)
Hyperplasia | 1 (2%) | – | – | –
Inflammation, granulomatous | 1 (2%) | – | – | –
Inflammation, chronic active | 17 (35%) | 20 (40%) | 28 (56%) | 27 (54%)
Mineralization | – | – | 1 (2%) | –
Vacuolization cytoplasmic | – | – | – | 1 (2%)
Epithelium, hyperplasia | – | 1 (2%) | – | –
Seminal vesicle | (49) | (46) | (50) | (49)
Hyperplasia | – | – | – | 1 (2%)
Inflammation, acute | 1 (2%) | 1 (2%) | – | 2 (4%)
Inflammation, chronic active | – | 1 (2%) | 1 (2%) | 1 (2%)
Testes | (49) | (49) | (50) | (50)
Cyst | – | – | – | 1 (2%)
Degeneration | 14 (29%) | 11 (22%) | 12 (24%) | 6 (12%)
Inflammation, acute | – | – | 1 (2%) | –
Mineralization | – | – | 1 (2%) | –
Interstitial cell, hyperplasia, focal | – | – | 1 (2%) | –
Interstitial cell, hyperplasia, multifocal | – | 1 (2%) | – | –
Hematopoietic System
Bone marrow | (49) | (48) | (50) | (50)
Hyperplasia | – | 1 (2%) | – | –
Lymph node | (2) | (6) | (5) | (6)
Ectasia | – | 1 (17%) | – | –
Mediastinal, congestion | – | 1 (17%) | – | –
Mediastinal, ectasia | – | – | 2 (40%) | 2 (33%)
Mediastinal, hemorrhage | 1 (50%) | 2 (33%) | 1 (20%) | 2 (33%)
Mediastinal, hyperplasia, plasma cell | 1 (50%) | – | – | –
Mediastinal, pigmentation, hemosiderin | – | 1 (17%) | 1 (20%) | 1 (17%)
Pancreatic, ectasia | – | – | 1 (20%) | –
Pancreatic, inflammation, chronic | – | – | – | 1 (17%)
Renal, ectasia | – | 1 (17%) | – | –
Lymph node, mandibular | (48) | (49) | (50) | (50)
Angiectasis | – | 1 (2%) | – | –
Ectasia | 2 (4%) | 7 (14%) | 8 (16%) | 7 (14%)
Hemorrhage | 4 (8%) | 1 (2%) | 2 (4%) | 1 (2%)
Hyperplasia, plasma cell | – | – | 1 (2%) | –
Pigmentation, hemosiderin | 1 (2%) | – | – | –
Lymph node, mesenteric | (49) | (49) | (50) | (50)
Ectasia | – | 2 (4%) | 2 (4%) | 1 (2%)
Hemorrhage | 2 (4%) | 1 (2%) | 1 (2%) | 4 (8%)
Pigmentation, hemosiderin | – | – | 2 (4%) | –
Spleen | (47) | (46) | (50) | (49)
Accessory spleen | – | – | 1 (2%) | –
Fibrosis, focal | 1 (2%) | – | 1 (2%) | –
Hematopoietic cell proliferation | 23 (49%) | 30 (65%) | 22 (44%) | 13 (27%)
Hemorrhage, focal | 1 (2%) | – | – | 1 (2%)
Pigmentation | 12 (26%) | 11 (24%) | 17 (34%) | 27 (55%)
Lymphoid follicle, atrophy | – | – | 1 (2%) | 5 (10%)
Thymus | (45) | (49) | (49) | (50)
Atrophy | 14 (31%) | 11 (22%) | 15 (31%) | 26 (52%)
Ectopic parathyroid gland | – | – | 3 (6%) | 2 (4%)
Fibrosis | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | 3 (6%) | 1 (2%) | 3 (6%)
Integumentary System
Mammary gland | (33) | (38) | (39) | (41)
Cyst | – | – | 1 (3%) | –
Galactocele | – | 1 (3%) | – | 1 (2%)
Hyperplasia | – | – | 3 (8%) | –
Pigmentation, hemosiderin | 3 (9%) | 9 (24%) | 2 (5%) | 13 (32%)
Duct, dilatation | 4 (12%) | 1 (3%) | 1 (3%) | 1 (2%)
Skin | (49) | (49) | (50) | (50)
Cyst epithelial inclusion | 1 (2%) | 3 (6%) | 1 (2%) | –
Fibrosis | – | 1 (2%) | – | –
Hyperkeratosis | – | 3 (6%) | – | –
Inflammation, granulomatous | – | – | 1 (2%) | –
Inflammation, acute | 1 (2%) | 1 (2%) | – | –
Inflammation, chronic | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | 3 (6%) | – | –
Pigmentation | – | – | – | 1 (2%)
Ulcer | 1 (2%) | 2 (4%) | – | –
Epidermis, hyperplasia | – | 4 (8%) | – | –
Musculoskeletal System
Bone | (49) | (50) | (50) | (50)
Skeletal muscle | (1) | (2) | (4) | (0)
Fibrosis | – | – | 1 (25%) | –
Inflammation, chronic active | – | – | 1 (25%) | –
Nervous System
Brain | (49) | (50) | (50) | (50)
Compression | 10 (20%) | 9 (18%) | 10 (20%) | 26 (52%)
Meninges, hyperplasia, granulocytic | – | – | 1 (2%) | –
Peripheral nerve | (2) | (1) | (3) | (0)
Spinal cord | (2) | (1) | (3) | (0)
Respiratory System
Lung | (49) | (50) | (50) | (50)
Hemorrhage | – | – | 1 (2%) | –
Infiltration cellular, histiocyte | 24 (49%) | 24 (48%) | 32 (64%) | 30 (60%)
Inflammation, granulomatous, multifocal | 1 (2%) | – | – | –
Inflammation, acute | 2 (4%) | 1 (2%) | – | 1 (2%)
Inflammation, chronic | 4 (8%) | – | – | 1 (2%)
Mineralization | – | – | 2 (4%) | –
Alveolar epithelium, hyperplasia | 2 (4%) | 3 (6%) | 1 (2%) | 5 (10%)
Artery, mineralization | – | – | – | 1 (2%)
Bronchus, hyperplasia, lymphoid | – | – | – | 2 (4%)
Mediastinum, inflammation, granulomatous | 1 (2%) | – | – | –
Serosa, fibrosis | – | – | – | 1 (2%)
Vein, mineralization | – | 1 (2%) | – | –
Nose | (49) | (49) | (50) | (50)
Fungus | 2 (4%) | – | 1 (2%) | 1 (2%)
Inflammation, acute | 2 (4%) | – | 2 (4%) | 2 (4%)
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%)
Ulcer, multifocal | – | – | – | 1 (2%)
Squamous epithelium, cyst | 1 (2%) | – | – | –
Trachea | (49) | (46) | (50) | (49)
Inflammation, acute | 1 (2%) | – | – | –
Special Senses System
Eye | (46) | (46) | (50) | (45)
Retina, atrophy | 6 (13%) | 8 (17%) | 8 (16%) | 3 (7%)
Harderian gland | (49) | (49) | (50) | (50)
Atrophy | – | – | 1 (2%) | –
Hyperplasia, focal | 1 (2%) | – | – | –
Lacrimal gland | (0) | (0) | (1) | (2)
Inflammation, chronic | – | – | 1 (100%) | 1 (50%)
Karyomegaly | – | – | 1 (100%) | 2 (100%)
Zymbal’s gland | (0) | (0) | (0) | (1)
Urinary System
Kidney | (49) | (46) | (50) | (50)
Bacterium | – | – | 1 (2%) | –
Casts protein | – | – | – | 1 (2%)
Cyst | 1 (2%) | – | 3 (6%) | –
Cyst, multiple | – | – | 1 (2%) | –
Hydronephrosis | 1 (2%) | 5 (11%) | 8 (16%) | 10 (20%)
Hyperplasia, oncocytic | – | – | – | 1 (2%)
Inflammation, acute | – | – | 1 (2%) | 1 (2%)
Inflammation, chronic | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | – | –
Nephropathy | 37 (76%) | 35 (76%) | 32 (64%) | 37 (74%)
Vacuolization cytoplasmic | – | – | – | 1 (2%)
Pelvis, inflammation, acute | – | – | – | 1 (2%)
Pelvis, inflammation, chronic active | 22 (45%) | 14 (30%) | 8 (16%) | 2 (4%)
Pelvis, mineralization | 18 (37%) | 5 (11%) | 5 (10%) | 3 (6%)
Renal tubule, dilatation | – | – | 1 (2%) | –
Renal tubule, hyperplasia | 1 (2%) | – | – | –
Transitional epithelium, hyperplasia | – | 1 (2%) | – | 1 (2%)
Ureter | (1) | (0) | (0) | (0)
Cyst | 1 (100%) | – | – | –
Urinary bladder | (49) | (48) | (50) | (50)
Calculus gross observation | – | – | – | 1 (2%)
Inflammation, chronic | – | 1 (2%) | – | 1 (2%)
Ulcer | – | – | 1 (2%) | –
Transitional epithelium, hyperplasia | – | 1 (2%) | 1 (2%) | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.