# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-588

Report Series: NTP Technical Report Series

Report Series Number: 588

Official citation: National Toxicology Program (NTP). 2014. NTP technical report on the toxicology and carcinogenesis studies of glycidamide (CASRN 5694-00-8) in F344/N Nctr rats and B6C3F1/Nctr mice (drinking water studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 588.