# Collaborators

- National Center for Toxicological Research, Food and Drug Administration
  Conducted study, evaluated and interpreted results and pathology findings, reported findings and prepared study report
  F.A. Beland, Ph.D., Study Scientist
  D.R. Doerge, Ph.D., Co-Investigator
  L.P. McDaniel, B.S., Study Coordinator
- Conducted microbiology surveillance and diagnostics
  R.M. Colvert, B.S.
  M.A. Holland, B.S.
  D.D. Paine, B.S.
  L.M. Sims, B.S.
  R.S. Steele, B.S.
  C.V. Summage-West, B.S.
  R.D. Wagner, Ph.D.
- Conducted dose certifications and chemical analyses
  S.M. Billedeau, M.S.
  C.R. Cozart, B.S.
  F.E. Evans, Ph.D.
  J.P. Freeman, Ph.D.
  T.M. Heinze, M.S.
  J.J. James, B.S.
  P.H. Siitonen, B.S.
- Conducted statistical analyses
  M.C.B. Mendoza, Ph.D.
- Conducted quality assurance audits
  J.M. Fowler, B.S.
  Y.E. Whiteside, B.S.
- Prepared technical report
  A.R. Babb, B.S.
  S.C. Matson, Ph.D.
  R.L. Stingley, Ph.D., Project Leader
- Toxicologic Pathology Associates
  Evaluated pathology findings
  G.R. Olson, D.V.M., Ph.D., Study Pathologist
  A. Warbritton
  L. Wiley, B.S.
- National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Reviewed and evaluated the technical report, interpreted results and reported findings
  C.J. Alden, Ph.D.
  B.J. Collins, M.S.P.H.
  J.K. Dunnick, Ph.D.
  P.M. Foster, Ph.D.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  G.S. Travlos, D.V.M.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review and coordinated NTP Pathology Working Groups (March and April 2010)
  J.F. Hardisty, D.V.M., Pathology Quality Assessment Pathologist (Mice)
  R.R. Maronpot, D.V.M., M.S., M.P.H., Pathology Quality Assessment Pathologist (Male Rats) and PWG Coordinator (April 2010 Rats)
  R.A. Miller, D.V.M., Ph.D., Quality Assessment Pathologist (Female Rats) and PWG Coordinator (April 2010 Mouse)
- Charles Rivers Laboratories, Pathology Associates, Research Triangle Park, North Carolina, USA
  Coordinated NTP neuropathology working group (November 2010)
  M.P. Jokinen, D.V.M., Coordinator (Rat), Charles Rivers Laboratories, Pathology Associates
  J.P. Morrison, D.V.M., Ph.D., Coordinator (Mouse), Charles Rivers Laboratories, Pathology Associates