# References

1 Payne GB Williams PH Reactions of hydrogen peroxide. VI. Alkaline epoxidation of acrylonitrile. J Org Chem. 1961;26(3):651–659. 10.1021/jo01062a003
2 Becke F, Buckschewski H, Sander B. inventors. Production of glycidamide. United States patent 3217016; 1965
3 Shipp A Lawrence G Gentry R McDonald T Bartow H Bounds J Macdonald N Clewell H Allen B Van Landingham C Acrylamide: review of toxicity data and dose-response analyses for cancer and noncancer effects. Crit Rev Toxicol. 2006;36(6-7):481–608. http://dx.doi.org/10.1080/10408440600851377 16973444
4 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of acrylamide (CASRN 79-06-1) in F344/N rats and B6C3F1 mice (feed and drinking water studies). Research Triangle Park, NC: National Institutes of Health, Public Health Service, U.S. Department of Health and Human Services; 2012. Technical Report Series No. 575. NIH Publication No. 12-5917.
5 Granvogl M Koehler P Latzer L Schieberle P Development of a stable isotope dilution assay for the quantitation of glycidamide and its application to foods and model systems. J Agric Food Chem. 2008;56(15):6087–6092. http://dx.doi.org/10.1021/jf800280b 18624425
6 Doerge DR Young JF McDaniel LP Twaddle NC Churchwell MI Toxicokinetics of acrylamide and glycidamide in B6C3F1 mice. Toxicol Appl Pharmacol. 2005;202(3):258–267. http://dx.doi.org/10.1016/j.taap.2004.07.001 15667831
7 Doerge DR Young JF McDaniel LP Twaddle NC Churchwell MI Toxicokinetics of acrylamide and glycidamide in Fischer 344 rats. Toxicol Appl Pharmacol. 2005;208(3):199–209. http://dx.doi.org/10.1016/j.taap.2005.03.003 16239164
8 Sumner SCJ MacNeela JP Fennell TR Characterization and quantitation of urinary metabolites of [1,2,3-13C]acrylamide in rats and mice using 13C nuclear magnetic resonance spectroscopy. Chem Res Toxicol. 1992;5(1):81–89. http://dx.doi.org/10.1021/tx00025a014 1581543
9 Sumner SC Fennell TR Moore TA Chanas B Gonzalez F Ghanayem BI Role of cytochrome P450 2E1 in the metabolism of acrylamide and acrylonitrile in mice. Chem Res Toxicol. 1999;12(11):1110–1116. http://dx.doi.org/10.1021/tx990040k 10563837
10 Doerge DR Twaddle NC Boettcher MI McDaniel LP Angerer J Urinary excretion of acrylamide and metabolites in Fischer 344 rats and B6C3F(1) mice administered a single dose of acrylamide. Toxicol Lett. 2007;169(1):34–42. http://dx.doi.org/10.1016/j.toxlet.2006.12.002 17224249
11 Fennell TR Sumner SC Snyder RW Burgess J Spicer R Bridson WE Friedman MA Metabolism and hemoglobin adduct formation of acrylamide in humans. Toxicol Sci. 2005;85(1):447–459. http://dx.doi.org/10.1093/toxsci/kfi069 15625188
12 Kopp EK Dekant W Toxicokinetics of acrylamide in rats and humans following single oral administration of low doses. Toxicol Appl Pharmacol. 2009;235(2):135–142. http://dx.doi.org/10.1016/j.taap.2008.12.001 19118568
13 Sumner SC Williams CC Snyder RW Krol WL Asgharian B Fennell TR Acrylamide: a comparison of metabolism and hemoglobin adducts in rodents following dermal, intraperitoneal, oral, or inhalation exposure. Toxicol Sci. 2003;75(2):260–270. http://dx.doi.org/10.1093/toxsci/kfg191 12883088
14 Kurebayashi H Ohno Y Metabolism of acrylamide to glycidamide and their cytotoxicity in isolated rat hepatocytes: protective effects of GSH precursors. Arch Toxicol. 2006;80(12):820–828. http://dx.doi.org/10.1007/s00204-006-0109-x 16699760
15 Backman J Kronberg L Reaction of glycidamide with 2′-deoxyadenosine and 2′-deoxyguanosine—mechanism for the amide hydrolysis. Nucleosides Nucleotides Nucleic Acids. 2007;26(2):129–148. http://dx.doi.org/10.1080/15257770601112697 17365793
16 Backman J Sjöholm R Kronberg L Characterization of the adducts formed in the reactions of glycidamide with thymidine and cytidine. Chem Res Toxicol. 2004;17(12):1652–1658. http://dx.doi.org/10.1021/tx049823i 15606141
17 Gamboa da Costa G Churchwell MI Hamilton LP Von Tungeln LS Beland FA Marques MM Doerge DR DNA adduct formation from acrylamide via conversion to glycidamide in adult and neonatal mice. Chem Res Toxicol. 2003;16(10):1328–1337. http://dx.doi.org/10.1021/tx034108e 14565774
18 Kotova N Jurén T Myöhänen K Cornelius M Abramsson-Zetterberg L Backman J Menzel U Rydberg P Kronberg L Vähäkangas K ^32^P-HPLC analysis of N1-(2-carboxy-2-hydroxyethyl)deoxyadenosine: a DNA adduct of the acrylamide-derived epoxide glycidamide. Toxicol Lett. 2011;207(1):18–24. http://dx.doi.org/10.1016/j.toxlet.2011.08.007 21878374
19 Segerbäck D Calleman CJ Schroeder JL Costa LG Faustman EM Formation of N-7-(2-carbamoyl-2-hydroxyethyl)guanine in DNA of the mouse and the rat following intraperitoneal administration of [14C]acrylamide. Carcinogenesis. 1995;16(5):1161–1165. http://dx.doi.org/10.1093/carcin/16.5.1161 7767980
20 Solomon JJ Cyclic adducts and intermediates induced by simple epoxides. IARC Sci Publ. 1999;(150):123–135. 10626214
21 Doerge DR Gamboa da Costa G McDaniel LP Churchwell MI Twaddle NC Beland FA DNA adducts derived from administration of acrylamide and glycidamide to mice and rats. Mutat Res. 2005;580(1-2):131–141. http://dx.doi.org/10.1016/j.mrgentox.2004.10.013 15668115
22 Tareke E Twaddle NC McDaniel LP Churchwell MI Young JF Doerge DR Relationships between biomarkers of exposure and toxicokinetics in Fischer 344 rats and B6C3F1 mice administered single doses of acrylamide and glycidamide and multiple doses of acrylamide. Toxicol Appl Pharmacol. 2006;217(1):63–75. http://dx.doi.org/10.1016/j.taap.2006.07.013 17007897
23 Von Tungeln LS Churchwell MI Doerge DR Shaddock JG McGarrity LJ Heflich RH Gamboa da Costa G Marques MM Beland FA DNA adduct formation and induction of micronuclei and mutations in B6C3F1/Tk mice treated neonatally with acrylamide or glycidamide. Int J Cancer. 2009;124(9):2006–2015. http://dx.doi.org/10.1002/ijc.24165 19123476
24 Martins C Oliveira NG Pingarilho M Gamboa da Costa G Martins V Marques MM Beland FA Churchwell MI Doerge DR Rueff J Cytogenetic damage induced by acrylamide and glycidamide in mammalian cells: correlation with specific glycidamide-DNA adducts. Toxicol Sci. 2007;95(2):383–390. http://dx.doi.org/10.1093/toxsci/kfl155 17088317
25 Mei N Hu J Churchwell MI Guo L Moore MM Doerge DR Chen T Genotoxic effects of acrylamide and glycidamide in mouse lymphoma cells. Food Chem Toxicol. 2008;46(2):628–636. http://dx.doi.org/10.1016/j.fct.2007.09.093 18029077
26 Bergmark E Calleman CJ Costa LG Formation of hemoglobin adducts of acrylamide and its epoxide metabolite glycidamide in the rat. Toxicol Appl Pharmacol. 1991;111(2):352–363. http://dx.doi.org/10.1016/0041-008X(91)90036-E 1957318
27 Calleman CJ Bergmark E Costa LG Acrylamide is metabolized to glycidamide in the rat: evidence from hemoglobin adduct formation. Chem Res Toxicol. 1990;3(5):406–412. http://dx.doi.org/10.1021/tx00017a004 2133091
28 Bergmark E Calleman CJ He F Costa LG Determination of hemoglobin adducts in humans occupationally exposed to acrylamide. Toxicol Appl Pharmacol. 1993;120(1):45–54. http://dx.doi.org/10.1006/taap.1993.1085 8511782
29 Annola K Karttunen V Keski-Rahkonen P Myllynen P Segerbäck D Heinonen S Vähäkangas K Transplacental transfer of acrylamide and glycidamide are comparable to that of antipyrine in perfused human placenta. Toxicol Lett. 2008;182(1-3):50–56. http://dx.doi.org/10.1016/j.toxlet.2008.08.006 18790027
30 Annola K Keski-Rahkonen P Vähäkangas K Lehtonen M Simultaneous determination of acrylamide, its metabolite glycidamide and antipyrine in human placental perfusion fluid and placental tissue by liquid chromatography-electrospray tandem mass spectrometry. J Chromatogr B Analyt Technol Biomed Life Sci. 2008;876(2):191–197. http://dx.doi.org/10.1016/j.jchromb.2008.10.044 19010089
31 Koyama N Yasui M Oda Y Suzuki S Satoh T Suzuki T Matsuda T Masuda S Kinae N Honma M Genotoxicity of acrylamide in vitro: acrylamide is not metabolically activated in standard in vitro systems. Environ Mol Mutagen. 2011;52(1):11–19. http://dx.doi.org/10.1002/em.20560 20209648
32 Costa LG Deng H Gregotti C Manzo L Faustman EM Bergmark E Calleman CJ Comparative studies on the neuro- and reproductive toxicity of acrylamide and its epoxide metabolite glycidamide in the rat. Neurotoxicology. 1992;13(1):219–224. 1508423
33 Abou-Donia MB Ibrahim SM Corcoran JJ Lack L Friedman MA Lapadula DM Neurotoxicity of glycidamide, an acrylamide metabolite, following intraperitoneal injections in rats. J Toxicol Environ Health. 1993;39(4):447–464. http://dx.doi.org/10.1080/15287399309531764 8345532
34 Costa LG Deng H Calleman CJ Bergmark E Evaluation of the neurotoxicity of glycidamide, an epoxide metabolite of acrylamide: behavioral, neurochemical and morphological studies. Toxicology. 1995;98(1-3):151–161. http://dx.doi.org/10.1016/0300-483X(94)02986-5 7740544
35 Deng H Jiao X He F [A study on neurotoxicity of acrylamide and glycidamide]. Chin J Prev Med. 1997;31(4):202–205.
36 Brevik A Rusnakova V Duale N Slagsvold HH Olsen AK Storeng R Kubista M Brunborg G Lindeman B Preconceptional paternal glycidamide exposure affects embryonic gene expression: single embryo gene expression study following in vitro fertilization. Reprod Toxicol. 2011;32(4):463–471. http://dx.doi.org/10.1016/j.reprotox.2011.09.005 21978862
37 Olstørn HB Paulsen JE Alexander J Effects of perinatal exposure to acrylamide and glycidamide on intestinal tumorigenesis in Min/+ mice and their wild-type litter mates. Anticancer Res. 2007;27(6B) 6b:3855–3864. 18225543
38 Von Tungeln LS Doerge DR Gamboa da Costa G Matilde Marques M Witt WM Koturbash I Pogribny IP Beland FA Tumorigenicity of acrylamide and its metabolite glycidamide in the neonatal mouse bioassay. Int J Cancer. 2012;131(9):2008–2015. http://dx.doi.org/10.1002/ijc.27493 22336951
39 Hashimoto K Tanii H Mutagenicity of acrylamide and its analogues in Salmonella typhimurium. Mutat Res. 1985;158(3):129–133. http://dx.doi.org/10.1016/0165-1218(85)90075-8 3908926
40 El-Assouli SM Acrylamide in selected foods and genotoxicity of their extracts. J Egypt Public Health Assoc. 2009;84(3-4):371–392. 19889361
41 Voogd CE van der Stel JJ Jacobs JJ The mutagenic action of aliphatic epoxides. Mutat Res. 1981;89(4):269–282. http://dx.doi.org/10.1016/0165-1218(81)90108-7 7027032
42 Barfknecht TR Mecca DJ Naismith RW The genotoxic activity of acrylamide. Environ Mol Mutagen. 1988;11 Suppl 11:9.
43 Baum M Fauth E Fritzen S Herrmann A Mertes P Merz K Rudolphi M Zankl H Eisenbrand G Acrylamide and glycidamide: genotoxic effects in V79-cells and human blood. Mutat Res. 2005;580(1-2):61–69. http://dx.doi.org/10.1016/j.mrgentox.2004.11.007 15668108
44 Baum M Loeppky RN Thielen S Eisenbrand G Genotoxicity of glycidamide in comparison to 3-N-nitroso-oxazolidin-2-one. J Agric Food Chem. 2008;56(15):5989–5993. http://dx.doi.org/10.1021/jf703741a 18624445
45 Thielen S Baum M Hoffmann M Loeppky RN Eisenbrand G Genotoxicity of glycidamide in comparison to (+/-)-anti-benzo[a]pyrene-7,8-dihydrodiol-9,10-epoxide and alpha-acetoxy-N-nitroso-diethanolamine in human blood and in mammalian V79-cells. Mol Nutr Food Res. 2006;50(4-5):430–436. http://dx.doi.org/10.1002/mnfr.200500227 16598810
46 Johansson F Lundell T Rydberg P Erixon K Jenssen D Mutagenicity and DNA repair of glycidamide-induced adducts in mammalian cells. Mutat Res. 2005;580(1-2):81–89. http://dx.doi.org/10.1016/j.mrgentox.2004.11.011 15668110
47 Besaratinia A Pfeifer GP Genotoxicity of acrylamide and glycidamide. J Natl Cancer Inst. 2004;96(13):1023–1029. http://dx.doi.org/10.1093/jnci/djh186 15240786
48 Koyama N Sakamoto H Sakuraba M Koizumi T Takashima Y Hayashi M Matsufuji H Yamagata K Masuda S Kinae N Genotoxicity of acrylamide and glycidamide in human lymphoblastoid TK6 cells. Mutat Res. 2006;603(2):151–158. http://dx.doi.org/10.1016/j.mrgentox.2005.11.006 16387526
49 Hansen SH Olsen AK Søderlund EJ Brunborg G In vitro investigations of glycidamide-induced DNA lesions in mouse male germ cells and in mouse and human lymphocytes. Mutat Res. 2010;696(1):55–61. http://dx.doi.org/10.1016/j.mrgentox.2009.12.012 20026424
50 Puppel N Tjaden Z Fueller F Marko D DNA strand breaking capacity of acrylamide and glycidamide in mammalian cells. Mutat Res. 2005;580(1-2):71–80. http://dx.doi.org/10.1016/j.mrgentox.2004.11.009 15668109
51 Butterworth BE Eldridge SR Sprankle CS Working PK Bentley KS Hurtt ME Tissue-specific genotoxic effects of acrylamide and acrylonitrile. Environ Mol Mutagen. 1992;20(3):148–155. http://dx.doi.org/10.1002/em.2850200303 1396605
52 Generoso WM Sega GA Lockhart AM Hughes LA Cain KT Cacheiro NL Shelby MD Dominant lethal mutations, heritable translocations, and unscheduled DNA synthesis induced in male mouse germ cells by glycidamide, a metabolite of acrylamide. Mutat Res. 1996;371(3-4):175–183. http://dx.doi.org/10.1016/S0165-1218(96)90106-8 9008719
53 Paulsson B Kotova N Grawé J Henderson A Granath F Golding B Törnqvist M Induction of micronuclei in mouse and rat by glycidamide, genotoxic metabolite of acrylamide. Mutat Res. 2003;535(1):15–24. http://dx.doi.org/10.1016/S1383-5718(02)00281-4 12547279
54 Manjanatha MG Aidoo A Shelton SD Bishop ME McDaniel LP Lyn-Cook LE Doerge DR Genotoxicity of acrylamide and its metabolite glycidamide administered in drinking water to male and female Big Blue mice. Environ Mol Mutagen. 2006;47(1):6–17. http://dx.doi.org/10.1002/em.20157 15957192
55 Wang RS McDaniel LP Manjanatha MG Shelton SD Doerge DR Mei N Mutagenicity of acrylamide and glycidamide in the testes of big blue mice. Toxicol Sci. 2010;117(1):72–80. http://dx.doi.org/10.1093/toxsci/kfq190 20581126
56 Mei N McDaniel LP Dobrovolsky VN Guo X Shaddock JG Mittelstaedt RA Azuma M Shelton SD McGarrity LJ Doerge DR The genotoxicity of acrylamide and glycidamide in big blue rats. Toxicol Sci. 2010;115(2):412–421. http://dx.doi.org/10.1093/toxsci/kfq069 20200216
57 Twaddle NC Churchwell MI McDaniel LP Doerge DR Autoclave sterilization produces acrylamide in rodent diets: implications for toxicity testing. J Agric Food Chem. 2004;52(13):4344–4349. http://dx.doi.org/10.1021/jf0497657 15212490
58 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
59 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
60 McConnell EE Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986;76(2):283–289. 3456066
61 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53(282):457–481. 10.1080/01621459.1958.10501452
62 Cox DR Regression models and life-tables. J R Stat Soc B. 1972;34:187–220.
63 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
64 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. http://dx.doi.org/10.2307/2531856 3390507
65 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. http://dx.doi.org/10.2307/2532200 8241374
66 Haseman JK Statistical issues in the design, analysis and interpretation of animal carcinogenicity studies. Environ Health Perspect. 1984;58:385–392. http://dx.doi.org/10.1289/ehp.8458385 6525993
67 Code of Federal Regulations (CFR). 21:Part 58.
68 Friedman MA Dulak LH Stedham MA A lifetime oncogenicity study in rats with acrylamide. Fundam Appl Toxicol. 1995;27(1):95–105. http://dx.doi.org/10.1006/faat.1995.1112 7589934
69 Johnson KA Gorzinski SJ Bodner KM Campbell RA Wolf CH Friedman MA Mast RW Chronic toxicity and oncogenicity study on acrylamide incorporated in the drinking water of Fischer 344 rats. Toxicol Appl Pharmacol. 1986;85(2):154–168. http://dx.doi.org/10.1016/0041-008X(86)90109-2 3764902
70 Beland FA Benson RW Mellick PW Kovatch RM Roberts DW Fang JL Doerge DR Effect of ethanol on the tumorigenicity of urethane (ethyl carbamate) in B6C3F1 mice. Food Chem Toxicol. 2005;43(1):1–19. http://dx.doi.org/10.1016/j.fct.2004.07.018 15582191
71 Bucher JR Huff J Haseman JK Eustis SL Peters A Toft JD Neurotoxicity and carcinogenicity of N-methylolacrylamide in F344 rats and B6C3F1 mice. J Toxicol Environ Health. 1990;31(3):161–177. http://dx.doi.org/10.1080/15287399009531446 2231776
72 Melnick RL Sills RC Comparative carcinogenicity of 1,3-butadiene, isoprene, and chloroprene in rats and mice. Chem Biol Interact. 2001;135-136:27–42. http://dx.doi.org/10.1016/S0009-2797(01)00213-7 11397379
73 Irwin RD Eustis SL Stefanski S Haseman JK Carcinogenicity of glycidol in F344 rats and B6C3F1 mice. J Appl Toxicol. 1996; 16(3):201-209. 10.1002/(SICI)1099-1263(199605)16:3<201::AID-JAT333>3.0.CO;2-0 8818859
74 Beland FA Mellick PW Olson GR Mendoza MC Marques MM Doerge DR Carcinogenicity of acrylamide in B6C3F(1) mice and F344/N rats from a 2-year drinking water exposure. Food Chem Toxicol. 2013;51:149–159. 10.1016/j.fct.2012.09.017 23009883
75 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: V. Results from the testing of 311 chemicals. Environ Mol Mutagen. 1992;19 Suppl 21:2–141. 10.1002/em.2850190603 1541260
76 European Food Safety Authority (EFSA) Guidance of the Scientific Committee on a request from EFSA on the use of the benchmark dose approach in risk assessment. EFSA J. 2009;1150:1–72. 10.2903/j.efsa.2009.1150