# Discussion

Glycidamide is a reactive electrophile that occurs primarily as a metabolite of acrylamide. Acrylamide can be formed by Maillard reactions involving asparagine and reducing sugars and thus is found as a contaminant in baked and fried starchy foods and roasted coffee. NTP conducted simultaneous studies to compare the effects of acrylamide and glycidamide in male and female F344/N Nctr rats and B6C3F1/Nctr mice. In NTP TR 575, acrylamide was shown to be a multi-site carcinogen in males and females of both species. Acrylamide was hypothesized to be activated to a carcinogen through its metabolism to glycidamide. The present study tests this hypothesis by comparing the effects of administering equimolar doses of glycidamide to the same rodent strains.

The administration of glycidamide in the drinking water to F344/N Nctr rats resulted in significant dose-related decreases in body weight, with the effect being most pronounced in the 0.70 mM glycidamide dose group (Table 10 and Table 11 and Figure 7). F344/N Nctr rats administered acrylamide in the drinking water for 2 years also had significant dose-related decreases in body weight,^4^ and a comparison of body weights between these two bioassays indicated that the mean body weights for all dose groups through the entire 2 year treatment period were typically within 5% of one another.

The survival of the F344/N Nctr rats also was affected by glycidamide, with significant decreases in survival being observed at the 0.35 and 0.70 mM doses (Table 9 and Figure 6). Similar trends existed with F344/N Nctr rats given acrylamide.^4^ Furthermore, F344/N Nctr rats exposed to glycidamide or acrylamide typically consumed similar (±10%) amounts of each of the compounds (on a μMol per kg body weight basis; Table 42), thus permitting a direct comparison between the neoplasms arising as a result of the treatments.

Table 42 Comparison of Mean Daily Acrylamide and Glycidamide Consumption in Male and Female B6C3F1/Nctr Mice and F344/N Nctr Rats in Two-year Drinking Water Studies^a^

| Dose (mM) | Acrylamide (µmol/kg bw/day) | Glycidamide (µmol/kg bw/day)
F344/N Nctr Rats
Male | 0.0875*** | 4.6 | 4.4
| 0.175* | 9.1 | 8.9
| 0.35*** | 18.4 | 17.6
| 0.70 | 37.6 | 37.5
Female | 0.0875 | 6.2 | 6.1
| 0.175 | 12.3 | 12.3
| 0.35* | 25.8 | 25.4
| 0.70*** | 56.1 | 52.6
B6C3F1/Nctr Mice
Male | 0.0875*** | 14.6 | 13.8
| 0.175 | 30.9 | 30.4
| 0.35 | 57.7 | 58.8
| 0.70*** | 125.4 | 109.5
Female | 0.0875 | 15.5 | 15.7
| 0.175*** | 31.3 | 33.0
| 0.35 | 65.3 | 64.6
| 0.70** | 139.7 | 147.6

^a^ The data are reported as the mean amount consumed of acrylamide or glycidamide, in μMol kg body weight per day, for the entire 2-year experiment. An asterisk (*) associated with a specific dose indicates a significant (*, p ≤ 0.05; **, p ≤ 0.01; ***, p ≤ 0.001) difference between acrylamide and glycidamide at the particular mM dose.

Glycidamide induced follicular cell adenoma or carcinoma of the thyroid gland in both male and female F344/N Nctr rats. In male rats, the incidence of follicular cell adenoma or carcinoma was significantly increased at 0.70 mM glycidamide (Table 14) and in female rats, the incidence was increased significantly at 0.175, 0.35, and 0.70 mM glycidamide (Table 14); in both sexes the incidence in each of the glycidamide dose groups exceeded the historical range observed in control F344/N Nctr rats at the NCTR. Follicular cell carcinoma also was detected in each of the glycidamide dose groups of F344/N Nctr rats, except females administered 0.0875 mM glycidamide. Follicular cell carcinoma has not been observed in either male or female control F344/N Nctr rats in bioassays at the NCTR.

Follicular cell adenoma or carcinoma has been reported in F344 rats given acrylamide,^4,68,69^ and the incidence of follicular cell adenoma or carcinoma induced by acrylamide at NCTR^4^ did not differ statistically from that induced by glycidamide (Table 43). In addition to having similar incidences of follicular cell neoplasms, F344 rats treated with equimolar levels of acrylamide or glycidamide have high levels of N7-GA-Gua in their thyroid gland DNA.^21^ Furthermore, Big Blue rats administered equimolar quantities of acrylamide or glycidamide have increased mutant frequencies at the cII transgene of their thyroid glands.^56^ Thus, the combined data are consistent with the conversion of acrylamide to glycidamide being an important step in the induction of follicular cell tumors in F344 rats.

Table 43 Comparison of Incidences of Selected Neoplasms in Male and Female F344/N Nctr Rats Administered Acrylamide or Glycidamide in Two-year Drinking Water Studies^a^

| Dose (mM) | Acrylamide^b^ (%) | Glycidamide (%)
Thyroid Gland: Follicular Cell Adenoma or Carcinoma
Male | 0 | 2 | 4
| 0.0875 | 6 | 7
| 0.175 | 9 | 13
| 0.35 | 13 | 9
| 0.70 | 19 | 28
Female | 0 | 0 | 0
| 0.0875 | 0 | 6
| 0.175 | 4 | 11
| 0.35 | 6 | 9
| 0.70 | 9 | 17
Mammary Gland: Fibroadenoma
Female | 0** | 33 | 33
| 0.0875 | 38 | 54
| 0.175* | 52 | 73
| 0.35** | 47 | 69
| 0.70 | 65 | 75
Clitoral Gland: Carcinoma
Female | 0* | 2 | 8
| 0.0875 | 13 | 13
| 0.175 | 26 | 15
| 0.35* | 6 | 23
| 0.70 | 17 | 30
Oral Mucosa or Tongue: Squamous Cell Papilloma or Carcinoma
Female | 0 | 0 | 2
| 0.0875 | 4 | 4
| 0.175 | 2 | 4
| 0.35 | 6 | 4
| 0.70 | 10 | 15
Epididymis or Testes: Malignant Mesothelioma
Male | 0** | 4 | 0
| 0.0875 | 4 | 2
| 0.175 | 2 | 6
| 0.35 | 10 | 21
| 0.70* | 17 | 35
Heart: Malignant Schwannoma
Male | 0 | 2 | 4
| 0.0875 | 4 | 6
| 0.175 | 6 | 6
| 0.35 | 8 | 15
| 0.70 | 13 | 17

^a^ The data are reported the % incidence. An asterisk (*) associated with the 0 mM acrylamide or glycidamide indicates a significant (*, p ≤ 0.05; **, p ≤ 0.01) difference in regression line slopes. An asterisk (*) associated with a specific dose indicates a significant (*, p ≤ 0.05; **, p ≤ 0.01) difference between acrylamide and glycidamide at the particular mM dose.

^b^ Data for acrylamide are from NTP TR 575.^4^

The most sensitive site for tumor induction in female F344/N Nctr rats administered glycidamide in the drinking water was the mammary gland, where there was a significant increase in fibroadenoma at all dose levels of glycidamide (Table 19). Furthermore, the incidence of mammary gland fibroadenoma in each of the glycidamide dose groups exceeded the range observed in control female F344/N Nctr rats at the NCTR. The mammary gland was also the most sensitive site for tumor induction in female F344/N Nctr rats administered acrylamide in the drinking water^4^ and the fibroadenoma incidences observed with glycidamide were very similar to those occurring with acrylamide (Table 43).

In addition to having similar incidences of mammary gland fibroadenomas, female F344 rats administered a single intraperitoneal injection of 0.7 mMole acrylamide or glycidamide per kg body weight form high levels of N7-GA-Gua in their mammary gland DNA,^21^ which supports the concept that the fibroadenomas result from a genotoxic mechanism as a consequence of the metabolic conversion of acrylamide to glycidamide. This interpretation conflicts with the fact that Big Blue rats treated with 0.12 mMol glycidamide or acrylamide per kg body weight/day for 2 months did not have an increased mutant frequency in the cII transgene in the mammary gland^56^; however, this may be a consequence of the high spontaneous mutant frequencies that occur with transgenic mutation assays in general.

Female F344/N Nctr rats treated with glycidamide in the drinking water also had increased incidences of clitoral gland carcinoma (Table 20) and oral cavity neoplasms (primarily squamous cell papilloma; Table 15) that, in each of the glycidamide dose groups, exceeded the NCTR historical range for control female F344/N Nctr rats. These neoplasms were also observed in female F344/N Nctr rats administered acrylamide in the drinking water,^4^ with incidences very similar to those recorded in the glycidamide bioassay (Table 43). Oral cavity neoplasms (primarily squamous cell papilloma) also occurred in male F344/N Nctr rats given glycidamide (Table 15). The incidence in the 0.70 mM glycidamide group was significant and the incidence in all dose groups, including the control group, exceeded the historical control range for male F344/N Nctr rats at the NCTR. These neoplasms were also observed in male F344/N Nctr rats administered acrylamide, but the incidences were not significant.^4^

Female F344/N Nctr rats treated with 0.70 mM glycidamide had a low, but statistically significant, occurrence of forestomach papilloma (Table 21), the incidence of which exceeded the NCTR historical control range. Mononuclear cell leukemia was also observed in all dose groups of male and female F344/N Nctr rats, with the incidence in the 0.70 mM glycidamide group (Table 16) exceeding the NCTR historical control range for female F344/N Nctr rats.

In addition to thyroid gland and oral cavity neoplasms and leukemia, malignant mesothelioma of the epididymis or testes was observed in male F344/N Nctr rats administered glycidamide (Table 17). The incidence of these neoplasms was significant at 0.35 and 0.70 mM glycidamide and exceeded the NCTR historical control range. Malignant mesothelioma of the epididymis or testes has been reported in F344 rats given acrylamide^4,68,69^ and the incidence of these neoplasms was similar to that induced by acrylamide at NCTR^4^ except at the 0.70 mM dose, where the incidence was greater with glycidamide (Table 43). The higher tumor incidence in rats treated with 0.70 mM glycidamide compared to 0.70 mM acrylamide may reflect the saturation of enzymatic oxidation that occurs at high doses of acrylamide in rats.^26^ Higher levels of N7-GA-Gua have been detected in testicular DNA from rats administered glycidamide as compared to acrylamide,^21^ which again may be a consequence of metabolic saturation occurring with acrylamide. Nonetheless, the concordance in tumor incidence that occurred at the lower doses supports the concept that the testicular tumors are a result of acrylamide being converted to glycidamide. Although these data suggest a genotoxic mechanism for the induction of testicular tumors, Big Blue rats treated with either acrylamide or glycidamide did not show an increased mutant frequency in the testes.^56^ This may be due to the fact that the entire testicular tissue rather than just the target tunica vaginalis was assessed.

Male F344/N Nctr rats administered glycidamide developed malignant schwannoma of the heart (Table 18), with the incidence in all dose groups, including the control group, exceeding the historical control range at the NCTR. This neoplasm was also observed in male F344/N Nctr rats treated with acrylamide.^4^ In contrast, the increased incidence of adenoma or carcinoma of the pancreatic islets that was observed in male F344/N Nctr rats treated with acrylamide^4^ was not detected in the current bioassay with glycidamide.

Special attention was given to the brain and spinal cord during the histopathological examinations because in one previous bioassay with acrylamide^69^ tumors of glial cell origin were detected in the brain and spinal cord of male and female F344 rats. These tumors were not observed in two subsequent bioassays with acrylamide in F344 rats^4,68^ nor were they observed in the current bioassay with glycidamide. A treatment-related nonneoplastic lesion was gliosis, which was detected in both male and female F344/N Nctr rats (Table 22 and Table 23). A nonneoplastic lesion reported in F344 rats during previous 2-year bioassays with acrylamide was peripheral nerve degeneration.^4,68,69^ An increased prevalence of this lesion was not observed in F344/N Nctr rats in the current study, although it should be noted that a high incidence of the lesion was detected in all dose groups, including the controls. Peripheral nerve degeneration was also observed in male and female F344/N Nctr rats administered 3.52 mM glycidamide for 3 months (Table 5). Rats from this group also displayed hind limb paresis. Hind limb paresis was also evident in both sexes of rats administered 7.03 mM glycidamide for 2 weeks (Table 5). Peripheral nerve degeneration was not evident in these rats. Hind limb paresis was not observed in any of the dose groups in the 2-year study.

The administration of glycidamide in the drinking water to B6C3F1/Nctr mice resulted in only sporadic changes in body weight (Table 30, Table 31 and Figure 11). The doses selected for the glycidamide bioassay (0, 0.0875, 0.175, 0.35, and 0.70 mM in the drinking water) were identical to those used in the acrylamide bioassay, and there were only sporadic differences in body weights when comparisons were made between mice administered acrylamide and mice given glycidamide. The survival of the B6C3F1/Nctr mice was affected by glycidamide, with significant decreases in survival being observed at the three highest doses in male mice and the two highest doses in female mice (Table 29). Similar trends existed with B6C3F1/Nctr mice given acrylamide.^4^ In addition to having comparable body weights and survival, B6C3F1/Nctr mice exposed to glycidamide or acrylamide typically consumed similar (±10%) amounts of each of the compounds (on a μMol per kg body weight basis; Table 42). These results indicate that any differences in the incidence of neoplasms between mice given glycidamide and those administered acrylamide would not be a consequence of differences in body weights, survival, or amount of test compound consumed.

The most sensitive site for tumor induction in the B6C3F1/Nctr mice administered glycidamide in the drinking water was the Harderian gland. In male B6C3F1/Nctr mice, the incidence of Harderian gland adenoma increased from 6% in the control group to 89% in mice receiving 0.70 mM glycidamide in the drinking water (Table 34), and in female B6C3F1/Nctr mice, the incidence of Harderian gland adenoma increased from 4% in the control group to 87% in mice administered 0.70 mM glycidamide (Table 34). Even at the lowest dose of glycidamide (0.0875 mM), the incidence of Harderian gland adenoma exceeded the range observed in control male and female B6C3F1/Nctr mice in experiments conducted at the NCTR. As reported previously, the Harderian gland was also the most sensitive site for tumor induction in the B6C3F1/Nctr mice administered acrylamide in the drinking water^4^ and a comparison of the bioassays (Table 44) indicates that the tumor incidences were similar. These data, plus the fact that other low-molecular-weight carcinogens that are thought to be metabolized to electrophilic epoxides also target the Harderian gland in B6C3F1 mice,^70-72^ strongly support the concept that the carcinogenic activity of acrylamide in the Harderian gland of B6C3F1/Nctr mice is due to its metabolism to glycidamide.

Table 44 Comparison of Incidences of Selected Neoplasms in Male and Female B6C3F1/Nctr Mice Administered Acrylamide or Glycidamide in Two-year Drinking Water Studies^a^

| Dose (mM) | Acrylamide^b^ (%) | Glycidamide (%)
Harderian Gland: Adenoma
Male | 0 | 4 | 6
| 0.0875 | 28 | 36
| 0.175 | 57 | 49
| 0.35 | 77 | 70
| 0.70 | 83 | 89
Female | 0 | 0 | 4
| 0.0875* | 18 | 40
| 0.175 | 42 | 43
| 0.35 | 68 | 52
| 0.70 | 72 | 87
Lung: Alveolar/Bronchiolar Adenoma
Male | 0 | 11 | 0
| 0.0875 | 13 | 15
| 0.175 | 28 | 15
| 0.35 | 22 | 28
| 0.70 | 40 | 36
Female | 0 | 2 | 7
| 0.0875 | 9 | 10
| 0.175 | 13 | 6
| 0.35 | 24 | 15
| 0.70 | 42 | 21
Stomach (Forestomach): Squamous Cell Papilloma or Carcinoma
Male | 0 | 0 | 0
| 0.0875 | 4 | 4
| 0.175 | 4 | 6
| 0.35 | 15 | 4
| 0.70 | 18 | 29
Skin: Mesenchymal Tumors
Female | 0 | 0 | 0
| 0.0875 | 0 | 2
| 0.175 | 6 | 6
| 0.35 | 22 | 11
| 0.70 | 14 | 27
Mammary Gland: Adenoacanthoma or Adenocarcinoma
Female | 0 | 0 | 2
| 0.0875 | 9 | 2
| 0.175 | 15 | 4
| 0.35 | 9 | 19
| 0.70 | 41 | 40

^a^ The data are reported the % incidence. An asterisk (*) associated with a specific dose indicates a significant (p ≤ 0.05) difference between acrylamide and glycidamide at the particular mM dose.

^b^ Data for acrylamide are from NTP TR 575.^4^

In both sexes of B6C3F1/Nctr mice, there were significant dose-dependent increases in alveolar/bronchiolar adenoma of the lung (Table 35), and the incidences in the 0.35 and 0.70 mM glycidamide dose groups exceeded the range observed in control B6C3F1/Nctr mice in experiments at the NCTR. As with Harderian gland adenoma, the incidence of alveolar/bronchiolar adenoma in B6C3F1/Nctr mice administered glycidamide (Table 44) did not differ significantly from the incidence in mice given acrylamide.^4^ These results, coupled with the observation that glycidamide and acrylamide give very similar DNA adduct profiles in the lungs of B6C3F1/Nctr and other strains of mice^17,21,23^ are consistent with the premise that the lung neoplasms induced in B6C3F1/Nctr mice are due to acrylamide being metabolized to glycidamide.

In addition to Harderian gland and lung adenoma, the drinking water exposure to glycidamide resulted in significant dose-related increases in forestomach and skin neoplasms in both sexes of B6C3F1/Nctr mice and mammary gland neoplasms in female B6C3F1/Nctr mice. Forestomach neoplasms were also observed in male B6C3F1/Nctr mice administered acrylamide in the drinking water,^4^ and the incidence of these tumors did not differ significantly between the two compounds (Table 44). Likewise, skin and mammary gland neoplasms occurred in female B6C3F1/Nctr mice treated with acrylamide, and as was the case with forestomach neoplasms in male mice, the incidence of these neoplasms did not differ significantly between female mice given glycidamide and those treated with acrylamide. Other low-molecular-weight epoxides (e.g., glycidol^73^) or alkenes that are thought to be metabolized to electrophilic epoxides (e.g., 1,3-butadiene, chloroprene, and urethane^70,72^) also induce mammary gland neoplasms in female B6C3F1 mice. Glycidol, 1,3-butadiene, and chloroprene also induce mammary gland tumors in female F344 rats,^72,73^ as is the case with glycidamide (this report) and acrylamide.^4^

Male B6C3F1 mice treated neonatally with glycidamide developed a high incidence of combined hepatocellular adenoma or carcinoma.^38^ In other studies, high levels of N7-GA-Gua and N3-GA-Ade have been detected in liver DNA from mice and rats treated as adults with glycidamide,^6,7,17,21,22^ which suggests that glycidamide had the potential to be hepatocarcinogenic in the current bioassays. Liver necrosis was observed in male F344/N Nctr rats (Table 22) and female B6C3F1/Nctr mice (Table 41) administered glycidamide; nonetheless, an increased incidence of hepatocellular tumors was not observed in either species. F344/N Nctr rats and B6C3F1/Nctr mice treated with acrylamide also did not have increased incidences of liver neoplasms.^4^

At the initiation of this study we hypothesized that acrylamide is carcinogenic due to its metabolic conversion to glycidamide. To determine the validity of this hypothesis, benchmark dose modeling was conducted to estimate the doses of glycidamide that would give a 10% excess risk for specific neoplasms (BMD); these doses were then compared to BMD values previously determined for acrylamide.^74^ In F344/N Nctr rats, the most sensitive site for tumor induction was the mammary gland in females (BMD of 2.39 µmol glycidamide per kg body weight per day for fibroadenoma) and the epididymis or testes in males (BMD of 11.23 to 17.94 µmol glycidamide per kg body weight per day for malignant mesothelioma) (Table K-1). In B6C3F1/Nctr mice, the most sensitive site for tumor induction by glycidamide was the Harderian gland, with a BMD for Harderian gland adenoma of 5.24 to 5.91 µmol glycidamide per kg body weight per day in males and 4.55 µmol glycidamide per kg body weight per day in females (Table K-2).

A comparison of these data with those previously reported for acrylamide^74^ indicate that both chemicals have similar potencies in the target tissues (Table K-3 and Table K-4). For example, in female F344/N Nctr rats, the BMD for mammary gland fibroadenoma was 2.39 μMol per kg body weight per day for glycidamide and 7.74 μMol per kg body weight per day for acrylamide, and in male F344/N Nctr rats, the BMD for malignant mesothelioma of the epididymis or testes was 11.59 to 17.94 μMol per kg body weight per day for glycidamide and 29.90 to 30.66 μMol per kg body weight per day for acrylamide (Table K-3). The BMD for Harderian gland adenoma in male B6C3F1/Nctr mice was 5.51 to 5.91 μMol per kg body weight per day for glycidamide as compared to 5.14 to 5.39 μMol per kg body weight per day for acrylamide (Table K-4). Likewise, in female B6C3F1/Nctr mice the BMD for Harderian gland adenoma was 4.55 μMol per kg body weight per day for glycidamide as compared to 6.65 μMol per kg body weight per day for acrylamide. These data reinforce the concept that, under the conditions of these bioassays, acrylamide is efficiently metabolized to glycidamide in both sexes of both species and that the carcinogenic activity of acrylamide is due to its metabolic conversion into glycidamide.

We also hypothesized that because the metabolic conversion of acrylamide to glycidamide occurs to a greater extent in mice as compared to rats, mice would be more sensitive to the carcinogenic effects of acrylamide. The results from the benchmark dose modeling are in accord with this hypothesis. For instance, as noted previously the most sensitive site for tumor induction by acrylamide in B6C3F1/Nctr mice was the Harderian gland, with a BMD of 5.14 to 5.39 µmol acrylamide per kg body weight per day in males and 6.65 to 7.30 µmol acrylamide per kg body weight per day in females.^74^ By comparison, the most sensitive site for tumor induction by acrylamide was the mammary gland in female F344/N Nctr rats (BMD of 7.74 to 12.86 µmol acrylamide per kg body weight per day) and the thyroid gland in male F344/N Nctr rats (BMD of 16.45 to 28.19 µmol acrylamide per kg body weight per day). Nonetheless, it is quite apparent that acrylamide and its electrophilic metabolite glycidamide induce a substantial neoplastic response in both species and sexes.