# Results

## Rats

### Two-week Study

One female rat given 7.03 mM glycidamide in the drinking water died after 12 days of treatment. Hind limb paresis was observed on day 14 in four of four male rats and one of four female rats administered 7.03 mM glycidamide in the drinking water (Table 3). Paresis was not observed in any other treatment groups. There were no other significant in-life observations in any of the other treatment groups.

Table 3 Incidence of Observations and Nonneoplastic Lesions in Rats in the Two-week Glycidamide Studies^a^

| 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM | 7.03 mM
Males
Animals initially in study | 4 | 4 | 4 | 4 | 4 | 4 | 4
Hind limb
Paresis | 0 | 0 | 0 | 0 | 0 | 0 | 4
Urinary bladder
Dilatation | 0 | 0 | 0 | 0 | 0 | 0 | 3 (2.6)
Testes
Seminiferous tubule degeneration | 0 | 0 | 0 | 0 | 0 | 0 | 4 (2.5)
Females
Animals initially in study | 4 | 4 | 4 | 4 | 4 | 4 | 4
Hind limb
Paresis | 0 | 0 | 0 | 0 | 0 | 0 | 1
Urinary bladder
Dilatation | 0 | 0 | 0 | 0 | 0 | 0 | 1 (3.0)

^a^ Data are reported as the number of lesions per number of rats (4) examined microscopically. The average severity is given in parentheses. Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

Male and female rats administered 7.03 mM glycidamide and male rats given 3.52 mM glycidamide in the drinking water for 14 days had significantly decreased body weights as compared to controls (Table 4). Water consumption generally paralleled body weight changes, with groups given the highest dose of glycidamide typically having the lowest consumption of drinking water (Table 4). The same trend occurred with food consumption (Table 4).

Table 4 Survival, Body Weights, Food Consumption, and Water Consumption of Rats in the Two-week Drinking Water Study of Glycidamide

Treatment | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%) | Mean Food Consumption^c^ | | Mean Water Consumption^c^
Treatment | Survival^a^ | Day 1 | Day 7 | Day 14 | Final Weight Relative to Controls (%) | Week 1 | Week 2 | Week 1 | Week 2
Drinking Water
Male
0.0 mM | 4/4 | 86.7 ± 5.1 | 115.7 ± 7.2 | 143.6 ± 6.9 | | 12.9 (100) | 15.6 (100) | 18.2^d^ (100) | 20.3 (100)
0.14 mM | 4/4 | 82.6 ± 10.0 | 117.6 ± 8.8 | 148.1 ± 8.5 | 103 | 14.3 (111) | 15.3 (98) | 18.6 (102) | 20.7 (102)
0.35 mM | 4/4 | 80.6 ± 6.5 | 109.4 ± 5.2 | 136.5 ± 5.4 | 95 | 14.1 (109) | 15.1 (97) | 17.7 (97) | 20.9 (103)
0.70 mM | 4/4 | 82.3 ± 7.2 | 118.7 ± 7.2 | 147.8 ± 7.3 | 103 | 14.7 (114) | 15.9 (102) | 20.6 (113) | 22.3 (110)
1.41 mM | 4/4 | 82.7 ± 3.6 | 116.0 ± 4.1 | 144.0 ± 4.7 | 100 | 14.0 (109) | 15.9 (102) | 20.7^d^ (114) | 22.3 (110)
3.52 mM | 4/4 | 81.1 ± 3.3 | 100.4 ± 1.5 | 120.6 ± 1.9* | 84 | 11.8 (91) | 13.7 (88) | 17.4 (96) | 18.2 (90)
7.03 mM | 4/4 | 80.6 ± 0.8 | 81.9 ± 0.4* | 86.4 ± 1.2* | 60 | 11.3 (88) | 12.0 (77) | 12.9 (71) | 11.7 (58)
Female
0.0 mM | 4/4 | 61.2 ± 8.0 | 85.5 ± 6.5 | 104.8 ± 4.1 | | 12.9 (100) | 12.6 (100) | 13.1 (100) | 18.1 (100)
0.14 mM | 4/4 | 60.2 ± 14.2 | 84.5 ± 12.5 | 105.0 ± 9.8 | 100 | 12.8 (99) | 13.0 (103) | 15.7 (120) | 19.9 (110)
0.35 mM | 4/4 | 62.8 ± 13.6 | 85.6 ± 11.7 | 106.8 ± 10.2 | 102 | 11.3 (88) | 12.7 (101) | 16.3^d^ (124) | 16.8 (93)
0.70 mM | 4/4 | 64.5 ± 8.0 | 88.7 ± 6.5 | 108.7 ± 4.5 | 104 | 11.4 (88) | 13.0 (103) | 16.4 (125) | 17.8 (98)
1.41 mM | 4/4 | 63.4 ± 6.1 | 89.0 ± 3.6 | 106.1 ± 3.3 | 101 | 12.1 (94) | 12.9 (102) | 19.3 (147) | 18.8 (104)
3.52 mM | 4/4 | 63.1 ± 3.7 | 76.2 ± 2.8 | 91.3 ± 1.9 | 87 | 9.1 (71) | 10.7 (85) | 10.5 (80) | 15.4 (85)
7.03 mM | 3/4 | 65.3 ± 11.4 | 62.6 ± 7.4 | 60.5 ± 10.2* | 58 | 7.1 (55) | 6.6 (52) | 19.2 (147) | 8.7 (48)

^a^ Number of animals surviving at 14 days/number initially in group.

^b^ Weights are given as mean ± standard error. An asterisk (*) denotes those that are significantly different (p < 0.05) from controls.

^c^ Food and water consumption are expressed as grams per animal per day and were measured on a per cage basis and presented as mean of two cages and, in parentheses, the percentage of the respective control. Statistical analyses were not conducted on food and water consumption because there were only two cages per treatment group.

^d^ Data based upon one cage only.

Male rats administered 0.14, 0.35, 0.70, 1.41, 3.52, or 7.03 mM glycidamide in the drinking water consumed approximately 1.8, 4.8, 9.9, 20.5, 49.7, or 89.7 mg glycidamide per kg body weight per day; the comparable values for female rats were 2.3, 5.3, 10.6, 24.2, 47.0, or 138 mg glycidamide per kg body weight per day.

Necropsy body weights, liver weights, and liver to brain weight ratios were decreased in all rats administered 7.03 mM glycidamide in the drinking water for 14 days (Table E-1). The necropsy body weights were decreased in male rats receiving 3.52 mM glycidamide.

Dilatation of the urinary bladder was observed grossly in three of four male rats given 7.03 mM glycidamide in the drinking water, in one of four females given 7.03 mM glycidamide in the drinking water (Table 3). When dilatation was observed grossly, the lesion was examined microscopically, confirming the presence of the lesion with a mild-to-moderate average severity.

Most of the rats having dilatation of the urinary bladder had displayed hind limb paresis. This correlation suggested that the dilatation of the urinary bladders in these rats may have been due to impairment of neurological function rather than to a direct toxic effect on the urinary bladder; however, microscopic examination of three levels of brain, three levels of spinal cord, and sciatic nerves of all of these animals failed to reveal any morphologic changes in nervous tissue that could be attributed to glycidamide administration.

A mild-to-moderate average severity for degeneration of the germinal epithelium in the seminiferous tubules of the testes was noted microscopically in all male rats given 7.03 mM glycidamide in the drinking water (Table 3). The lesion was characterized by decreased numbers of germinal cells and the presence of multinucleated spermatids in the lumens of seminiferous tubules.

Exposure Concentration Selection Rationale: The selection of doses for the 3-month glycidamide drinking water study was based upon the effects observed in the 2-week studies of glycidamide (this study) and acrylamide,^4^ which were conducted simultaneously. Both 7.03 mM glycidamide and 7.03 mM acrylamide in drinking water resulted in hind limb paresis and decreased body weight. Since one of the goals of this study was to compare acrylamide with glycidamide, a high dose of 3.52 mM glycidamide (306 ppm glycidamide) was selected for the 3-month drinking water study, with the remaining doses being 0, 0.14, 0.35, 0.70, and 1.41 mM glycidamide (0, 12.2, 30.6, 61.2, and 122 ppm glycidamide). These doses were identical to those used in the 3-month drinking water study with acrylamide.^4^

### Three-month Study

All animals survived to the end of the 3-month experiment. In rats administered 3.52 mM glycidamide in the drinking water, a 100% incidence of hind limb paresis was observed after approximately 5 weeks of treatment. The paresis was not of sufficient severity to necessitate removing the animals from the study (Table 5).

Table 5 Incidence of Observations and Nonneoplastic Lesions in Rats in the Three-month Drinking Water Study of Glycidamide^a^

| 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Males
Animals initially in study | 8 | 8 | 8 | 8 | 8 | 8
Hind limb
Paresis | 0 | 0 | 0 | 0 | 0 | 8
Peripheral nerve
Axon degeneration | 0 | –^b^ | – | – | – | 0
Schwann cell degeneration | 0 | – | – | – | – | 0
Spinal cord
Lumbar axon degeneration | 0 | – | – | – | – | 2 (1.0)
Urinary bladder
Dilatation | 0 | – | – | – | – | 2 (2.5)
Spleen
Congestion | 0 | – | – | – | – | 1 (2.0)
Pigmentation | 0 | – | – | – | – | 0
Testes
Germinal epithelium degeneration | 0 | 2 (1.0) | 3 (1.0) | 8 (1.9) | 8 (2.8) | 8 (3.9)
Epididymis
Exfoliated germ cell | 0 | 0 | 3 (1.0) | 8 (1.9) | 8 (3.0) | 8 (4.0)
Hypospermia | 0 | 0 | 0 | 6 (1.5) | 8 (2.9) | 8 (4.0)
Females
Animals initially in study | 8 | 8 | 8 | 8 | 8 | 8
Hind limb
Paresis | 0 | 0 | 0 | 0 | 0 | 8
Peripheral nerve
Axon degeneration | 0 | – | – | – | – | 1 (1.0)
Schwann cell degeneration | 0 | – | – | – | – | 1 (1.0)
Spinal cord
Lumbar axon degeneration | 0 | – | – | – | – | 3 (1.3)
Urinary bladder
Dilatation | 0 | – | – | – | – | 0
Spleen
Congestion | 0 | – | – | – | – | 0
Pigmentation | 0 | – | – | – | – | 0

^a^ Data are reported as the number of lesions per number of rats (8) examined microscopically. The average severity is given in parentheses. Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

^b^ Not examined. If paresis was observed, then a microscopic examination of the peripheral nerve and spinal cord was conducted.

There were significant dose-related effects in body weight in both male and female rats exposed to glycidamide in the drinking water (Table 6 and Figure 5). Pairwise comparisons indicated significant decreases in body weight gain in both sexes over the 3-month treatment period in rats administered 1.41 or 3.52 mM glycidamide. Mean body weights in the 3.52 mM glycidamide group were depressed by >10% after two (females) to three (males) weeks of dosing and at the end of the 3-month period, the rats weighed 78% of their respective control groups (Table 6). Mean body weights in the 1.41 mM glycidamide group were depressed by >10% after six (males) to seven (females) weeks of dosing and at the end of the 3-month, the rats weighed 86% (males) to 88% (females) of their respective control groups (Table 6).

Table 6 Survival and Body Weights of Rats in the Three-month Drinking Water Studies of Glycidamide

Treatment | Survival^a^ | Mean Body Weight^b^ (g) | | Final Weight Relative to Controls (%)
Treatment | Survival^a^ | Week 0 | Week 14 | Final Weight Relative to Controls (%)
Male
0.0 mM | 8/8 | 121.6 ± 2.2 | 340.6 ± 2.2
0.14 mM | 8/8 | 120.1 ± 2.2 | 329.6 ± 2.2 | 97
0.35 mM | 8/8 | 123.2 ± 2.2 | 340.3 ± 2.2 | 100
0.70 mM | 8/8 | 121.4 ± 2.2 | 325.7 ± 2.2 | 96
1.41 mM | 8/8 | 122.7 ± 2.2 | 292.9 ± 2.2* | 86
3.52 mM | 8/8 | 119.7 ± 2.2 | 264.8 ± 2.2* | 78
Female
0.0 mM | 8/8 | 104.8 ± 1.2 | 202.6 ± 1.2
0.14 mM | 8/8 | 101.1 ± 1.2 | 198.5 ± 1.2 | 98
0.35 mM | 8/8 | 98.9 ± 1.2 | 191.7 ± 1.2 | 95
0.70 mM | 8/8 | 101.9 ± 1.2 | 195.4 ± 1.2 | 97
1.41 mM | 8/8 | 98.5 ± 1.2 | 177.7 ± 1.2* | 88
3.52 mM | 8/8 | 100.3 ± 1.3 | 157.4 ± 1.2* | 78

^a^ Number of animals surviving until study termination/number of animals initially in group.

^b^ Weights are given as LS means ± population standard error of the mean. An asterisk (*) denotes those that are significantly different (p < 0.05) from controls.

Figure 5

Growth Curves for Male and Female Rats in the Three-month Drinking Water Study of Glycidamide

Necropsy body weights and liver weights were decreased in male rats administered 1.41 and 3.52 mM glycidamide in the drinking water for 3 months (Table E-2). Brain weights were decreased in male rats given 3.52 mM glycidamide and the liver-weight-to-brain-weight ratios were decreased in male rats given 1.41 mM glycidamide (Table E-2). The liver weights were decreased at all dose levels in female rats administered glycidamide in the drinking water, brain weights were decreased at 0.70, 1.41, and 3.52 mM glycidamide, and the liver-weight-to-brain-weight ratios were decreased at 0.35 and 1.41 mM glycidamide (Table E-2).

There were significant dose effects in water consumption in male and female rats given glycidamide, and pairwise comparisons indicated significant decreases in water consumption over the 3-month treatment period at 1.41 and 3.52 mM glycidamide (Table 7).

Table 7 Water Consumption of Rats in the Three-month Drinking Water Study of Glycidamide^a^

Week | 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Male
2 | 20.9 ± 0.8 | 20.7 ± 0.8 | 21.2 ± 0.8 | 19.9 ± 0.8 | 21.1 ± 0.8 | 20.5 ± 0.8
3 | 20.5 ± 0.8 | 20.6 ± 0.8 | 21.7 ± 0.8 | 20.9 ± 0.8 | 21.9 ± 0.8 | 21.3 ± 0.8
4 | 22.8 ± 0.8 | 18.3 ± 0.8 | 19.5 ± 0.8 | 18.4 ± 0.8 | 19.4 ± 0.8 | 17.9 ± 0.8
5 | 22.3 ± 0.8 | 20.5 ± 0.8 | 21.3 ± 0.8 | 21.5 ± 0.8 | 20.4 ± 0.8 | 19.8 ± 0.8
6 | 20.1 ± 0.8 | 19.6 ± 0.8 | 19.3 ± 0.8 | 18.6 ± 0.8 | 17.3 ± 0.8 | 16.9 ± 0.8
7 | 20.4 ± 0.8 | 19.8 ± 0.8 | 21.6 ± 0.8 | 20.4 ± 0.8 | 17.0 ± 0.8 | 17.3 ± 0.8
8 | 20.3 ± 0.8 | 20.7 ± 0.8 | 20.6 ± 0.8 | 20.2 ± 0.8 | 16.4 ± 0.8 | 17.0 ± 0.8
9 | 20.7 ± 0.8 | 19.9 ± 0.8 | 20.1 ± 0.8 | 18.8 ± 0.8 | 17.4 ± 0.8 | 18.1 ± 0.8
10 | 21.9 ± 0.8 | 19.7 ± 0.8 | 20.9 ± 0.8 | 19.7 ± 0.8 | 18.1 ± 0.8 | 16.1 ± 0.8
11 | 21.3 ± 0.8 | 20.9 ± 0.8 | 21.2 ± 0.8 | 19.8 ± 0.8 | 18.4 ± 0.8 | 16.9 ± 0.8
12 | 23.2 ± 0.8 | 20.2 ± 0.8 | 20.1 ± 0.8 | 22.1 ± 0.8 | 18.9 ± 0.8 | 17.5 ± 0.8
13 | 21.4 ± 0.8 | 19.7 ± 0.8 | 21.4 ± 0.8 | 19.5 ± 0.8 | 19.1 ± 0.8 | 18.1 ± 0.8
Female
2 | 20.5 ± 0.7 | 18.7 ± 0.7 | 18.3 ± 0.7 | 19.9 ± 0.7 | 18.4 ± 0.7 | 19.2 ± 0.7
3 | 19.4 ± 0.7 | 19.4 ± 0.7 | 19.1 ± 0.7 | 20.0 ± 0.7 | 19.7 ± 0.7 | 19.4 ± 0.7
4 | 18.4 ± 0.7 | 19.0 ± 0.7 | 18.4 ± 0.7 | 18.8 ± 0.7 | 18.8 ± 0.7 | 16.6 ± 0.7
5 | 19.5 ± 0.7 | 17.9 ± 0.7 | 20.1 ± 0.7 | 17.6 ± 0.7 | 18.4 ± 0.7 | 16.8 ± 0.7
6 | 17.1 ± 0.7 | 17.0 ± 0.7 | 17.6 ± 0.7 | 17.9 ± 0.7 | 16.2 ± 0.7 | 14.7 ± 0.7
7 | 19.3 ± 0.7 | 17.6 ± 0.7 | 17.2 ± 0.7 | 17.7 ± 0.7 | 16.2 ± 0.7 | 13.9 ± 0.7
8 | 18.3 ± 0.7 | 18.0 ± 0.7 | 18.5 ± 0.7 | 19.3 ± 0.7 | 16.5 ± 0.7 | 13.8 ± 0.7
9 | 17.6 ± 0.7 | 16.4 ± 0.7 | 16.9 ± 0.7 | 16.8 ± 0.7 | 15.5 ± 0.7 | 13.0 ± 0.7
10 | 17.3 ± 0.7 | 16.7 ± 0.7 | 17.2 ± 0.7 | 15.8 ± 0.7 | 15.6 ± 0.7 | 13.1 ± 0.7
11 | 17.5 ± 0.7 | 17.0 ± 0.7 | 16.3 ± 0.7 | 16.3 ± 0.7 | 15.6 ± 0.7 | 13.7 ± 0.7
12 | 17.7 ± 0.7 | 17.2 ± 0.7 | 17.9 ± 0.7 | 16.5 ± 0.7 | 15.9 ± 0.7 | 13.3 ± 0.7
13 | 17.9 ± 0.7 | 17.2 ± 0.7 | 16.1 ± 0.7 | 18.7 ± 0.7 | 16.3 ± 0.7 | 14.1 ± 0.7

^a^ Water consumption is given as LS mean ± population standard error of the mean and is expressed as grams per animal per day.

There were significant dose effects in food consumption in male and female rats administered glycidamide in the drinking water. Pairwise comparisons indicated a significant decrease in food consumption over the 3-month treatment period in male but not female rats given 3.52 mM glycidamide (Table 8).

Table 8 Food Consumption of Rats in the Three-month Drinking Water Study of Glycidamide^a^

Week | 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Male
3 | 15.1 ± 0.5 | 14.4 ± 0.5 | 16.4 ± 0.5 | 15.5 ± 0.5 | 16.2 ± 0.5 | 14.9 ± 0.5
4 | 15.7 ± 0.5 | 13.7 ± 0.5 | 15.1 ± 0.5 | 14.8 ± 0.5 | 15.7 ± 0.5 | 13.4 ± 0.5
5 | 16.0 ± 0.5 | 16.8 ± 0.5 | 16.4 ± 0.5 | 15.5 ± 0.5 | 16.3 ± 0.5 | 14.6 ± 0.5
6 | 16.2 ± 0.5 | 15.2 ± 0.5 | 15.7 ± 0.5 | 14.9 ± 0.5 | 14.1 ± 0.5 | 14.8 ± 0.5
7 | 16.3 ± 0.5 | 15.7 ± 0.5 | 16.7 ± 0.5 | 15.3 ± 0.5 | 14.4 ± 0.5 | 14.3 ± 0.5
8 | 15.3 ± 0.5 | 15.9 ± 0.5 | 16.5 ± 0.5 | 15.7 ± 0.5 | 13.9 ± 0.5 | 14.3 ± 0.5
9 | 16.9 ± 0.5 | 16.2 ± 0.5 | 16.5 ± 0.5 | 15.4 ± 0.5 | 14.2 ± 0.5 | 14.2 ± 0.5
10 | 17.3 ± 0.5 | 17.7 ± 0.5 | 16.8 ± 0.5 | 16.2 ± 0.5 | 15.8 ± 0.5 | 15.1 ± 0.5
11 | 15.8 ± 0.5 | 17.2 ± 0.5 | 17.7 ± 0.5 | 14.5 ± 0.5 | 16.0 ± 0.5 | 14.9 ± 0.5
12 | 20.2 ± 0.5 | 17.6 ± 0.5 | 17.5 ± 0.5 | 18.5 ± 0.5 | 15.0 ± 0.5 | 15.1 ± 0.5
13 | 17.7 ± 0.5 | 17.7 ± 0.5 | 18.8 ± 0.5 | 18.1 ± 0.5 | 17.6 ± 0.5 | 19.2 ± 0.5
Female
3 | 12.2 ± 0.4 | 12.0 ± 0.4 | 11.9 ± 0.4 | 13.5 ± 0.4 | 11.9 ± 0.4 | 11.0 ± 0.4
4 | 11.5 ± 0.4 | 11.2 ± 0.4 | 11.9 ± 0.4 | 11.8 ± 0.4 | 13.0 ± 0.4 | 10.3 ± 0.4
5 | 12.3 ± 0.4 | 12.8 ± 0.4 | 12.9 ± 0.4 | 13.4 ± 0.4 | 12.0 ± 0.4 | 11.9 ± 0.4
6 | 11.8 ± 0.4 | 12.4 ± 0.4 | 13.2 ± 0.4 | 11.8 ± 0.4 | 11.8 ± 0.4 | 12.4 ± 0.4
7 | 11.3 ± 0.4 | 12.5 ± 0.4 | 12.8 ± 0.4 | 11.6 ± 0.4 | 11.5 ± 0.4 | 11.7 ± 0.4
8 | 11.8 ± 0.4 | 12.4 ± 0.4 | 12.1 ± 0.4 | 12.5 ± 0.4 | 10.8 ± 0.4 | 11.0 ± 0.4
9 | 11.6 ± 0.4 | 12.8 ± 0.4 | 12.3 ± 0.5 | 12.1 ± 0.5 | 11.9 ± 0.4 | 11.0 ± 0.4
10 | 12.2 ± 0.4 | 13.6 ± 0.4 | 13.2 ± 0.4 | 12.8 ± 0.4 | 11.6 ± 0.4 | 11.8 ± 0.4
11 | 11.2 ± 0.4 | 11.9 ± 0.4 | 12.4 ± 0.4 | 11.6 ± 0.4 | 12.3 ± 0.4 | 11.0 ± 0.4
12 | 13.4 ± 0.4 | 12.9 ± 0.4 | 13.0 ± 0.4 | 13.2 ± 0.4 | 12.2 ± 0.4 | 11.2 ± 0.4
13 | 13.3 ± 0.4 | 12.5 ± 0.4 | 13.6 ± 0.4 | 14.1 ± 0.4 | 13.7 ± 0.4 | 12.2 ± 0.4

^a^ Food consumption is given as LS mean ± population standard error of the mean and is expressed as grams per animal per day.

Male rats administered 0.14, 0.35, 0.70, 1.41, or 3.52 mM glycidamide in the drinking water consumed approximately 1.0, 2.4, 5.0, 10.1, or 26.9 mg glycidamide per kg body weight per day; the comparable values for female rats were 1.3, 3.4, 6.6, 13.5, or 33.8 mg glycidamide per kg body weight per day.

The only gross observation that was considered to be treatment-related was marked dilatation of the urinary bladder of two of eight male rats administered 3.52 mM glycidamide (Table 5). These animals had a clinical observation of paresis of the hind legs.

In rats administered glycidamide in the drinking water, treatment-related changes were observed in the following target tissues: sciatic nerve, spinal cord, spleen, testes, and epididymis. These tissues were examined microscopically in progressively lower dose groups until a no-observed-effect level was reached. The most significant treatment-related changes were peripheral neuropathy involving the sciatic nerve in one of eight female rats administered 3.52 mM glycidamide, and myelopathy of the lumbar spinal cord of three of eight female rats and two of eight male rats administered 3.52 mM glycidamide (Table 5). These degenerative changes were characterized by nerve fiber degeneration with dilatation and vacuolization of myelin sheaths along with swollen and shrunken axons. The severity of these changes was minimal to moderate. Luminal dilation of the urinary bladder was also diagnosed in the same male rats.

Testicular germ cell degeneration occurred in all male rats in the 0.70, 1.41, and 3.52 mM glycidamide dose groups, in three of eight male rats given 0.35 mM glycidamide, and in two of eight male rats given 0.14 mM glycidamide (Table 5). The severity of the degenerative change was moderate to marked in the 1.41 and 3.52 mM glycidamide groups and mild to minimal in 0.14, 0.35, and 0.70 mM glycidamide groups (Table 5). A corresponding lesion that consisted of exfoliated degenerating germ cells, cellular debris, and hypospermia was observed in the epididymides of these rats (Table 5).

Exposure Concentration Selection Rationale for Two-year Drinking Water Study: The selection of doses for the 2-year glycidamide drinking water study was based upon the effects observed in the 3-month drinking water studies with glycidamide (this study) and acrylamide,^4^ which were conducted simultaneously. Both 3.52 mM glycidamide and 3.52 mM acrylamide in drinking water resulted in hind limb paresis and decreased body weight. Decreases in body weight were also observed with 1.41 mM glycidamide and 1.41 mM acrylamide. In addition, hind limb paresis also occurred in female rats administered 1.41 mM acrylamide. Since one of the goals of this study was to compare acrylamide with glycidamide, a high dose of 0.70 mM glycidamide (61.2 ppm glycidamide) was selected for the chronic 2-year drinking water study, with the remaining doses being 0.0, 0.0875, 0.175, or 0.35 mM glycidamide (0, 7.65, 15.3, or 30.6 ppm glycidamide). These doses were identical to those used in the 2-year study with acrylamide.^4^

### Two-year Study

#### Survival and Cause of Death

There was a dose-related trend in survival in male and female F344/N Nctr rats given glycidamide in the drinking water (Table 9 and Figure 6). Compared to control rats, both male and female rats administered 0.35 and 0.70 mM glycidamide had decreased survival. The primary cause for the early removal or death of male rats was neoplasms, including mononuclear cell leukemia, pituitary gland adenoma or carcinoma, preputial gland carcinoma, thyroid gland adenoma or carcinoma, and Zymbal’s gland carcinoma. The primary cause for the early removal or death of female rats was neoplasms, including mononuclear cell leukemia, mammary gland fibroadenoma, clitoral gland adenoma or carcinoma, pituitary gland adenoma, and Zymbal’s gland carcinoma.

Table 9 Survival and Disposition of Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male
Animals initially in study | 48 | 48 | 48 | 48 | 48
Wrong sex^a^ | 0 | 0 | 0 | 1 | 0
Moribund | 23 | 18 | 28 | 36 | 43
Natural deaths | 4 | 12 | 5 | 4 | 3
Animals surviving to study termination^a^ | 21 | 18 | 15 | 7 | 2
Percent probability of survival at end of study^b^ | 44 | 38 | 31 | 15 | 4
Mean survival (weeks)^c^ | 94.7 | 92.6 | 93.7 | 92.1 | 84.1
Survival analysis^d^ | P < 0.001 | P = 0.418 | P = 0.199 | P = 0.006 | P < 0.001
Female
Animals initially in study | 48 | 48 | 48 | 48 | 48
Moribund | 10 | 21 | 16 | 28 | 43
Natural deaths | 3 | 1 | 5 | 3 | 3
Animals surviving to study termination^a^ | 35 | 26 | 27 | 17 | 2
Percent probability of survival at end of study^b^ | 73 | 54 | 58 | 35 | 4
Mean survival (weeks)^c^ | 98.8 | 97.2 | 97.5 | 91.6 | 81.1
Survival analysis^d^ | P < 0.001 | P = 0.070 | P = 0.101 | P < 0.001 | P < 0.001

^a^ Censored from the survival analyses.

^b^ Kaplan-Meier survival estimates.

^c^ Mean of all deaths (censored and uncensored).

^d^ The result of the trend test is in the 0.0 mM glycidamide column, and the results of the pairwise comparisons^62^ with the 0.0 mM glycidamide are in the treatment group columns. P-values <0.05 were considered significant.

Figure 6

Kaplan-Meier Survival Curves for Male and Female Rats Administered Glycidamide (mM) in Drinking Water for Two Years

#### Body Weights and Food and Water Consumption

There were significant dose-related trends in body weights beginning at 8 weeks in male F344/N Nctr rats administered glycidamide in the drinking water (Figure 7 and Table 10). Pairwise comparisons indicated that treatment with 0.70 mM glycidamide resulted in significant decreases in body weight gain beginning at week 8 in the male rats; significant decreases in body weight gain occurred sporadically in male rats given 0.35 mM glycidamide (Figure 7 and Table 10).

Figure 7

Growth Curves for Male and Female Rats Administered Glycidamide (mM) in Drinking Water for Two Years

Table 10 Mean Body Weights^a^ and Survival of Male Rats in the Two-year Drinking Water Study of Glycidamide

Weeks on Study | 0 mM | | 0.0875 mM | | | 0.175 mM | | | 0.35 mM | | | 0.70 mM
Weeks on Study | Mean Wt. (g) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors
4 | 206.8 | 48 | 206.4 | 99.8 | 48 | 205.5 | 99.4 | 48 | 203.4 | 98.4 | 47 | 203.8 | 98.5 | 48
8 | 275.2* | 48 | 272.0 | 98.8 | 48 | 271.2 | 98.5 | 48 | 268.4 | 97.5 | 47 | 265.1* | 96.3 | 48
12 | 323.0* | 48 | 316.1 | 97.9 | 48 | 316.4 | 98.0 | 48 | 311.8 | 96.5 | 47 | 308.3* | 95.5 | 48
16 | 354.8* | 48 | 347.6 | 98.0 | 48 | 348.6 | 98.3 | 48 | 341.9 | 96.4 | 47 | 340.0* | 95.8 | 48
20 | 380.0* | 48 | 372.8 | 98.1 | 48 | 372.2 | 98.0 | 48 | 366.6 | 96.5 | 47 | 362.1* | 95.3 | 48
24 | 395.9* | 48 | 392.0 | 99.0 | 48 | 390.4 | 98.6 | 48 | 386.5 | 97.6 | 47 | 381.0* | 96.2 | 48
28 | 408.8* | 48 | 405.0 | 99.1 | 48 | 404.0 | 98.8 | 48 | 400.5 | 98.0 | 47 | 395.8* | 96.8 | 48
32 | 417.5* | 48 | 414.9 | 99.4 | 48 | 412.1 | 98.7 | 48 | 408.5 | 97.8 | 47 | 404.7* | 96.9 | 48
36 | 426.6* | 48 | 423.7 | 99.3 | 48 | 420.3 | 98.5 | 48 | 418.1 | 98.0 | 47 | 411.7* | 96.5 | 48
40 | 430.9* | 48 | 427.1 | 99.1 | 48 | 425.9 | 98.8 | 48 | 422.8 | 98.1 | 47 | 417.2* | 96.8 | 48
44 | 434.0* | 48 | 429.8 | 99.0 | 48 | 426.9 | 98.4 | 48 | 424.5 | 97.8 | 47 | 419.3* | 96.6 | 48
48 | 439.3* | 48 | 434.2 | 98.8 | 47 | 433.2 | 98.6 | 48 | 428.6* | 97.6 | 47 | 425.2* | 96.8 | 48
52 | 443.8* | 48 | 439.4 | 99.0 | 47 | 438.8 | 98.9 | 48 | 432.8 | 97.5 | 47 | 430.8* | 97.1 | 48
56 | 453.2* | 48 | 449.0 | 99.1 | 47 | 445.2 | 98.2 | 48 | 442.2 | 97.6 | 47 | 439.1* | 96.9 | 47
60 | 463.5* | 47 | 457.6 | 98.7 | 47 | 451.9 | 97.5 | 48 | 450.5* | 97.2 | 46 | 444.5* | 95.9 | 46
64 | 469.6* | 47 | 466.6 | 99.4 | 47 | 461.3 | 98.2 | 47 | 460.0 | 97.9 | 46 | 448.3* | 95.5 | 43
68 | 474.5* | 47 | 476.8 | 100.5 | 44 | 467.6 | 98.6 | 47 | 466.4 | 98.3 | 46 | 457.5* | 96.4 | 40
72 | 472.4* | 44 | 481.1 | 101.8 | 43 | 471.9 | 99.9 | 44 | 474.2 | 100.4 | 44 | 456.2* | 96.6 | 39
76 | 475.8* | 40 | 484.9 | 101.9 | 42 | 475.1 | 99.8 | 43 | 476.7 | 100.2 | 44 | 451.5* | 94.9 | 35
80 | 478.3* | 40 | 484.7 | 101.3 | 41 | 476.5 | 99.6 | 40 | 477.6 | 99.9 | 42 | 449.7* | 94.0 | 28
84 | 474.0* | 39 | 482.3 | 101.7 | 39 | 474.1 | 100.0 | 38 | 469.3 | 99.0 | 34 | 445.7* | 94.0 | 27
88 | 472.5* | 36 | 472.2 | 99.9 | 37 | 471.4 | 99.7 | 35 | 463.5 | 98.1 | 31 | 436.9* | 92.5 | 20
92 | 470.1* | 32 | 458.1 | 97.5 | 32 | 449.9 | 95.7 | 32 | 450.2 | 95.8 | 26 | 423.8* | 90.2 | 17
96 | 455.9* | 32 | 436.5 | 95.7 | 28 | 428.5 | 94.0 | 26 | 418.7* | 91.8 | 23 | 394.0* | 86.4 | 11
100 | 440.0* | 29 | 428.2 | 97.3 | 21 | 426.3 | 96.9 | 20 | 407.2* | 92.5 | 14 | 381.4* | 86.7 | 6
104 | 428.0* | 22 | 411.4 | 96.1 | 18 | 410.9 | 96.0 | 17 | 375.4* | 87.7 | 8 | 352.2* | 82.3 | 2
Mean for Weeks
4–104 | 421.7 | | 418.1 | | | 414.5 | | | 409.5 | | | 397.9

^a^ An * in the 0.0 mM glycidamide column indicates a significant dose-related trend (p < 0.05); an * in the treatment column indicates a significant (p < 0.05) pairwise comparison of the dose group to the 0.0 mM glycidamide group as determined by Dunnett’s test.

In female rats, there were significant dose-related trends beginning at 4 weeks (Figure 7 and Table 11). In female rats, pairwise comparisons indicated that treatment with 0.175, 0.35, or 0.70 mM glycidamide resulted in significant decreases in body weight gain beginning at 4 weeks (Figure 7 and Table 11); significant decreases in body weight gain were also observed at 0.0875 mM glycidamide at 84 weeks and at 92 to 104 weeks. At the end of the 104-week period, the male rats administered 0.70 mM glycidamide weighed 82% of the control group; the female rats administered 0.70 mM glycidamide weighed 79% of the control group.

Table 11 Mean Body Weights^a^ and Survival of Female Rats in the Two-year Drinking Water Study of Glycidamide

Weeks on Study | 0 mM | | 0.0875 mM | | | 0.175 mM | | | 0.35 mM | | | 0.70 mM
Weeks on Study | Mean Wt. (g) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors
4 | 149.8* | 48 | 146.9 | 98.1 | 48 | 143.9* | 96.1 | 48 | 142.9* | 95.4 | 48 | 142.5* | 95.1 | 48
8 | 176.8* | 48 | 173.7 | 98.3 | 48 | 170.1* | 96.2 | 48 | 168.3* | 95.2 | 48 | 167.7* | 94.9 | 48
12 | 194.7* | 48 | 190.2 | 97.7 | 48 | 186.6* | 95.8 | 48 | 183.8* | 94.4 | 48 | 183.1* | 94.1 | 48
16 | 205.4* | 48 | 202.4 | 98.5 | 48 | 197.5* | 96.1 | 48 | 196.1* | 95.5 | 48 | 193.7* | 94.3 | 48
20 | 217.5* | 48 | 212.9 | 97.9 | 48 | 207.1* | 95.2 | 48 | 206.1* | 94.8 | 48 | 203.9* | 93.8 | 48
24 | 226.6* | 48 | 220.8 | 97.4 | 48 | 216.1* | 95.4 | 48 | 214.9* | 94.8 | 48 | 212.3* | 93.7 | 48
28 | 233.8* | 48 | 228.0 | 97.5 | 48 | 223.4* | 95.5 | 48 | 221.8* | 94.8 | 48 | 218.8* | 93.6 | 48
32 | 239.9* | 48 | 234.2 | 97.6 | 48 | 228.7* | 95.4 | 48 | 228.1* | 95.1 | 48 | 224.9* | 93.8 | 48
36 | 244.8* | 48 | 239.0 | 97.6 | 48 | 233.6* | 95.4 | 48 | 232.8* | 95.1 | 48 | 229.5* | 93.7 | 48
40 | 249.8* | 48 | 243.4 | 97.5 | 48 | 237.6* | 95.1 | 48 | 236.8* | 94.8 | 48 | 234.9* | 94.0 | 48
44 | 252.3* | 48 | 248.3 | 98.4 | 48 | 241.8* | 95.8 | 48 | 241.1* | 95.5 | 47 | 239.6* | 95.0 | 48
48 | 256.7* | 48 | 252.9 | 98.5 | 48 | 246.7* | 96.1 | 48 | 245.4* | 95.6 | 47 | 243.1* | 94.7 | 48
52 | 260.7* | 48 | 255.2 | 97.9 | 48 | 251.3* | 96.4 | 48 | 250.8* | 96.2 | 46 | 247.6* | 95.0 | 47
56 | 268.0* | 48 | 262.4 | 97.9 | 48 | 257.8* | 96.2 | 47 | 256.9* | 95.9 | 46 | 254.3* | 94.9 | 46
60 | 278.4* | 48 | 271.4 | 97.5 | 48 | 267.1* | 95.9 | 47 | 263.8* | 94.8 | 46 | 261.7* | 94.0 | 45
64 | 289.6* | 47 | 282.4 | 97.5 | 48 | 276.7* | 95.5 | 47 | 269.9* | 93.2 | 45 | 269.5* | 93.1 | 42
68 | 302.9* | 47 | 293.0 | 96.7 | 48 | 287.0* | 94.7 | 47 | 278.8* | 92.1 | 44 | 281.5* | 92.9 | 40
72 | 313.4* | 47 | 300.9 | 96.0 | 45 | 295.0* | 94.1 | 46 | 287.3* | 91.7 | 42 | 279.7* | 89.2 | 38
76 | 321.9* | 47 | 309.2 | 96.1 | 43 | 302.6* | 94.0 | 44 | 294.9* | 91.6 | 40 | 285.9* | 88.8 | 31
80 | 328.7* | 45 | 315.5 | 96.0 | 43 | 310.0* | 94.3 | 41 | 299.8* | 91.2 | 36 | 288.6* | 87.8 | 27
84 | 334.7* | 43 | 319.3* | 95.4 | 42 | 315.9* | 94.4 | 40 | 306.9* | 91.7 | 35 | 284.8* | 85.1 | 22
88 | 340.0* | 42 | 325.4 | 95.7 | 39 | 323.3* | 95.1 | 40 | 312.6* | 91.9 | 35 | 288.3* | 84.8 | 17
92 | 344.6* | 40 | 326.5* | 94.8 | 37 | 325.3* | 94.4 | 38 | 315.5* | 91.6 | 32 | 283.4* | 82.2 | 12
96 | 345.0* | 39 | 324.9* | 94.2 | 35 | 326.0* | 94.5 | 35 | 312.8* | 90.7 | 28 | 292.2* | 84.7 | 8
100 | 347.1* | 37 | 318.9* | 91.9 | 31 | 322.6* | 92.9 | 31 | 313.6* | 90.3 | 22 | 274.8* | 79.2 | 6
104 | 347.2* | 35 | 326.5* | 94.0 | 27 | 319.8* | 92.1 | 28 | 314.1* | 90.5 | 17 | 275.5* | 79.4 | 2
Mean for Weeks
4–104 | 271.9 | | 262.5 | | | 258.2 | | | 253.7 | | | 244.7

^a^ An * in the 0.0 mM glycidamide column indicates a significant dose-related trend (p < 0.05); an * in the treatment column indicates a significant (p < 0.05) pairwise comparison of the dose group to the 0.0 mM glycidamide group as determined by Dunnett’s test.

Glycidamide in the drinking water resulted in sporadic dose-related trends in food consumption in male (Table G-1) and female (Table G-2) F344/N Nctr rats.

Glycidamide in the drinking water resulted in sporadic dose-related trends in water consumption in male (Table 12) and female (Table 13) F344/N Nctr rats.

Table 12 Water and Glycidamide Consumption by Male Rats in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0 mM | 0.0875 mM | | 0.175 mM | | 0.35 mM | | 0.70 mM
Week^a^ | Water (g/day) | Water (g/day) | Dose^b^ | Water (g/day) | Dose | Water (g/day) | Dose | Water (g/day) | Dose
4 | 21.3 | 21.3 | 0.70 | 21.5 | 1.42 | 21.4 | 2.86 | 20.9 | 5.62
8 | 20.2 | 20.0 | 0.52 | 20.3 | 1.07 | 20.2 | 2.16 | 19.8 | 4.29
12 | 19.4 | 18.9 | 0.44 | 19.3 | 0.89 | 18.8 | 1.77 | 19.3 | 3.68
16 | 18.8 | 18.2 | 0.39 | 18.6 | 0.79 | 18.0 | 1.57 | 18.8 | 3.28
20 | 18.5 | 18.1 | 0.36 | 18.5 | 0.74 | 18.1 | 1.47 | 18.7 | 3.07
24 | 18.0 | 17.7 | 0.34 | 18.1 | 0.69 | 18.0 | 1.40 | 18.3 | 2.89
28 | 17.6 | 17.8 | 0.33 | 17.7 | 0.66 | 17.6 | 1.33 | 17.9 | 2.74
32 | 17.5 | 17.5 | 0.32 | 17.7 | 0.65 | 17.5 | 1.29 | 17.8 | 2.66
36 | 17.2 | 17.4 | 0.31 | 17.4 | 0.63 | 17.3 | 1.25 | 17.7 | 2.60
40 | 17.1 | 17.0 | 0.30 | 17.2 | 0.62 | 17.1 | 1.22 | 17.4 | 2.53
44 | 17.1 | 16.7 | 0.30 | 17.2 | 0.61 | 16.8 | 1.20 | 17.5 | 2.54
48 | 16.9 | 16.7 | 0.29 | 16.9 | 0.59 | 16.8 | 1.18 | 17.3 | 2.48
52 | 17.4 | 16.9 | 0.29 | 17.4 | 0.60 | 17.0 | 1.19 | 17.6 | 2.48
56 | 17.7 | 17.2 | 0.29 | 17.6 | 0.60 | 17.2 | 1.17 | 17.6 | 2.47
60 | 17.7* | 17.3 | 0.29 | 17.7 | 0.59 | 17.7 | 1.19 | 18.7 | 2.59
64 | 18.3 | 17.7 | 0.29 | 18.3 | 0.61 | 17.9 | 1.17 | 18.9 | 2.59
68 | 18.6 | 18.2 | 0.29 | 18.4 | 0.60 | 18.2 | 1.19 | 19.5 | 2.64
72 | 19.3 | 19.1 | 0.30 | 19.3 | 0.64 | 19.5 | 1.24 | 19.8 | 2.73
76 | 20.8 | 20.6 | 0.32 | 19.4 | 0.63 | 20.2 | 1.29 | 21.5 | 2.94
80 | 21.6 | 21.5 | 0.34 | 20.9 | 0.68 | 21.4 | 1.38 | 22.6 | 3.07
84 | 22.5* | 22.0 | 0.35 | 22.1 | 0.72 | 22.4 | 1.46 | 24.3 | 3.40
88 | 23.7 | 22.3 | 0.36 | 22.4 | 0.74 | 23.7 | 1.54 | 24.7 | 3.42
92 | 23.9 | 23.1 | 0.39 | 22.6 | 0.77 | 23.8 | 1.58 | 24.6 | 3.57
96 | 24.8 | 24.5 | 0.42 | 24.0 | 0.84 | 19.2* | 1.49 | 22.6 | 3.51
100 | 27.3* | 26.2 | 0.47 | 25.9 | 0.94 | 20.0* | 1.64 | 21.0 | 4.24
104 | 30.9 | 26.2 | 0.41 | 28.6 | 0.92 | 19.7* | 1.68 | 25.9 | 6.54
Mean for Weeks
4–104 | 20.1 | 19.6 | 0.39 | 19.8 | 0.79 | 19.1 | 1.56 | 20.0 | 3.34

^a^ Week indicates the last week of a 4-week interval of daily water consumption, measured weekly by cage.

^b^ Dose is expressed as the mean value measured in mg/kg body weight/day.

* An * in the 0.0 mM glycidamide column indicates a significant dose-related trend (p < 0.05); an * in the treatment column indicates a significant (p < 0.05) pairwise comparison of the dose group to the 0.0 mM glycidamide group as determined by Dunnett’s test.

Table 13 Water and Glycidamide Consumption by Female Rats in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0 mM | 0.0875 mM | | 0.175 mM | | 0.35 mM | | 0.70 mM
Week^a^ | Water (g/day) | Water (g/day) | Dose^b^ | Water (g/day) | Dose | Water (g/day) | Dose | Water (g/day) | Dose
4 | 17.6 | 17.5 | 0.84 | 17.3 | 1.71 | 16.8 | 3.34 | 17.1 | 6.84
8 | 16.4 | 16.1 | 0.68 | 16.2 | 1.41 | 15.7 | 2.76 | 15.8 | 5.56
12 | 15.7* | 15.1 | 0.59 | 15.3 | 1.23 | 15.0 | 2.43 | 14.8 | 4.84
16 | 15.3 | 15.1 | 0.56 | 14.9 | 1.13 | 14.7 | 2.23 | 14.9 | 4.60
20 | 15.0 | 14.9 | 0.53 | 14.9 | 1.08 | 14.5 | 2.10 | 15.0 | 4.42
24 | 15.0 | 15.1 | 0.52 | 15.2 | 1.06 | 14.9 | 2.09 | 15.0 | 4.28
28 | 15.3 | 15.4 | 0.51 | 15.2 | 1.03 | 15.0 | 2.04 | 15.3 | 4.22
32 | 15.6 | 15.6 | 0.50 | 15.4 | 1.02 | 15.4 | 2.05 | 15.6 | 4.20
36 | 15.7 | 15.5 | 0.49 | 15.3 | 0.99 | 15.5 | 2.02 | 15.7 | 4.14
40 | 15.7 | 15.5 | 0.48 | 15.2 | 0.97 | 15.4 | 1.97 | 15.7 | 4.06
44 | 15.6 | 15.9 | 0.49 | 15.4 | 0.97 | 15.7 | 1.97 | 15.7 | 3.99
48 | 15.6 | 15.9 | 0.48 | 15.5 | 0.95 | 15.7 | 1.93 | 15.7 | 3.91
52 | 15.8 | 16.1 | 0.48 | 15.5 | 0.94 | 16.3 | 1.98 | 16.4 | 4.03
56 | 16.5* | 16.4 | 0.47 | 16.2 | 0.95 | 16.5 | 1.94 | 17.2 | 4.09
60 | 16.6 | 16.8 | 0.47 | 16.4 | 0.93 | 16.8 | 1.92 | 17.3 | 4.04
64 | 17.1* | 17.1 | 0.45 | 16.9 | 0.92 | 17.5 | 1.96 | 18.2 | 4.11
68 | 17.6 | 17.8 | 0.47 | 17.1 | 0.91 | 18.5 | 2.01 | 18.4 | 3.96
72 | 18.1* | 18.4 | 0.47 | 17.7 | 0.92 | 19.2 | 2.01 | 19.2 | 4.24
76 | 18.4* | 19.1 | 0.47 | 18.5 | 0.96 | 19.8 | 2.04 | 20.6* | 4.44
80 | 19.2* | 20.0 | 0.49 | 19.6 | 0.95 | 21.0 | 2.11 | 22.6* | 4.69
84 | 19.5* | 20.7 | 0.50 | 19.9 | 0.93 | 21.9* | 2.16 | 21.8 | 4.22
88 | 20.0 | 20.5 | 0.47 | 19.9 | 0.92 | 21.3 | 2.08 | 21.7 | 4.28
92 | 20.7 | 20.6 | 0.47 | 20.5 | 0.93 | 21.6 | 2.12 | 22.3 | 4.27
96 | 20.7* | 21.0 | 0.48 | 20.7 | 0.96 | 21.1 | 2.09 | 24.1* | 4.52
100 | 21.9 | 22.3 | 0.51 | 20.8 | 0.99 | 22.1 | 2.09 | 24.4 | 4.82
104 | 22.5 | 22.8 | 0.51 | 20.2 | 0.95 | 23.3 | 2.05 | 22.4 | 4.38
Mean for Weeks
4–104 | 17.4 | 17.6 | 0.54 | 17.2 | 1.08 | 17.7 | 2.23 | 18.2 | 4.65

^a^ Week indicates the last week of a 4-week interval of daily water consumption, measured weekly by cage.

^b^ Dose is expressed as the mean value measured in mg/kg body weight/day.

* In the 0.0 mM glycidamide column “*” indicates a significant trend (p < 0.05); in the treatment column “*” indicates a significant (p < 0.05) pairwise comparison of the dose group to the 0.0 mM glycidamide group as determined by Dunnett’s test.

The mean glycidamide exposure for rats, calculated at 4-week intervals, is presented in Figure 8 and Table 12 and Table 13. The mean amount of glycidamide consumed by male rats for the entire 2-year experiment was 0.39, 0.79, 1.56, and 3.34 mg glycidamide per kg body weight per day for the 0.0875, 0.175, 0.35, and 0.70 mM glycidamide dose groups, respectively (Figure 8 and Table 12). The corresponding values for female rats were 0.54, 1.08, 2.23, and 4.65 mg glycidamide per kg body weight per day (Figure 8 and Table 13).

Figure 8

Glycidamide Intake in Male and Female Rats Administered Glycidamide (mM) in Drinking Water for Two Years

#### Neoplastic Findings

Glycidamide in the drinking water resulted in thyroid gland neoplasms in male and female F334/N rats. In both sexes of rats, there was a dose-related increase in follicular cell adenoma, follicular cell carcinoma, and combined follicular cell adenoma or carcinoma (Table 14). In male rats, the incidence of follicular cell adenoma, follicular cell carcinoma, and combined follicular cell adenoma or carcinoma was significantly increased at 0.70 mM glycidamide. In female rats, the incidence of follicular cell adenoma was significantly increased in the 0.70 mM glycidamide dose group and the incidence of combined follicular cell adenoma or carcinoma was significant at 0.175, 0.35, and 0.70 mM glycidamide.

Table 14 Incidences of Neoplasms and Nonneoplastic Lesions of the Thyroid Gland in Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male
Follicular Cell Adenoma, Multiple^a^ | 0/47 | 0/42 | 0/48 | 0/47 | 1/46
Follicular Cell Adenoma (including multiple)^b^
Overall rate^a^ | 2/47 (4%) | 1/42 (2%) | 3/48 (6%) | 3/47 (6%) | 8/46 (17%)
Poly-3 test^c^ | P < 0.001 | P = 0.534N | P = 0.494 | P = 0.454 | P = 0.011
Follicular Cell Carcinoma^d^
Overall rate | 0/47 (0%) | 2/42 (5%) | 3/48 (6%) | 1/47 (2%) | 5/46 (11%)
Poly-3 test | P = 0.014 | P = 0.217 | P = 0.114 | P = 0.481 | P = 0.011
Follicular Cell Adenoma or Carcinoma^e^
Overall rate | 2/47 (4%) | 3/42 (7%) | 6/48 (13%) | 4/47 (9%) | 13/46 (28%)
Poly-3 test | P < 0.001 | P = 0.460 | P = 0.130 | P = 0.295 | P < 0.001
Female
Follicular Cell Adenoma^f^
Overall rate | 0/48 (0%) | 3/48 (6%) | 3/46 (7%) | 1/46 (2%) | 5/47 (11%)
Poly-3 test | P = 0.017 | P = 0.109 | P = 0.104 | P = 0.459 | P = 0.007
Follicular Cell Carcinoma, Multiple^a^ | 0/48 | 0/48 | 0/46 | 0/46 | 1/47
Follicular Cell Carcinoma (including multiple)^g^
Overall rate | 0/48 (0%) | 0/48 (0%) | 2/46 (4%) | 3/46 (7%) | 3/47 (6%)
Poly-3 test | P = 0.006 | – | P = 0.219 | P = 0.085 | P = 0.051
Follicular Cell Adenoma or Carcinoma^h^
Overall rate | 0/48 (0%) | 3/48 (6%) | 5/46 (11%) | 4/46 (9%) | 8/47 (17%)
Poly-3 test | P < 0.001 | P = 0.109 | P = 0.025 | P = 0.037 | P < 0.001

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ The historical incidence of thyroid gland follicular cell adenoma in NCTR control male F344/N Nctr rats is 0.6% (range 0.0–4.2%; Table A-3) for all studies and 2.1% (range 0.0–4.2%; Table A-3) for drinking water studies.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^d^ The historical incidence of thyroid gland follicular cell carcinoma in NCTR control male F344/N Nctr rats is 0.2% (range 0.0–2.1%; Table A-3) for all studies and 1.1% (range 0.0–2.1%; Table A-3) for drinking water studies.

^e^ The historical incidence of thyroid gland follicular cell adenoma or carcinoma in NCTR control male F344/N Nctr rats is 0.8% (range 0.0–4.2%; Table A-3) for all studies and 3.2% (range 2.1–4.2%; Table A-3) for drinking water studies.

^f^ The historical incidence of thyroid gland follicular cell adenoma in NCTR control female F344/N Nctr rats is 0.1% (range 0.0–2.9%; Table B-3) for all studies and 0.0% (Table B-3) for drinking water studies.

^g^ The historical incidence of thyroid gland follicular cell carcinoma in NCTR control female F344/N Nctr rats is 0.0% (Table B-3) for all studies and 0.0% (Table B-3) for drinking water studies.

^h^ The historical incidence of thyroid gland follicular cell adenoma or carcinoma in NCTR control female F344/N Nctr rats is 0.1% (range 0.0–2.9%; Table B-3) for all studies and 0.0% (Table B-3) for drinking water studies.

Morphologically, both follicular cell adenomas and follicular cell carcinomas were typical of spontaneous thyroid follicular neoplasms in F344/N Nctr rats. Adenomas were small circumscribed solitary lesions that slightly compressed adjacent parenchyma. The well-differentiated follicular cells were usually arranged in a single layer on the basement membrane. Adenomas were arranged in either a follicular or a papillary pattern that sometimes included cystic structures. Follicular cell carcinomas were larger masses without definite boundaries and with disorganized growth patterns. The cells were pleomorphic, sometimes atypical, and were often piled in multiple layers or arranged in solid clusters or sheets, with invasion of the thyroid capsule or blood vessels.

The drinking water administration of glycidamide was associated with a dose-related increase in squamous cell papilloma of the oral mucosa and squamous cell papilloma of the tongue in male F344/N Nctr rats, squamous cell papilloma and squamous cell carcinoma of the oral mucosa in female F344/N Nctr rats, and combined squamous cell papilloma or carcinoma of the oral mucosa or tongue in both sexes (Table 15). The incidence of squamous cell papilloma of the tongue was significant in male rats at 0.70 mM glycidamide and the incidence of combined squamous cell papilloma or carcinoma of the oral mucosa or tongue was significant in both sexes at 0.70 mM glycidamide. Microscopically, the oral squamous cell papillomas were elevated nodules or masses consisting of several layers of well-differentiated squamous cells covering multiple projections of a fibrovascular core. The squamous cell carcinomas on the tongue were gross lesions situated on the dorsum of the tongue. Microscopic examination revealed that they consisted of atypical squamous cells that invaded tissues underlying the epithelium.

Table 15 Incidences of Neoplasms of the Oral Cavity in Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | | 0.175 mM | 0.35 mM | 0.70 mM
Male
Oral Mucosa, Squamous Cell Papilloma^c^
Overall rate^a^ | 1/48 (2%) | 1/48 (2%) | | 0/48 (0%) | 2/47 (4%) | 3/48 (6%)
Poly-3 test^b^ | P = 0.050 | P = 0.754 | | P = 0.509N | P = 0.462 | P = 0.201
Oral Mucosa, Squamous Cell Carcinoma^d^
Overall rate | 1/48 (2%) | 0/48 (0%) | | 1/48 (2%) | 1/47 (2%) | 0/48 (0%)
Poly-3 test | P = 0.489N | P = 0.509N | | P = 0.751 | P = 0.735 | P = 0.568N
Tongue, Squamous Cell Papilloma^c^
Overall rate | 0/48 (0%) | 1/48 (2%) | | 0/48 (0%) | 1/47 (2%) | 4/48 (8%)
Poly-3 test | P = 0.003 | P = 0.493 | | – | P = 0.475 | P = 0.031
Tongue, Squamous Cell Carcinoma^d^
Overall rate | 0/48 (0%) | | 0/48 (0%) | 1/48 (2%) | 0/47 (0%) | 0/48 (0%)
Poly-3 test | P = 0.649N | | – | P = 0.494 | – | –
Oral Mucosa or Tongue, Squamous Cell Papilloma or Carcinoma^e^
Overall rate | 2/48 (4%) | | 2/48 (4%) | 2/48 (4%) | 3/47 (6%) | 7/48 (15%)
Poly-3 test | P = 0.005 | P = 0.686 | | P = 0.685 | P = 0.454 | P = 0.030
Female
Oral Mucosa: Squamous Cell Papilloma^f^
Overall rate | 1/48 (2%) | 1/48 (2%) | | 2/48 (4%) | 0/48 (0%) | 4/48 (8%)
Poly-3 test | P = 0.045 | P = 0.747 | | P = 0.477 | P = 0.539N | P = 0.070
Oral Mucosa: Squamous Cell Carcinoma^g^
Overall rate | 0/48 (0%) | 0/48 (0%) | | 0/48 (0%) | 1/48 (2%) | 2/48 (4%)
Poly-3 test | P = 0.015 | – | | – | P = 0.461 | P = 0.145
Tongue: Squamous Cell Papilloma^f^
Overall rate | 0/48 (0%) | 1/48 (2%) | | 0/48 (0%) | 1/48 (2%) | 0/48 (0%)
Poly-3 test | P = 0.548 | P = 0.488 | | – | P = 0.464 | –
Tongue: Squamous Cell Carcinoma^g^
Overall rate | 0/48 (0%) | 0/48 (0%) | | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Poly-3 test | P = 0.105 | – | | – | – | P = 0.397
Oral Mucosa or Tongue: Squamous Cell Papilloma or Carcinoma^h^
Overall rate | 1/48 (2%) | 2/48 (4%) | | 2/48 (4%) | 2/48 (4%) | 7/48 (15%)
Poly-3 test | P = 0.001 | P = 0.481 | | P = 0.477 | P = 0.437 | P = 0.005

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^c^ The historical incidence of squamous cell papilloma or papilloma in the oral cavity in NCTR control male F344/N Nctr rats is 0.3% (range 0.0–2.1%; Table A-7) for all studies and 1.0% (range 0.0–2.1%; Table A-7) for drinking water studies.

^d^ The historical incidence of squamous cell carcinoma in the oral cavity in NCTR control male F344/N Nctr rats is 0.2% (range 0.0–0.6%; Table A-7) for all studies and 0.0% (Table A-7) for drinking water studies.

^e^ The historical incidence of squamous cell papilloma, papilloma, or squamous cell carcinoma in the oral cavity in NCTR control male F344/N Nctr rats is 0.5% (range 0.0–2.1%; Table A-7) for all studies and 1.0% (range 0.0–2.1%; Table A-7) for drinking water studies.

^f^ The historical incidence of squamous cell papilloma or papilloma in the oral cavity in NCTR control female F344/N Nctr rats is 0.3% (range 0.0–2.1%; Table B-6) for all studies and 0% (Table B-6) for drinking water studies.

^g^ The historical incidence of squamous cell carcinoma in the oral cavity in NCTR control female F344/N Nctr rats is 0% (Table B-6) for all studies.

^h^ The historical incidence of squamous cell papilloma, papilloma, or squamous cell carcinoma in the oral cavity in NCTR control female F344/N Nctr rats is 0.3% (range 0.0–2.1%; Table B-6) for all studies and 0% (Table B-6) for drinking water studies.

Both sexes of F344/N Nctr rats had dose related increases in the incidence of mononuclear cell leukemia, with the increase in incidence being significant at 0.70 mM glycidamide (Table 16).

Table 16 Incidences of Mononuclear Cell Leukemia in Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male^a^
Overall rate^b^ | 21/48 (44%) | 26/48 (54%) | 27/48 (56%) | 27/47 (57%) | 31/48 (65%)
Poly-3 test^c^ | P = 0.008 | P = 0.211 | P = 0.093 | P = 0.097 | P = 0.006
Female^d^
Overall rate | 14/48 (29%) | 11/48 (23%) | 21/48 (44%) | 19/48 (40%) | 27/48 (56%)
Poly-3 test | <0.001 | 0.382N | 0.076 | 0.076 | <0.001

^a^ The historical incidence of mononuclear cell leukemia in NCTR control male F344/N Nctr rats is 47.1% (range 31.3–64.6%; Table A-6) for all studies and 60.4% (range 56.3–64.6%; Table A-6) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^d^ The historical incidence of mononuclear cell leukemia in NCTR control female F344/N Nctr rats is 33.2% (range 12.5–45.0%; Table B-8) for all studies and 20.8% (range 20.8%; Table B-8) for drinking water studies.

The consumption of glycidamide in the drinking water was associated with development of malignant mesothelioma on membranes surrounding the epididymis and on testicular tunics in male rats (Table 17). The incidence of malignant mesothelioma was significantly increased in the epididymis, testes, and combined testes and epididymis in male rats administered 0.35 and 0.70 mM glycidamide. Microscopically, malignant mesotheliomas in the epididymis and testicular tunics were characterized by complex papillary surface growths of one to several layers of polyhedral to cuboidal mesothelial cells on pedunculated fibrovascular stalks. The neoplastic cells had either abundant weakly eosinophilic cytoplasm and ovoid nuclei with one or more nucleoli or scanty cytoplasm and numerous small basophilic nuclei.

Table 17 Incidences of Malignant Mesothelioma in Male Rats in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Epididymis
Overall rate^b^ | 0/48 (0%) | 1/45 (2%) | 3/48 (6%) | 10/47 (21)% | 17/47 (36%)
Poly-3 test^c^ | P < 0.001 | P = 0.483 | P = 0.110 | P < 0.001 | P < 0.001
Testes
Overall rate | 0/48 (0%) | 1/47 (2%) | 3/48 (6%) | 6/47 (13)% | 13/48 (27%)
Poly-3 test | P < 0.001 | P = 0.490 | P = 0.110 | P = 0.010 | P < 0.001
Epididymis or Testes
Overall rate | 0/48 (0%) | 1/48 (2%) | 3/48 (6%) | 10/47 (21)% | 17/48 (35%)
Poly-3 test | P < 0.001 | P = 0.491 | P = 0.110 | P < 0.001 | P < 0.001
All Organs
Overall rate | 0/48 (0%) | 1/48 (2%) | 4/48 (8%) | 10/47 (21%) | 17/48 (35%)
Poly-3 test | P < 0.001 | P = 0.491 | P = 0.054 | P < 0.001 | P < 0.001

^a^ The historical incidence of malignant mesothelioma (all sites) in NCTR control male F344/N Nctr rats is 4.5% (range 0.0–6.4%; Table A-4) for all studies and 2.1% (range 0.0–4.2%; Table A-4) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

Glycidamide in the drinking water resulted in dose-related increases in malignant schwannoma in the heart of male F344/N Nctr rats (Table 18), with the incidence being significant at 0.70 mM glycidamide. The microscopic morphology of schwannomas in the heart was similar in lesions located in either subendocardial or intramural locations and consisted of spindeloid cells with fusiform granular to hyperchromatic nuclei and pale indistinct cytoplasm. The neoplastic cells were arranged in either discreet foci or more commonly infiltrated around and between adjacent myocardial fibers. The designation of malignancy was based primarily on the infiltrative characteristic.

Table 18 Incidences of Neoplasms of the Heart in Male Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Malignant Schwannoma^a^
Overall rate^b^ | 2/48 (4%) | 3/48 (6%) | 3/48 (6%) | 7/47 (15%) | 8/48 (17%)
Poly-3 test^c^ | P = 0.002 | P = 0.481 | P = 0.478 | P = 0.061 | P = 0.015

^a^ The historical incidence of malignant schwannoma of the heart in NCTR control male F344/N Nctr rats is 0.3% (range 0.0–2.1%; Table A-5) for all studies and 2.1% (range 2.1%; Table A-5) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

Female F344/N Nctr rats exposed to glycidamide in the drinking water had an increased prevalence of fibroadenomas in the mammary gland, with the incidence in all dose groups being significantly increased compared to the control group (Table 19). Microscopically mammary gland fibroadenomas were characterized by variable amounts of uniform well-differentiated glandular tissue or epithelium embedded in dense mature fibrous connective tissue. The neoplasms were well circumscribed and well demarcated from adjacent tissue.

Table 19 Incidences of Neoplasms of the Mammary Gland in Female Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Fibroadenoma^a^
Overall rate^b^ | 16/48 (33%) | 26/48 (54%) | 35/48 (73%) | 33/48 (69%) | 36/48 (75%)
Poly-3 test^c^ | P < 0.001 | P = 0.019 | P < 0.001 | P < 0.001 | P < 0.001

^a^ The historical incidence of mammary gland fibroadenoma in NCTR control female F344/N Nctr rats is 34.3% (range 25.5–42.6%; Table B-5) for all studies and 29.5% (range 25.5–33.3%; Table B-5) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

In female F344/N Nctr rats, there were dose-related increases in clitoral gland carcinoma, with the incidence being significantly increased at 0.35 and 0.70 mM glycidamide (Table 20). Acinar arrangement was typically not present in carcinomas; instead, the neoplastic cells were arranged in irregular lobules, cords, or sheets. The degree of cellular anaplasia varied. Female F344/N Nctr rats also had dose-related increases in squamous cell papilloma of the forestomach, with the incidence being significantly increased at 0.70 mM glycidamide (Table 21).

Table 20 Incidences of Neoplasms of the Clitoral Gland in Female Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Adenoma
Overall rate^a^ | 6/48 (13%) | 3/48 (6%) | 6/48 (13%) | 3/48 (6%) | 5/47 (11%)
Poly-3 test^b^ | P = 0.340 | P = 0.278N | P = 0.570 | P = 0.346N | P = 0.409
Carcinoma^c^
Overall rate | 4/48 (8%) | 6/48 (13%) | 7/48 (15%) | 11/48 (23%) | 14/47 (30%)
Poly-3 test | P < 0.001 | P = 0.345 | P = 0.233 | P = 0.017 | P < .001
Squamous Cell Papilloma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 2/47 (4%)
Poly-3 test | P = 0.013 | – | – | P = 0.461 | P = 0.136
Squamous Cell Carcinoma
Overall rate | 2/48 (4%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/47 (0%)
Poly-3 test | P = 0.111N | P = 0.252N | P = 0.252N | P = 0.283N | P = 0.387N
Adenoma, Carcinoma, and Squamous Cell Papilloma and Carcinoma (Combined)
Overall rate | 11/48 (23%) | 9/48 (19%) | 13/48 (27%) | 14/48 (29%) | 20/47 (43%)
Poly-3 test | P < 0.001 | P = 0.442N | P = 0.347 | P = 0.165 | P = 0.001

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^c^ The historical incidence of clitoral carcinoma in NCTR control female F344/N Nctr rats is 4.9% (range 0.0–10.4%; Table B-4) for all studies and 4.2% (range 2.1–6.3%; Table B-4) for drinking water studies.

Table 21 Incidences of Neoplasms of the Stomach (Forestomach) in Female Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Squamous Cell Papilloma^a^
Overall rate^b^ | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 0/47 (0%) | 3/46 (7%)
Poly-3 test^c^ | P = 0.015 | P = 0.487 | – | – | P = 0.048

^a^ The historical incidence squamous cell papilloma or carcinoma (combined) of the forestomach in NCTR control female F344/N Nctr rats is 0.1% (range 0.0–2.1%; Table B-7) for all studies and 1.0% (range 0.0–2.1%; Table B-7) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

#### Nonneoplastic Findings

Male and female F344/N Nctr rats administered glycidamide in the drinking water had dose-related increases in brain gliosis (Table 22 and Table 23).

Table 22 Incidences of Selected Nonneoplastic Lesions in Male Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Brain
Gliosis
Overall rate^a^ | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 0/47 (0%) | 4/48 (8%)
Poly-3 test^b^ | P = 0.003 | P = 0.491 | – | – | P = 0.030
Average severity^c^ | – | 1.0 | – | – | 2.8
Epididymis
Exfoliated Germ Cells
Overall rate | 0/48 (0%) | 1/45 (2%) | 2/48 (4%) | 3/47 (6%) | 4/47 (9%)
Poly-3 test | P = 0.009 | P = 0.485 | P = 0.228 | P = 0.102 | P = 0.029
Average severity | – | 3.0 | 2.5 | 3.0 | 3.3
Liver
Hepatocyte Degeneration
Overall rate | 2/47 (4%) | 6/47 (13%) | 6/48 (13%) | 10/47 (21%) | 8/47 (17%)
Poly-3 test | P = 0.006 | P = 0.128 | P = 0.130 | P = 0.007 | P = 0.011
Average severity | 4.0 | 3.8 | 3.8 | 3.6 | 3.8
Necrosis
Overall rate | 1/47 (2%) | 5/47 (11%) | 2/48 (4%) | 7/47 (15%) | 5/47 (11%)
Poly-3 test | P = 0.025 | P = 0.092 | P = 0.495 | P = 0.019 | P = 0.043
Average severity | 1.0 | 3.2 | 3.0 | 3.0 | 3.4

^a^ Number of animals with lesion per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated (0.0875, 0.175, 0.35, and 0.70 mM glycidamide) group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

^c^ Severity was graded as 1, minimal; 2, mild; 3, moderate; and 4, marked.

Table 23 Incidence of Selected Nonneoplastic Lesions in Female Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Brain
Gliosis
Overall rate^a^ | 0/48 (0%) | 0/48 (0%) | 4/48 (8%) | 4/48 (8%) | 4/48 (8%)
Poly-3 test^b^ | P = 0.003 | – | P =0.052 | P = 0.042 | P = 0.020
Average severity^c^ | – | – | 2.5 | 2.0 | 2.5
Bone Marrow
Hyperplasia
Overall rate | 2/48 (4%) | 6/48 (13%) | 7/46 (15%) | 8/47 (17%) | 14/47 (30%)
Poly-3 test | P < 0.001 | P = 0.123 | P = 0.067 | P = 0.025 | P < 0.001
Average severity | 2.0 | 2.3 | 2.3 | 2.1 | 2.4
Spinal Cord (Lumbar)
Axonal Degeneration
Overall rate | 5/48 (10%) | 6/48 (13%) | 5/47 (11%) | 6/48 (13%) | 9/48 (19%)
Poly-3 test | P = 0.027 | P = 0.458 | P = 0.584 | P = 0.388 | P = 0.042
Average severity | 1.0 | 1.0 | 1.0 | 1.0 | 1.0
Uterus
Endometrium, Hyperplasia, Cystic
Overall rate | 11/48 (23%) | 17/48 (35%) | 14/48 (29%) | 14/48 (29%) | 23/48 (48%)
Poly-3 test | P < 0.001 | P = 0.089 | P = 0.277 | P = 0.170 | P < 0.001
Average severity | 1.6 | 1.5 | 2.2 | 2.4 | 1.8

^a^ Number of animals with lesion per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated (0.0875, 0.175, 0.35, and 0.70 mM glycidamide) group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^c^ Severity was graded as 1, minimal; 2, mild; 3, moderate; and 4, marked.

Male F344/N Nctr rats also had glycidamide-related increases in exfoliated germ cells in the epididymis, hepatocyte degeneration, and liver necrosis (Table 22). The hepatocellular degeneration was characterized by either affected cells displaying increased cytoplasmic granularity, cell swelling, and eosinophilia or by cystic enlargement of cells of variable size that in some areas contained finely stained eosinophilic material. The hepatocellular necrosis featured single cells with condensed hyper-eosinophilic cytoplasm with an irregular cell outline or by single or multiple foci of swollen hepatocytes with increased eosinophilia and a nucleus undergoing lysis. The distribution of these changes was variable.

Additional nonneoplastic lesions associated with glycidamide exposure in female F344/N Nctr rats included bone marrow hyperplasia, axonal degeneration of the lumbar spinal cord, and uterine endometrial hyperplasia (Table 23).

## Mice

### Two-week Study

Three of the male mice exposed to 7.03 mM glycidamide in the drinking water displayed an abnormal posture or gait after 14 days of treatment. A single female mouse treated with 7.03 mM glycidamide in the drinking water displayed an abnormal posture and gait after 14 days of treatment. There were no other significant in-life observations in any of the other treatment groups.

Male mice administered 3.52 and 7.03 mM glycidamide in the drinking water for 14 days weighed 87% and 61% of the control mice; female mice given 7.03 mM glycidamide in the drinking water for 14 days weighed 69% of the control mice (Table 24). Body weights in the other treatment groups after 14 days of exposure were within 10% of the control mice.

Table 24 Survival, Body Weights, Food Consumption, and Water Consumption of Mice in the Two-week Drinking Water Study of Glycidamide

tab | Survival^a^ | Mean Body Weight^b^ (g) | | | Final Weight Relative to Controls (%) | Mean Food Consumption^c^ | | Mean Water Consumption^c^
tab | Survival^a^ | Day 1 | Day 7 | Day 14 | Final Weight Relative to Controls (%) | Week 1 | Week 2 | Week 1 | Week 2
Drinking Water
Male
0.0 mM | 4/4 | 19.0 ± 0.7 | 20.9 ± 0.9 | 22.1 ± 1.0 | | 2.8 (100) | 3.2 (100) | 5.0 (100) | 4.7 (100)
0.14 mM | 4/4 | 19.0 ± 0.6 | 20.7 ± 0.7 | 20.0 ± 0.6 | 91 | 2.6 (93) | 3.0 (94) | 5.1 (102) | 4.3 (91)
0.35 mM | 4/4 | 18.9 ± 0.9 | 20.9 ± 0.6 | 21.4 ± 0.6 | 97 | 2.9 (104) | 3.2 (100) | 5.3 (106) | 4.3 (91)
0.70 mM | 4/4 | 19.1 ± 0.7^d^ | 20.3 ± 1.0^d^ | 21.4 ± 0.5^d^ | 97 | 4.2 (150) | 3.1 (97) | 5.6 (112) | 4.5 (96)
1.41 mM | 4/4 | 19.2 ± 0.4 | 20.4 ± 0.5 | 20.7 ± 0.6 | 94 | 2.7 (96) | 3.2 (100) | 3.3 (66) | 5.2 (111)
3.52 mM | 4/4 | 19.1 ± 0.8 | 19.0 ± 0.6 | 19.3 ± 0.8* | 87 | 3.0 (107) | 2.9 (91) | 5.2 (104) | 4.5 (96)
7.03 mM | 4/4 | 19.6 ± 0.7 | 15.7 ± 0.6* | 13.4 ± 0.4* | 61 | 1.8 (64) | 1.6 (50) | 4.6 (92) | 3.4 (72)
Female
0.0 mM | 4/4 | 15.4 ± 0.3 | 16.5 ± 0.05 | 16.3 ± 0.2 | | 2.4 (100) | 3.6 (100) | 5.7 (100) | 4.2 (100)
0.14 mM | 4/4 | 15.6 ± 0.4 | 17.4 ± 0.2 | 16.9 ± 0.1 | 104 | 2.7 (113) | 2.8 (78) | 5.0 (88) | 4.1 (98)
0.35 mM | 4/4 | 15.2 ± 0.1 | 16.7 ± 0.3 | 16.5 ± 0.2 | 102 | 2.9 (121) | 2.7 (75) | 5.3 (93) | 4.4 (105)
0.70 mM | 4/4 | 15.1 ± 0.6 | 16.1 ± 0.5 | 16.7 ± 0.3 | 103 | 2.8 (117) | 3.0 (83) | 4.3 (75) | 3.8 (90)
1.41 mM | 4/4 | 15.5 ± 0.3 | 16.6 ± 0.2 | 16.3 ± 0.1 | 100 | 2.4 (100) | 2.6 (72) | 4.7 (82) | 4.0 (95)
3.52 mM | 4/4 | 15.4 ± 0.3 | 14.8 ± 0.5* | 14.9 ± 0.5* | 92 | 2.2 (92) | 2.3 (64) | 5.1 (89) | 4.1 (98)
7.03 mM | 4/4 | 15.9 ± 0.3 | 13.4 ± 0.1* | 11.3 ± 0.3* | 69 | 1.5 (63) | 1.8 (50) | 4.1 (72) | 2.6 (62)

^a^ Number of animals surviving at 14 days/number initially in group.

^b^ Weights are given as mean ± standard error. An asterisk (*) denotes significant difference (p < 0.05) from control at the same time point.

^c^ Food and water consumption are expressed as grams per animal per day and were measured on a per cage basis. Values in parentheses indicate the percentage of controls. Statistical analyses were not conducted on food and water consumption because there was only one cage per treatment group.

^d^ Based upon three animals: at necropsy, one of the mice was discovered to be mis-sexed.

Water and food consumption were relatively constant at each time point and for each dose group, with the possible exception of food consumption in mice receiving 7.03 mM glycidamide in the drinking water (Table 24). Male mice administered 0.14, 0.35, 0.70, 1.41, 3.52, and 7.03 mM glycidamide in the drinking water consumed approximately 2.8, 6.9, 14.8, 25.4, 77.7, and 167 mg glycidamide per kg body weight per day, respectively; the comparable values for female mice were 3.2, 8.9, 15.1, 32.5, 95.0, and 164 mg glycidamide per kg body weight per day.

There were no nonneoplastic lesions observed either grossly or microscopically that could be attributed to the administration of glycidamide in the drinking water.

Exposure Concentration Selection Rationale: The selection of doses for the 3-month glycidamide drinking water study was based upon the effects observed in the 2-week studies of glycidamide (this study) and acrylamide,^4^ which were conducted simultaneously. Both 7.03 mM glycidamide and 7.03 mM acrylamide in drinking water resulted in decreased body weight. In addition, none of the mice receiving 7.03 mM acrylamide survived the 2-week treatment period. Since one of the goals of this study was to compare acrylamide with glycidamide, a high dose of 3.52 mM glycidamide (306 ppm glycidamide) was selected for the 3-month drinking water study, with the remaining doses being 0, 0.14, 0.35, 0.70, and 1.41 mM glycidamide (0, 12.2, 30.6, 61.2, and 122 ppm glycidamide). These doses were identical to those used in the 3-month drinking water study with acrylamide.^4^

### Three-month Study

One female mouse administered 1.41 mM glycidamide in the drinking water died on day 22 (Table 25). Two male mice administered 3.52 mM glycidamide in the drinking water developed hind limb paresis beginning at 68 to 70 days on the experiment. The paresis was not of sufficient severity to necessitate removing the mice from the study. Hind limb paresis did not occur in female mice administered 3.52 mM glycidamide. There were no other significant in-life observations in any of the other treatment groups.

Table 25 Survival and Body Weights of Mice in the Three-month Drinking Water Study of Glycidamide

Treatment | Survival^a^ | Mean Body Weight (g)^b^ | | Final weight Relative to Controls (%)
Treatment | Survival^a^ | Week 0 | Week 14 | Final weight Relative to Controls (%)
Male
0.0 mM | 8/8 | 17.9 ± 0.4 | 27.1 ± 0.4
0.14 mM | 8/8 | 18.1 ± 0.4 | 27.2 ± 0.4 | 100
0.35 mM | 8/8 | 16.7 ± 0.4 | 29.5 ± 0.4 | 109
0.70 mM | 8/8 | 17.8 ± 0.4 | 25.4 ± 0.4 | 94
1.41 mM | 8/8 | 17.4 ± 0.4 | 25.1 ± 0.4 | 92
3.52 mM | 8/8 | 18.1 ± 0.4 | 24.4 ± 0.4 | 90
Female
0.0 mM | 8/8 | 13.9 ± 0.2 | 21.3 ± 0.2
0.14 mM | 8/8 | 13.6 ± 0.2 | 21.1 ± 0.2 | 99
0.35 mM | 8/8 | 13.5 ± 0.2 | 21.5 ± 0.2 | 101
0.70 mM | 8/8 | 14.6 ± 0.2 | 21.5 ± 0.2 | 101
1.41 mM | 7/8 | 14.4 ± 0.2 | 20.9 ± 0.2 | 98
3.52 mM | 8/8 | 14.6 ± 0.2 | 19.5 ± 0.2 | 91

^a^ Number of animal surviving until study termination/number of animals initially in group.

^b^ Weights are given as LS means ± population standard error of the mean.

Glycidamide in the drinking water resulted in significant dose-related effects on body weight in male mice only (Table 25 and Figure 9). Pairwise comparisons indicated that 3.52 mM glycidamide was associated with significant decreases in body weight gain in the male mice over the 3 month treatment period. At the end of the 3-month period, the mice weighed 90% of the male control group.

Figure 9

Growth Curves for Male and Female Mice in the Three-month Drinking Water Study of Glycidamide

Male mice given 0.0, 0.14, 0.35, 0.70, 1.41, and 3.52 mM glycidamide in the drinking water consumed approximately 6.4, 6.1, 7.0, 7.0, 6.5, and 5.7 ml drinking water per day (Table 26), which was equivalent to 0.0, 3.2, 9.1, 19.2, 36.0, and 81.5 mg glycidamide per kg body weight per day; the comparable values for female mice were 6.4, 6.2, 6.3, 6.1, 6.8, and 5.5 ml drinking water per day (Table 26), which was equivalent to 0.0, 4.1, 10.8, 20.1, 45.3, and 96.5 mg glycidamide per kg body weight per day.

Table 26 Water Consumption^a^ of Mice in the Three-month Drinking Water Study of Glycidamide

Week | 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Male
2 | 4.9 | 4.9 | 5.0 | 4.7 | 5.7 | 5.0
3 | 7.0 | 8.7 | 6.9 | 7.9 | 6.8 | 8.7
4 | 5.6 | 6.6 | 6.7 | 11.8 | 5.8 | 5.1
5 | 5.4 | 6.1 | 6.1 | 5.1 | 5.3 | 5.0
6 | 6.9 | 6.8 | 7.3 | 7.3 | 7.2 | 6.7
7 | 8.0 | 7.4 | 8.0 | 9.6 | 7.4 | 5.6
8 | 6.6 | 6.0 | 6.3 | 7.0 | 5.8 | 5.2
9 | 6.4 | 6.3 | 6.5 | 6.3 | 6.8 | 5.5
10 | 5.9 | 6.6 | 6.2 | 7.5 | 7.3 | 5.4
11 | 4.7 | 3.1 | 7.9 | 7.8 | 6.6 | 5.6
12 | 7.3 | 6.1 | 9.7 | 6.1 | 7.2 | 5.5
13 | 9.9 | 6.1 | 7.5 | 6.0 | 6.3 | 5.4
14 | 5.3 | 5.4 | 7.1 | 5.0 | 7.1 | 5.1
Female
2 | 3.9 | 5.7 | 3.6 | 5.0 | 6.0 | 4.1
3 | 5.9 | 7.0 | 6.0 | 6.7 | 7.6 | 5.6
4 | 6.3 | 5.4 | 6.1 | 6.0 | 6.7 | 5.1
5 | 5.2 | 5.1 | 5.0 | 4.1 | 5.9 | 4.1
6 | 7.6 | 5.8 | 5.1 | 5.9 | 7.5 | 5.5
7 | 6.2 | 5.2 | 6.0 | 5.7 | 5.7 | 4.6
8 | 5.4 | 6.3 | 5.9 | 5.7 | 6.7 | 4.4
9 | 5.4 | 5.4 | 5.1 | 4.6 | 5.4 | 4.0
10 | 5.5 | 4.9 | 6.6 | 4.9 | 5.4 | 4.8
11 | 4.9 | 4.4 | 6.0 | 7.0 | 5.4 | 8.0
12 | 5.0 | 4.9 | 4.6 | 4.8 | 5.4 | 4.0
13 | 5.9 | 4.9 | 6.4 | 5.2 | 5.8 | 5.0

^a^ Water consumption is given the mean of two cages and is expressed as grams per animal per day.

Male mice given 0.0, 0.14, 0.35, 0.70, 1.41, and 3.52 mM glycidamide in the drinking water consumed approximately 3.4, 4.1, 3.5, 3.3, 3.2, and 3.2 g feed per day (Table 27); the comparable values for female mice were 4.2, 4.0, 3.8, 3.7, 4.0, and 3.7 g feed per day (Table 27).

Table 27 Food Consumption^a^ of Mice in the Three-month Drinking Water Study of Glycidamide

Week | 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Male
3 | 4.7 | 6.2 | 4.0 | 3.4 | 3.8 | 5.8
4 | 2.5 | 3.6 | 3.1 | 2.7 | 2.8 | 2.7
5 | 3.1 | 3.3 | 3.7 | 3.6 | 3.5 | 3.9
6 | 3.3 | 3.1 | 2.6 | 3.1 | 3.1 | 2.8
7 | 3.5 | 4.1 | 4.4 | 3.3 | 3.4 | 3.1
8 | 2.7 | 3.0 | 2.9 | 3.1 | 3.3 | 3.0
9 | 3.8 | 4.5 | 3.4 | 3.2 | 2.8 | 2.7
10 | 2.8 | 3.3 | 2.7 | 3.0 | 3.0 | 2.5
11 | 1.0 | 7.0 | 4.3 | 4.1 | 1.4 | 1.1
12 | 7.3 | 8.1 | 3.4 | 3.6 | 5.1 | 4.0
13 | 2.8 | 3.4 | 4.1 | 3.0 | 3.5 | 3.0
14 | 3.2 | 3.1 | 3.2 | 3.1 | 2.8 | 3.5
Female
3 | 4.1 | 6.9 | 2.8 | 2.8 | 4.6 | 3.4
4 | 2.7 | 3.7 | 3.7 | 3.2 | 2.9 | 2.7
5 | 3.7 | 3.4 | 2.9 | 2.8 | 3.1 | 2.9
6 | 6.0 | 3.0 | 1.9 | 3.0 | 3.1 | 2.8
7 | 3.2 | 3.4 | 4.0 | 3.4 | 2.7 | 3.1
8 | 2.7 | 2.6 | 2.7 | 4.2 | 3.9 | 2.8
9 | 3.4 | 3.4 | 3.4 | 3.1 | 3.6 | 3.2
10 | 2.6 | 2.6 | 3.9 | 2.8 | 3.0 | 3.0
11 | 5.2 | 1.2 | 1.9 | 2.0 | 2.2 | 5.6
12 | 4.4 | 6.5 | 3.5 | 3.7 | 7.4 | 3.4
13 | 2.9 | 2.6 | 3.6 | 2.9 | 3.0 | 2.9

^a^ Food consumption is given the mean of two cages and is expressed as grams per animal per day.

Necropsy body weights were decreased in male and female mice administered 3.52 mM glycidamide in the drinking water for 3 months (Table E-4). Necropsy body weights and the liver-weight-to-brain-weight ratio were increased in male mice receiving 0.35 mM glycidamide. Brain weights were decreased in male mice given 3.52 mM glycidamide (Table E-4).

The only gross observation in the mice given glycidamide in the drinking water that was considered to be treatment related was marked dilatation of the urinary bladder in one of eight males in the 3.52 mM group (Table 28). This animal also had a clinical observation of partial paresis of the rear legs.

Table 28 Incidence of Observations and Nonneoplastic Lesions in Mice in the Three-month Drinking Water Study of Glycidamide^a^

| 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Males
Animals initially in study | 8 | 8 | 8 | 8 | 8 | 8
Hind limb
Paresis | 0 | 0 | 0 | 0 | 0 | 2
Peripheral nerve
Axon degeneration | 0 | –^b^ | – | – | – | 1 (1.0)
Urinary bladder
Dilatation | 0 | – | – | – | – | 1 (4.0)
Testes
Germinal epithelium degeneration | 0 | – | – | – | 0 | 7 (1.7)
Females
Animals initially in study | 8 | 8 | 8 | 8 | 8 | 8
Hind limb
Paresis | 0 | 0 | 0 | 0 | 0 | 0
Peripheral nerve
Axon degeneration | 0 | – | – | – | – | 1 (1.0)
Urinary bladder
Dilatation | 0 | – | – | – | – | 0

^a^ Data are reported as the number of lesions per number of mice (8) examined microscopically. The average severity is given in parentheses. Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

^b^ Not examined.

Target tissues (sciatic nerve, spinal cord, skeletal muscle of the hind limb, testes, and ovaries) were examined microscopically in progressively lower dose groups until a no-observed-adverse-effect level was reached. Peripheral neuropathy was observed in the sciatic nerve of one female and one male treated with 3.52 mM glycidamide (Table 28). The changes were characterized by nerve fiber degeneration with dilatation and vacuolization of myelin sheaths along with swollen and shrunken axons, with minimal severity. In male mice, minimal to mild depletion of the testicular germinal cell epithelium occurred in seven of eight mice administered 3.52 mM glycidamide (Table 28).

Exposure Concentration Selection Rationale: The selection of doses for the 2-year glycidamide drinking water study was based upon the effects observed in the 3-month drinking water studies with glycidamide (this study) and acrylamide,^4^ which were conducted simultaneously. Both 3.52 mM glycidamide and 3.52 mM acrylamide in drinking water resulted in hind limb paresis and decreased body weight. Decreases in body weight were also observed with 1.41 mM acrylamide. Since one of the goals of this study was to compare acrylamide with glycidamide, a high dose of 0.70 mM glycidamide (61.2 ppm glycidamide) was selected for the chronic 2-year drinking water study, with the remaining doses being 0.0, 0.0875, 0.175, and 0.35 mM glycidamide (0, 7.65, 15.3, and 30.6 ppm glycidamide). These doses were identical to those used in the 2-year chronic bioassay with acrylamide.^4^

### Two-year Study

#### Survival and Cause of Death

Glycidamide in the drinking water resulted in a dose-related trend in survival in male and female B6C3F1/Nctr mice (Table 29 and Figure 10). Compared to control mice, male mice administered 0.175, 0.35, and 0.70 mM glycidamide and female mice administered 0.35 and 0.70 mM glycidamide had decreased survival. The primary cause for early removal or death of male mice was neoplasms, including Harderian gland adenoma, malignant lymphoma, hepatocellular carcinoma, and various types of mesenchymal skin tumors. The primary cause for early removal or death of female mice was neoplasms, including Harderian gland adenoma, malignant lymphoma, mammary gland adenoacanthoma or adenocarcinoma, and various types of mesenchymal skin tumors.

Table 29 Survival and Disposition of Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male
Animals initially in study | 48 | 48 | 48 | 48 | 48
Moribund | 2 | 4 | 12 | 18 | 13
Natural deaths | 1 | 3 | 2 | 4 | 10
Animals surviving to study termination^a^ | 45 | 41 | 34 | 26 | 25
Percent probability of survival at end of study^b^ | 94 | 85 | 71 | 54 | 52
Mean survival (weeks)^c^ | 100.5 | 97.9 | 97.1 | 94.7 | 93.9
Survival analysis^d^ | P < 0.001 | P = 0.191 | P = 0.008 | P < 0.001 | P < 0.001
Female
Animals initially in study | 48 | 48 | 48 | 48 | 48
Moribund | 4 | 2 | 8 | 12 | 34
Natural deaths | 3 | 4 | 2 | 5 | 6
Animals surviving to study termination | 41 | 42 | 38 | 31 | 8
Percent probability of survival at end of study | 85 | 88 | 79 | 67 | 17
Mean survival (weeks) | 101.1 | 98.9 | 100.5 | 98.3 | 82.6
Survival analysis | P < 0.001 | P = 0.804 | P = 0.408 | P = 0.024 | P < 0.001

^a^ Censored from the survival analyses.

^b^ Kaplan-Meier survival estimates.

^c^ Mean of all deaths (censored and uncensored).

^d^ The result of the trend test is in the 0.0 mM glycidamide column, and the results of the pairwise comparisons^62^ with the 0.0 mM glycidamide are in the treatment group columns.

Figure 10

Kaplan-Meier Survival Curves for Male and Female Mice Administered Glycidamide (mM) in Drinking Water for Two Years

#### Body Weights and Food and Water Consumption

There were no significant body weight changes in male B6C3F1/Nctr mice administered glycidamide in the drinking water (Figure 11 and Table 30). Administering glycidamide in the drinking water to female B6C3F1/Nctr mice resulted in only sporadic statistically significant decreases in body weight, with the magnitude of the change never exceeding 5% of the mean control body weight at the same time point (Figure 11 and Table 31).

Figure 11

Growth Curves for Male and Female Mice Administered Glycidamide (mM) in Drinking Water for Two Years

Table 30 Mean Body Weights and Survival of Male Mice in the Two-year Drinking Water Study of Glycidamide

Weeks on Study | 0 mM | | 0.0875 mM | | | 0.175 mM | | | 0.35 mM | | | | 0.70 mM
Weeks on Study | Mean Wt. (g) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors
4 | 21.7 | 48 | 21.9 | 101.0 | 48 | 22.0 | 101.6 | 48 | 21.5 | 98.9 | | 48 | 21.4 | 98.7 | 48
8 | 25.1 | 48 | 25.0 | 99.3 | 48 | 25.2 | 100.2 | 48 | 24.4 | 97.0 | | 48 | 24.6 | 98.0 | 48
12 | 27.2 | 48 | 26.6 | 97.8 | 48 | 26.8 | 98.6 | 48 | 26.5 | 97.5 | | 48 | 26.6 | 97.7 | 48
16 | 29.0 | 48 | 29.0 | 99.8 | 48 | 28.6 | 98.5 | 48 | 28.3 | 97.4 | | 48 | 28.9 | 99.4 | 47
20 | 30.5 | 48 | 30.2 | 98.7 | 48 | 29.9 | 97.8 | 48 | 30.1 | 98.4 | | 48 | 30.2 | 98.9 | 47
24 | 31.2 | 48 | 31.1 | 99.5 | 48 | 30.8 | 98.7 | 48 | 31.0 | 99.2 | | 48 | 31.2 | 99.8 | 47
28 | 31.7 | 48 | 31.6 | 99.6 | 48 | 31.4 | 98.9 | 48 | 31.5 | 99.4 | | 47 | 31.8 | 100.2 | 47
32 | 32.1 | 48 | 31.8 | 98.8 | 48 | 31.6 | 98.4 | 48 | 31.6 | 98.4 | | 47 | 32.0 | 99.5 | 47
36 | 32.5 | 47 | 31.9 | 98.2 | 48 | 31.8 | 98.0 | 47 | 32.1 | 98.7 | | 47 | 32.3 | 99.3 | 47
40 | 32.2 | 47 | 31.9 | 99.1 | 48 | 31.6 | 98.2 | 47 | 31.7 | 98.3 | | 47 | 32.2 | 99.9 | 47
44 | 32.7 | 47 | 32.1 | 98.2 | 48 | 32.1 | 98.2 | 47 | 32.2 | 98.7 | | 47 | 32.1 | 98.3 | 47
48 | 32.3 | 47 | 32.0 | 98.9 | 48 | 32.3 | 99.9 | 47 | 31.9 | 98.5 | | 47 | 32.2 | 99.6 | 47
52 | 32.6 | 47 | 32.0 | 98.1 | 48 | 31.8 | 97.7 | 47 | 31.9 | 97.9 | | 46 | 32.3 | 99.2 | 47
56 | 32.8 | 47 | 32.7 | 99.5 | 48 | 32.1 | 97.9 | 47 | 32.4 | 98.8 | | 46 | 32.5 | 99.1 | 47
60 | 33.4 | 47 | 32.6 | 97.7 | 47 | 33.3 | 99.6 | 46 | 32.7 | 98.0 | | 45 | 33.0 | 98.9 | 46
64 | 33.4 | 47 | 33.3 | 99.8 | 47 | 33.0 | 98.9 | 46 | 32.9 | 98.7 | | 45 | 33.5 | 100.3 | 46
68 | 33.9 | 47 | 33.7 | 99.3 | 47 | 33.3 | 98.2 | 46 | 33.6 | 99.0 | | 45 | 33.7 | 99.4 | 46
72 | 33.8 | 47 | 32.9 | 97.3 | 47 | 33.0 | 97.5 | 46 | 33.7 | 99.6 | | 44 | 33.5 | 99.1 | 45
76 | 33.6 | 47 | 33.5 | 99.5 | 46 | 33.5 | 99.5 | 45 | 33.2 | 98.8 | | 44 | 33.7 | 100.3 | 45
80 | 33.7 | 47 | 33.3 | 98.8 | 46 | 33.4 | 99.0 | 45 | 32.8 | 97.4 | | 41 | 33.1 | 98.3 | 43
84 | 33.6 | 47 | 33.4 | 99.7 | 46 | 33.0 | 98.5 | 43 | 33.0 | 98.3 | | 38 | 33.7 | 100.5 | 39
88 | 33.1 | 47 | 33.2 | 100.3 | 46 | 32.8 | 99.2 | 40 | 32.8 | 99.0 | | 37 | 33.4 | 100.9 | 35
92 | 33.0 | 47 | 32.7 | 98.9 | 45 | 32.9 | 99.7 | 38 | 32.8 | 99.4 | | 36 | 33.2 | 100.4 | 33
96 | 33.1 | 47 | 32.6 | 98.5 | 43 | 32.5 | 98.1 | 37 | 32.4 | 97.7 | | 31 | 33.1 | 100.1 | 31
100 | 33.3 | 46 | 32.7 | 98.4 | 42 | 32.8 | 98.7 | 36 | 32.1 | 96.7 | | 30 | 33.1 | 99.6 | 29
104 | 32.9 | 45 | 32.6 | 99.3 | 41 | 32.6 | 99.3 | 34 | 32.3 | 98.3 | | 28 | 33.0 | 100.5 | 25
Mean for Weeks
4–104 | 31.7 | | 31.4 | | | 31.3 | | | 31.2 | | | | 31.6

Table 31 Mean Body Weights and Survival of Female Mice in the Two-year Drinking Water Study of Glycidamide

Weeks on Study | 0 mM | | 0.0875 mM | | | 0.175 mM | | | 0.35 mM | | | 0.70 mM
Weeks on Study | Mean Wt. (g) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors | Mean Wt. (g) | Wt. (% of controls) | No. of Survivors
4 | 17.3* | 48 | 17.2 | 99.6 | 48 | 17.3 | 99.9 | 48 | 16.8 | 97.1 | 48 | 16.9 | 97.6 | 48
8 | 19.3* | 48 | 19.0 | 98.5 | 48 | 19.0 | 98.3 | 48 | 18.9 | 97.7 | 48 | 18.7* | 96.6 | 48
12 | 20.5 | 48 | 20.6 | 100.4 | 48 | 20.3 | 99.2 | 48 | 20.3 | 98.8 | 48 | 20.2 | 98.5 | 48
16 | 21.6 | 48 | 21.8 | 101.3 | 48 | 21.4 | 99.0 | 48 | 21.6 | 100.1 | 48 | 21.3 | 98.6 | 48
20 | 22.8* | 48 | 22.4 | 98.4 | 48 | 22.4 | 98.2 | 48 | 22.3 | 98.0 | 48 | 22.0* | 96.5 | 48
24 | 23.3* | 48 | 23.0 | 98.5 | 48 | 23.0 | 98.5 | 48 | 22.9 | 98.3 | 48 | 22.7 | 97.2 | 48
28 | 24.1* | 48 | 23.8 | 98.4 | 48 | 24.0 | 99.2 | 48 | 23.6 | 97.9 | 48 | 23.2* | 96.0 | 48
32 | 24.3 | 48 | 23.9 | 98.2 | 48 | 24.7 | 101.4 | 48 | 24.3 | 99.8 | 48 | 23.7 | 97.5 | 48
36 | 25.0* | 48 | 24.4 | 97.9 | 48 | 24.7 | 99.0 | 48 | 24.6 | 98.3 | 47 | 24.1* | 96.4 | 48
40 | 25.0* | 48 | 24.5 | 97.8 | 48 | 24.7 | 98.8 | 48 | 24.7 | 98.8 | 47 | 24.3* | 96.9 | 48
44 | 25.3* | 48 | 24.9 | 98.6 | 48 | 24.9 | 98.6 | 48 | 24.9 | 98.6 | 47 | 24.3* | 96.3 | 46
48 | 25.4* | 48 | 25.0 | 98.5 | 48 | 25.4 | 100.1 | 48 | 24.9 | 98.0 | 47 | 24.7 | 97.4 | 46
52 | 25.5 | 48 | 25.2 | 99.0 | 48 | 25.5 | 100.1 | 48 | 25.5 | 100.1 | 47 | 24.9 | 97.7 | 45
56 | 26.2* | 48 | 25.8 | 98.4 | 48 | 26.0 | 99.1 | 48 | 25.5 | 97.3 | 46 | 25.3* | 96.5 | 44
60 | 26.4* | 47 | 26.3 | 99.5 | 48 | 26.3 | 99.8 | 48 | 26.0 | 98.6 | 46 | 25.6* | 96.9 | 43
64 | 26.7 | 47 | 26.6 | 99.3 | 48 | 27.1 | 101.2 | 48 | 27.0 | 100.9 | 46 | 26.2 | 97.8 | 41
68 | 27.1 | 47 | 27.1 | 100.0 | 48 | 27.3 | 100.7 | 48 | 27.6 | 101.7 | 46 | 27.2 | 100.2 | 41
72 | 27.3 | 47 | 26.8 | 98.0 | 48 | 27.0 | 98.8 | 48 | 27.1 | 99.1 | 46 | 26.9 | 98.4 | 38
76 | 27.6 | 47 | 26.9 | 97.5 | 47 | 27.8 | 100.7 | 47 | 27.4 | 99.4 | 44 | 27.2 | 98.5 | 37
80 | 27.7 | 47 | 27.0 | 97.5 | 44 | 27.5 | 99.5 | 45 | 27.3 | 98.7 | 42 | 28.0 | 101.3 | 29
84 | 27.9 | 46 | 27.1 | 97.3 | 44 | 27.5 | 98.8 | 43 | 27.6 | 99.0 | 42 | 28.0 | 100.3 | 24
88 | 28.1* | 46 | 27.3 | 97.0 | 44 | 27.6 | 98.4 | 42 | 28.0 | 99.7 | 42 | 29.2 | 103.8 | 23
92 | 27.9* | 45 | 27.6 | 98.8 | 44 | 27.5 | 98.6 | 41 | 28.1 | 100.5 | 40 | 28.9 | 103.5 | 19
96 | 28.0* | 45 | 27.6 | 98.7 | 44 | 27.9 | 99.7 | 41 | 28.5 | 101.7 | 39 | 29.2 | 104.5 | 12
100 | 28.7 | 43 | 28.1 | 98.1 | 44 | 27.9 | 97.3 | 41 | 28.2 | 98.5 | 36 | 27.9 | 97.2 | 9
104 | 28.6 | 41 | 28.1 | 98.3 | 42 | 28.0 | 97.9 | 39 | 28.9 | 101.1 | 34 | 28.0 | 97.8 | 8
Mean for Weeks
4–104 | 25.3 | | 24.9 | | | 25.1 | | | 25.1 | | | 24.9

* In the 0.0 mM glycidamide column “*” indicates a significant trend (p < 0.05); in the treatment column “*” indicates a significant (p < 0.05) pairwise comparison of the dose group to the 0.0 mM glycidamide group as determined by Dunnett’s test.

Glycidamide in the drinking water resulted in dose-related trends in food consumption in male B6C3F1/Nctr mice beginning at week 84 (Table G-3) and in female B6C3F1/Nctr mice beginning at week 60 (Table G-4). In male mice, pairwise comparisons indicated that food consumption was significantly increased at later time points in the 0.35 and 0.70 mM glycidamide groups (Table G-3). In female mice, food consumption in the 0.70 mM glycidamide group was significantly increased at weeks 68 and 76 to 104 (Table G-4) compared to the control group.

Glycidamide in the drinking water resulted in sporadic dose-related trends in water consumption in male B6C3F1/Nctr mice (Table 32). In female mice, there were dose-related trends in water consumption beginning at week 76 (Table 33). Pairwise comparisons indicated that water consumption in the 0.70 mM glycidamide group of female mice was significantly increased compared to the control group beginning at week 80 (Table 33).

Table 32 Water and Glycidamide Consumption by Male Mice in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0 mM | 0.0875 mM | | 0.175 mM | | 0.35 mM | | 0.70 mM
Week^a^ | Water (g/day) | Water (g/day) | Dose^b^ | Water (g/day) | Dose | Water (g/day) | Dose | Water (g/day) | Dose
4 | 4.9 | 4.8 | 1.78 | 5.2 | 3.81 | 4.9 | 7.36 | 5.0 | 14.75
8 | 5.0 | 4.9 | 1.57 | 5.3 | 3.40 | 4.8 | 6.35 | 4.9 | 12.63
12 | 5.2 | 5.1 | 1.51 | 5.4 | 3.14 | 5.0 | 5.97 | 5.0 | 11.80
16 | 5.6 | 5.6 | 1.52 | 5.6 | 3.09 | 5.3 | 5.85 | 5.2 | 11.53
20 | 5.8 | 5.7 | 1.47 | 5.7 | 2.97 | 5.3 | 5.54 | 5.4 | 11.28
24 | 5.4* | 5.3 | 1.33 | 5.4 | 2.72 | 5.2 | 5.20 | 4.9 | 9.77
28 | 5.1 | 5.2 | 1.26 | 5.2 | 2.58 | 5.0 | 4.92 | 4.8 | 9.43
32 | 5.0* | 5.1 | 1.22 | 5.2 | 2.49 | 5.0 | 4.78 | 4.7 | 9.04
36 | 5.1 | 5.1 | 1.22 | 5.4 | 2.61 | 5.0 | 4.73 | 4.7 | 8.95
40 | 4.8* | 4.6 | 1.11 | 5.1 | 2.48 | 4.8 | 4.57 | 4.5 | 8.47
44 | 4.8* | 4.7 | 1.12 | 5.1 | 2.43 | 4.8 | 4.61 | 4.5 | 8.54
48 | 4.8 | 4.9 | 1.17 | 5.1 | 2.43 | 4.7 | 4.49 | 4.5 | 8.64
52 | 4.6* | 4.4 | 1.04 | 4.8 | 2.27 | 4.6 | 4.40 | 4.2 | 7.82
56 | 4.6 | 4.5 | 1.07 | 4.9 | 2.36 | 4.7 | 4.43 | 4.4 | 8.27
60 | 4.5 | 4.4 | 1.03 | 5.1 | 2.37 | 4.6 | 4.31 | 4.4 | 8.17
64 | 4.8 | 4.6 | 1.05 | 4.8 | 2.23 | 4.6 | 4.31 | 4.4 | 8.13
68 | 5.2 | 4.4* | 1.01 | 5.0 | 2.28 | 4.5 | 4.16 | 4.5 | 8.17
72 | 4.8 | 4.6 | 1.07 | 5.4 | 2.47 | 4.9 | 4.47 | 4.5 | 8.30
76 | 5.0 | 4.8 | 1.11 | 5.2 | 2.41 | 4.8 | 4.44 | 4.6 | 8.30
80 | 4.8 | 4.8 | 1.09 | 5.3 | 2.47 | 5.5* | 5.30 | 4.6 | 8.60
84 | 4.8 | 4.5 | 1.05 | 5.1 | 2.38 | 5.5 | 5.11 | 4.6 | 8.51
88 | 4.6* | 4.5 | 1.04 | 5.3 | 2.43 | 5.4 | 5.07 | 5.5 | 9.80
92 | 4.7 | 4.9 | 1.14 | 5.6 | 2.62 | 5.3 | 5.01 | 5.3 | 9.76
96 | 4.6* | 4.6 | 1.06 | 5.5 | 2.57 | 6.1* | 6.04 | 5.3 | 9.73
100 | 5.1 | 4.7 | 1.09 | 6.3 | 2.94 | 6.4 | 6.03 | 5.4 | 9.94
104 | 4.3 | 4.6 | 1.06 | 6.1* | 2.90 | 6.2* | 5.90 | 5.3 | 9.96
Mean for Weeks
4–104 | 4.9 | 4.8 | 1.20 | 5.3 | 2.65 | 5.1 | 5.13 | 4.8 | 9.55

^a^ Week indicates the last week of a 4-week interval of daily water consumption, measured weekly by cage.

^b^ Dose is expressed as the mean value measured in mg/kg body weight/day.

* In the 0.0 mM glycidamide column “*” indicates a significant trend (p < 0.05); in the treatment column “*” indicates a significant (p < 0.05) pairwise comparison of the dose group to the 0.0 mM glycidamide group as determined by Dunnett’s test.

Table 33 Water and Glycidamide Consumption by Female Mice in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0 mM | 0.0875 mM | | 0.175 mM | | 0.35 mM | | 0.70 mM
Week^a^ | Water (g/day) | Water (g/day) | Dose^b^ | Water (g/day) | Dose | Water (g/day) | Dose | Water (g/day) | Dose
4 | 4.4 | 4.5 | 2.09 | 4.5 | 4.12 | 4.4 | 8.34 | 4.7 | 19.54
8 | 4.4 | 4.5 | 1.84 | 4.3 | 3.54 | 4.2 | 7.08 | 4.2 | 14.25
12 | 4.3 | 4.3 | 1.65 | 4.3 | 3.32 | 4.2 | 6.48 | 4.1 | 12.90
16 | 4.1 | 4.3 | 1.54 | 4.3 | 3.12 | 4.3 | 6.23 | 4.2 | 12.21
20 | 4.2 | 4.1 | 1.43 | 4.1 | 2.85 | 4.1 | 5.71 | 4.3 | 12.26
24 | 4.0 | 4.1 | 1.37 | 4.0 | 2.67 | 4.1 | 5.48 | 4.0 | 10.84
28 | 4.2 | 4.2 | 1.38 | 4.1 | 2.68 | 4.1 | 5.34 | 4.1 | 10.94
32 | 4.1 | 4.1 | 1.32 | 4.2 | 2.60 | 4.3 | 5.40 | 4.2 | 10.77
36 | 4.3 | 4.3 | 1.34 | 4.4 | 2.73 | 4.3 | 5.46 | 4.3 | 10.94
40 | 4.4 | 4.2 | 1.30 | 4.3 | 2.67 | 4.4 | 5.49 | 4.2 | 10.64
44 | 4.2 | 4.1 | 1.27 | 4.5 | 2.75 | 4.4 | 5.44 | 4.2 | 10.61
48 | 4.5 | 4.1 | 1.26 | 4.5 | 2.77 | 4.3 | 5.27 | 4.4 | 11.00
52 | 4.3 | 4.1 | 1.23 | 4.3 | 2.54 | 4.1 | 4.97 | 4.4 | 10.70
56 | 4.3 | 4.1 | 1.22 | 4.4 | 2.60 | 4.6 | 5.49 | 4.4 | 10.76
60 | 4.4 | 4.2 | 1.23 | 4.7 | 3.07 | 4.5 | 5.22 | 4.4 | 10.62
64 | 4.5 | 4.2 | 1.20 | 4.3 | 2.48 | 4.4 | 5.03 | 4.6 | 10.67
68 | 4.7 | 4.2 | 1.18 | 4.5 | 2.51 | 4.3 | 4.87 | 4.6 | 10.46
72 | 4.3 | 4.2 | 1.20 | 5.1 | 2.85 | 4.6 | 5.10 | 5.3 | 12.06
76 | 4.6* | 4.7 | 1.34 | 5.0 | 2.80 | 4.8 | 5.36 | 5.7 | 12.83
80 | 4.7* | 4.6 | 1.32 | 4.7 | 2.59 | 4.7 | 5.29 | 5.8* | 13.42
84 | 4.4* | 4.8 | 1.33 | 4.8 | 2.72 | 4.9 | 5.43 | 6.4* | 14.09
88 | 4.6* | 4.9 | 1.35 | 5.0 | 2.77 | 5.0 | 5.47 | 7.4* | 15.72
92 | 4.5* | 4.8 | 1.33 | 5.9 | 3.28 | 5.0 | 5.51 | 7.4* | 16.26
96 | 4.7* | 4.7 | 1.30 | 5.7 | 3.19 | 4.9 | 5.41 | 8.9* | 19.89
100 | 5.0* | 4.8 | 1.33 | 5.7 | 3.20 | 5.3 | 5.76 | 8.5* | 18.45
104 | 5.1* | 4.7 | 1.28 | 5.0 | 2.76 | 5.3 | 5.88 | 9.8* | 20.15
Mean for Weeks
4–104 | 4.4 | 4.4 | 1.37 | 4.6 | 2.89 | 4.5 | 5.64 | 5.3 | 12.99

^a^ Week indicates the last week of a 4-week interval of daily water consumption, measured weekly by cage.

^b^ Dose is expressed as the mean value measured in mg/kg body weight/day.

* In the 0.0 mM glycidamide column “*” indicates a significant trend (p < 0.05); in the treatment column “*” indicates a significant (p < 0.05) pairwise comparison of the dose group to the 0.0 mM glycidamide group as determined by Dunnett’s test.

The mean glycidamide exposure for mice, calculated at 4 week intervals, is presented in Table 32 and Table 33 and Figure 12. The mean amount of glycidamide consumed by male mice for the entire 2-year experiment was 1.20, 2.65, 5.13, and 9.55 mg glycidamide per kg body weight per day for the 0.0875, 0.175, 0.35, and 0.70 mM glycidamide dose groups, respectively (Table 32 and Figure 12). The corresponding values for female mice were 1.37, 2.89, 5.64, and 12.99 mg glycidamide per kg body weight per day (Table 33 and Figure 12).

Figure 12

Glycidamide Intake in Male and Female Mice Administered Glycidamide (mM) in Drinking Water for Two Years

#### Neoplastic Findings

Glycidamide in the drinking water resulted in significant dose-related trends in the incidence of Harderian gland adenoma in both sexes of B6C3F1/Nctr mice (Table 34). Compared to the control groups the incidence of Harderian gland adenoma was significantly increased at all doses of glycidamide. The Harderian gland adenomas were characterized by cuboidal-to-tall columnar neoplastic cells that generally had an abundant foamy pale cytoplasm with round-to-ovoid nuclei. Several patterns were present, including papillary, cystic, and cystic papillary. Harderian gland carcinoma was present in a single female mouse administered 0.175 mM glycidamide and in a single male mouse administered 0.70 mM glycidamide.

Table 34 Incidences of Neoplasms and Nonneoplastic Lesions of the Eye in Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male
Harderian Gland
Adenoma, Bilateral | 0/47 | 2/47 | 4/47 | 15/46 | 31/47
Adenoma (includes bilateral)^a^
Overall rate^b^ | 3/47 (6%) | 17/47 (36%) | 23/47 (49%) | 32/46 (70%) | 42/47 (89%)
Poly-3 test^c^ | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Eye
Cataract
Overall rate | 1/47 (2%) | 3/45 (7%) | 7/46 (15%) | 8/44 (18%) | 17/42 (41%)
Poly-3 test | P < 0.001 | P = 0.282 | P = 0.019 | P = 0.005 | P < 0.001
Average severity^d^ | 4.0 | 1.0 | 2.1 | 2.3 | 2.0
Corneal Inflammation
Overall rate | 0/47 (0%) | 0/45 (0%) | 2/46 (4%) | 0/44 (0%) | 8/42 (19%)
Poly-3 test | P < 0.001 | – | P = 0.209 | – | P < 0.001
Average severity | – | – | 2.5 | – | 2.1
Female
Harderian Gland
Adenoma, Bilateral | 0/45 | 1/47 | 3/47 | 7/46 | 13/46
Adenoma (includes bilateral)^e^
Overall rate | 2/45 (4%) | 19/47 (40%) | 20/47 (43%) | 24/46 (52%) | 40/46 (87%)
Poly-3 test | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001 | P < 0.001
Eye
Cataract
Overall rate | 1/45 (2%) | 2/44 (5%) | 8/47 (17%) | 8/44 (18%) | 9/43 (21%)
Poly-3 test | P < 0.001 | P = 0.496 | P = 0.016 | P = 0.010 | P < 0.001
Average severity | 1.0 | 3.0 | 3.1 | 2.5 | 1.6
Corneal Inflammation
Overall rate | 0/45 (0%) | 2/44 (5%) | 1/47 (2%) | 3/44 (7%) | 5/43 (12%)
Poly-3 test | P = 0.002 | P = 0.238 | P = 0.501 | P = 0.103 | P = 0.007
Average severity | – | 2.0 | 1.0 | 1.3 | 2.2

^a^ The historical incidence of Harderian gland adenoma in NCTR control male B6C3F1/Nctr mice is 5.9% (range 0.0–10.6%; Table C-3) for all studies and 5.7% (range 4.3–6.4%; Table C-3) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

^d^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

^e^ The historical incidence of Harderian gland adenoma in NCTR control female B6C3F1/Nctr mice is 5.0% (range 0.0–8.7%; Table D-5) for all studies and 4.4% (range 0.0–7.0%; Table D-5) for drinking water studies.

A dose-related increase in alveolar/bronchiolar adenoma of the lung was observed in both sexes of B6C3F1/Nctr mice (Table 35). The incidence of alveolar/bronchiolar adenoma was significantly increased at all doses of glycidamide in male mice and at 0.70 mM glycidamide in female mice. A low incidence (≤5%) of alveolar/bronchiolar carcinoma was observed in both sexes of mice, but this did not appear to be related to glycidamide treatment. The alveolar/bronchiolar adenomas were primarily of the papillary type, with tumor cells supported by a fine fibrovascular stroma forming short projections that extended into the alveolar sacs. Tumor margins were well demarcated and compression of the surrounding tissue was distinct. Other types of growth patterns, such as solid or mixed, were present, but with a lower incidence. Carcinomas were irregular growths displaying a pleomorphic histologic pattern, with some being highly infiltrative and poorly demarcated.

Table 35 Incidences of Neoplasms and Nonneoplastic Lesions of the Lung in Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male
Alveolar/Bronchiolar Adenoma, multiple
| 0/47 | 1/46 | 2/47 | 5/47 | 4/47
Alveolar/Bronchiolar Adenoma (including multiple)^a^
Overall rate^b^ | 0/47 (0%) | 7/46 (15%) | 7/47 (15%) | 13/47 (28%) | 17/47 (36%)
Poly-3 test^c^ | P < 0.001 | P = 0.006 | P = 0.005 | P < 0.001 | P < 0.001
Alveolar/Bronchiolar Carcinoma^d^
Overall rate | 0/47 (0%) | 0/46 (0%) | 1/47 (2%) | 0/47 (0%) | 2/47 (4%)
Poly-3 test | P = 0.058 | – | P = 0.477 | – | P = 0.196
Alveolar/Bronchiolar Adenoma or Carcinoma^e^
Overall rate | 0/47 (0%) | 7/46 (15%) | 8/47 (17%) | 13/47 (28%) | 19/47 (40%)
Poly-3 test | P < 0.001 | P = 0.006 | P = 0.002 | P < 0.001 | P < 0.001
Alveolar Epithelial Hyperplasia
Overall rate | 0/47 | 1/46 | 4/47 | 3/47 | 6/47
Poly-3 test | P = 0.003 | P = 0.487 | P = 0.048 | P = 0.088 | P = 0.008
Average severity^f^ | – | 2.0 | 2.3 | 3.3 | 2.5
Female
Alveolar/Bronchiolar Adenoma, multiple
| 0/46 | 0/48 | 0/47 | 0/47 | 2/44
Alveolar/Bronchiolar Adenoma (including multiple)^g^
Overall rate | 3/46 (7%) | 5/48 (10%) | 3/47 (6%) | 7/47 (15%) | 9/44 (21%)
Poly-3 test | P = 0.002 | P = 0.363 | P = 0.650 | P = 0.139 | P = 0.007
Alveolar/Bronchiolar Carcinoma^h^
Overall rate | 1/46 (2%) | 1/48 (2%) | 0/47 (0%) | 1/47 (2%) | 2/44 (5%)
Poly-3 test | P = 0.166 | P = 0.755N | P = 0.505N | P = 0.744 | P = 0.328
Alveolar/Bronchiolar Adenoma or Carcinoma^i^
Overall rate | 4/46 (9%) | 6/48 (13%) | 3/47 (6%) | 8/47 (17%) | 11/44 (25%)
Poly-3 test | P < 0.001 | P = 0.385 | P = 0.514N | P = 0.155 | P = 0.003

^a^ The historical incidence of alveolar/bronchiolar adenoma of the lung in NCTR control male B6C3F1/Nctr mice is 13.5% (range 6.3–27.1%; Table C-4) for all studies and 8.4% (range 6.3–10.6%; Table C-4) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^d^ The historical incidence of alveolar/bronchiolar carcinoma of the lung in NCTR control male B6C3F1/Nctr mice is 2.8% (range 0.0–8.3%; Table C-4) for all studies and 4.2% (range 2.1–6.3%; Table C-4) for drinking water studies.

^e^ The historical incidence of alveolar/bronchiolar adenoma or carcinoma (combined) of the lung in NCTR control male B6C3F1/Nctr mice is 16.1% (range 10.4–31.3%; Table C-4) for all studies and 11.9% (range 10.4–12.8%; Table C-4) for drinking water studies.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

^g^ The historical incidence of alveolar/bronchiolar adenoma of the lung in NCTR control female B6C3F1/Nctr mice is 4.7% (range 2.1–8.3%; Table D-3) for all studies and 5.7% (range 2.1–8.3%; Table D-3) for drinking water studies.

^h^ The historical incidence of alveolar/bronchiolar carcinoma (combined) of the lung in NCTR control female B6C3F1/Nctr mice is 1.1% (range 0.0–4.3%; Table D-3) for all studies and 2.1% (range 0.0–4.2%; Table D-3) for drinking water studies.

^i^ The historical incidence of alveolar/bronchiolar adenoma or carcinoma (combined) of the lung in NCTR control female B6C3F1/Nctr mice is 5.7% (range 2.1–12.5%; Table D-3) for all studies and 7.9% (range 4.3–12.5%; Table D-3) for drinking water studies.

Dose-related increases in squamous cell papilloma of the forestomach occurred in male and female B6C3F1/Nctr mice, with the incidence being increased significantly in the 0.70 mM glycidamide group (Table 36). Squamous cell carcinoma of the forestomach also occurred in two male mice exposed to 0.70 mM glycidamide. Squamous cell papillomas were characterized by a solitary stalk of lamina propria protruding into the forestomach lumen, with multiple finger-like projections arising from the stalk. The epithelium covering the projections usually displayed marked hyperplasia. Squamous cell carcinomas showed proliferation into the submucosa and in some cases had features of squamous cell differentiation, such as keratin production, while others were composed of large flattened cells typical of squamous morphology.

Table 36 Incidences of Neoplasms and Nonneoplastic Lesions of the Stomach in Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male
Forestomach, Squamous Cell Papilloma
Overall rate^a^ | 0/47 (0%) | 2/45 (4%) | 3/48 (6%) | 2/45 (4%) | 10/41 (24%)
Poly-3 test^b^ | P < 0.001 | P = 0.218 | P = 0.100 | P = 0.193 | P < 0.001
Forestomach, Squamous Cell Carcinoma
Overall rate | 0/47 (0%) | 0/45 (0%) | 0/48 (0%) | 0/45 (0%) | 2/41 (5%)
Poly-3 test | P = 0.014 | – | – | – | 0.176
Forestomach, Squamous Cell Papilloma or Carcinoma^c^
Overall rate | 0/47 (0%) | 2/45 (4%) | 3/48 (6%) | 2/45 (4%) | 12/41 (29%)
Poly-3 test | P < 0.001 | P = 0.218 | P = 0.100 | P = 0.193 | P < 0.001
Forestomach Epithelial Hyperplasia
Overall rate | 5/47 | 2/45 | 5/48 | 5/45 | 12/41
Poly-3 test | P < 0.001 | P = 0.250N | P = 0.585 | P = 0.493 | P = 0.010
Average severity^d^ | 1.6 | 2.0 | 1.8 | 2.2 | 2.0
Female
Forestomach, Squamous Cell Papilloma^e^
Overall rate | 1/45 (2%) | 1/45 (2%) | 1/47 (2%) | 5/45 (11%) | 9/44 (21%)
Poly-3 test | P < 0.001 | P = 0.759 | P = 0.759 | P = 0.086 | P < 0.001
Forestomach Epithelial Hyperplasia
Overall rate | 4/45 (9%) | 4/45 (9%) | 10/47 (21%) | 11/45 (24%) | 5/44 (11%)
Poly-3 test | P = 0.048 | P = 0.641 | P = 0.072 | P = 0.028 | P = 0.231
Average severity | 3.0 | 2.8 | 2.4 | 2.5 | 2.4

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^c^ The historical incidence of squamous cell papilloma or carcinoma (combined) of the forestomach in NCTR control male B6C3F1/Nctr mice is 0.3% (range 0.0–2.1%; Table C-5) for all studies and 0.0% (Table C-5) for drinking water studies.

^d^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

^e^ The historical incidence of squamous cell papilloma or carcinoma (combined) of the forestomach in NCTR control female B6C3F1/Nctr mice is 1.6% (range 0.0–8.7%; Table D-7) for all studies and 4.4% (range 0.0–8.7%; Table D-7) for drinking water studies.

Male B6C3F1/Nctr mice exposed to glycidamide had a dose-related increase in squamous cell papilloma of the skin (Table 37), with the incidence being significant at 0.70 mM glycidamide. Squamous cell carcinoma of the skin also occurred in two male mice exposed to 0.70 mM glycidamide. The squamous cell papillomas arose from the epidermis as cauliflower-shaped or wart-like growths that featured a proliferating inner connective tissue core with an overlying proliferative squamous epithelium and an outer layer of keratin. The thickness of the epithelial layers varied from one papilloma to another. Mitotic figures were not uncommon. The squamous cell carcinomas appeared as ulcerated solid masses and arose from hyperplastic areas and borders of ulcers, with one arising from a papilloma. They were composed of irregular masses or cords of squamous epithelial cells that proliferated downward and invaded the adjacent dermis and subcutis. Keratin was present in these growths, with some forming characteristic epithelial pearls. The basal layers had frequent mitotic figures.

Table 37 Incidences of Neoplasms of the Skin in Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Male
Squamous Cell Papilloma
Overall rate^a^ | 0/47 (0%) | 1/48 (2%) | 2/47 (4%) | 1/47 (2%) | 8/46 (17%)
Poly-3 test^b^ | P < 0.001 | P = 0.493 | P = 0.213 | P = 0.462 | P = 0.001
Squamous Cell Carcinoma
Overall rate | 0/47 (0%) | 0/48 (0%) | 0/47 (0%) | 0/47 (0%) | 2/46 (4%)
Poly-3 test | P = 0.017 | – | – | – | P = 0.191
Squamous Cell Papilloma or Carcinoma^c^
Overall rate | 0/47 (0%) | 1/48 (2%) | 2/47 (4%) | 1/47 (2%) | 9/46 (20%)
Poly-3 test | P < 0.001 | P = 0.493 | P = 0.213 | P = 0.462 | P < 0.001
Female
Fibrosarcoma
Overall rate | 0/45 (0%) | 1/48 (2%) | 2/47 (4%) | 2/47 (4%) | 9/45 (20%)
Poly-3 test | P < 0.001 | P = 0.506 | P = 0.236 | P = 0.229 | P < 0.001
Sarcoma
Overall rate | 0/45 (0%) | 0/48 (0%) | 1/47 (2%) | 3/47 (6%) | 3/45 (7%)
Poly-3 test | P = 0.004 | – | P = 0.499 | P = 0.110 | P = 0.059
Fibrosarcoma or Sarcoma^d^
Overall rate | 0/45 (0%) | 1/48 (2%) | 3/47 (6%) | 5/47 (11%) | 12/45 (27%)
Poly-3 test | P < 0.001 | P = 0.506 | P = 0.118 | P = 0.028 | P < 0.001

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

^c^ The historical incidence of squamous cell papilloma or carcinoma (combined) of the skin in NCTR control male B6C3F1/Nctr mice is 0.2% (range 0.0–2.1%; Table C-7) for all studies and 0.7% (range 0.0–2.1%; Table C-7) for drinking water studies.

^d^ The historical incidence of mescenchymal skin tumors in NCTR control female B6C3F1/Nctr mice is 1.7% (range 0.0–11.4%; Table D-6) for all studies and 6.4% (range 0.0–11.4%; Table D-6) for drinking water studies.

Female B6C3F1/Nctr mice had dose-related increases in malignant mesenchymal skin tumors (fibrosarcoma or combined fibrosarcoma or sarcoma; Table 37). The incidence of fibrosarcoma was significant at 0.70 mM glycidamide and the incidence of combined fibrosarcoma or sarcoma was significant at 0.35 and 0.70 mM glycidamide. These mesenchymal tumors looked histologically similar to subcutaneous neoplasms previously seen in B6C3F1/Nctr mice.

Female B6C3F1/Nctr mice administered glycidamide in the drinking water had dose-related increasing trends in adenoacanthoma, adenocarcinoma, and combined adenoacanthoma or adenocarcinoma of the mammary gland (Table 38). The incidence of adenoacanthoma was increased significantly in the 0.70 mM glycidamide dose group and the incidence of adenocarcinoma and combined adenoacanthoma or adenocarcinoma was increased significantly in the 0.35 and 0.70 mM glycidamide dose groups. Mammary gland adenocarcinomas contained variably sized cystic structures lined by a pleomorphic to anaplastic cuboidal epithelium with frequent mitoses. Multiple growth patterns, such as acinar, tubular, solid, and papillary, were recognized. Adenoacanthomas showed similar features as carcinomas, except that at least 25% of the tumor consisted of squamous metaplasia. Female B6C3F1/Nctr mice also had dose-related increases in benign, malignant, and combined benign and malignant granulosa cell tumor of the ovary (Table 39).

Table 38 Incidences of Neoplasms of the Mammary Gland in Female Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Adenoacanthoma^a^
Overall rate^b^ | 0/45 (0%) | 0/48 (0%) | 0/47 (0%) | 1/47 (2%) | 8/45 (18%)
Poly-3 test^c^ | P < 0.001 | – | – | P = 0.489 | P < 0.001
Adenocarcinoma^d^
Overall rate | 1/45 (2%) | 1/48 (2%) | 2/47 (4%) | 9/47 (19%) | 11/45 (24%)
Poly-3 test | P < 0.001 | P = 0.755N | P = 0.496 | P = 0.006 | P < 0.001
Adenoacanthoma or Adenocarcinoma^e^
Overall rate | 1/45 (2%) | 1/48 (2%) | 2/47 (4%) | 9/47 (19%) | 18/45 (40%)
Poly-3 test | P < 0.001 | P = 0.755N | P = 0.496 | P = 0.006 | P < 0.001

^a^ The historical incidence of adenoacanthoma of the mammary gland in NCTR control female B6C3F1/Nctr mice is 0.4% (range 0.0–4.3%; Table D-4) for all studies and 0% (Table D-4) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

^d^ The historical incidence of adenocarcinoma of the mammary gland in NCTR control female B6C3F1/Nctr mice is 3.3% (range 0.0–11.4%; Table D-4) for all studies and 6.5% (range 0.0–11.4%; Table D-4) for drinking water studies.

^e^ The historical incidence of adenoacanthoma or adenocarcinoma of the mammary gland in NCTR control female B6C3F1/Nctr mice is 3.7% (range 0.0–11.4%; Table D-4) for all studies and 6.5% (range 0.0–11.4%; Table D-4) for drinking water studies.

Table 39 Incidences of Neoplasms and Nonneoplastic Lesions of the Reproductive System in Female Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Ovary: Benign Granulosa Cell Tumor^a^
Overall rate^b^ | 0/45 (0%) | 0/47 (0%) | 0/47 (0%) | 1/46 (2%) | 2/44 (5%)
Poly-3 test^c^ | P = 0.014 | – | – | P = 0.487 | P = 0.146
Ovary: Malignant Granulosa Cell Tumor^d^
Overall rate | 0/45 (0%) | 0/47 (0%) | 0/47 (0%) | 2/46 (4%) | 1/44 (2%)
Poly-3 test | P = 0.048 | – | – | P = 0.223 | P = 0.402
Ovary: Benign or Malignant Granulosa Cell Tumor^e^
Overall rate | 0/45 (0%) | 0/47 (0%) | 0/47 (0%) | 3/46 (4%) | 3/44 (7%)
Poly-3 test | P = 0.001 | – | – | P = 0.108 | P = 0.055
Ovary: Cyst
Overall rate | 14/45 | 17/47 | 25/47 | 22/46 | 18/44
Poly-3 test | P = 0.011 | P = 0.383 | P = 0.016 | P = 0.039 | P = 0.022
Average severity^f^ | 2.6 | 2.6 | 2.9 | 2.9 | 2.9

^a^ The historical incidence of benign granulosa cell tumor in NCTR control female B6C3F1/Nctr mice is 0.1% (range 0.0–0.7%; Table D-8) for all studies and 0% (Table D-8) for drinking water studies.

^b^ Number of animals with neoplasm per number of animals examined microscopically.

^c^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

^d^ The historical incidence of malignant granulosa cell tumor in NCTR control female B6C3F1/Nctr mice is 0.1% (range 0.0–0.6%; Table D-8) for all studies and 0% (Table D-8) for drinking water studies.

^e^ The historical incidence of benign or malignant granulosa cell tumor in NCTR control female B6C3F1/Nctr mice is 0.3% (range 0.0–0.7%; Table D-8) for all studies and 0% (Table D-8) for drinking water studies.

^f^ Severity was scored as: 1 = minimal, 2 = mild, 3 = moderate, and 4 = marked.

#### Nonneoplastic Findings

The drinking water administration of glycidamide to B6C3F1/Nctr mice resulted in cataracts in both sexes, with the incidence being significantly increased in the 0.175, 0.35, and 0.70 mM glycidamide dose groups (Table 34). Histopathologically, the cataracts displayed an irregular swelling of fiber cells with a granular vacuolated cytoplasm. Early mineralization was also noted along with disorganization of the lens epithelium. In addition, corneal inflammation was associated with glycidamide dosing in both male and female B6C3F1/Nctr mice, with the incidence being significant at 0.70 mM glycidamide.

Glycidamide administration resulted in a dose-related increasing trend in epithelial hyperplasia of the forestomach in both sexes of mice. In male mice, the incidence was significantly increased in the 0.70 mM glycidamide treatment group (Table 36). In female mice, the incidence was significantly increased in the 0.35 mM glycidamide dose group (Table 36). Focal squamous cell hyperplasia of the forestomach was evident as having multiple finger-like projections each with its own lamina propria and with excessive keratin on the surface. Focal rather than diffuse hyperplasia was the predominant pattern.

Both sexes of B6C3F1/Nctr mice had increasing dose-related trends in hematopoietic cell proliferation of the spleen, with the incidence being significantly increased at 0.35 and 0.70 mM glycidamide (Table 40 and Table 41). Hematopoietic cell proliferation was characterized in most animals by an increase in myeloid precursors, although erythroid hyperplasia was noted occasionally.

Table 40 Incidences of Selected Nonneoplastic Lesions in Male Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Preputial Gland
Degeneration
Overall rate^a^ | 4/47 (9%) | 10/47 (21%) | 5/46 (11%) | 12/46 (26%) | 9/44 (21%)
Poly-3 test^b^ | P = 0.041 | P = 0.068 | P = 0.419 | P = 0.012 | P = 0.048
Average severity^c^ | 2.8 | 2.9 | 3.8 | 3.3 | 3.1
Ductal Dilatation
Overall rate | 0/47 (0%) | 0/47 (0%) | 1/46 (2%) | 0/46 (0%) | 4/44 (9%)
Poly-3 test | P = 0.001 | – | P = 0.473 | – | P = 0.034
Average severity | – | – | 4.0 | – | 3.5
Inflammation
Overall rate | 1/47 (2%) | 6/47 (13%) | 2/46 (4%) | 3/46 (7%) | 9/44 (21%)
Poly-3 test | P = 0.002 | P = 0.047 | P = 0.453 | P = 0.237 | P = 0.002
Average severity | 1.0 | 2.2 | 2.5 | 2.0 | 2.8
Spleen
Hematopoietic Cell Proliferation
Overall rate | 6/47 (13%) | 6/47 (13%) | 12/47 (26%) | 14/46 (30%) | 17/44 (39%)
Poly-3 test | P < 0.001 | P = 0.587 | P = 0.071 | P = 0.016 | P = 0.001
Average severity | 3.7 | 3.2 | 3.3 | 3.1 | 3.1

^a^ Number of animals with lesion per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated (0.0875, 0.175, 0.35, and 0.70 mM glycidamide) group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

^c^ Severity was graded as 1, minimal; 2, mild; 3, moderate; and 4, marked.

Table 41 Incidences of Selected Nonneoplastic Lesions in Female Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Liver
Angiectasis
Overall rate^a^ | 0/47 (0%) | 0/48 (0%) | 1/47 (2%) | 0/46 (0%) | 5/43 (12%)
Poly-3 test^b^ | P < 0.001 | – | P = 0.491 | – | P = 0.006
Average severity^c^ | – | – | 2.0 | – | 2.4
Necrosis
Overall rate | 0/47 (0%) | 0/48 (0%) | 0/47 (0%) | 0/46 (0%) | 5/43 (12%)
Poly-3 test | P < 0.001 | – | – | – | P = 0.006
Average severity | – | – | – | – | 2.2
Spinal Cord (Cervical)
Axonal Degeneration
Overall rate | 4/45 (9%) | 9/44 (21%) | 10/47 (21%) | 9/45 (20%) | 10/43 (23%)
Poly-3 test | P = 0.011 | P = 0.104 | P = 0.069 | P = 0.085 | P = 0.005
Average severity | 1.0 | 1.0 | 1.0 | 1.0 | 1.0
Spleen
Hematopoietic Cell Proliferation
Overall rate | 6/46 (13%) | 10/47 (21%) | 11/47 (23%) | 14/47 (30%) | 29/45 (64%)
Poly-3 test | P < 0.001 | P = 0.208 | P = 0.144 | P = 0.029 | P < 0.001
Average severity | 3.0 | 3.3 | 3.5 | 3.6 | 3.4

^a^ Number of animals with lesion per number of animals examined microscopically.

^b^ Beneath the 0 mM glycidamide are the p-values associated with the trend test. Beneath the treated (0.0875, 0.175, 0.35, and 0.70 mM glycidamide) group incidences are the p-values corresponding to pairwise comparisons between the 0 mM glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice.

^c^ Severity was graded as 1, minimal; 2, mild; 3, moderate; and 4, marked.

Other nonneoplastic lesions in male B6C3F1/Nctr mice included degeneration, ductal dilatation, and inflammation of the preputial gland (Table 40). Additional nonneoplastic lesions in female B6C3F1/Nctr mice included ovarian cysts (Table 39), hepatic angiectasis and necrosis, and axonal degeneration of the cervical spinal cord (Table 41). Hepatocellular necrosis had an irregular distribution of variably sized foci of hepatocytes that were either swollen with nuclear lysis or advanced featuring a condensed cytoplasm with minimal or no nuclear remnants present. A small inflammatory response was usually associated with this necrosis.