# Materials and Methods

## Procurement and Characterization

### Glycidamide

Glycidamide (oxirane-2-carboxamide; C_3_H_5_NO_2_; molecular weight 87.08) was purchased from Toronto Research Chemicals, North York, Ontario, Canada (Lot # 4AQL-43-5). The identity and purity of the chemical was assessed at the National Center for Toxicological Research (NCTR) by gas chromatography coupled with electron impact mass spectrometry (GC/EI-MS), nuclear magnetic resonance (NMR) spectrometry, and gas chromatography using flame ionization detection (GC-FID).

GC/EI-MS of the glycidamide indicated a major component with the proper mass (m/z = 87) and fragments (m/z = 86, 71, 70, 69, 59, 57, 44, 43, 42, and 41) consistent with the proposed structure. The purity was estimated to be >99%. ^1^H and ^13^C NMR spectra were consistent with the structure of glycidamide, and based upon the ^1^H NMR spectra, the purity was estimated to be 98.5%. Identified impurities included acrylamide (0.7%), methylene chloride (0.13%), and other aliphatics (0.6%). GC-FID of the glycidamide indicated one major peak that accounted for 98.4% of the material and three minor peaks, with areas of 0.3, 1.1, and 0.2%.

## Preparation and Analysis of Dose Formulations

The stability of glycidamide in drinking water was assessed at a concentration of 30.6 μg per ml for a period of 35 days at room temperate in the absence of light. From 0–21 days, the recovery of glycidamide varied between 97.7% and 118%; at 28 and 35 days, the recovery was 73.7% and 66.5%, respectively.

For the 2-week study, glycidamide drinking water solutions were prepared weekly for treating animals. The target concentrations were 12.2, 30.6, 61.2, 122, 306, and 612 μg glycidamide per ml corresponding to 0.14, 0.35, 0.70, 1.41, 3.52, and 7.03 mM glycidamide. Concentrations were deemed acceptable if they were within 10% of the target concentrations; for the 12.2 μg per ml concentration, due to analytical limitations, 20%of the target concentration was considered acceptable. Dose certification analyses were conducted on all glycidamide drinking water solutions and each met the indicated specifications.

For the 3-month study, drinking water solutions were prepared at 2 to 3 week intervals beginning on 28 July 2004 and ending on 21 October 2004. The target concentrations were 12.2, 30.6, 61.2, 122, and 306 μg glycidamide per ml corresponding to 0.14, 0.35, 0.70, 1.41, and 3.52 mM glycidamide. Concentrations were deemed acceptable if they were within 10% of the target concentrations; for the 12.2 μg per ml concentration, 20% of the target concentration was considered acceptable. Solutions prepared on 28 July 2004 were found to contain 74.0% to 84.3% of the desired concentrations; the 30.6 and 306 μg per ml solutions prepared on 16 August 2004 were found to contain 72.9% to 74.8% of the desired concentrations. The rats received these low doses of glycidamide for approximately 3 weeks. The low concentrations of glycidamide were traced to the use of a stainless-steel mixing vessel. Subsequent mixes were conducted with a polypropylene vessel, which eliminated the problem of low recoveries. The 61.2 μg per ml drinking water solution prepared on 10 September 2004 was found to contain 119% of the desired concentration; two additional analyses indicated a value of 113%. All the other glycidamide drinking water solutions met the indicated specifications.

For the 2-year study, glycidamide drinking water solutions for treating the animals were prepared weekly, beginning on 24 May 2005 and ending on 14 August 2007. The target concentrations were 7.65, 15.3, 30.6, and 61.2 μg glycidamide per ml corresponding to 0.0875, 0.175, 0.35, and 0.70 mM glycidamide. Concentrations were deemed acceptable if they were within 10% of the target concentrations; for the 7.65 μg per ml concentration, 20% of the target concentration was considered acceptable. Dose certification analyses were conducted at approximately bi-monthly intervals (Table F-4). Each of the assayed glycidamide drinking water solutions met the indicated specifications. Glycidamide was not detected in the control drinking water solutions (limit of quantitation was 1.5 μg per ml).

## Two-week Studies

F344/N Nctr rats and B6C3F1/Nctr (C57BL/6N × C3H/HeN MTV^-^) mice were obtained from the NCTR breeding colony at three weeks of age. The animals were tail-tattooed for identification, weight-ranked, and randomly loaded on the MultiGen Support System. In addition, mice were ear-clipped for identification. Treatment was initiated when the animals were 4 to 5 weeks of age. On the first day of dosing, female rats weighed between 37.3 g and 98.2 g, male rats weighed between 63.1 g and 100.4 g, female mice weighed between 13.6 g and 16.4 g, and male mice weighed between 16.3 g and 20.8 g.

Groups of four F344/N Nctr rats per sex and four B6C3F1/Nctr mice per sex were dosed with 0.0, 0.14, 0.35, 0.70, 1.41, 3.52, or 7.03 mM glycidamide in the drinking water (0, 12.2, 30.6, 61.2, 122, 306, or 612 ppm glycidamide). The animals were treated for 14 days and were monitored twice daily, in the morning and afternoon. The rats were housed two of the same sex per cage and mice were housed four of the same sex per cage. Purina 5LG6 diet (also referred to as NIH-31 IR) was selected for the study because it has a very low acrylamide content (< 50 ppb) compared to other commercial formulations.^57^ Irradiated Purina 5LG6 meal and Millipore-filtered tap water were provided ad libitum. Feed was subjected to routine chemical analyses. The acrylamide content of the 5LG6 diet was determined to be 28 ± 25 ng per ml (n = 9; Table H-4); acrylamide was not detected in the control drinking water solutions (limit of quantitation 2 μg/ml). The animal rooms were maintained on a 12-hour light-dark cycle, with 10 to 15 air changes per hour. Environmental controls were set to maintain the temperature at 22 ± 4°C, with a relative humidity of 40% to 70%. Body weights were recorded on dose days 1, 7, and 14. Food and water consumption was measured weekly.

On the afternoon of dose day 14, the animals were delivered to the necropsy holding area. They continued to receive dosed water. On dose day 15, all animals were weighed (designated as necropsy body weight) and euthanized by exposure to carbon dioxide. Under the supervision of a pathologist, a gross examination was performed on all animals. Gross examination data were recorded with the Individual Animal Necropsy Recording system. The livers and brains were dissected and weighed. Gross lesions and the following organs were processed for microscopic examination: brain (cerebrum, cerebellum, and brain stem), Harderian glands, heart, liver, lungs, peripheral nerve (sciatic), ovaries, thyroid gland, parathyroid gland, skin, mammary glands, spinal cord (thoracic, lumbar, and cervical), forestomach, glandular stomach, and testes. The pathology data were recorded in Micropath.

## Three-month Studies

F344/N Nctr rats and B6C3F1/Nctr (C57BL/6N × C3H/HeN MTV^−^) mice were obtained from the NCTR breeding colony at three weeks of age. Rats were tail-tattooed and mice were ear-clipped for identification. Mice were also tail-tattooed at 8 to 12 weeks of age. The animals were weight-ranked, and randomly loaded on the MultiGen Support System. Treatment was initiated when the rats were 4 to 5 weeks of age and the mice were 5 to 6 weeks of age. On the first day of dosing, female rats weighed between 84.7 g and 117.0 g, male rats weighed between 106.3 g and 139.7 g, female mice weighed between 11.8 g and 16.5 g and male mice weighed between 13.6 g and 20.3 g.

The rats were housed two of the same sex per cage and mice were housed four of the same sex per cage in polycarbonate cages with hardwood chips bedding. Irradiated Purina 5L6G meal and Millipore-filtered tap water were provided ad libitum. Feed and water were subjected to routine microbiological and chemical analyses. The animal rooms were maintained on a 12-hour light-dark cycle, with 10 to 15 air changes per hour. Environmental controls were set to maintain the temperature at 22 ± 4°C, with a relative humidity of 40% to 70%.

Each dose group consisted of eight animals per sex. The dosage groups were 0.0, 0.14, 0.35, 0.70, 1.41, or 3.52 mM glycidamide in the drinking water (0, 12.2, 30.6, 61.2, 122, or 306 ppm glycidamide). The animals were treated for 3 months and were monitored twice daily, in the morning and afternoon. Body weights, food consumption, and water consumption were measured weekly.

On the afternoon before the scheduled terminal sacrifice, the animals were delivered to the necropsy holding area. They continued to receive dosed water. On the following day, all animals were weighed (designated as necropsy body weight), and euthanized by exposure to carbon dioxide. Under the supervision of a pathologist, a gross examination was performed on all animals. Gross examination data were recorded with the Individual Animal Necropsy Recording system. The livers and brains were dissected and weighed. Gross lesions and the following organs were processed for microscopic examination: adrenal glands, bone marrow (femur), brain (cerebrum, cerebellum, and brain stem), clitoral glands, epididymides, esophagus, eyes, Harderian glands, heart (aorta), intestine (large: cecum, colon, and rectum), intestine (small: duodenum, jejunum, and ileum), kidneys, liver, lungs/bronchi, lymph nodes (mesenteric and mandibular), muscle (thigh), nerve (sciatic), nose, ovaries, pancreas, parathyroid glands, pituitary glands, preputial glands, prostate, salivary glands, seminal vesicles, skin (mammary glands), spinal cord (thoracic, lumbar, and cervical), spleen, stomach (forestomach and glandular), testes, thymus, thyroid glands, tongue, trachea, urinary bladder, and uterus. The pathology data were recorded in the Laboratory Data Acquisition System (LDAS).

## Two-year Studies

### Study Design

Each dose group consisted of 48 animals per sex per species. The dosage groups were 0, 0.0875, 0.175, 0.35, and 0.70 mM glycidamide in the drinking water (0, 7.65, 15.3, 30.6, and 61.2 ppm glycidamide). The animals were treated for 2 years and were monitored twice daily, in the morning and afternoon. Body weights, food consumption, and water consumption were measured weekly.

### Source and Specification of Animals

Male and female F344/N Nctr rats were obtained from the NCTR breeding colony at 3 weeks of age, tail-tattooed for identification, weight-ranked, and randomly loaded on the MultiGen Support System. The animals were loaded to the study in twelve balanced replicates. Treatment was initiated when the rats were 4 to 5 weeks of age. On the first day of dosing, the female rats weighed between 50.9 g and 110.8 g; the male rats weighed between 65.5 g and 123.6 g.

Male and female B6C3F1/Nctr (C57BL/6N × C3H/HeN MTV^-^) mice were obtained from the NCTR breeding colony at 3 weeks of age, ear-clipped for identification (at 8 to 12 weeks of age, their tails were also tattooed to provide additional identification), weight ranked, and randomly loaded on the MultiGen Support System. The animals were loaded to the study in twelve balanced replicates. Treatment was initiated when the mice were 5 to 6 weeks of age. On the first day of dosing, the female mice weighed between 11.5 g and 18.9 g; the male mice weighed between 13.9 g and 21.3 g.

### Animal Maintenance

All animal experimental procedures were performed in accordance with an animal study protocol approved by the Institutional Animal Care and Use Committee at the NCTR.

The rats were housed two of the same sex per cage in polycarbonate cages with hardwood chip bedding. The mice were housed four of the same sex per cage in polycarbonate cages with hardwood chip bedding and micro-isolator tops. Microbiological surveillance of sentinel rats and mice was conducted on a routine basis (Appendix I).

Irradiated Purina 5LG6 meal and Millipore-filtered tap water were provided ad libitum. Feed was subjected to routine chemical analyses; water underwent routine microbiological surveillance.

The animal rooms were maintained on a 12-hour light-dark cycle, with 10 to 15 air changes per hour. Environmental controls were set to maintain the temperature at 22 ± 4°C, with a relative humidity of 40% to 70%. Microbiological surveillance of the animal rooms was conducted on a routine basis.

### Clinical Examinations and Pathology

On the afternoon before the scheduled terminal sacrifice, the animals were delivered to the necropsy holding area. They continued to receive the dosed water. On the following day, all animals were weighed (designated as necropsy body weight) and then euthanized by exposure to carbon dioxide. Under the supervision of a pathologist, complete necropsies were performed on all terminal sacrifice animals. Complete necropsies were also performed on all animals that died naturally or that were submitted moribund prior to the scheduled terminal sacrifice. The protocol-designated tissues (see below) were examined grossly, removed, and preserved in 10% neutral buffered formalin, except the eyes and testes, which were placed in modified Davidson's fixative. Gross findings were recorded in the automated Gross Pathology System. The protocol-designated tissues were trimmed, processed, and embedded in Formula R^®^ infiltrating medium, sectioned at approximately 5 microns, and stained with hematoxylin and eosin for microscopic evaluation. In a few cases, special staining procedures were applied to selected lesions to aid in characterizing the pathology changes. The protocol-designated tissues were: brain (cerebrum, cerebellum, and brain stem), Harderian glands, heart, liver, lungs, pancreas, peripheral nerve (sciatic), ovaries, thyroid gland, parathyroid gland, skin, mammary glands, spinal cord (thoracic, lumbar, and cervical), forestomach, glandular stomach, duodenum, ileum, jejunum, cecum, colon, rectum, testes, kidneys, urinary bladder, spleen, prostate, trachea, esophagus, uterus, eye, aorta, nose, pituitary, preputial/clitoral glands, epididymis, lymph nodes (mesenteric and mandibular), seminal vesicles, thymus, salivary glands, bone (femur), and adrenal glands.

Upon completion of the microscopic evaluations, the pathology data were entered into the LDAS. The slides, paraffin blocks, and residual wet tissues were sent to the Block and Slide Laboratory for inventory, slide/block match, and wet tissue audit. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment group. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. A quality assessment pathologist evaluated slides of all proliferative lesions and target organs. Differences of opinion were reconciled between the study pathologist and the quality assessment pathologist.

Histopathology slides containing the diagnoses made by the study pathologist and quality assessment pathologist were reviewed by a Pathology Working Group (PWG). The PWG consisted of the quality assessment pathologist, the study pathologist, and other pathologists experienced in rodent toxicologic pathology. The quality assessment pathologist served as the coordinator. Representative histopathology slides containing examples of lesions related to glycidamide administration, examples of disagreements in diagnoses between the study pathologist and quality assessment pathologist, and lesions of general interest were presented by the Coordinator to the PWG for review. This group examined the tissues without any knowledge of dose groups or previously rendered diagnoses. Final diagnoses for reviewed lesions represent a consensus between the study pathologist, reviewing pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^58^ and Boorman et al.^59^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^60^

Acrylamide is neurotoxic in experimental animals (reviewed in NTP^4^), and the possibility exists that glycidamide is likewise. In view of this possibility, an additional Pathology Quality Assessment Review was conducted on sections of brain, spinal cord, and peripheral nerve. This additional review was conducted by pathologists from an independent laboratory who had special expertise in neuropathology. During this review, all changes in the nervous system were documented, regardless of their severity. Based upon these very stringent criteria, additional lesions in the nervous system were detected. Subsequently, a special PWG, consisting of six experienced pathologists, was convened to evaluate the results. The special PWG utilized stringent criteria similar to those used in the special neuropathology quality assessment in making their evaluations and recommended that all of the lesions, regardless of their severity, be added to the pathology results for the study. This recommendation was adopted.

The experimental design and materials and methods for the 2-week, 3-month, and 2-year drinking waters studies of glycidamide are summarized in Table 2.

Table 2 Experimental Design and Materials and Methods in the Drinking Water Studies of Glycidamide

Two-week Studies | Three-month Studies | Two-year Studies
Study Laboratory
U.S. FDA National Center for Toxicological Research (NCTR, Jefferson, AR) | Same as 2-week studies | Same as 2-week studies
Strain and Species
Rats: F344/N Nctr Mice: B6C3F1/Nctr (C57BL/6N × C3H/HeN MTV−) | Same as 2-week studies | Same as 2-week studies
Animal Source
NCTR breeding colony | Same as 2-week studies | Same as 2-week studies
Time Held Before Studies
1 to 2 weeks | 1 to 2 weeks | 2 to 3 weeks
Average Age When Studies Began
4 to 5 weeks | 4 to 5 weeks | 5 to 6 weeks
Date of First Exposure
Rats: April 12, 2004 | Rats: August 4/5, 2004 | Rats: May 30/31, 2005; June 6/7, 13/14, 20/21, and 27/28, 2005; July 4/5, 11/12, 18/19, and 25/26, 2005; and August 1/2, 8/9, and 15, 2005
Mice: April 13, 2004 | Mice: August 2/3, 2004 | Mice: June 2, 9, 16, 23, and 30, 2005; July 7, 14, 21, and 28, 2005; and August 4, 11, and 18, 2005
Duration of Exposure
2 weeks | 13 weeks | 104 weeks
Date of Last Exposure
Rats: April 27, 2004 | Rats: November 4/5, 2004 | Rats: June 6, 13, 20, and 27, 2007; July 5, 11, 18, 25, and 31, 2007; and August 8, 15, and 22, 2007
Mice: April 28, 2004 | Mice: November 2/3, 2004 | Mice: June 5, 12, 19, and 26, 2007; July 3, 10, 17, 24, and 31, 2007; and August 7, 14, and 21, 2007
Necropsy Dates
Rats: April 27, 2004 | Rats: November 4/5, 2004 | Rats: June 6, 13, 20, and 27, 2007; July 5, 11, 18, 25, and 31, 2007; and August 8, 15, and 22, 2007
Mice: April 28, 2004 | Mice: November 2/3, 2004 | Mice: June 5, 12, 19, and 26, 2007; July 3, 10, 17, 24, and 31, 2007; and August 7, 14, and 21, 2007
Average Age at Necropsy
6 to 7 weeks | 17 to 18 weeks | 2 years
Size of Study Groups
4 males and 4 females | 8 males and 8 females | 48 males and 48 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial body weights. | Same as 2-week studies | Same as 2-week studies
Animals per Cage
Rats: 2 same sex | Same as 2-week studies | Same as 2-week studies
Mice: 4 same sex
Method of Animal Identification
Rats: Tail tattoo | Same as 2-week studies | Same as 2-week studies
Mice: Ear clip and tail tattoo
Diet
Irradiated Purina 5LG6 meal feed (also designated NIH-31 IR), available ad libitum | Same as 2-week studies | Same as 2-week studies
Water
Millipore-filtered tap water, available ad libitum | Same as 2-week studies | Same as 2-week studies
Cages
Polycarbonate cages (Lab Products, Inc., Seaford, DE and Allentown Caging and Equipment, Allentown, NJ), changed twice weekly (rats) or once weekly (mice) | Same as 2-week studies | Same as 2-week studies
Bedding
Autoclaved hardwood chip bedding (Northeastern Products Corp., Caspian, MI), changed twice weekly (rats) or once weekly (mice) | Same as 2-week studies | Same as 2-week studies
Cage Filters
Spunbonded polyester (Lab Products, Inc., Seaford, DE and Allentown Caging and Equipment, Allentown, NJ), changed every 2 weeks | Same as 2-week studies | Same as 2-week studies
Racks
Stainless steel (Research Equipment Co., Bryan, TX), changed every 3 weeks | Same as 2-week studies | Same as 2-week studies
Animal Room/Chamber Environment
Temperature: 22° ± 4°C Relative humidity: 40% to 70% Room fluorescent light: 12 hours/day Room air changes: 10 to 15/hour | Same as 2-week studies | Same as 2-week studies
Exposure Concentrations
0.0, 0.14, 0.35, 0.70, 1.41, 3.52, and 7.03 mM glycidamide (0, 12.2, 30.6, 61.2, 122, 306, and 612 ppm glycidamide) | 0.0, 0.14, 0.35, 0.70, 1.41, and 3.52 mM glycidamide (0, 12.2, 30.6, 61.2, 122, and 306 ppm glycidamide) | 0.0, 0.0875, 0.175, 0.35, and 0.70 mM glycidamide (0, 7.65, 15.3, 30.6, and 61.2 ppm glycidamide)
Type and Frequency of Observation
Observed twice daily; animals were weighed on dose days 1, 7, and 14; and food and water consumption measured weekly | Observed twice daily; animals were weighed weekly; and food and water consumption were measured weekly | Same as 3-month studies
Method of Sacrifice
Carbon dioxide asphyxiation | Same as 2-week studies | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were liver and brain. Processing for microscopic examination was performed on gross lesions, brain (cerebrum, cerebellum, and brain stem), Harderian glands, heart, liver, lungs, pancreas, peripheral nerve (sciatic), ovaries, thyroid gland, parathyroid gland, skin, mammary glands, spinal cord (thoracic, lumbar, and cervical), forestomach, glandular stomach, and testes. | Necropsies were performed on all animals. Organs weighed were liver and brain. Processing for microscopic examination was performed on gross lesions, brain (cerebrum, cerebellum, and brain stem), Harderian glands, heart, liver, lungs, pancreas, peripheral nerve (sciatic), ovaries, thyroid gland, parathyroid gland, skin, mammary glands, spinal cord (thoracic, lumbar, and cervical), forestomach, glandular stomach, and testes. | Necropsies were performed on all animals. Processing for microscopic examination was performed on gross lesions, brain (cerebrum, cerebellum, and brain stem), Harderian glands, heart, liver, lungs, pancreas, peripheral nerve (sciatic), ovaries, thyroid gland, parathyroid gland, skin, mammary glands, spinal cord (thoracic, lumbar, and cervical), forestomach, glandular stomach, duodenum, ileum, jejunum, cecum, colon, testes, kidneys, urinary bladder, spleen, prostate, trachea, esophagus, uterus, eye, aorta, nose, pituitary, preputial/clitoral gland, epididymis, lymph nodes (mesenteric and mandibular), seminal vesicles, thymus, salivary glands, bone (femur), and adrenal glands.

## Statistical Methods

### Survival Analyses

Mean and median survival times and plots of rodent survival functions were obtained using Kaplan-Meier estimation.^61^ Cox proportional hazards regression analyses^62^ were conducted to compare the hazard function of each dose group to that of the control group and to test for a linear trend between the hazard and glycidamide dose. The hazard for each dose group was defined as a function of both glycidamide dose and time on study, measured in weeks.

Differences in survival at each dose between B6C3F1/Nctr mice given acrylamide in the drinking water for 2 years^4^ and B6C3F1/Nctr mice given glycidamide in the drinking water in the current study were also investigated. Homogeneity of survival curves was tested at each dose level between mice administered acrylamide and those administered glycidamide. A similar analysis was conducted for F344/N Nctr rats given acrylamide in the drinking water for 2 years^4^ and F344/N Nctr rats given glycidamide in the drinking water in the current study.

### Body Weight Analyses

The effect of glycidamide dose on body weight was investigated using a sex-stratified, repeated measures, mixed models analysis of variance (ANOVA), with dose and week main effects and a dose × week interaction effect. Within-group correlations were modeled using a heterogeneous first order autoregressive (ARH(1)) covariance structure that allows for (1) increasing variability in the animal’s weight over time and (2) body weights being correlated at adjacent time points to a greater extent than at distant time points. Least squares estimates of mean body weight were obtained for each dose group from weeks 4 to 104 in 4 week intervals. Pairwise comparisons of dose group to control group (0.0 mM glycidamide) body weight means were performed to determine if there was a difference between the control and the respective dose group means. Dunnett’s adjustment^63^ was used to correct for multiple pairwise comparisons to controls. Trend tests were conducted to determine if body weight means decreased or increased with increasing dose.

The difference in mean body weight at each dose between B6C3F1/Nctr mice given acrylamide in the drinking water for 2 years^4^ and B6C3F1/Nctr mice given glycidamide in the drinking water in the current study was investigated using a sex-stratified, repeated measures, mixed models, three-way ANOVA with main effects of compound, dose, week, and all higher-order interaction effects. Within-group correlations were modeled using a heterogeneous first order autoregressive (ARH(1)) covariance structure, which allows for (1) differences in weight variability over time, and (2) body weights being correlated more at adjacent time points than at distant time points. Least squares estimates of mean body weight were obtained for each compound and dose group at 4 week intervals. A similar analysis was conducted for F344/N Nctr rats given acrylamide in the drinking water for 2 years^4^ and F344/N Nctr rats given glycidamide in the drinking water in the current study.

### Water and Food Consumption Analyses

The effect of glycidamide dose on food and water consumption was determined on a cage basis. For each cage and for each consumption period, food and water consumption were calculated by subtracting the container weight at the end of the period from the container weight at the beginning of the period. Consumption periods were grouped into 4 week study periods based on the observation date. The sum of the food and water consumption within the study period was then divided by the number of animal-days to obtain the food and water consumption per day for each study period for each animal. With study periods defined as such the effect of glycidamide dose on food and water consumption was analyzed using a sex-stratified, repeated measures, mixed models ANOVA with dose and study period main effects and a dose by study period interaction effect. Within-group correlations were modeled using a heterogeneous first order autoregressive (ARH(1)) covariance structure that allows for (1) differences over time in the variability of the amount of food and water consumed, and (2) the amount of consumed food and water being correlated to a greater extent at adjacent time points than at distant time points. Least squares estimates of the mean amount of food and water consumed were obtained for each dose group at four week intervals. Pairwise comparisons of the amount of food and water consumed by the dose group to that of the control group were performed to determine if there was a difference between the control and the respective dose group means. Dunnett’s adjustment^63^ was used to correct for multiple pairwise comparisons to controls. Trend tests were conducted to determine if the mean amount of food and water consumed decreased or increased with increasing dose.

The difference in mean food and water consumption at each dose between B6C3F1/Nctr mice given acrylamide in the drinking water for 2 years^4^ and B6C3F1/Nctr mice given glycidamide in the drinking water in the current study was also examined. For each cage and for each consumption period food and water consumption was calculated by subtracting the container weight at the end of the period from the container weight at the beginning of the period. Consumption periods were grouped into 4-week study periods based on the observation date. The sum of the food (or water) consumptions within the study period was then divided by the number of animal-days to obtain the food (or water) consumption per day for each study period for each animal. Differences in mean food and water consumption were then tested using a sex-stratified, repeated measures, mixed models, three-way ANOVA with main effects of compound, dose, week, and all higher-order interaction effects. Within-group correlations were modeled using a heterogeneous first order autoregressive (ARH(1)) covariance structure, which allows for (1) differences over time in the variability of the amount of food and water consumed, and (2) the amount of consumed food and water being correlated more at adjacent time points than at distant time points. Least squares estimates of mean amount of food and water consumed were obtained for each compound and dose group at 4 week intervals. A similar analysis was conducted for F344/N Nctr rats given acrylamide in the drinking water for 2 years^4^ and F344/N Nctr rats given glycidamide in the drinking water in the current study.

Water consumption and body weight data were used to determine glycidamide exposure. For each consumption period, the amount of water consumed per cage was calculated by subtracting the container weight at the end of the period from the container weight at the beginning of the period. The amount of body weight-days for a cage in a consumption period was computed by first multiplying, for each animal in a cage, the body weight of each mouse or rat by the number of days that mouse or rat was on study in that consumption period, and then summing these products over all the mice or rats in the cage. For each cage of mice or rats, the amount of compound consumed in milligrams per kilogram of animal weight per day was then calculated by dividing the amount of water consumed per cage by the calculated body weight-days per cage, and then converting this quantity to milligrams using the dose concentration and the molecular weight of glycidamide (87.08 g per mol). Consumption periods were then grouped into 1-week study periods based on the observation date.

Differences in mean compound consumption at each dose between B6C3F1/Nctr mice given acrylamide in the drinking water for 2 years^4^ and B6C3F1/Nctr mice given glycidamide in the drinking water in the current study were also investigated using a sex and dose-stratified fixed effects analysis of variance (ANOVA) with main effects of compound and study period and a compound by study period interaction effect. Comparisons of the amount of compound consumed by the acrylamide-treated mice to the corresponding glycidamide-treated mice were conducted to determine if there was a difference in least squares mean compound consumption between mice treated with acrylamide and those treated with glycidamide. A similar analysis was conducted for F344/N Nctr rats given acrylamide in the drinking water for 2 years^4^ and F344/N Nctr rats given glycidamide in the drinking water in the current study.

### Pathology Data Analyses

The continuity-corrected Poly-3 test,^64^ as modified by Bieler and Williams,^65^ was used to assess prevalence of neoplasms and nonneoplastic lesions. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal sacrifice; if the animal died prior to terminal sacrifice and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the 3rd power. This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^64^ A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions.

Tests of significance included pairwise comparisons of each exposed group with controls and a test for an overall exposure-related trend. Continuity-corrected Poly-3 tests^66^ were used in the analysis of neoplasm incidence; the reported P values are one sided. Positive trends are reported with right-tailed P values. Negative trends are reported with left-tailed P values, with the letter N added to indicate a lower incidence as exposure increases. P values <0.05 were considered significant.

Differences in tumor incidences between B6C3F1/Nctr mice given acrylamide in the drinking water for 2 years^4^ and B6C3F1/Nctr mice given glycidamide in the drinking water in the current study were also investigated. Logistic regression using Poly-3 weights was used to model the dose response of acrylamide and glycidamide and determine if the slopes of their regression lines were equal. The model included a continuous dose term and a term for the interaction of dose with compound. Equality of slopes between the regression lines was assessed by testing the statistical significance of the interaction effect. Logistic regression using Poly-3 weights and conditioning on each dose level was used to compare tumor incidence between the two compounds at each dose. A similar analysis was conducted for F344/N Nctr rats given acrylamide in the drinking water for 2 years^4^ and F344/N Nctr rats given glycidamide in the drinking water in the current study.

## Quality Assurance

This study was conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^67^ The Quality Assurance Unit at the NCTR performed audits and inspections of the protocols, procedures, data, and reports throughout the course of the study. Separate audits covering completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this technical report were conducted. Audit procedures and findings are on file at the NCTR. The audit findings were reviewed and assessed by the NCTR staff, and all comments were resolved or otherwise addressed either before or during the preparation of the technical report.

Raw data sheets from the study are archived by the NCTR’s record management unit. Histopathology samples collected during the course of the study are stored in the archives of Toxicologic Pathology Associates at the NCTR. Backup computer data are maintained by the computer staff at the NCTR. All records and samples are stored in accordance with Food and Drug Administration Good Laboratory Practice Regulations.