# Introduction

Figure 1

Glycidamide (CASRN 5694-00-8; Chemical Formula: C_3_H_5_NO_2_; Molecular Weight: 87.08)

Synonyms: 2,3-epoxypropanamide; glycidic acid amide; oxirane-2-carboxamide; oxiranecarboxamide.

## Chemical and Physical Properties

Glycidamide (Figure 2) is a pale orange, hygroscopic crystalline solid. It is soluble in acetone, dichloromethane, and water, and has a melting point of 32° to 34°C (recrystallized from acetone).^1^

Figure 2

Metabolites of Glycidamide

## Production, Use, and Human Exposure

Glycidamide is prepared by the epoxidation of acrylonitrile under basic conditions.^1^ The primary use of glycidamide is as an intermediate in organic synthesis, for example, as a synthetic intermediate in the production of dyes and plasticizers.^2^

Glycidamide is a major metabolite of the α,β-unsaturated amide acrylamide (reviewed in Shipp et al.^3^; NTP^4^). As a consequence, the major source of human exposure to glycidamide occurs through exposure to acrylamide either in occupational situations, through the diet, or by the use of tobacco products (reviewed in Shipp et al.^3^; NTP^4^). Glycidamide has also been reported to be present in certain foods, at a level of less than 1% that of acrylamide.^5^

## Biological and Toxicological Properties

### Absorption, Distribution, Metabolism, and Excretion in Experimental Animals

The absorption, distribution, metabolism, and excretion of acrylamide in experimental animals have been reviewed.^3,4^

The toxicokinetic parameters of glycidamide have been determined in B6C3F1 mice and F344 rats after a single intravenous or oral (gavage) administration.^6,7^ After intravenous injection of glycidamide to B6C3F1 mice, the elimination half-life (t_1/2_) was 1.0–1.1 hr, the time-serum concentration curve from zero to infinity (AUC) was 2.9 μM hr, and the volume of distribution (V_d_) was 0.70–0.74 ml/g^6^ (Table 1). In B6C3F1 mice treated by gavage with glycidamide, the maximum concentration (C_max_) was observed at the initial sampling point of 15 min, and the t_1/2_ and AUC values were similar to those determined in B6C3F1 mice injected intravenously^6^ (Table 1).

Table 1 Toxicokinetic Parameters for Glycidamide Administered to B6C3F1 Mice and F344 Rats^a^

| B6C3F1 Mice | | | | F344 Rats
| Intravenous | | Gavage | | Intravenous | | Gavage
| Male | Female | Male | Female | Male | Female | Male | Female
Glycidamide AUC^b^ (μM hr) | 2.9 | 2.9 | 3.4 | 3.3 | 2.8 | 3.3 | 2.8 | 3.8
Glycidamide t_1/2_ absorption (hr) | – | – | – | – | – | – | 0.31 | 1.8
Glycidamide t_1/2_ elimination (hr) | 1.1 | 1.0 | 1.1 | 1.2 | 1.3 | 1.4 | 1.7 | 1.8
Glycidamide V_d_ (ml/g) | 0.74 | 0.70 | – | – | 0.77 | 0.68 | – | –
Glycidamide C_max_ (μM) | – | – | 1.5 | 1.6 | – | – | 0.70 | 0.92

^a^ The pharmacokinetic parameters were determined after a single administration of 0.12 mg/kg glycidamide (1.4 µmol/kg). Adapted from Doerge et al.^6,7^

^b^ The abbreviations used are: AUC, area under the curve; t_1/2_, half-life; V_d_, volume of distribution; C_max_, maximum concentration.

Intravenous administration of glycidamide to F344 rats resulted in V_d_ and AUC values similar to those observed in B6C3F1 mice and a slightly longer elimination t_1/2_^7^ (Table 1). After oral gavage of glycidamide to F344 rats, the C_max_ values occurred at 1 hr and were approximately 50% of those observed in B6C3F1 mice, the AUC values were comparable to those in B6C3F1 mice, while the t_1/2_ values were slightly longer^7^ (Table 1).

Glycidamide reacts with glutathione to give S-(1-carbamoyl-2-hydroxyethyl)glutathione and S-(2-carbamoyl-2-hydroxyethyl)glutathione, which after further metabolic processing yield N-acetyl-S-(1-carbamoyl-2-hydroxyethyl)cysteine and N-acetyl-S-(2-carbamoyl-2-hydroxyethyl)cysteine^8^ (Figure 2). Glycidamide also undergoes hydrolysis to form 2,3-dihydroxypropanamide (glyceramide) and subsequently 2,3-dihydroxypropionic acid^8,9^ (Figure 2). The cysteine conjugates, glyceramide, and 2,3-dihydroxypropionic acid have been detected in the urine of mice and rats treated with acrylamide.^8-13^ The formation of these metabolites does not appear to have been examined in experimental animals administered glycidamide.

Incubation of primary liver hepatocytes from male Sprague-Dawley rats with 0.3, 1, or 3 mM glycidamide resulted in a rapid statistically significant decrease in the glutathione content of the cells.^14^ Glutathione depletion was not observed with 0.1 mM glycidamide and the effect with glycidamide was more pronounced than that observed with an equimolar concentration of acrylamide. The depletion of glutathione could be prevented partially by co-incubation with N-acetylcysteine or methionine.

A number of DNA adducts have been characterized from the reaction of glycidamide with DNA and/or deoxynucleosides. These include N7-(2-carbamoyl-2-hydroxyethyl)guanine (N7-GA-Gua; from the depurination of N7-(2-carbamoyl-2-hydroxyethyl)deoxyguanosine), N3-(2-carbamoyl-2-hydroxyethyl)adenine (N3-GA-Ade; from the depurination of N3-(2-carbamoyl-2-hydroxyethyl)deoxyadenosine), N1-(2-carboxy-2-hydroxyethyl)deoxyadenosine, N^6^-(2-carboxy-2-hydroxyethyl)deoxyadenosine (from a Dimroth rearrangement of N1-(2-carboxy-2-hydroxyethyl)deoxyadenosine), N3-(2-carbamoyl-2-hydroxyethyl)thymidine, N3-(2-carboxy-2-hydroxyethyl)deoxycytidine, N1-(2-carboxy-2-hydroxyethyl)deoxyguanosine, N1-(2-carbamoyl-2-hydroxyethyl)deoxyguanosine, N1,N^6^-(2-hydroxypropanoyl)deoxyadenosine, and N3,N^4^-(2-hydroxypropanoyl)deoxycytidine^15-20^ (Figure 3).

Figure 3

DNA Adducts of Glycidamide

N7-GA-Gua and N3-GA-Ade have been detected in mice and rats treated with glycidamide.^6,7,17,21-23^ Both adducts are typically detected in all tissues examined, with N7-GA-Gua being formed to a 100-fold greater extent than N3-GA-Ade,^17,22,23^ a ratio that corresponds to that observed in DNA reacted with glycidamide in vitro.^17^ N7-GA-Gua and N3-GA-Ade have been found in Chinese hamster lung V79 cells^24^ and L5178Y/Tk^+/−^ mouse lymphoma cells^25^ treated in vitro with glycidamide, with the ratio again being ~100:1 (N7-GA-Gua:N3-GA-Ade). N1-(2-Carboxy-2-hydroxyethyl)deoxyadenosine has been reported in DNA from cells treated in vitro with glycidamide; it was not detected in vivo.^18^

Glycidamide reacts with cysteine residues in hemoglobin and other proteins.^26,27^ After hydrolysis with 6 N HCl, the adduct is released as S-(2-carboxy-2-hydroxyethyl)cysteine (Figure 4). Glycidamide also reacts with the N-terminal valine of hemoglobin to give (after acid hydrolysis) N-(2-carboxy-2-hydroxyethyl)valine^28^ (Figure 4).

Figure 4

Hemoglobin (Hb) Adducts of Glycidamide

N-(2-Carboxy-2-hydroxyethyl)valine was detected in hemoglobin isolated from B6C3F1 mice and F344 rats receiving single doses of glycidamide by either intravenous or oral (gavage) administration. In B6C3F1 mice, the levels of N-(2-carboxy-2-hydroxyethyl)valine were comparable by both routes of administration and did not differ between sexes. With F344 rats, the adduct levels were also comparable by both routes of administration, but were somewhat higher in females as compared to males.^22^

In Sprague-Dawley rats administered a single intraperitoneal dose of glycidamide (0–100 mg per kg body weight), the formation of glycidamide hemoglobin adducts (measured as S-(2-carboxy-2-hydroxyethyl)cysteine) varied linearly with the dose.^26^ Likewise, there were linear correlations between the serum AUC for glycidamide in B6C3F1 mice and F344 rats and the levels of glycidamide hemoglobin adducts (measured as N-(2-carboxy-2-hydroxyethyl)valine) and between the levels of glycidamide hemoglobin adducts (also measured as N-(2-carboxy-2-hydroxyethyl)valine) and the levels of N7-GA-Gua in hepatic DNA of B6C3F1 mice and F344 rats.^22^

### Absorption, Distribution, Metabolism, and Excretion in Humans

The absorption, distribution, metabolism, and excretion of acrylamide in humans have been reviewed.^3,4^

The placental transfer of glycidamide has been investigated in vitro using perfused human placentas. When incubations were conducted with 5 μg per ml glycidamide (60 μM glycidamide), the concentration after 4 hr in the fetal perfusate was nearly identical to that in the maternal perfusate. The transfer index was 33%, a value similar to that observed with acrylamide and the positive control antipyrine.^29,30^

Glycidamide was not detected in perfusion samples or placental tissue samples from incubations conducted with acrylamide. N1-(2-Carboxy-2-hydroxyethyl)deoxyadenosine was not detected in perfused placental tissue; the presence of N7-GA-Gua or N3-GA-Ade was not assessed.^29^ N7-GA-Gua has been reported to be present in human lymphoid TK6 cells incubated in vitro with glycidamide.^31^

### Toxicity in Experimental Animals

Glycidamide is neurotoxic in experimental animals. Male Sprague-Dawley rats injected intraperitoneally daily for eight days with 50 or 100 mg glycidamide per kg body weight had a significant decrease in body weight and a decreased performance on a rotarod apparatus (at only the 100 mg glycidamide per kg body weight dose). Hind limb splay, a response observed with comparable doses of acrylamide, was not apparent.^32^

In a subsequent study, male Sprague-Dawley rats received subcutaneous injections of 15.3, 30.6, or 61.3 mg glycidamide per kg body weight (0.18, 0.35, or 0.70 mMol glycidamide per kg body weight) for 39 days. None of the animals displayed any signs of neurotoxicity when monitored for 70 days after the initial injection. When male Sprague-Dawley rats were injected intraperitoneally with 0.70 mMol glycidamide per kg body weight per day, all animals developed hind limb paralysis by 13 days of treatment.^33^

In a further experiment, male Sprague-Dawley rats were treated daily for 8 days by intraperitoneal injection with 50 or 100 mg glycidamide per kg body weight. Rats administered 100 mg glycidamide per kg body weight had a significant decrease in body weight, decreased performance on a rotarod apparatus, and decreased creatine kinase activity in the sciatic nerve, tibial nerve, and whole brain. The decrease in creatine kinase activity was also observed at 50 mg glycidamide per kg body weight.^34^ A decrease in glyceraldehyde-3-phosphate dehydrogenase activity has also been reported in peripheral nerves of rats treated intraperitoneally for 8 days with 50 or 100 mg glycidamide per kg body weight.^35^

### Toxicity in Humans

Although the toxicity of acrylamide in humans is well documented (reviewed in Shipp et al.^3^; NTP^4^), there are no toxicity data in humans from the direct exposure to glycidamide.

### Reproductive Toxicity and Teratogenicity in Experimental Animals

Male Sprague-Dawley rats treated daily for 8 days with 50 mg glycidamide per kg body weight had significant decreases in testis protein content, epididymis weight, vas deferens sperm count, and sperm cell viability when measured one day after the final dose. Total testis weight was not affected.^32^

Male B6D2F1 mice were treated daily for 8 days with intraperitoneal injections of 61 mg glycidamide per kg body weight per day. One day after the last injection, sperm was isolated and used in an in vitro fertilization experiment with oocytes from female B6C3F1 mice. The expression of 39 genes involved in the response to DNA damage and in embryo development was assessed in zygotes and embryos at 1-, 2-, 4-, and 8-cell stages. Fourteen genes were significantly affected by glycidamide treatment, with there being decreased expression at early time points and increased expression at later time points.^36^

### Reproductive Toxicity and Teratogenicity in Humans

There are no data pertaining to the reproductive toxicity and teratogenicity of glycidamide in humans.

### Carcinogenicity in Experimental Animals

The effect of perinatal exposure to glycidamide was investigated in C57BL/6J Min/+ mice, a strain susceptible to intestinal neoplasia, and their wild type littermates. In one experiment, C57BL/6J Min/+ mice and their wild type C57BL/6J littermates were treated subcutaneously at one and two weeks after birth with 10 or 50 mg glycidamide per kg body weight. When assessed at eight weeks of age, C57BL/6J Min/+ mice (males and females combined) had a slight but significant dose-related induction of small intestinal tumors, with the increase being significant at 50 mg glycidamide per kg body weight. The wild-type C57BL/6J littermates were assessed at 32 weeks of age. At this time, mice administered 50 mg glycidamide per kg body weight had a significant increase in intestinal lesions (small intestinal tumors, and either flat or classical aberrant crypt foci).^37^

In a second experiment, the mothers of one group of C57BL/6J Min/+ mice were exposed to 50 mg (0.57 mMol) glycidamide per kg body weight 1 week before giving birth, a second group was treated at the same dose level 1 and 2 weeks after birth, and a third group received both the prenatal and postnatal treatments. In addition, the mothers of one group of wild type littermates were treated with 50 mg glycidamide per kg body weight 1 week before giving birth and then their pups were treated weekly from weeks 5 to 11 with 50 mg glycidamide per kg body weight; a second group was treated at weeks 1, 2, and 5 to 11 of age, and a third group received both the prenatal and postnatal treatments. When assessed at 12 weeks of age, there was a significant increase in colonic tumors in male C57BL/6J Min/+ mice treated prenatally and postnatally. None of the other treatments caused an increase in the tumor incidence in either C57BL/6J Min/+ mice or their wild type littermates.^37^

Male B6C3F1 mice were injected intraperitoneally on postnatal days 1, 8, and 15 with 0.0, 0.14, or 0.70 mMol glycidamide per kg body weight per day and tumorigenicity was assessed after 1 year. The only treatment-related neoplasms involved the liver. The incidence of combined hepatocellular adenoma or carcinoma was 3.8% in the control group, 8.3% in the 0.14 mMol glycidamide per kg body weight group, and 71.4% in the 0.70 mMol glycidamide per kg body weight group. The hepatic tumor incidence in the 0.70 mMol glycidamide per kg body weight group was significantly different from the control group. Analysis of the hepatocellular tumors indicated that the increased incidence observed in mice administered 0.70 mMol glycidamide per kg body weight was associated with A→G and A→T mutations at codon 61 of the H-ras oncogene.^38^

### Carcinogenicity in Humans

There are no data pertaining to the carcinogenicity of glycidamide in humans.

## Genetic Toxicity

Glycidamide is a well-documented genotoxicant, giving positive responses in vitro and in vivo in a variety of assays and test systems in somatic and germinal cells measuring gene mutations, DNA damage, and chromosomal aberrations. A brief summary of the literature follows.

### Bacterial Mutagenesis Assays

Glycidamide is mutagenic in Salmonella typhimurium base-substitution strains TA100 and TA1535 in the absence of a rat liver S9 mix, suggesting that glycidamide is a direct-acting mutagen; the addition of S9 had no effect upon the mutagenicity of glycidamide in strain TA1535 but increased the number of revertants in strain TA100.^39^ In another study, glycidamide was mutagenic in strain TA100 in the presence of S9; it did not appear to have been tested in the absence of S9.^40^ Glycidamide also induced the umuC gene, a gene that contributes to post-replication DNA repair, in Salmonella typhimurium TA1535/pSK1002 in the absence of S9.^31^

Glycidamide was not mutagenic in the fluctuation test with Klebsiella pneumoniae when tested at doses up to 50 mM.^41^

### In Vitro Mammalian Cell Gene Assays

The mutagenicity of glycidamide has been assessed in L5178Y/Tk^+/−^ mouse lymphoma cells. Positive responses, in the absence of metabolic activation, were obtained at concentrations of 2.5 mM^42^ and 2–4 mM.^25^ The induction of mutations was associated with a dose-dependent formation of N7-GA-Gua and N3-GA-Ade DNA adducts and was attributed to a clastogenic mode of action (i.e., loss of heterozygosity).^25^ An increase in mutations was not detected in the presence of an external activation system.^42^

Glycidamide induced a dose-dependent increase in the mutant frequency at the hypoxanthine-guanine phosphoribosyltransferase (Hprt) gene of Chinese hamster lung V79 cells at concentrations of 0.8–2.0 mM.^43-45^ An increased Hprt mutant frequency was detected in Chinese hamster ovary cells that had been treated with ~1–4 mM glycidamide.^46^ Glycidamide also induced chromosomal aberrations at concentrations of 0.25–1.0 mM and sister chromatid exchanges at concentrations of 10–1000 μM in Chinese hamster lung V79 cells. These cytogenetic alterations were correlated with the formation of N7-GA-Gua and N3-GA-Ade DNA adducts.^24^

Incubation of Big Blue^®^ mouse embryo fibroblasts with 50 nM to 5 mM glycidamide resulted in a dose-dependent increase in the mutant frequency at the cII transgene. The increase in mutant frequency was attributed primarily to G→T transversion mutations, along with A→G transition and G→C transversion mutations.^47^

Glycidamide induced a dose-related increase in the mutant frequency of the thymidine kinase (TK) gene of human lymphoblastoid TK6 cells at concentrations of 0.6–2.5 mM, with the increase being statistically significant at 2.5 mM glycidamide; the increase in the mutant frequency was due primarily to point mutations.^48^ Additional endpoints measured in the TK6 cells included the induction of micronuclei, which was significantly increased at 2.5 mM glycidamide, and DNA damage, as measured by the comet assay, which was significantly increased at concentrations ≥0.6 mM glycidamide.

Incubation of human peripheral blood lymphocytes with 0.3–3 mM glycidamide^43^ or 1–10 mM glycidamide^40^ resulted in a dose dependent increase in DNA damage, as measured by the comet assay. An increase in micronuclei was not apparent in these cells under similar treatment conditions.^43^ When comet assays were performed in the presence of formamidopyrimidine DNA glycosylase (Fpg), a bacterial enzyme that allows for assessment of oxidative DNA damage, an increase in DNA damage was observed at concentrations as low as 10 μM glycidamide.^45^ In another study, human peripheral blood lymphocytes, mouse peripheral blood lymphocytes, and mouse testicular cells were incubated with 0–5 mM glycidamide, and strand breaks and alkali-labile sites were assessed by the comet assay. The maximum response was again observed when assays were conducted in the presence of Fpg and yielded effective concentrations (EC_10_) of 3.7 μM in human peripheral blood lymphocytes, 8.6 μM in mouse peripheral blood lymphocytes, and 13.5 μM in mouse testicular cells.^49^ An increased response in a comet assay, conducted in the presence of Fpg, was also reported for Chinese hamster lung V79 cells that had been incubated with 10–300 μM glycidamide.^44^ An increase in DNA damage, as indicated by the comet assay, also occurred in Chinese hamster lung V79 cells, human epithelial colorectal adenocarcinoma cells (Caco-2), and primary hepatocytes from male Wistar rats exposed to ≥30, ≥300, and ≥60 μM glycidamide, respectively.^50^

When glycidamide was incubated with primary rat liver hepatocytes at concentrations up to 4 mM, there was not an increase in unscheduled DNA synthesis in one experiment^42^; however, in a subsequent study, incubation with 1 or 10 mM glycidamide, but not 0.01 or 0.1 mM glycidamide, resulted in a significant increase in unscheduled DNA synthesis in hepatocytes from male F344 rats.^51^ The induction of unscheduled DNA synthesis was also observed in primary human mammary epithelial cells treated with 1 or 10 mM glycidamide.^51^

### In Vivo Mammalian Cell Assays

A single intraperitoneal injection of 125 mg glycidamide per kg body weight produced positive results in the dominant lethal mutation test when assessed in germ cells from male (C3H/RL × 101/RL)F_1_ mice. Likewise, a single intraperitoneal injection of 100 mg glycidamide per kg body weight caused a significant increase in reciprocal translocations in germ cells of male mice. In addition, a single intraperitoneal injection with 150 mg glycidamide per kg body weight induced unscheduled DNA synthesis in mouse sperm at the early spermatid stage.^52^

Male and female B6C3F1/Tk^+/−^ and B6C3F1/Tk^+/+^ mice were treated intraperitoneally on postnatal days 1, 8, and 15 or postnatal days 1 to 8 with 0.14 or 0.70 mMol glycidamide per kg body weight per day. One day after the final dose, DNA adduct levels and peripheral blood micronuclei were measured in B6C3F1/Tk^+/+^ mice, and three weeks after the last treatment, Hprt and Tk mutant frequencies were assessed in spleen lymphocytes from B6C3F1/Tk^+/−^ mice. The administration of 0.70 mMol glycidamide per kg body weight on postnatal days 1, 8, and 15 produced an increase in mutant frequency at the Hprt gene in splenic T-lymphocytes of B6C3F1/Tk^+/−^ mice and an increased frequency of micronucleated reticulocytes and micronucleated normochromatic erythrocytes in peripheral blood of B6C3F1/Tk^+/+^ mice. The administration of 0.14 mMol glycidamide per kg body weight on postnatal days 1–8 was associated with an increased mutant frequency at the Tk gene in splenic T-lymphocytes of B6C3F1/Tk^+/−^ mice and an increased frequency of micronucleated normochromatic erythrocytes in peripheral blood from B6C3F1/Tk^+/+^ mice. Molecular analysis indicated that the glycidamide-induced increases in the Tk mutant frequency were due, in part, to loss of heterozygosity.^23^ A dose-related increase in micronucleated polychromatic erythrocytes has also been reported in male CBA mice receiving a single intraperitoneal injection of 0.18, 0.35, or 0.70 mMol glycidamide per kg body weight.^53^

Male and female Big Blue^®^ mice administered 7.0 mM glycidamide (600 ppm glycidamide) in the drinking water for four weeks had an increased mutant frequency at the Hprt gene in splenic T-lymphocytes, an increased mutant frequency at the cII transgene in liver, and an increased frequency of micronucleated reticulocytes in peripheral blood samples. An increased Hprt mutant frequency in splenic T-lymphocytes was also observed in mice given 1.4 mM glycidamide (120 ppm glycidamide) for four weeks. The increased mutant frequency in the cII transgene in liver was associated with G→T transversion mutations and also with −1/+1 frameshift mutations in a sequence of six guanine residues.^54^ A subsequent report indicated that there was an increased mutant frequency in the cII transgene from the testes of these mice.^55^

Male and female Big Blue^®^ rats given 1.4 mM glycidamide (120 ppm) in the drinking water for 60 days had an increased mutant frequency at the Hprt gene in splenic T-lymphocytes, and increased mutant frequencies at the cII transgene in the bone marrow and thyroid gland, but not in the testis, mammary gland, or liver. No increase in mutant frequency was observed at the cII transgene in the livers of either sex, or in the testes of male rats or mammary gland of female rats, and no increase was detected in the frequency of micronucleated reticulocytes in either sex when measured 24 hr after the treatment ended.^56^ The lack of a micronucleus response in these rats was somewhat surprising given the clear responses for this endpoint in other studies, and may be due to the lower doses used by Mei et al.^56^ as well the lower sensitivity of rats to glycidamide-induced micronucleus formation.^53^

## Study Rationale

Acrylamide has recently been detected in roasted coffee and many baked and fried starchy foods. Existing data indicated that acrylamide is carcinogenic; however, the Center for Food Safety and Applied Nutrition, FDA, desired a modern, more definitive bioassay to perform a quantitative risk assessment. Consequently the FDA nominated acrylamide for evaluation by the NTP.

Acrylamide was hypothesized to be a genotoxic carcinogen as a result of metabolic conversion to glycidamide, which reacts with DNA. Since the metabolic conversion of acrylamide to glycidamide occurs to a greater extent in mice as compared to rats,^8,21^ mice were hypothesized to be more sensitive than rats to the carcinogenic effects of acrylamide. To test these hypotheses and to provide data for a meaningful risk assessment, studies were conducted simultaneously to compare the extent and types of tumors in B6C3F1/Nctr mice and F344/N Nctr rats treated chronically with either acrylamide or glycidamide. The data from the animals exposed to acrylamide formed the basis for NTP Technical Report 575.^4^ The results from the studies with glycidamide form the basis for the current report.