# Appendix L Summary of Peer Review Panel Comments

On October 29, 2013, the draft Technical Report on the toxicology and carcinogenesis studies of glycidamide received public review by the National Toxicology Program’s Technical Report Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. F.A. Beland, NCTR, introduced the toxicology and carcinogenesis drinking water studies of glycidamide by describing glycidamide as a metabolite of acrylamide, a contaminant present in certain baked goods and fried, starchy foods, as well as cigarette smoke. NTP performed parallel studies to determine and compare the long-term effects of acrylamide and glycidamide in rats and mice. Dr. Beland also described the design and result of the 2-week, 3-month, and 2-year studies. The proposed conclusions were clear evidence of carcinogenic activity in male and female F344/N Nctr rats and male and female B6C3F1/Nctr mice.

Dr. Cory-Slechta, the first primary reviewer, remarked that the studies were well done and that she agreed with the proposed conclusions.

Dr. Cattley, the second primary reviewer, noted that the presentation had clarified the dose selection rationale for glycidamide, but that the issue should be clarified in the Technical Report. He suggested adding historical control data for the incidence of alveolar/bronchiolar carcinomas in female mice to Table 13 and Appendix Table D-3. He noted that “gliosis” should be moved from neoplastic to nonneoplastic lesions in the Abstract Summary Table. He agreed in principle with the proposed conclusions; however, he suggested limiting “clear evidence” in rats to oral cavity squamous papillomas, because the incidence of oral cavity squamous papilloma or carcinoma (combined) is almost entirely derived from the papilloma and not the carcinoma incidence. Similarly, for mice, he suggested limiting the conclusion of “clear evidence” to alveolar/bronchiolar adenomas, because the combined incidence of alveolar/bronchiolar neoplasms is almost entirely derived from the adenoma and not the carcinoma incidence.

Dr. Barlow, the third primary reviewer, agreed that Dr. Beland’s presentation had cleared up the issue of the dose rationale, and suggested the explanation should be added to the Technical Report. He noted that the Technical Report states there was decreased survival compared to controls due to tumors, but some of the tumors listed were not actually treatment-related and suggested clarification in the report. Dr. Barlow noted that only two males and females in the high-dose group survived to study termination, and asked whether the study should have been terminated earlier. He thought that oral cavity papillomas or carcinomas merited only “some evidence of carcinogenicity,” rather than “clear evidence.” He suggested deleting squamous cell papillomas as increased in the results text for female rats and changing the conclusion regarding squamous cell papillomas to “may have been related.” He stated that axonal degeneration should not be as significantly highlighted as it was in the draft Technical Report. He asked whether the nonneoplastic findings listed in the conclusions are truly increased related to treatment. He had similar comments for mesenteric lymph node cellular infiltrate and pituitary gland hyperplasia. He also questioned the conclusion regarding Zymbal’s gland carcinoma, because only a few animals were examined. He suggested that the increase in the incidences of alveolar/bronchiolar neoplasms in female mice should be listed as “considered related to,” given a lack of clear dose response and only a mild increase at the high dose and that the benign granulosa cell tumors should be combined with several malignant granulosa cell tumors to strengthen the statement, perhaps to the level of “some evidence.”

Dr. Cory-Slechta noted that Dr. Barlow seemed to discount the axonal degeneration because it appears in different places in the two sexes. She said that axonal degeneration is probably one of the best-documented effects of acrylamide in the neurotoxicology literature. She questioned why Dr. Barlow was discounting it. Dr. Barlow replied that he based his position on the doses that were used and the lack of a robust dose response.

Dr. Beland responded to Dr. Cattley’s comments. He would address the dose selection more thoroughly, add references to lung carcinomas, and correct the erroneous reference to gliosis in the Abstract Summary Table. Regarding the oral cavity tumors, he said squamous cell carcinoma is very rare in the control animals, so it was important to mention. Regarding the lung neoplasms in the mice, he said the conclusion states they were primarily adenomas, and he agreed to modify the text to describe that more clearly.

Regarding Dr. Barlow’s comment, Dr. Beland agreed to explain better that the two studies were conducted simultaneously. Addressing the comment about survival, he clarified that the animals were not removed due to overt toxicity or weight loss, noting that the veterinary staff monitored the animals very closely. Animals were removed because of spontaneous or treatment-related tumors. Given the need for direct comparison with acrylamide-treated animals, he proposed it was permissible to keep animals on the study until tumor development dictated their removal.

Regarding the suggestion that the call be changed for oral cavity tumors in rats, Dr. Beland stated that the response was robust and monotonic. He believed that the conclusions regarding the clitoral gland and forestomach tumors were correct. He noted that there was much interest in neurotoxicity of glycidamide and acrylamide, and the axonal degeneration was included to demonstrate that a careful examination for potential neurotoxicity in the animals was conducted. He said that the squamous cell papillomas discussed in the Results text for female rats would be deleted.

Regarding Zymbal’s gland tumors, Dr. Beland said if a lesion were observed during necropsy, the histopathology would be conducted. The statistics were compiled according to how many animals have such a tumor versus the entire cohort.

Regarding the suggestion to change the call on the lung neoplasms in female mice, Dr. Beland noted that the two highest doses exceeded the historical control by two- to three-fold, so “clear evidence” was proposed. Statistical analysis combining the benign granulose cell tumor with other malignant granulosa cell tumors indicated no significant effect.

Dr. Cullen asked how Dr. Beland would explain the lack of esophageal problems, given the mechanism of action. He also asked whether it was correct to assume that fibroadenomas do not have a high risk of converting into mammary carcinomas. Dr. Cullen understood the requirement for “clear evidence” of benign tumors is that it be a benign tumor with a high risk of conversion into a malignant form. He felt the call of “clear evidence” on the fibroadenomas might be overreaching.

Referring to the lack of esophageal problems, Dr. Beland said he could not explain why cancer did not occur. He recalled discussion in the acrylamide study about fibroadenomas and the possibility of progressing to a malignant tumor. Dr. Bucher, NIEHS, commented that the definition of clear evidence includes the presence of a marked increase in benign tumors. Dr. Beland was hesitant to change the clear evidence call because several regulatory agencies are using fibroadenomas in developing risk estimates for acrylamide. Editorial changes will also be made to the conclusions.

Dr. Malarkey, NIEHS, noted that axonal degeneration is a common background lesion in mice and rats, so what is being sought is exacerbation beyond background levels, which did not occur in this study.

Dr. Cullen called for a motion to accept the conclusions in the draft report as written. Dr. Cory-Slechta moved to accept the conclusions as written and Dr. Gordon seconded. The peer review panel voted (six in favor, one opposed, and zero abstentions) to accept the conclusions on glycidamide as written in the draft report. Dr. Cattley explained that his negative vote was based on the combination of papilloma and carcinoma for oral cavity lesions in the rats, and the combination of adenomas and carcinomas in alveolar/bronchiolar lung neoplasms. He proposed that both of those responses for “clear evidence” are based on the benign neoplasm, not the malignant neoplasm.