# Appendix K Benchmark Dose Modeling

## K.1 Methods

### K.1.1 Benchmark Dose Estimations

Benchmark doses (BMD) and the lower (BMDL) 95% confidence limits were calculated using Environmental Protection Agency Benchmark Dose Software (version 2.1.1; https://www.epa.gov/ncea/bmds). The calculations were conducted using gamma, logistic, log-logistic, log-probit, multistage, probit, and Weibull models to fit the neoplastic incidences and the mean doses of glycidamide for the entire 2-year study. The BMD was defined as the dose that caused a 10% excess risk of the specified adverse effect over that observed in the appropriate control group. Models were rejected if 1) p < 0.05 for the fitted model versus the full model; 2) p < 0.05 for the goodness of fit; or 3) The scaled residual for one or more of the doses in goodness of fit determination was >|2.00|.^76^ In some instances the BMD calculations failed. If a model was rejected, the results are not reported.

## K.2 Results

Benchmark dose modeling was conducted to estimate the doses of glycidamide that would give a 10% excess risk for specific neoplasms (BMD). In F344/N Nctr rats, the most sensitive site for tumor induction was the mammary gland in females (BMD of 2.39 µmol glycidamide per kg body weight per day for fibroadenoma) and the thyroid gland in males (BMD of 18.89–22.62 µmol glycidamide per kg body weight per day for combined follicular cell adenoma or carcinoma) (Table K-1). In B6C3F1/Nctr mice, the most sensitive site for tumor induction by glycidamide was the Harderian gland, with a BMD for Harderian gland adenoma of 5.24–5.91 µmol glycidamide per kg body weight per day in males and 4.55 µmol glycidamide per kg body weight per day in females (Table K-2).

A comparison of the glycidamide data with those previously reported for acrylamide^74^ indicates that both chemicals have similar potencies in the target tissues (Table K-3 and Table K-4). For example, in female F344/N Nctr rats, the BMD for mammary gland fibroadenoma was 2.39 μMol per kg body weight per day for glycidamide and 7.74 μMol per kg body weight per day for acrylamide, and in male F344/N Nctr rats, the BMD for follicular cell adenoma or carcinoma of the thyroid gland was 19.33–22.62 μMol per kg body weight per day for glycidamide and 19.41–28.19 μMol per kg body weight per day for acrylamide (Table K-3). The BMD for Harderian gland adenoma in male B6C3F1/Nctr mice was 5.51–5.91 μMol per kg body weight per day for glycidamide as compared to 5.14–5.39 μMol per kg body weight per day for acrylamide (Table K-4). Likewise, in female B6C3F1/Nctr mice the BMD for Harderian gland adenoma was 4.55 μMol per kg body weight per day for glycidamide as compared to 6.55 μMol per kg body weight per day for acrylamide.

Table K-1 Benchmark Dose Modeling of Neoplastic Incidences in F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide^a^

| AIC^b^ | Fitted Model^c^ | GOF^d^ | BMD^e^ | BMDL^f^
Thyroid Gland
Carcinoma
Male
Gamma | 88.1 | 0.232 | 0.294 | 40.32 | 19.71
Logistic | 88.5 | 0.202 | 0.300 | 42.24 | 29.43
Log-Logistic | 88.1 | 0.236 | 0.294 | 39.76 | 18.96
Log-Probit | 86.3 | 0.475 | 0.560 | 70.34 | 17.40
Multistage | 88.1 | 0.232 | 0.294 | 40.32 | 19.71
Probit | 88.4 | 0.203 | 0.300 | 42.65 | 28.45
Weibull | 88.1 | 0.232 | 0.294 | 40.32 | 19.71
Adenoma or Carcinoma
Male
Gamma | 164.6 | 0.338 | 0.350 | 19.33 | 10.56
Logistic | 162.3 | 0.611 | 0.603 | 22.62 | 17.85
Log-Logistic | 164.7 | 0.332 | 0.336 | 20.77 | 9.75
Log-Probit | 164.9 | 0.291 | 0.307 | 18.89 | 6.42
Multistage | 164.4 | 0.378 | 0.381 | 20.85 | 10.75
Probit | 162.3 | 0.602 | 0.599 | 21.65 | 16.73
Weibull | 164.6 | 0.345 | 0.350 | 20.50 | 10.60
Female
Gamma | 132.2 | 0.256 | 0.294 | 27.00 | 16.20
Logistic | 134.0 | 0.118 | 0.251 | 42.74 | 31.72
Log-Logistic | 131.9 | 0.293 | 0.300 | 24.05 | 14.61
Multistage | 132.2 | 0.256 | 0.294 | 27.00 | 16.20
Probit | 133.8 | 0.127 | 0.257 | 41.31 | 29.90
Weibull | 132.2 | 0.256 | 0.294 | 27.00 | 16.20
Heart
Malignant Schwannoma
Male
Gamma | 149.2 | 0.829 | 0.821 | 25.06 | 14.24
Logistic | 149.9 | 0.672 | 0.644 | 31.09 | 22.19
Log-Logistic | 149.2 | 0.841 | 0.835 | 24.40 | 13.30
Log-Probit | 151.1 | 0.689 | 0.687 | 23.23 | 8.60
Multistage | 149.2 | 0.829 | 0.821 | 25.06 | 14.24
Probit | 149.8 | 0.699 | 0.674 | 30.17 | 20.97
Weibull | 149.2 | 0.829 | 0.821 | 25.06 | 14.24
Epididymis or Testes
Malignant Mesothelioma
Male
Gamma | 148.2 | 0.801 | 0.794 | 11.71 | 7.80
Log-Logistic | 148.1 | 0.840 | 0.835 | 11.56 | 7.53
Log-Probit | 147.7 | 0.916 | 0.913 | 11.23 | 7.61
Multistage | 148.7 | 0.691 | 0.691 | 11.59 | 7.58
Probit | 153.6 | 0.094 | 0.128 | 17.94 | 15.01
Weibull | 148.3 | 0.778 | 0.772 | 11.69 | 7.75
Mammary Gland
Fibroadenoma
Female
Log-Logistic | 306.5 | 0.140 | 0.141 | 2.39 | 1.39
Oral Mucosa or Tongue
Squamous Cell Papilloma or Carcinoma
Female
Gamma | 105.9 | 0.801 | 0.814 | 50.94 | 29.59
Logistic | 104.0 | 0.916 | 0.917 | 48.94 | 36.92
Log-Logistic | 105.9 | 0.803 | 0.815 | 51.03 | 29.29
Log-Probit | 105.9 | 0.799 | 0.813 | 50.82 | 28.90
Multistage | 106.1 | 0.753 | 0.758 | 49.97 | 29.20
Probit | 104.1 | 0.902 | 0.906 | 48.73 | 35.39
Weibull | 105.9 | 0.803 | 0.815 | 51.09 | 29.60

^a^ Benchmark doses (BMD) and the lower (BMDL) 95% confidence limits, in units of mg per kg body weight per day, were calculated using Environmental Protection Agency Benchmark Dose Software (version 2.1.1; https://www.epa.gov/ncea/bmds). The calculations were conducted using gamma, logistic, log-logistic, log-probit, multistage, probit, and Weibull models to fit the neoplastic incidences and the mean doses of glycidamide from the entire 2-year study. The BMD was defined as the dose that caused a 10% excess risk in the specified adverse effect over that observed in the appropriate control group. Models were rejected if (1) p < 0.05 for the fitted model versus the full model; (2) p < 0.05 for the goodness of fit; or (3) the scaled residual for one or more of the doses in goodness of fit determination was >|2.00|.^76^ In some instances the BMD calculations failed. If a model was rejected, the results are not reported.

^b^ AIC, Akaike information criterion.

^c^ p-value of fitted model compared to the full model.

^d^ GOF, Goodness of fit p-value.

^e^ BMD, benchmark dose (μmol glycidamide per kg body weight per day).

^f^ BMDL, lower 95% confidence limit of benchmark dose (μmol glycidamide per kg body weight per day).

Table K-2 Benchmark Dose Modeling of Neoplastic Incidences in B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide^a^

| AIC^b^ | Fitted Model^c^ | GOF^d^ | BMD^e^ | BMDL^f^
Harderian Gland
Adenoma
Male
Gamma | 242.4 | 0.784 | 0.778 | 5.24 | 4.32
Log-Logistic | 245.1 | 0.418 | 0.425 | 5.51 | 2.49
Log-Probit | 244.9 | 0.459 | 0.464 | 5.91 | 2.49
Multistage | 242.4 | 0.784 | 0.778 | 5.24 | 4.32
Weibull | 242.4 | 0.784 | 0.778 | 5.24 | 4.32
Female
Log-Logistic | 253.5 | 0.099 | 0.100 | 4.55 | 3.39
Lung
Alveolar/Bronchiolar Adenoma
Male
Log-Logistic | 200.9 | 0.540 | 0.454 | 17.16 | 12.83
Log-Probit | 200.8 | 0.769 | 0.804 | 9.41 | 0.71^g^
Female
Gamma | 167.9 | 0.554 | 0.570 | 99.36 | 51.88
Logistic | 166.0 | 0.734 | 0.742 | 112.72 | 77.57
Log-Logistic | 167.9 | 0.555 | 0.570 | 99.08 | 48.23
Log-Probit | 167.9 | 0.552 | 0.563 | 100.00 | 25.29
Multistage | 167.9 | 0.554 | 0.571 | 98.98 | 51.88
Probit | 166.0 | 0.742 | 0.750 | 110.13 | 73.58
Weibull | 167.9 | 0.554 | 0.570 | 99.33 | 51.88
Stomach (Forestomach)
Squamous Cell Papilloma
Male
Gamma | 106.0 | 0.470 | 0.536 | 52.55 | 36.13
Logistic | 108.2 | 0.287 | 0.390 | 76.50 | 63.10
Log-Logistic | 108.1 | 0.298 | 0.355 | 51.96 | 34.39
Log-Probit | 108.5 | 0.256 | 0.310 | 49.72 | 28.18
Multistage | 107.9 | 0.334 | 0.373 | 55.10 | 36.51
Probit | 108.3 | 0.280 | 0.375 | 73.15 | 59.15
Weibull | 106.0 | 0.470 | 0.536 | 52.55 | 36.13
Mammary Gland
Adenoacanthoma
Female
Gamma | 56.0 | 0.973 | 0.987 | 117.96 | 93.37
Logistic | 56.8 | 0.803 | 0.858 | 129.97 | 112.32
Log-Logistic | 56.1 | 0.963 | 0.982 | 119.46 | 93.94
Log-Probit | 56.1 | 0.963 | 0.982 | 115.08 | 89.64
Multistage | 55.1 | 0.860 | 0.938 | 116.96 | 90.94
Probit | 56.5 | 0.871 | 0.912 | 125.67 | 106.43
Weibull | 56.1 | 0.960 | 0.980 | 120.56 | 95.40
Adenocarcinoma
Female
Gamma | 140.8 | 0.226 | 0.212 | 59.73 | 38.68
Logistic | 141.7 | 0.119 | 0.087 | 89.16 | 72.35
Log-Logistic | 140.7 | 0.242 | 0.230 | 58.43 | 36.20
Log-Probit | 140.2 | 0.308 | 0.294 | 56.99 | 34.86
Multistage | 141.0 | 0.200 | 0.201 | 56.03 | 38.07
Probit | 141.1 | 0.155 | 0.118 | 83.45 | 67.03
Weibull | 140.8 | 0.220 | 0.208 | 59.37 | 38.54
Adenoacanthoma or Adenocarcinoma
Female
Gamma | 149.6 | 0.533 | 0.530 | 53.46 | 35.44
Logistic | 150.1 | 0.283 | 0.255 | 71.73 | 59.97
Log-Logistic | 149.5 | 0.554 | 0.554 | 52.72 | 35.13
Log-Probit | 149.1 | 0.691 | 0.692 | 51.98 | 35.27
Multistage | 150.2 | 0.392 | 0.386 | 55.63 | 33.92
Probit | 149.3 | 0.391 | 0.364 | 66.26 | 55.26
Weibull | 149.8 | 0.482 | 0.481 | 53.41 | 34.90

^a^ Benchmark doses (BMD) and the lower (BMDL) 95% confidence limits, in units of mg per kg body weight per day, were calculated using Environmental Protection Agency Benchmark Dose Software (version 2.1.1; https://www.epa.gov/ncea/bmds). The calculations were conducted using gamma, logistic, log-logistic, log-probit, multistage, probit, and Weibull models to fit the neoplastic incidences and the mean doses of glycidamide from the entire 2-year study. The BMD was defined as the dose that caused a 10% excess risk in the specified adverse effect over that observed in the appropriate control group. Models were rejected if (1) p < 0.05 for the fitted model versus the full model; (2) p < 0.05 for the goodness of fit; or (3) The scaled residual for one or more of the doses in goodness of fit determination was >|2.00|.^76^ In some instances the BMD calculations failed. If a model was rejected, the results are not reported.

^b^ AIC, Akaike information criterion.

^c^ p-value of fitted model compared to the full model.

^d^ GOF, Goodness of fit p-value.

^e^ BMD, benchmark dose (μmol glycidamide per kg body weight per day).

^f^ BMDL, lower 95% confidence limit of benchmark dose (μmol glycidamide per kg body weight per day).

^g^ Due to the disparity between the BMDL obtained from the log-probit model and the BMDL obtained from the other model, the log-probit BMDL value was not considered further.^76^

Table K-3 Comparison of BMD for Selected Neoplasms in F344/N Nctr Rats Administered Glycidamide or Acrylamide in Two-year Drinking Water Studies

| Glycidamide (BMD, µmol/kg body weight/day)^a^ | Acrylamide (BMD, µmol/kg body weight/day)^b^
Thyroid Gland
Follicular Cell Carcinoma
Male
Gamma | 40.32 | 28.57
Logistic | 42.24 | 35.95
Log-Logistic | 39.76 | 27.87
Log-Probit | 70.34 | 26.72
Multistage | 40.32 | 28.57
Probit | 42.65 | 35.00
Weibull | 40.32 | 28.57
Follicular Cell Adenoma or Carcinoma
Male
Gamma | 19.33 | 20.37
Logistic | 22.62 | 28.19
Log-Logistic | 20.77 | 19.47
Multistage | 20.85 | 20.37
Probit | 21.65 | 27.14
Weibull | 20.50 | 20.37
Female
Gamma | 27.00 | 54.15
Logistic | 42.74 | 60.24
Log-Logistic | 24.05 | 54.80
Multistage | 27.00 | 54.15
Probit | 41.31 | 59.36
Weibull | 27.00 | 54.15
Heart
Malignant Schwannoma
Male
Gamma | 25.06 | 34.13
Logistic | 31.09 | 37.68
Log-Logistic | 24.40 | 33.91
Log-Probit | 23.23 | 34.76
Multistage | 25.06 | 34.13
Probit | 30.17 | 37.23
Weibull | 25.06 | 34.13
Epididymis or Testes
Malignant Mesothelioma
Male
Gamma | 11.71 | 29.90
Multistage | 11.59 | 30.66
Probit | 17.94 | 30.36
Weibull | 11.69 | 30.06
Mammary Gland
Fibroadenoma
Female
Log-Logistic | 2.39 | 7.74
Oral Mucosa or Tongue
Squamous Cell Papilloma or Carcinoma
Female
Gamma | 50.94 | 49.49
Logistic | 48.94 | 58.01
Log-Logistic | 51.03 | 48.42
Log-Probit | 50.82 | 61.93
Multistage | 49.97 | 49.49
Probit | 48.73 | 57.54
Weibull | 51.09 | 49.49

^a^ The BMD for glycidamide in μMol/kg body weight/day are from the data presented in Table K-1.

^b^ The BMD for acrylamide in μMol/kg body weight/day are calculated from the data presented in Beland et al.^74^

Table K-4 Comparison of BMD for Selected Neoplasms in B6C3F1/Nctr Mice Administered Glycidamide or Acrylamide in Two-year Drinking Water Studies

| Glycidamide (BMD, µmol/kg body weight/day)^a^ | Acrylamide (BMD, µmol/kg body weight/day)^b^
Harderian Gland
Adenoma
Male
Log-Logistic | 5.51 | 5.14
Log-Probit | 5.91 | 5.39
Female
Log-Logistic | 4.55 | 6.65
Lung
Alveolar/Bronchiolar Adenoma
Male
Log-Logistic | 17.16 | 29.59
Female
Gamma | 99.36 | 27.69
Logistic | 112.72 | 56.06
Log-Logistic | 99.08 | 27.15
Log-Probit | 100.00 | 26.89
Multistage | 98.98 | 27.69
Probit | 110.13 | 51.97
Weibull | 99.33 | 27.69
Stomach (Forestomach)
Squamous Cell Papilloma
Male
Gamma | 52.55 | 63.98
Logistic | 76.50 | 105.74
Log-Logistic | 51.96 | 62.30
Log-Probit | 49.72 | 60.51
Multistage | 55.10 | 63.98
Probit | 73.15 | 101.39
Weibull | 52.55 | 63.98
Mammary Gland
Adenoacanthoma
Female
Gamma | 117.96 | 140.56
Logistic | 129.97 | 146.10
Log-Logistic | 119.46 | 142.80
Log-Probit | 115.08 | 172.55
Multistage | 116.96 | 140.56
Probit | 125.67 | 145.74
Weibull | 120.56 | 140.56
Adenoacanthoma or Adenocarcinoma
Female
Gamma | 53.46 | 31.22
Log-Logistic | 52.72 | 28.31
Log-Probit | 51.98 | 24.23
Multistage | 55.63 | 31.22
Weibull | 53.41 | 31.22

^a^ The BMD for glycidamide in μMol/kg body weight/day are from the data presented in Table K-2.

^b^ The BMD for acrylamide in μMol/kg body weight/day are calculated from the data presented in Beland et al.^74^

Figure K-1

Benchmark Dose Modeling of Thyroid Gland Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-2

Benchmark Dose Modeling of Thyroid Gland Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-3

Benchmark Dose Modeling of Thyroid Gland Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-4

Benchmark Dose Modeling of Thyroid Gland Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-5

Benchmark Dose Modeling of Thyroid Gland Adenoma or Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-6

Benchmark Dose Modeling of Thyroid Gland Adenoma or Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-7

Benchmark Dose Modeling of Thyroid Gland Adenoma or Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-8

Benchmark Dose Modeling of Thyroid Gland Adenoma or Carcinoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-9

Benchmark Dose Modeling of Thyroid Gland Adenoma or Carcinoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-10

Benchmark Dose Modeling of Thyroid Gland Adenoma or Carcinoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: Multistage Model)

Figure K-11

Benchmark Dose Modeling of Thyroid Gland Adenoma or Carcinoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Probit Model; Bottom: Weibull Model)

Figure K-12

Benchmark Dose Modeling of Heart Malignant Schwannoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-13

Benchmark Dose Modeling of Heart Malignant Schwannoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-14

Benchmark Dose Modeling of Heart Malignant Schwannoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-15

Benchmark Dose Modeling of Heart Malignant Schwannoma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-16

Benchmark Dose Modeling of Epididymis or Testes Malignant Mesothelioma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Log-Logistic Model)

Figure K-17

Benchmark Dose Modeling of Epididymis or Testes Malignant Mesothelioma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: LogProbit Model; Bottom: Multistage Model)

Figure K-18

Benchmark Dose Modeling of Epididymis or Testes Malignant Mesothelioma in Male F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Probit Model; Bottom: Weibull Model)

Figure K-19

Benchmark Dose Modeling of Mammary Gland Fibroadenoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Log-Logistic Model)

Figure K-20

Benchmark Dose Modeling of Oral Mucosa or Tongue Squamous Cell Papilloma or Carcinoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-21

Benchmark Dose Modeling of Oral Mucosa or Tongue Squamous Cell Papilloma or Carcinoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-22

Benchmark Dose Modeling of Oral Mucosa or Tongue Squamous Cell Papilloma or Carcinoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-23

Benchmark Dose Modeling of Oral Mucosa or Tongue Squamous Cell Papilloma or Carcinoma in Female F344/N Nctr Rats in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-24

Benchmark Dose Modeling of Harderian Gland Adenoma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Log-Logistic Model)

Figure K-25

Benchmark Dose Modeling of Harderian Gland Adenoma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: LogProbit Model; Bottom: Multistage Model)

Figure K-26

Benchmark Dose Modeling of Harderian Gland Adenoma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-27

Benchmark Dose Modeling of Harderian Gland Adenoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Log-Logistic Model)

Figure K-28

Benchmark Dose Modeling of Lung Alveolar/Bronchiolar Adenoma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Log-Logistic Model)

Figure K-29

Benchmark Dose Modeling of Lung Alveolar/Bronchiolar Adenoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-30

Benchmark Dose Modeling of Lung Alveolar/Bronchiolar Adenoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-31

Benchmark Dose Modeling of Lung Alveolar/Bronchiolar Adenoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-32

Benchmark Dose Modeling of Lung Alveolar/Bronchiolar Adenoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-33

Benchmark Dose Modeling of Stomach (Forestomach) Squamous Cell Papilloma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-34

Benchmark Dose Modeling of Stomach (Forestomach) Squamous Cell Papilloma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-35

Benchmark Dose Modeling of Stomach (Forestomach) Squamous Cell Papilloma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-36

Benchmark Dose Modeling of Stomach (Forestomach) Squamous Cell Papilloma in Male B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-37

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-38

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-39

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-40

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-41

Benchmark Dose Modeling of Mammary Gland Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-42

Benchmark Dose Modeling of Mammary Gland Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-43

Benchmark Dose Modeling of Mammary Gland Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-44

Benchmark Dose Modeling of Mammary Gland Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Weibull Model)

Figure K-45

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma or Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Gamma Multi-hit Model; Bottom: Logistic Model)

Figure K-46

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma or Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Log-Logistic Model; Bottom: LogProbit Model)

Figure K-47

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma or Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Top: Multistage Model; Bottom: Probit Model)

Figure K-48

Benchmark Dose Modeling of Mammary Gland Adenoacanthoma or Adenocarcinoma in Female B6C3F1/Nctr Mice in the Two-year Drinking Water Study of Glycidamide (Weibull Model)