# Appendix I Sentinel Animal Program

## I.1 Methods

Rodents used in the Carcinogenesis Program of the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of chemical compounds. Under this program, the disease state of the rodents is monitored via serology on sera from extra (sentinel) animals in the study rooms. These animals and the study animals are subject to identical environmental conditions. The sentinel animals come from the same production source and weanling groups as the animals used for the studies of chemical compounds.

Blood from each sentinel animal was collected, allowed to clot, and the serum was separated. The serum was analyzed by Multiplex Fluorescent Immunoassay (MFI) for the presence of specific antibodies by the Research Animal Diagnostic Laboratory, University of Missouri, Columbia, Missouri. The laboratory serology method and viral/mycoplasma agent for which testing was performed are tabulated below; the times at which blood was collected during the studies are also listed.

Table I-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program^a^

Method and Test | | Time of Analysis
Mice
MFI
Mouse Hepatitis Virus (MHV) | | 26, 53, 79, 104, & 117 weeks
Sendai | | 26, 53, 79, 104, & 117 weeks
Pneumonia Virus of Mice (PVM) | | 26, 53, 79, 104, & 117 weeks
Reovirus Type 3 (REO3) | | 26, 53, 79, 104, & 117 weeks
Theiler’s Murine Encephalomyelitis Virus (TMEV) | | 26, 53, 79, 104, & 117 weeks
Ectromelia | | 26, 53, 79, 104, & 117 weeks
Polyoma | | 26, 53, 79, 104, & 117 weeks
Mycoplasma pulmonis | | 26, 53, 79, 104, & 117 weeks
Minute Virus of Mice (MMV) | | 26, 53, 79, 104, & 117 weeks
Mouse Parvovirus (MPV) | | 26, 53, 79, 104, & 117 weeks
Parvo NS-1 | | 26, 53, 79, 104, & 117 weeks
Epizootic Diarrhea of Infant Mice Virus (EDIM) | | 26, 53, 79, 104, & 117 weeks
Lymphocytic Choriomeningitis Virus (LCM) | | 26, 53, 79, 104, & 117 weeks
Rats
MFI
Rat Coronavirus/Sialodacryoadenitis (RCV/SDAV) | | 26, 53, 79, & 104 weeks
Sendai | | 26, 53, 79, & 104 weeks
Pneumonia Virus of Mice (PVM) | | 26, 53, 79, & 104 weeks
TMEV GDVII | | 26, 53, 79, & 104 weeks
Mycoplasma pulmonis | | 26, 53, 79, & 104 weeks
Parvo NS-1 | | 26, 53, 79, & 104 weeks
Rats and Mice
Additional Screening
Bordetella bronchiseptica | Listeria monocytogenes | | Ectoparasites
Citrobacter freundii | Pasteurella pneumontropica | | Endoparasites
Corynebacterium kutscheri | Pasteurella multocida
Erysipelothrix rhusiopathiae | Pseudomonas aeruginosa
Helicobacter bilis | Salmonella sp.
Helicobacter hepaticus | Streptococcus pneumoniae

^a^ One on-test mouse and five on-test rats were screened in addition to sentinel animals.

## I.2 Results

All serology test results were negative.

Helicobacter hepaticus was detected via polymerase chain reaction (PCR) in three of the sentinel mice. Pseudomonas aeruginosa was detected in two of the sentinel rats.