# Appendix H Ingredients, Nutrient Composition, and Contaminant Levels in NIH-31 Rat and Mouse Ration

Table H-1 Ingredients of NIH-31 IR Rat and Mouse Ration

Ingredients^a^ | Percent by Weight
Ground whole hard wheat | 35.5
Ground #2 yellow shelled corn | 21.0
Ground whole oats | 10.0
Wheat middlings | 10.0
Fish meal (60% protein) | 9.0
Soybean meal (48.5% protein) | 5.0
Alfalfa meal (17% protein) | 2.0
Corn gluten meal (60%) | 2.0
Dicalcium phosphate^b^ | 1.5
Soy oil | 1.5
Brewers dried yeast | 1.0
Ground limestone^b^ | 0.5
Premixes | 0.5
Salt | 0.5

^a^ Ingredients ground to pass through a U.S. Standard Screen No. 16 before mixing.

^b^ Specific ingredient requirement for cadmium content not to exceed 1 mg/kg.

Table H-2 Vitamins and Minerals in NIH-31 IR Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 22,000,000 IU | Vitamin A palmitate or acetate
D_3_ | 3,800,000 IU | D-activated animal sterol
K_3_ | 20 g | Menadione activity
Choline | 700 g | Choline chloride
dl-α-Tocopheryl acetate | 15 g | –
Folic acid | 1 g | –
Niacin | 20 g | –
d-Pantothenic acid | 25 g | d-Calcium pantothenate
Riboflavin | 5 g | –
Thiamine | 65 g | Thiamine mononitrate
B_12_ | 14 g | –
Pyridoxine | 2 g | Pyridoxine hydrochloride
Biotin | 0.12 g | d-Biotin
Minerals
Magnesium | 400 g | Magnesium oxide
Manganese | 100 g | Manganese oxide
Iron | 60 g | Iron sulfate
Zinc | 10 g | Zinc oxide
Copper | 4 g | Copper sulfate
Iodine | 1.5 g | Calcium iodate
Cobalt | 0.4 g | Cobalt carbonate

^a^ Per ton (2000 lb) of finished product.

Table H-3 Nutrient Composition of NIH-31 IR Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Number of Lots
Crude protein (% by weight) | 18.3 ± 0.5 | 10
Crude fat (% by weight) | 6.24 ± 0.60 | 10
Volatiles (% by weight) | 8.50 ± 0.49 | 10
Vitamins
A (µg/g) | 3.09 ± 0.57 | 10
E (µg/g) | 38.5 ± 11.9 | 10
B1 (µg/g) | 26.0 ± 0.03 | 10
Minerals
Selenium (µg/g) | 0.39 ± 0.08 | 10

Table H-4 Contaminant Levels in NIH-31 IR Rat and Mouse Ration

| Mean ± Standard Deviation | Number of Samples (Number Positive)
Contaminants
Acrylamide (ppb) | 28.1 ± 24.7 | 10 (9)
Arsenic (µg/g) | 0.18 ± 0.02 | 10 (10)
Cadmium (µg/g) | 0.19 ± 0.07 | 10 (10)
Lead (µg/g) | 0.42 ± 0.09 | 10 (10)
Aflatoxin B1 (ppb) | <mdl | 10 (0)
Aflatoxin B2 (ppb) | <mdl | 10 (0)
Aflatoxin G1 (ppb) | <mdl | 10 (0)
Aflatoxin G2 (ppb) | <mdl | 10 (0)
Total Fumonisin (ppb) | 343 ± 213 | 10 (10)
Pesticides (ppb)
Heptachlor | <mdl | 1 (0)
Total DDT | <mdl | 1 (0)
Dieldrin | <mdl | 1 (0)
PCB | <mdl | 1 (0)
Malathion | <mdl | 1 (0)
Lindane | <mdl | 1 (0)