# Appendix G Food Consumption in the Two-year Drinking Water Study of Glycidamide

Table G-1 Food Consumption of Male Rats in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0.0 mM | | | 0.0875 mM | | | | 0.175 mM | | | | 0.35 mM | | | | 0.70 mM
Week^a^ | N^b^ | Mean ± SE^c^ | P-Value^d^ | N | Mean ± SE | Pct^e^ | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | Pct | P-Value
4 | 24 | 16.4 ± 0.2 | 0.387 | 24 | 16.5 ± 0.2 | 100.5 | 0.995 | 24 | 16.3 ± 0.2 | 99.6 | 0.997 | 24 | 16.1 ± 0.2 | 98.3 | 0.724 | 24 | 16.2 ± 0.2 | 99.1 | 0.962
8 | 24 | 16.4 ± 0.2 | 0.246 | 24 | 16.4 ± 0.2 | 100.1 | 1.000 | 24 | 16.3 ± 0.2 | 99.3 | 0.975 | 24 | 16.3 ± 0.2 | 99.7 | 0.999 | 24 | 16.1 ± 0.2 | 98.3 | 0.672
12 | 24 | 16.9 ± 0.2 | 0.049 | 24 | 16.1 ± 0.2 | 95.8 | 0.047 | 24 | 16.3 ± 0.2 | 97.0 | 0.234 | 24 | 16.1 ± 0.2 | 95.8 | 0.051 | 24 | 16.1 ± 0.2 | 95.5 | 0.032
16 | 24 | 16.5 ± 0.2 | 0.403 | 24 | 16.1 ± 0.2 | 97.7 | 0.290 | 24 | 16.2 ± 0.2 | 98.0 | 0.419 | 24 | 16.0 ± 0.2 | 97.1 | 0.125 | 24 | 16.2 ± 0.2 | 98.2 | 0.515
20 | 24 | 16.6 ± 0.2 | 0.531 | 24 | 16.6 ± 0.2 | 99.8 | 1.000 | 24 | 16.7 ± 0.2 | 100.3 | 0.999 | 24 | 16.4 ± 0.2 | 98.8 | 0.834 | 24 | 16.5 ± 0.2 | 99.4 | 0.983
24 | 24 | 16.9 ± 0.2 | 0.530 | 24 | 16.9 ± 0.2 | 100.5 | 0.997 | 24 | 16.7 ± 0.2 | 99.1 | 0.955 | 24 | 16.9 ± 0.2 | 100.5 | 0.997 | 24 | 17.0 ± 0.2 | 100.9 | 0.964
28 | 24 | 17.1 ± 0.2 | 0.769 | 24 | 17.1 ± 0.2 | 99.7 | 0.999 | 24 | 16.7 ± 0.2 | 97.8 | 0.392 | 24 | 16.9 ± 0.2 | 98.8 | 0.863 | 24 | 17.0 ± 0.2 | 99.3 | 0.968
32 | 24 | 17.1 ± 0.2 | 0.728 | 24 | 17.1 ± 0.2 | 99.9 | 1.000 | 24 | 17.0 ± 0.2 | 99.3 | 0.982 | 24 | 17.0 ± 0.2 | 99.7 | 0.999 | 24 | 17.1 ± 0.2 | 100.4 | 0.997
36 | 24 | 16.9 ± 0.2 | 0.974 | 24 | 17.0 ± 0.2 | 100.5 | 0.994 | 24 | 16.9 ± 0.2 | 99.5 | 0.993 | 24 | 16.8 ± 0.2 | 99.1 | 0.952 | 24 | 17.0 ± 0.2 | 100.2 | 1.000
40 | 24 | 17.1 ± 0.2 | 0.456 | 24 | 17.0 ± 0.2 | 99.5 | 0.995 | 24 | 16.8 ± 0.2 | 98.2 | 0.668 | 24 | 17.4 ± 0.2 | 102.0 | 0.586 | 24 | 17.1 ± 0.2 | 100.2 | 1.000
44 | 24 | 17.9 ± 0.4 | 0.944 | 24 | 17.6 ± 0.4 | 98.0 | 0.922 | 24 | 18.2 ± 0.4 | 101.3 | 0.981 | 24 | 17.7 ± 0.4 | 98.7 | 0.983 | 24 | 17.9 ± 0.4 | 99.9 | 1.000
48 | 24 | 19.1 ± 0.5 | 0.556 | 24 | 18.8 ± 0.5 | 98.5 | 0.980 | 24 | 19.4 ± 0.5 | 101.4 | 0.983 | 24 | 19.2 ± 0.5 | 100.4 | 1.000 | 24 | 19.4 ± 0.5 | 101.4 | 0.982
52 | 24 | 20.6 ± 0.4 | 0.611 | 24 | 20.7 ± 0.4 | 100.2 | 1.000 | 24 | 20.7 ± 0.4 | 100.3 | 1.000 | 24 | 20.4 ± 0.4 | 98.8 | 0.983 | 24 | 21.0 ± 0.4 | 101.7 | 0.937
56 | 24 | 21.2 ± 0.3 | 0.129 | 24 | 20.7 ± 0.3 | 97.3 | 0.374 | 24 | 20.5 ± 0.3 | 96.4 | 0.148 | 24 | 20.6 ± 0.3 | 97.1 | 0.320 | 24 | 20.4 ± 0.3 | 96.3 | 0.133
60 | 24 | 21.0 ± 0.3 | 0.665 | 24 | 21.1 ± 0.3 | 100.5 | 0.999 | 24 | 20.9 ± 0.3 | 99.4 | 0.996 | 24 | 20.9 ± 0.3 | 99.2 | 0.991 | 24 | 21.3 ± 0.3 | 101.1 | 0.969
64 | 24 | 21.2 ± 0.4 | 0.422 | 24 | 21.3 ± 0.4 | 100.2 | 1.000 | 24 | 21.1 ± 0.4 | 99.3 | 0.997 | 24 | 20.9 ± 0.4 | 98.7 | 0.976 | 23 | 21.7 ± 0.4 | 102.2 | 0.848
68 | 24 | 20.9 ± 0.5 | 0.942 | 24 | 21.4 ± 0.5 | 102.8 | 0.820 | 24 | 20.7 ± 0.5 | 99.2 | 0.998 | 24 | 21.2 ± 0.5 | 101.7 | 0.963 | 22 | 21.0 ± 0.5 | 100.8 | 0.997
72 | 24 | 21.3 ± 0.6 | 0.176 | 24 | 21.3 ± 0.6 | 100.2 | 1.000 | 24 | 20.3 ± 0.6 | 95.7 | 0.625 | 24 | 21.4 ± 0.6 | 100.6 | 1.000 | 22 | 20.1 ± 0.6 | 94.4 | 0.401
76 | 24 | 21.4 ± 0.6 | 0.587 | 24 | 21.0 ± 0.6 | 97.8 | 0.954 | 23 | 20.0 ± 0.6 | 93.4 | 0.284 | 24 | 20.3 ± 0.6 | 94.6 | 0.453 | 22 | 20.8 ± 0.6 | 96.9 | 0.863
80 | 24 | 21.7 ± 0.7 | 0.443 | 24 | 20.7 ± 0.7 | 95.6 | 0.715 | 23 | 19.4 ± 0.7 | 89.2 | 0.053 | 24 | 20.4 ± 0.7 | 94.1 | 0.475 | 21 | 21.8 ± 0.7 | 100.4 | 1.000
84 | 24 | 23.0 ± 0.8 | 0.682 | 24 | 21.6 ± 0.8 | 93.9 | 0.536 | 22 | 19.5 ± 0.8 | 85.0 | 0.009 | 22 | 21.5 ± 0.8 | 93.5 | 0.479 | 21 | 22.4 ± 0.8 | 97.7 | 0.974
88 | 24 | 23.2 ± 0.9 | 0.431 | 24 | 21.0 ± 0.9 | 90.5 | 0.254 | 21 | 20.1 ± 0.9 | 86.5 | 0.054 | 21 | 23.2 ± 0.9 | 99.7 | 1.000 | 17 | 22.7 ± 1.0 | 97.6 | 0.982
92 | 21 | 22.7 ± 1.2 | 0.136 | 21 | 20.6 ± 1.2 | 90.8 | 0.524 | 21 | 19.4 ± 1.2 | 85.5 | 0.153 | 20 | 22.9 ± 1.2 | 100.7 | 1.000 | 15 | 23.5 ± 1.3 | 103.6 | 0.972
96 | 21 | 23.8 ± 1.3 | 0.148 | 21 | 20.9 ± 1.3 | 87.7 | 0.312 | 18 | 20.6 ± 1.3 | 86.8 | 0.261 | 18 | 18.2 ± 1.3 | 76.5 | 0.009 | 11 | 20.5 ± 1.5 | 86.2 | 0.280
100 | 21 | 24.9 ± 1.2 | 0.001 | 17 | 23.0 ± 1.2 | 92.5 | 0.632 | 15 | 22.9 ± 1.3 | 92.0 | 0.602 | 11 | 17.0 ± 1.3 | 68.1 | <0.001 | 6 | 19.4 ± 1.6 | 77.9 | 0.018
104 | 17 | 27.3 ± 1.7 | <0.001 | 14 | 21.0 ± 1.7 | 77.0 | 0.031 | 13 | 23.8 ± 1.8 | 87.0 | 0.397 | 7 | 16.6 ± 2.0 | 61.0 | <0.001 | 3 | 14.4 ± 2.7 | 52.8 | <0.001
Mean for Weeks
4–104 | | 20.0 ± 0.4 | | | 19.2 ± 0.4 | | | | 19.0 ± 0.4 | | | | 18.8 ± 0.4 | | | | 19.0 ± 0.4

^a^ Week indicates the last week of a 4-week interval of daily food consumption, measured weekly by cage.

^b^ N = Number of cages.

^c^ Mean ± SE (g per day) = Estimated least squares mean and standard error.

^d^ P-values in the 0.0 mM glycidamide column are the p-values for the trend test; p-values in the treatment columns are Dunnett's adjusted p-values for pairwise comparisons of the dose groups to the 0.0 mM glycidamide group.

^e^ Pct = Ratio of the mean food consumption of the dose groups to the mean food consumption of the 0.0 mM glycidamide group, expressed as a percent.

Table G-2 Food Consumption of Female Rats in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0.0 mM | | | 0.0875 mM | | | | 0.175 mM | | | | 0.35 mM | | | | 0.70 mM
Week^a^ | N^b^ | Mean ± SE^c^ | P-Value^d^ | N | Mean ± SE | Pct^e^ | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | | Pct | P-Value
4 | 24 | 12.0 ± 0.2 | 0.025 | 24 | 11.6 ± 0.2 | 96.6 | 0.176 | 24 | 11.6 ± 0.2 | 96.6 | 0.175 | 24 | 11.5 ± 0.2 | 96.0 | 0.080 | 24 | 11.4 ± 0.2 | 95.2 | | 0.025
8 | 24 | 11.6 ± 0.1 | 0.022 | 24 | 11.3 ± 0.1 | 97.7 | 0.504 | 24 | 11.3 ± 0.1 | 97.4 | 0.407 | 24 | 11.0 ± 0.1 | 95.1 | 0.023 | 24 | 11.1 ± 0.1 | 95.8 | | 0.071
12 | 24 | 11.2 ± 0.1 | 0.053 | 24 | 11.0 ± 0.1 | 98.6 | 0.867 | 24 | 11.0 ± 0.1 | 98.6 | 0.876 | 24 | 11.0 ± 0.1 | 98.1 | 0.699 | 24 | 10.8 ± 0.1 | 96.3 | | 0.150
16 | 24 | 11.3 ± 0.1 | 0.003 | 24 | 11.1 ± 0.1 | 98.2 | 0.695 | 24 | 11.0 ± 0.1 | 98.1 | 0.667 | 24 | 10.9 ± 0.1 | 96.7 | 0.199 | 24 | 10.7 ± 0.1 | 94.9 | | 0.014
20 | 24 | 11.4 ± 0.2 | 0.055 | 24 | 11.2 ± 0.2 | 98.1 | 0.712 | 24 | 11.1 ± 0.2 | 97.3 | 0.402 | 24 | 10.8 ± 0.2 | 95.0 | 0.028 | 24 | 11.0 ± 0.2 | 96.5 | | 0.187
24 | 24 | 11.7 ± 0.2 | 0.011 | 24 | 11.3 ± 0.2 | 96.3 | 0.174 | 24 | 11.5 ± 0.2 | 97.9 | 0.669 | 24 | 11.2 ± 0.2 | 95.2 | 0.052 | 24 | 11.1 ± 0.2 | 94.6 | | 0.021
28 | 24 | 11.8 ± 0.1 | <0.001 | 24 | 11.6 ± 0.1 | 98.0 | 0.499 | 24 | 11.7 ± 0.1 | 98.6 | 0.804 | 24 | 11.5 ± 0.1 | 97.2 | 0.216 | 24 | 11.2 ± 0.1 | 94.3 | | 0.001
32 | 24 | 12.1 ± 0.1 | 0.003 | 24 | 11.9 ± 0.1 | 98.6 | 0.832 | 24 | 11.7 ± 0.1 | 97.2 | 0.306 | 24 | 11.7 ± 0.1 | 97.0 | 0.248 | 24 | 11.4 ± 0.1 | 94.8 | | 0.010
36 | 24 | 12.1 ± 0.1 | 0.026 | 24 | 12.0 ± 0.1 | 99.7 | 0.999 | 24 | 12.0 ± 0.1 | 99.6 | 0.997 | 24 | 11.8 ± 0.1 | 97.8 | 0.435 | 24 | 11.7 ± 0.1 | 97.0 | | 0.197
40 | 24 | 12.3 ± 0.1 | 0.058 | 24 | 12.4 ± 0.1 | 100.3 | 0.998 | 24 | 12.1 ± 0.1 | 98.1 | 0.504 | 24 | 12.0 ± 0.1 | 96.9 | 0.112 | 24 | 12.1 ± 0.1 | 97.9 | | 0.403
44 | 24 | 12.7 ± 0.2 | 0.259 | 24 | 12.8 ± 0.2 | 100.8 | 0.988 | 24 | 12.7 ± 0.2 | 99.8 | 1.000 | 24 | 12.6 ± 0.2 | 99.2 | 0.988 | 24 | 12.5 ± 0.2 | 98.2 | | 0.836
48 | 24 | 14.0 ± 0.3 | 0.430 | 24 | 13.4 ± 0.3 | 96.1 | 0.562 | 24 | 13.8 ± 0.3 | 98.8 | 0.986 | 24 | 13.5 ± 0.3 | 96.5 | 0.641 | 24 | 13.5 ± 0.3 | 96.6 | | 0.678
52 | 24 | 14.9 ± 0.3 | 0.827 | 24 | 14.6 ± 0.3 | 97.9 | 0.861 | 24 | 14.7 ± 0.3 | 98.9 | 0.984 | 24 | 14.8 ± 0.3 | 99.7 | 1.000 | 24 | 14.6 ± 0.3 | 98.5 | | 0.949
56 | 24 | 15.7 ± 0.3 | 0.893 | 24 | 15.2 ± 0.3 | 96.6 | 0.539 | 24 | 15.6 ± 0.3 | 99.2 | 0.995 | 24 | 15.2 ± 0.3 | 97.1 | 0.656 | 24 | 15.5 ± 0.3 | 98.7 | | 0.974
60 | 24 | 15.6 ± 0.4 | 0.935 | 24 | 15.6 ± 0.4 | 100.3 | 1.000 | 24 | 15.9 ± 0.4 | 101.9 | 0.949 | 24 | 15.4 ± 0.4 | 98.9 | 0.992 | 24 | 15.7 ± 0.4 | 101.0 | | 0.996
64 | 24 | 16.0 ± 0.4 | 0.910 | 24 | 15.8 ± 0.4 | 98.9 | 0.991 | 24 | 16.0 ± 0.4 | 100.1 | 1.000 | 24 | 15.8 ± 0.4 | 98.6 | 0.979 | 24 | 16.0 ± 0.4 | 100.2 | | 1.000
68 | 24 | 16.5 ± 0.4 | 0.528 | 24 | 15.6 ± 0.4 | 94.8 | 0.410 | 24 | 16.2 ± 0.4 | 98.7 | 0.989 | 24 | 16.5 ± 0.4 | 100.5 | 1.000 | 23 | 16.4 ± 0.4 | 99.6 | | 1.000
72 | 24 | 16.2 ± 0.5 | 0.666 | 24 | 15.8 ± 0.5 | 97.2 | 0.925 | 24 | 16.2 ± 0.5 | 100.1 | 1.000 | 24 | 16.3 ± 0.5 | 100.7 | 1.000 | 23 | 15.7 ± 0.5 | 97.0 | | 0.910
76 | 24 | 15.6 ± 0.4 | 0.585 | 24 | 15.7 ± 0.4 | 100.7 | 0.999 | 24 | 16.0 ± 0.4 | 102.8 | 0.858 | 24 | 15.9 ± 0.4 | 101.7 | 0.974 | 20 | 15.4 ± 0.4 | 98.7 | | 0.990
80 | 24 | 16.0 ± 0.5 | 0.912 | 24 | 15.8 ± 0.5 | 98.8 | 0.997 | 23 | 16.9 ± 0.5 | 105.4 | 0.625 | 24 | 17.2 ± 0.5 | 107.3 | 0.350 | 19 | 15.8 ± 0.6 | 98.6 | | 0.996
84 | 24 | 17.1 ± 0.6 | 0.079 | 24 | 16.3 ± 0.6 | 95.5 | 0.784 | 23 | 17.3 ± 0.6 | 101.0 | 0.999 | 24 | 17.3 ± 0.6 | 101.1 | 0.999 | 16 | 15.4 ± 0.7 | 89.9 | | 0.165
88 | 24 | 17.0 ± 0.6 | 0.008 | 23 | 16.6 ± 0.7 | 97.4 | 0.971 | 23 | 17.3 ± 0.7 | 101.3 | 0.998 | 24 | 17.1 ± 0.6 | 100.2 | 1.000 | 13 | 14.5 ± 0.7 | 85.3 | | 0.038
92 | 24 | 17.7 ± 0.7 | 0.366 | 23 | 16.5 ± 0.7 | 93.3 | 0.519 | 23 | 17.0 ± 0.7 | 95.6 | 0.821 | 23 | 16.8 ± 0.7 | 94.5 | 0.687 | 10 | 16.4 ± 0.8 | 92.6 | | 0.533
96 | 24 | 17.7 ± 0.9 | 0.029 | 23 | 17.6 ± 0.9 | 99.3 | 1.000 | 22 | 17.5 ± 0.9 | 98.7 | 0.999 | 21 | 16.7 ± 0.9 | 94.0 | 0.828 | 8 | 20.9 ± 1.2 | 118.0 | | 0.115
100 | 23 | 18.7 ± 0.8 | 0.318 | 22 | 17.8 ± 0.8 | 95.2 | 0.828 | 20 | 17.5 ± 0.8 | 93.9 | 0.684 | 16 | 17.0 ± 0.8 | 90.8 | 0.342 | 6 | 17.2 ± 1.1 | 91.9 | | 0.630
104 | 21 | 18.4 ± 0.9 | 0.768 | 20 | 18.6 ± 0.9 | 100.6 | 1.000 | 20 | 17.4 ± 0.9 | 94.2 | 0.801 | 14 | 17.1 ± 0.9 | 92.8 | 0.684 | 2 | 19.1 ± 1.7 | 103.5 | | 0.992
Mean for Weeks
4–104 | | 14.5 ± 0.3 | | | 14.2 ± 0.3 | | | | 14.3 ± 0.3 | | | | 14.2 ± 0.3 | | | | 14.1 ± 0.3

^a^ Week indicates the last week of a 4-week interval of daily food consumption, measured weekly by cage.

^b^ N = Number of cages.

^c^ Mean ± SE (g per day) = Estimated least squares mean and standard error.

^d^ P-values in the 0.0 mM glycidamide column are the p-values for the trend test; p-values in the treatment columns are Dunnett's adjusted p-values for pairwise comparisons of the dose groups to the 0.0 mM glycidamide group.

^e^ Pct = Ratio of the mean food consumption of the dose groups to the mean food consumption of the 0.0 mM glycidamide group, expressed as a percent.

Table G-3 Food Consumption of Male Mice in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0.0 mM | | | 0.0875 mM | | | | 0.175 mM | | | | 0.35 mM | | | | 0.70 mM
Week^a^ | N^b^ | Mean ± SE^c^ | P-Value^d^ | N | Mean ± SE | Pct^e^ | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | Pct | P-Value
4 | 12 | 2.9 ± 0.3 | 0.536 | 12 | 3.5 ± 0.3 | 119.1 | 0.387 | 12 | 3.4 ± 0.3 | 115.1 | 0.595 | 12 | 3.0 ± 0.3 | 103.4 | 0.997 | 12 | 3.0 ± 0.3 | 102.8 | 0.999
8 | 12 | 3.2 ± 0.1 | 0.428 | 12 | 3.2 ± 0.1 | 101.4 | 0.998 | 12 | 3.2 ± 0.1 | 101.0 | 1.000 | 12 | 3.2 ± 0.1 | 98.8 | 0.999 | 12 | 3.4 ± 0.1 | 105.5 | 0.796
12 | 12 | 3.5 ± 0.2 | 0.670 | 12 | 3.5 ± 0.2 | 99.0 | 1.000 | 12 | 3.5 ± 0.2 | 99.0 | 1.000 | 12 | 3.5 ± 0.2 | 98.8 | 0.999 | 12 | 3.4 ± 0.2 | 97.0 | 0.979
16 | 12 | 3.7 ± 0.1 | 0.637 | 12 | 3.7 ± 0.1 | 101.5 | 0.995 | 12 | 3.7 ± 0.1 | 99.4 | 1.000 | 12 | 3.8 ± 0.1 | 102.8 | 0.952 | 12 | 3.8 ± 0.1 | 102.1 | 0.983
20 | 12 | 4.1 ± 0.1 | 0.131 | 12 | 4.0 ± 0.1 | 99.1 | 0.989 | 12 | 4.0 ± 0.1 | 97.8 | 0.793 | 12 | 3.9 ± 0.1 | 96.6 | 0.467 | 12 | 4.2 ± 0.1 | 103.3 | 0.499
24 | 12 | 3.9 ± 0.1 | 0.665 | 12 | 3.9 ± 0.1 | 99.9 | 1.000 | 12 | 4.1 ± 0.1 | 104.3 | 0.405 | 12 | 3.9 ± 0.1 | 100.3 | 1.000 | 12 | 4.0 ± 0.1 | 101.9 | 0.920
28 | 12 | 3.9 ± 0.1 | 0.393 | 12 | 3.9 ± 0.1 | 100.7 | 0.997 | 12 | 3.9 ± 0.1 | 99.8 | 1.000 | 12 | 3.9 ± 0.1 | 101.5 | 0.942 | 12 | 3.9 ± 0.1 | 101.9 | 0.876
32 | 12 | 3.8 ± 0.1 | 0.271 | 12 | 3.8 ± 0.1 | 100.2 | 1.000 | 12 | 3.9 ± 0.1 | 102.2 | 0.840 | 12 | 3.9 ± 0.1 | 101.2 | 0.976 | 12 | 3.9 ± 0.1 | 103.0 | 0.649
36 | 12 | 3.8 ± 0.1 | 0.744 | 12 | 3.8 ± 0.1 | 100.4 | 1.000 | 12 | 3.8 ± 0.1 | 100.0 | 1.000 | 12 | 4.0 ± 0.1 | 105.4 | 0.245 | 12 | 3.8 ± 0.1 | 100.0 | 1.000
40 | 12 | 3.9 ± 0.1 | 0.322 | 12 | 3.8 ± 0.1 | 96.1 | 0.711 | 12 | 3.8 ± 0.1 | 95.9 | 0.679 | 12 | 3.7 ± 0.1 | 94.1 | 0.369 | 12 | 3.8 ± 0.1 | 95.3 | 0.571
44 | 12 | 3.8 ± 0.1 | 0.322 | 12 | 3.6 ± 0.1 | 96.1 | 0.484 | 12 | 3.8 ± 0.1 | 99.6 | 1.000 | 12 | 3.8 ± 0.1 | 99.5 | 0.999 | 12 | 3.6 ± 0.1 | 95.8 | 0.426
48 | 12 | 4.3 ± 0.3 | 0.550 | 12 | 3.7 ± 0.3 | 85.8 | 0.490 | 12 | 3.9 ± 0.3 | 89.8 | 0.752 | 12 | 3.8 ± 0.3 | 87.5 | 0.599 | 12 | 3.8 ± 0.3 | 89.0 | 0.700
52 | 12 | 3.7 ± 0.1 | 0.620 | 12 | 3.5 ± 0.1 | 94.4 | 0.375 | 12 | 3.7 ± 0.1 | 99.2 | 0.998 | 12 | 3.6 ± 0.1 | 97.1 | 0.855 | 12 | 3.7 ± 0.1 | 99.8 | 1.000
56 | 12 | 3.6 ± 0.1 | 0.939 | 12 | 3.6 ± 0.1 | 98.4 | 0.986 | 12 | 3.5 ± 0.1 | 96.5 | 0.799 | 12 | 3.7 ± 0.1 | 102.0 | 0.962 | 12 | 3.5 ± 0.1 | 98.0 | 0.965
60 | 12 | 3.4 ± 0.1 | 0.098 | 12 | 3.4 ± 0.1 | 99.3 | 0.999 | 12 | 3.6 ± 0.1 | 106.5 | 0.351 | 12 | 3.5 ± 0.1 | 102.0 | 0.972 | 12 | 3.6 ± 0.1 | 106.9 | 0.297
64 | 12 | 3.2 ± 0.1 | 0.173 | 12 | 3.4 ± 0.1 | 104.4 | 0.754 | 12 | 3.4 ± 0.1 | 105.6 | 0.577 | 12 | 3.5 ± 0.1 | 108.3 | 0.230 | 12 | 3.5 ± 0.1 | 106.9 | 0.381
68 | 12 | 3.4 ± 0.2 | 0.555 | 12 | 3.3 ± 0.2 | 96.4 | 0.944 | 12 | 3.6 ± 0.2 | 105.3 | 0.817 | 12 | 3.7 ± 0.2 | 106.0 | 0.743 | 12 | 3.5 ± 0.2 | 101.7 | 0.996
72 | 12 | 3.5 ± 0.2 | 0.124 | 12 | 3.6 ± 0.2 | 101.8 | 0.995 | 12 | 3.9 ± 0.2 | 109.1 | 0.396 | 12 | 4.0 ± 0.2 | 113.2 | 0.111 | 12 | 3.8 ± 0.2 | 108.5 | 0.455
76 | 12 | 3.7 ± 0.1 | 0.351 | 12 | 3.8 ± 0.1 | 102.8 | 0.916 | 12 | 3.8 ± 0.1 | 102.7 | 0.925 | 12 | 4.0 ± 0.1 | 107.4 | 0.265 | 12 | 3.9 ± 0.1 | 103.9 | 0.791
80 | 12 | 3.6 ± 0.2 | 0.332 | 12 | 3.8 ± 0.2 | 105.2 | 0.914 | 12 | 3.8 ± 0.2 | 105.4 | 0.905 | 12 | 4.2 ± 0.2 | 114.9 | 0.195 | 12 | 3.9 ± 0.2 | 107.2 | 0.783
84 | 12 | 3.5 ± 0.3 | 0.014 | 12 | 3.5 ± 0.3 | 100.7 | 1.000 | 12 | 4.0 ± 0.3 | 113.3 | 0.511 | 12 | 4.4 ± 0.3 | 126.0 | 0.041 | 12 | 4.2 ± 0.3 | 120.4 | 0.152
88 | 12 | 3.6 ± 0.3 | 0.001 | 12 | 3.6 ± 0.3 | 101.9 | 0.999 | 12 | 3.8 ± 0.3 | 107.9 | 0.885 | 12 | 4.5 ± 0.3 | 127.6 | 0.042 | 12 | 4.6 ± 0.3 | 128.6 | 0.033
92 | 12 | 4.0 ± 0.3 | 0.006 | 12 | 3.7 ± 0.3 | 92.3 | 0.846 | 12 | 4.3 ± 0.3 | 107.4 | 0.864 | 12 | 4.7 ± 0.3 | 117.7 | 0.212 | 12 | 4.8 ± 0.3 | 118.8 | 0.168
96 | 12 | 3.7 ± 0.4 | <0.001 | 12 | 3.9 ± 0.4 | 106.6 | 0.977 | 12 | 4.7 ± 0.4 | 127.9 | 0.176 | 12 | 5.6 ± 0.4 | 151.7 | 0.002 | 12 | 5.4 ± 0.4 | 146.3 | 0.006
100 | 12 | 3.7 ± 0.6 | 0.004 | 12 | 4.1 ± 0.6 | 112.4 | 0.942 | 12 | 5.1 ± 0.6 | 138.8 | 0.209 | 12 | 6.1 ± 0.6 | 166.3 | 0.007 | 12 | 5.7 ± 0.6 | 155.1 | 0.035
104 | 12 | 3.7 ± 0.6 | <0.001 | 12 | 4.1 ± 0.6 | 111.7 | 0.962 | 12 | 5.3 ± 0.6 | 143.5 | 0.176 | 12 | 6.0 ± 0.6 | 162.7 | 0.022 | 12 | 6.3 ± 0.6 | 172.4 | 0.006
Mean for Weeks
4–104 | | 3.7 ± 0.1 | | | 3.7 ± 0.1 | | | | 3.9 ± 0.1 | | | | 4.1 ± 0.1 | | | | 4.0 ± 0.1

^a^ Week indicates the last week of a 4-week interval of daily food consumption, measured weekly by cage.

^b^ N = Number of cages.

^c^ Mean ± SE (g per day) = Estimated least squares mean and standard error.

^d^ P-values in the 0.0 mM glycidamide column are the p-values for the trend test; p-values in the treatment columns are Dunnett's adjusted p-values for pairwise comparisons of the dose groups to the 0.0 mM glycidamide group.

^e^ Pct = Ratio of the mean food consumption of the dose groups to the mean food consumption of the 0.0 mM glycidamide group, expressed as a percent.

Table G-4 Food Consumption of Female Mice in the Two-year Drinking Water Study of Glycidamide

Week^a^ | 0.0 mM | | | 0.0875 mM | | | | 0.175 mM | | | | 0.35 mM | | | | 0.70 mM
Week^a^ | N^b^ | Mean ± SE^c^ | P-Value^d^ | N | Mean ± SE | Pct^e^ | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | Pct | P-Value | N | Mean ± SE | Pct | P-Value
4 | 12 | 2.8 ± 0.1 | 0.533 | 12 | 2.8 ± 0.1 | 102.9 | 0.708 | 12 | 2.8 ± 0.1 | 102.4 | 0.809 | 12 | 2.7 ± 0.1 | 98.4 | 0.946 | 12 | 2.8 ± 0.1 | 100.4 | 1.000
8 | 12 | 3.0 ± 0.1 | 0.651 | 12 | 3.0 ± 0.1 | 99.8 | 1.000 | 12 | 3.0 ± 0.1 | 98.0 | 0.973 | 12 | 3.0 ± 0.1 | 99.0 | 0.998 | 12 | 3.0 ± 0.1 | 98.0 | 0.973
12 | 12 | 3.3 ± 0.2 | 0.683 | 12 | 3.5 ± 0.2 | 105.3 | 0.874 | 12 | 3.3 ± 0.2 | 100.6 | 1.000 | 12 | 3.3 ± 0.2 | 98.8 | 0.999 | 12 | 3.3 ± 0.2 | 99.9 | 1.000
16 | 12 | 3.7 ± 0.2 | 0.820 | 12 | 3.6 ± 0.2 | 99.5 | 1.000 | 12 | 3.5 ± 0.2 | 95.3 | 0.836 | 12 | 3.6 ± 0.2 | 99.0 | 0.999 | 12 | 3.7 ± 0.2 | 100.2 | 1.000
20 | 12 | 4.0 ± 0.1 | 0.715 | 12 | 4.0 ± 0.1 | 100.4 | 0.999 | 12 | 4.0 ± 0.1 | 100.1 | 1.000 | 12 | 3.9 ± 0.1 | 98.0 | 0.827 | 12 | 3.9 ± 0.1 | 99.8 | 1.000
24 | 12 | 3.8 ± 0.1 | 0.119 | 12 | 3.8 ± 0.1 | 100.0 | 1.000 | 12 | 3.9 ± 0.1 | 103.3 | 0.571 | 12 | 3.7 ± 0.1 | 98.2 | 0.909 | 12 | 3.7 ± 0.1 | 97.2 | 0.700
28 | 12 | 3.9 ± 0.1 | 0.102 | 12 | 3.8 ± 0.1 | 98.7 | 0.960 | 12 | 3.8 ± 0.1 | 98.7 | 0.964 | 12 | 3.8 ± 0.1 | 97.2 | 0.627 | 12 | 3.7 ± 0.1 | 96.1 | 0.340
32 | 12 | 3.8 ± 0.1 | 0.822 | 12 | 3.8 ± 0.1 | 98.9 | 0.979 | 12 | 3.9 ± 0.1 | 102.0 | 0.838 | 12 | 3.9 ± 0.1 | 102.2 | 0.774 | 12 | 3.8 ± 0.1 | 99.0 | 0.985
36 | 12 | 3.8 ± 0.1 | 0.089 | 12 | 3.8 ± 0.1 | 100.6 | 0.998 | 12 | 3.9 ± 0.1 | 101.4 | 0.960 | 12 | 3.8 ± 0.1 | 99.1 | 0.992 | 12 | 3.7 ± 0.1 | 96.6 | 0.526
40 | 12 | 3.8 ± 0.1 | 0.340 | 12 | 3.8 ± 0.1 | 99.9 | 1.000 | 12 | 3.8 ± 0.1 | 102.0 | 0.910 | 12 | 3.8 ± 0.1 | 101.4 | 0.969 | 12 | 3.7 ± 0.1 | 97.5 | 0.820
44 | 12 | 3.9 ± 0.1 | 0.353 | 12 | 3.7 ± 0.1 | 97.0 | 0.819 | 12 | 3.9 ± 0.1 | 101.5 | 0.981 | 12 | 3.9 ± 0.1 | 100.5 | 1.000 | 12 | 3.9 ± 0.1 | 102.0 | 0.950
48 | 12 | 3.8 ± 0.1 | 0.467 | 12 | 3.9 ± 0.1 | 102.3 | 0.922 | 12 | 3.8 ± 0.1 | 100.1 | 1.000 | 12 | 3.8 ± 0.1 | 100.9 | 0.998 | 12 | 3.9 ± 0.1 | 103.2 | 0.803
52 | 12 | 3.8 ± 0.1 | 0.413 | 12 | 3.7 ± 0.1 | 96.7 | 0.863 | 12 | 3.7 ± 0.1 | 97.2 | 0.917 | 12 | 3.9 ± 0.1 | 102.0 | 0.973 | 12 | 3.8 ± 0.1 | 100.9 | 0.999
56 | 12 | 3.6 ± 0.2 | 0.993 | 12 | 4.1 ± 0.2 | 114.6 | 0.278 | 12 | 3.7 ± 0.2 | 102.7 | 0.994 | 12 | 3.8 ± 0.2 | 105.5 | 0.925 | 12 | 3.8 ± 0.2 | 105.2 | 0.937
60 | 12 | 3.6 ± 0.1 | 0.036 | 12 | 3.5 ± 0.1 | 97.5 | 0.928 | 12 | 3.5 ± 0.1 | 99.3 | 0.999 | 12 | 3.5 ± 0.1 | 99.1 | 0.998 | 12 | 3.8 ± 0.1 | 106.6 | 0.287
64 | 12 | 3.5 ± 0.1 | 0.011 | 12 | 3.3 ± 0.1 | 96.6 | 0.809 | 12 | 3.5 ± 0.1 | 100.5 | 1.000 | 12 | 3.5 ± 0.1 | 102.5 | 0.919 | 12 | 3.7 ± 0.1 | 107.3 | 0.200
68 | 12 | 3.4 ± 0.2 | 0.002 | 12 | 3.4 ± 0.2 | 99.8 | 1.000 | 12 | 3.6 ± 0.2 | 105.7 | 0.825 | 12 | 3.6 ± 0.2 | 104.0 | 0.944 | 12 | 4.1 ± 0.2 | 119.3 | 0.019
72 | 12 | 3.7 ± 0.3 | 0.006 | 12 | 3.6 ± 0.3 | 96.7 | 0.995 | 12 | 3.7 ± 0.3 | 100.2 | 1.000 | 12 | 3.9 ± 0.3 | 103.7 | 0.992 | 12 | 4.7 ± 0.3 | 125.1 | 0.078
76 | 12 | 3.9 ± 0.4 | <0.001 | 12 | 3.8 ± 0.4 | 95.9 | 0.993 | 12 | 4.1 ± 0.4 | 105.0 | 0.984 | 12 | 4.1 ± 0.4 | 103.7 | 0.995 | 12 | 5.6 ± 0.4 | 141.3 | 0.004
80 | 12 | 3.8 ± 0.3 | <0.001 | 12 | 4.0 ± 0.3 | 104.2 | 0.982 | 12 | 4.0 ± 0.3 | 104.1 | 0.983 | 12 | 4.2 ± 0.3 | 109.8 | 0.731 | 12 | 5.3 ± 0.3 | 137.5 | 0.001
84 | 12 | 3.9 ± 0.3 | <0.001 | 12 | 4.0 ± 0.3 | 101.2 | 1.000 | 12 | 4.0 ± 0.3 | 101.2 | 1.000 | 12 | 4.1 ± 0.3 | 104.8 | 0.980 | 12 | 6.4 ± 0.3 | 163.6 | <0.001
88 | 12 | 3.8 ± 0.3 | <0.001 | 12 | 3.9 ± 0.3 | 103.4 | 0.996 | 12 | 4.2 ± 0.3 | 111.8 | 0.737 | 12 | 4.5 ± 0.3 | 120.0 | 0.299 | 12 | 6.9 ± 0.3 | 181.2 | <0.001
92 | 12 | 4.2 ± 0.5 | <0.001 | 12 | 4.0 ± 0.5 | 95.6 | 0.995 | 12 | 4.4 ± 0.5 | 104.7 | 0.994 | 12 | 4.5 ± 0.5 | 105.6 | 0.989 | 11 | 7.6 ± 0.5 | 178.6 | <0.001
96 | 12 | 4.0 ± 0.4 | <0.001 | 12 | 4.2 ± 0.4 | 105.3 | 0.988 | 12 | 4.7 ± 0.4 | 116.1 | 0.620 | 12 | 4.8 ± 0.4 | 118.8 | 0.487 | 11 | 8.5 ± 0.4 | 212.0 | <0.001
100 | 12 | 4.2 ± 0.4 | <0.001 | 12 | 4.3 ± 0.4 | 103.0 | 0.999 | 12 | 4.8 ± 0.4 | 112.7 | 0.777 | 12 | 5.2 ± 0.4 | 124.2 | 0.251 | 9 | 9.5 ± 0.4 | 224.0 | <0.001
104 | 12 | 4.4 ± 0.4 | <0.001 | 12 | 4.3 ± 0.4 | 97.3 | 0.998 | 12 | 4.8 ± 0.4 | 108.5 | 0.897 | 12 | 5.6 ± 0.4 | 128.4 | 0.073 | 7 | 10.3 ± 0.4 | 235.4 | <0.001
Mean for Weeks
4–104 | | 3.7 ± 0.1 | | | 3.8 ± 0.1 | | | | 3.9 ± 0.1 | | | | 3.9 ± 0.1 | | | | 4.9 ± 0.1

^a^ Week indicates the last week of a 4-week interval of daily food consumption, measured weekly by cage.

^b^ N = Number of cages.

^c^ Mean ± SE (g per day) = Estimated least squares mean and standard error.

^d^ P-values in the 0.0 mM glycidamide column are the p-values for the trend test; p-values in the treatment columns are Dunnett's adjusted p-values for pairwise comparisons of the dose groups to the 0.0 mM glycidamide group.

^e^ Pct = Ratio of the mean food consumption of the dose groups to the mean food consumption of the 0.0 mM glycidamide group, expressed as a percent.