# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization of Glycidamide

The glycidamide test article used was purchased from Toronto Research Chemicals, Inc. of North York, Ontario Canada (Lot 4-AQL-43-5) and received July 7, 2003. The compound was stored under argon at −20°C. Identity, purity, and stability analyses were conducted by the Division of Biochemical Toxicology Chemistry Support Group (DBT/CHEM) at the National Center for Toxicological Research (NCTR; Jefferson, AR). Reports on analyses performed in support of the glycidamide studies are on file at NCTR.

Test sample characterization was performed using gas chromatography with electron impact mass spectrometry (GC/EI-MS; MS model TSQ 700; DB-5 capillary GC column). The sample (1.5 mg) was dissolved with 1 ml of methanol and diluted 10-fold with methanol. GC/MS analyses were performed with the SPI Injector held at 200°C. A sample of acrylamide from previous analyses was analyzed to compare retention times and purity. Only one major component was apparent in the sample, with a purity >99%. Additional test sample characterization was performed using liquid chromatography with electrospray ionization mass spectrometry (LC/+ESI-MS; MS model TSQ 7000; Aquasil C18 column). The sample was dissolved in methanol to form a 1.5 mg/ml solution, which was diluted 10-fold with mobile phase. An initial gradient analysis with acetonitrile was performed to determine that no noticeable impurities were present. Subsequent analyses were performed isocratic, with H_2_O + 0.1% formic acid. Based on the mass spectra and product ion spectra obtained (t_r_ = 2.5 min; m/z 88), the major component was tentatively identified as glycidamide (CAS# 5694-00-8). No impurities were found with retention times greater than that of the major component.

Proton and carbon nuclear magnetic resonance (^1^H and ^13^C NMR) spectra of the glycidamide samples (Lot 4-AQL-43-5) were recorded with deuterated methanol as solvent (40 mg/ml for ^1^H NMR and 173 mg/ml for ^13^C NMR). The samples were briefly bubbled with argon as a precautionary measure and ^1^H NMR spectra were recorded as a function of time to check for instability. The ^1^H and ^13^C NMR spectral parameters were consistent with the glycidamide structure (Figure F-1 and Figure F-2). Additionally, two small broad proton resonances (7.48 and 7.22 ppm) from the NH_2_ group were detected in the vertically expanded ^1^H NMR spectrum. These arise from residual exchangeable protons that were present even though deuterated methanol was used as solvent. The ^1^H NMR spectrum exhibited considerable impurity. Perhaps most noteworthy is a relatively large singlet at 5.48 ppm, which is consistent with methylene chloride at a level of 0.13% (g/g). The possibility that the brief bubbling with argon lowered the amount of this material cannot be ruled out. There also appears to be a singlet at 54.80 ppm in the ^13^C NMR spectrum, which would likewise be consistent with methylene chloride, however, the signal is near the limit of detection due to the lower sensitivity of ^13^C NMR. The largest impurity resonances were assigned to acrylamide at 0.7% (mole/mole). These were detected in both the ^1^H and ^13^C NMR spectra. Other impurity resonances, all in the aliphatic region, suggest additional impurities totaling roughly 0.6% (g/g). A very rough estimate of the total organic impurity is 1.5% (g/g).

Purity analysis of samples of glycidamide Toronto Research Chemicals Lot # 4-AQL-43-5 was determined by capillary gas chromatography with flame ionization detection (GC/FID). The GC instrument was a Hewlett Packard HP 6980A operated in the capillary split mode (1:10) using a 320 μm diameter, 30 m length, 0.25 μm film thickness fused silica capillary J&W DB-1701, and the oven programmed from 35°C (0.2 min hold) to 200°C (2 min final hold). The capillary inlet and FID detector temperatures were held at 200°C and 250°C, respectively. One microliter injections of 2 mg/ml solutions of the test compound in EtOAc were made and compared to EtOAc solvent blank using GC/FID analysis. Glycidamide was analyzed for purity based on the percentage of total area observed by GC/FID response. Three impurity peaks were evident at 7.8, 10.4, and 10.6 min retention, indicating respective contents of 0.3, 1.1, and 0.2% for a total of 1.6% impurities (Figure F-3). Therefore, based on GC/FID, the purity of the glycidamide was 98.4%. Glycidamide samples (Lot 4-AQL-43-5) were analyzed for purity at approximately 1, 1.5, and 2 years into the 2-year study. Each evaluation including the end-of-study analysis indicated that no change had occurred in Lot 4-AQL-43-5 during the course of study.

## F.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by dissolving glycidamide in water to give the required concentrations (Table F-1). The dose formulations were mixed for 5 min. in high density polyethylene plastic drums (Saint-Gobain Performance Plastics) by a Leeson paddle-stirrer with a four inch stainless steel impeller and stored in stainless steel cases with lids at 4°C.

Periodic analyses of the dose formulations of glycidamide were conducted using GC-FID. Dose formulations were analyzed twice during the 2-week studies (Table F-2), approximately every 2 weeks during the 3-month studies (Table F-3), and approximately every 2 to 3 months during the 2-year studies (Table F-4). Of the dose formulations analyzed and used during the 2-week studies, 11 of 12 were within 10% of the target concentrations. Of the dose formulations analyzed and used during the 3-month studies, 25 of 35 were within 10% of the target concentrations. Of the dose formulations analyzed and used during the 2-year studies, 51 of 52 were within 10% of the target concentrations.

Table F-1 Preparation and Storage of Dose Formulations in the Drinking Water Study of Glycidamide

Two-week Studies | Three-month Studies | Two-year Studies
Preparation
A stock solution of glycidamide (6.12 mg/ml) in water was prepared in a volumetric flask. The stock solution was diluted with Millipore filtered water to the needed concentrations. The dose formulations in drinking water were prepared weekly. | Same as 2-week studies | Same as 2-week studies
Chemical Lot Number
4-AQL-43-5 | Same as 2-week studies | Same as 2-week studies
Storage Conditions
Dosed water was stored at 4°C with protection from light. | Same as 2-week studies | Same as 2-week studies
Study Laboratory
National Center for Toxicological Research (Jefferson, Arkansas) | Same as 2-week studies | Same as 2-week studies

Table F-2 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Two-week Drinking Water Study of Glycidamide

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
April 12, 2004 | July 19, 2004 | 0 | <LOQ^b^ | –
| | 12.2 | 10.4 | −15
| | 30.6 | 33.4 | +9
| | 61.2 | 61.5 | +1
| | 122 | 119 | −2
| | 306 | 337 | +10
| | 612 | 648 | +6
April 19, 2004 | July 19, 2004 | 0 | <LOQ | –
| | 12.2 | 11.4 | −7
| | 30.6 | 30.1 | −2
| | 61.2 | 66.7 | +9
| | 122 | 126 | +3
| | 306 | 291 | −5
| | 612 | 652 | +7

^a^ Dosed water was analyzed in duplicate and the average is reported.

^b^ Limit of quantitation determined by GC-FID was 2 ppm.

Table F-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Drinking Water Study of Glycidamide

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
July 28, 2004 | August 19, 2004 | 0 | <LOQ^b^ | –
| | 12.2 | 9.1^c^ | −25
| | 30.6 | 22.7^d^ | −26
| | 61.2 | 49.0^d^ | −20
| | 122 | 98.1^d^ | −20
| | 306 | 258^d^ | −16
August 16, 2004 | August 27, 2004 | 0 | <LOQ | –
| | 12.2 | 12.6^e^ | +4
| | 30.6 | 22.3^d^ | −27
| | 61.2 | 55.7 | −9
| | 122 | 113 | −7
| | 306 | 229^d^ | −25
August 24, 2004 | August 26, 2004 | 0 | <LOQ | –
| | 12.2 | 11.4 | −7
| | 30.6 | 29.8 | −3
| | 61.2 | 65.1 | +6
| | 122 | 124 | +2
| | 306 | 303 | −1
September 10, 2004 | October 5, 2004 | 0 | <LOQ | –
| | 12.2 | 10.6 | −13
| | 30.6 | 29.9 | −2
| | 61.2 | 70.9^d^ | +16
| | 122 | 111 | −9
| | 306 | 305 | 0
September 24, 2004 | October 5, 2004 | 0 | <LOQ | –
| | 12.2 | 10.6 | −13
| | 30.6 | 31.0 | +1
| | 61.2 | 59.2 | −3
| | 122 | 133 | +9
| | 306 | 333 | +9
October 8, 2004 | October 15, 2004 | 0 | <LOQ | –
| | 12.2 | 12.5 | +3
| | 30.6 | 31.0 | +1
| | 61.2 | 64.5 | +6
| | 122 | 133 | +9
| | 306 | 329 | +7
October 21, 2004 | November 1, 2004 | 0 | <LOQ | –
| | 12.2 | 12.9 | +6
| | 30.6 | 28.2 | −8
| | 61.2 | 57.8 | −5
| | 122 | 115 | −5
| | 306 | 293 | −4

^a^ Dosed water was analyzed in duplicate and the average is reported.

^b^ Limit of quantitation determined by GC-FID was 5 μg/ml.

^c^ Based on analysis of n = 3.

^d^ Based on analysis of n = 4.

^e^ Based on a single sample analysis.

Table F-4 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Two-year Drinking Water Studies of Glycidamide

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
May 24, 2005 | June 1, 2005 | 0 | <LOQ^b^ | –
| | 7.65 | 7.31 ± 1.00 | −3
| | 15.3 | 15.6 ± 0.4 | +2
| | 30.6 | 29.8 ± 1.1 | −3
| | 61.2 | 66.3 ± 0.2 | +8
August 2, 2005 | August 5, 2005 | 0 | <LOQ | –
| | 7.65 | 7.44 ± 0.10 | −3
| | 15.3 | 15.4 ± 0.4 | +1
| | 30.6 | 31.8 ± 0.2 | +4
| | 61.2 | 64.6 ± 4.8 | +5
October 11, 2005 | October 14, 2005 | 0 | <LOQ | –
| | 7.65 | 7.29 ± 0.32 | −5
| | 15.3 | 16.1 ± 1.2 | +5
| | 30.6 | 31.4 ± 1.3 | +3
| | 61.2 | 63.6 ± 4.7 | +4
December 13, 2005 | December 15, 2005 | 0 | <LOQ | –
| | 7.65 | 8.11 ± 0.63 | +6
| | 15.3 | 14.4 ± 0.2 | −6
| | 30.6 | 30.7 ± 1.4 | 0
| | 61.2 | 63.9 ± 5.5 | +4
February 14, 2006 | February 15, 2006 | 0 | <LOQ | –
| | 7.65 | 8.42 ± 0.30 | +10
| | 15.3 | 15.4 ± 0.3 | +1
| | 30.6 | 29.5 ± 1.7 | −4
| | 61.2 | 63.4 ± 0.2 | +4
April 25, 2006 | May 1, 2006 | 0 | <LOQ | –
| | 7.65 | 7.85 ± 0.15 | +3
| | 15.3 | 13.8 ± 1.4 | −10
| | 30.6 | 28.2 ± 0.1 | −8
| | 61.2 | 65.9 ± 4.9 | +8
July 4, 2006 | July 11, 2006 | 0 | <LOQ | –
| | 7.65 | 7.96^c^ | +4
| | 15.3 | 15.1 ± 0.5 | −1
| | 30.6 | 28.2 ± 0.6 | −8
| | 61.2 | 63.7 ± 8.6 | +4
September 5, 2006 | September 18, 2006 | 0 | <LOQ | –
| | 7.65 | 7.69 ± 0.21 | +1
| | 15.3 | 16.5 ± 0.6 | +8
| | 30.6 | 33.7 ± 1.2 | +10
| | 61.2 | 59.3 ± 7.8 | −3
November 14, 2006 | November 20, 2006 | 0 | <LOQ | –
| | 7.65 | 7.42 ± 0.65 | +1
| | 15.3 | 14.7 ± 2.0 | +8
| | 30.6 | 29.5 ± 5.1 | +10
| | 61.2 | 57.0 ± 11.9 | −7
January 23, 2007 | January 29, 2007 | 0 | <LOQ | –
| | 7.65 | 7.61 ± 1.5 | 0
| | 15.3 | 15.7 ± 1.4 | +3
| | 30.6 | 32.2 ± 2.4 | +5
| | 61.2 | 61.0 ± 13.0 | 0
March 27, 2007 | March 29, 2007 | 0 | <LOQ | –
| | 7.65 | 7.57 ± 1.78 | −1
| | 15.3 | 15.4 ± 0.5 | +1
| | 30.6 | 30.5 ± 2.3 | 0
| | 61.2 | 60.4 ± 0.1 | −1
June 5, 2007 | June 11, 2007 | 0 | <LOQ | –
| | 7.65 | 8.36 ± 0.16 | +9
| | 15.3 | 16.1 ± 0.5 | +5
| | 30.6 | 29.5 ± 5.9 | −4
| | 61.2 | 56.4 ± 12.5 | −8
August 14, 2007 | August 17, 2007 | 0 | <LOQ | –
| | 7.65 | 6.54 ± 0.23 | −14
| | 15.3 | 15.1 ± 1.2 | −1
| | 30.6 | 29.9 ± 0.3 | −2
| | 61.2 | 58.7 ± 3.2 | −4

^a^ Dosed water was analyzed in duplicate and the average ± S.D. is reported.

^b^ Limit of quantitation determined by GC-FID was 1.5 μg/ml.

^c^ Based on a single sample analysis.

Figure F-1

Proton Nuclear Magnetic Resonance Spectrum of Glycidamide

Figure F-2

Carbon Nuclear Magnetic Resonance Spectrum of Glycidamide

Figure F-3

Capillary Gas Chromatography with Flame Ionization Detection Purity Analysis of Glycidamide