# Appendix E Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table E-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Drinking Water Study of Glycidamide^a^

| 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM | 7.03 mM
Male
Necropsy body wt. | 133.6 ± 6.7 | 137.2 ± 7.8 | 126.8 ± 4.8 | 137.5 ± 7.3 | 134.9 ± 4.4 | 111.4 ± 1.7* | 79.2 ± 0.8*
Brain
Absolute | 1.68 ± 0.05 | 1.68 ± 0.05 | 1.60 ± 0.05 | 1.67 ± 0.03 | 1.61 ± 0.03 | 1.52 ± 0.04 | 1.43 ± 0.02*
Liver
Absolute | 6.59 ± 0.35 | 7.08 ± 0.33 | 6.03 ± 0.39 | 6.87 ± 0.50 | 7.31 ± 0.22 | 5.73 ± 0.19 | 4.06 ± 0.16*
Relative^c^ | 4.94 ± 0.13 | 5.17 ± 0.08 | 4.74 ± 0.17 | 4.98 ± 0.11 | 5.42 ± 0.07 | 5.14 ± 0.12 | 5.12 ± 0.20
Relative^d^ | 3.93 ± 0.16 | 4.22 ± 0.21 | 3.77 ± 0.23 | 4.10 ± 0.23 | 4.55 ± 0.19 | 3.78 ± 0.14 | 2.85 ± 0.11*
Female
Necropsy body wt. | 96.9 ± 4.2 | 96.3 ± 9.3 | 99.7 ± 10.3 | 99.8 ± 4.5 | 97.4 ± 2.8 | 83.0 ± 1.9 | 55.7 ± 9.9^b,^*
Brain
Absolute | 1.56 ± 0.02 | 1.58 ± 0.06 | 1.52 ± 0.08 | 1.54 ± 0.04 | 1.55 ± 0.03 | 1.44 ± 0.02 | 1.36 ± 0.03^b,^*
Liver
Absolute | 4.95 ± 0.31 | 4.66 ± 0.44 | 4.63 ± 0.32 | 4.73 ± 0.24 | 4.79 ± 0.15 | 3.85 ± 0.05 | 2.61 ± 0.51^b,^*
Relative^c^ | 5.10 ± 0.16 | 4.85 ± 0.11 | 4.70 ± 0.21 | 4.74 ± 0.07 | 4.92 ± 0.07 | 4.65 ± 0.17 | 4.66 ± 0.09^b^
Relative^d^ | 3.18 ± 0.16 | 2.94 ± 0.20 | 3.04 ± 0.10 | 3.09 ± 0.19 | 3.08 ± 0.10 | 2.68 ± 0.04 | 1.92 ± 0.35^b,^*

^a^ The data are presented in grams as the mean ± s.e.m. An asterisk (*) denotes significant difference (p < 0.05) from the control.

^b^ Data based upon three rats only.

^c^ Liver weight/body weight × 100.

^d^ Liver weight/brain weight.

Table E-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Drinking Water Study of Glycidamide^a^

| 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Male
Necropsy body wt. | 325.2 ± 8.6 | 314.0 ± 5.0 | 325.4 ± 7.0 | 310.0 ± 3.6 | 279.8 ± 7.0* | 253.5 ± 4.2*
Brain
Absolute | 1.96 ± 0.04 | 1.93 ± 0.03 | 1.99 ± 0.02 | 1.96 ± 0.02 | 1.87 ± 0.03 | 1.77 ± 0.03*
Liver
Absolute | 9.81 ± 0.37 | 8.79 ± 0.20 | 9.47 ± 0.40 | 9.41 ± 0.17 | 8.09 ± 0.38* | 7.93 ± 0.29*
Relative^b^ | 3.03 ± 0.12 | 2.80 ± 0.04 | 2.91 ± 0.10 | 3.04 ± 0.05 | 2.89 ± 0.08 | 3.13 ± 0.11
Relative^c^ | 5.01 ± 0.18 | 4.55 ± 0.05 | 4.76 ± 0.21 | 4.82 ± 0.09 | 4.33 ± 0.19* | 4.48 ± 0.17
Female
Necropsy body wt. | 207.6 ± 12.6 | 204.7 ± 16.7 | 178.2 ± 5.3 | 190.9 ± 15.6 | 162.8 ± 5.5 | 166.0 ± 14.2
Brain
Absolute | 1.82 ± 0.02 | 1.77 ± 0.02 | 1.76 ± 0.03 | 1.71 ± 0.03* | 1.70 ± 0.02* | 1.59 ± 0.03*
Liver
Absolute | 5.39 ± 0.18 | 4.80 ± 0.15* | 4.51 ± 0.16* | 4.73 ± 0.17* | 4.32 ± 0.16* | 4.17 ± 0.10*
Relative^b^ | 2.66 ± 0.17 | 2.42 ± 0.14 | 2.54 ± 0.10 | 2.61 ± 0.24 | 2.69 ± 0.18 | 2.61 ± 0.17
Relative^c^ | 2.96 ± 0.10 | 2.73 ± 0.11 | 2.57 ± 0.08* | 2.77 ± 0.11 | 2.55 ± 0.10* | 2.63 ± 0.09

^a^ The data are presented in grams as the mean ± s.e.m. An asterisk (*) denotes significant difference (p < 0.05) from the control.

^b^ Liver weight/body weight × 100.

^c^ Liver weight/brain weight.

Table E-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Drinking Water Study of Glycidamide

| 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM | 7.03 mM
Male
Necropsy body wt.^a^ | 20.7 ± 1.0 | 19.4 ± 0.6 | 21.4 ± 0.6 | 19.7 ± 0.8^b^ | 19.6 ± 0.4 | 18.0 ± 0.7* | 13.0 ± 0.6*
Brain
Absolute^c^ | 432 ± 9 | 435 ± 11 | 426 ± 22 | 424 ± 13^b^ | 415 ± 12 | 422 ± 14 | 396 ± 6
Liver
Absolute | 902 ± 38 | 868 ± 27 | 969 ± 42 | 840 ± 83^b^ | 817 ± 41 | 743 ± 26 | 577 ± 32*
Relative^d^ | 4.38 ± 0.12 | 4.48 ± 0.08 | 4.53 ± 0.12 | 4.24 ± 0.24^b^ | 4.16 ± 0.14 | 4.15 ± 0.11 | 4.43 ± 0.13
Relative^e^ | 2.09 ± 0.07 | 2.00 ± 0.04 | 2.28 ± 0.07 | 1.99 ± 0.23^b^ | 1.97 ± 0.05 | 1.77 ± 0.08 | 1.46 ± 0.09*
Female
Necropsy body wt. | 15.5 ± 0.2 | 16.0 ± 0.07 | 15.8 ± 0.3 | 16.1 ± 0.3 | 15.8 ± 0.2 | 14.6 ± 0.6 | 11.4 ± 0.4*
Brain
Absolute | 433 ± 6 | 422 ± 13 | 425 ± 6 | 432 ± 11 | 417 ± 8 | 411 ± 5 | 377 ± 6*
Liver
Absolute | 629 ± 9 | 652 ± 11 | 650 ± 6 | 684 ± 19 | 650 ± 24 | 601 ± 30 | 507 ± 36*
Relative^d^ | 4.06 ± 0.10 | 4.08 ± 0.09 | 4.13 ± 0.07 | 4.25 ± 0.19 | 4.12 ± 0.11 | 4.15 ± 0.24 | 4.43 ± 0.24
Relative^e^ | 1.45 ± 0.03 | 1.55 ± 0.04 | 1.53 ± 0.03 | 1.59 ± 0.07 | 1.56 ± 0.05 | 1.46 ± 0.07 | 1.35 ± 0.08

^a^ Body weight data are presented in grams as the mean ± s.e.m. An asterisk (*) denotes significant difference (p < 0.05) from the control.

^b^ Data based upon three mice only.

^c^ Organ weight data are presented in milligrams as the mean ± s.e.m. An asterisk (*) denotes significant difference (p < 0.05) from the control.

^d^ Liver weight/body weight × 0.1.

^e^ Liver weight/brain weight.

Table E-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Drinking Water Study of Glycidamide^a^

| 0 mM | 0.14 mM | 0.35 mM | 0.70 mM | 1.41 mM | 3.52 mM
Male
Necropsy body wt. | 25.6 ± 0.5 | 25.7 ± 0.3 | 27.5 ± 0.8* | 24.4 ± 0.3 | 24.4 ± 0.6 | 22.7 ± 0.2*
Brain
Absolute | 0.46 ± 0.009 | 0.47 ± 0.009 | 0.45 ± 0.005 | 0.46 ± 0.007 | 0.44 ± 0.005 | 0.43 ± 0.005*
Liver
Absolute | 1.07 ± 0.04 | 1.07 ± 0.02 | 1.20 ± 0.06 | 1.04 ± 0.01 | 1.02 ± 0.03 | 0.96 ± 0.02
Relative^b^ | 4.17 ± 0.08 | 4.16 ± 0.06 | 4.33 ± 0.11 | 4.28 ± 0.05 | 4.16 ± 0.06 | 4.24 ± 0.09
Relative^c^ | 2.31 ± 0.10 | 2.26 ± 0.07 | 2.63 ± 0.13* | 2.28 ± 0.05 | 2.31 ± 0.08 | 2.24 ± 0.05
Female
Necropsy body wt. | 21.3 ± 0.3 | 20.7 ± 0.4 | 21.7 ± 0.7 | 22.4 ± 1.4 | 21.4 ± 0.3 | 18.6 ± 0.3*
Brain
Absolute | 0.47 ± 0.009 | 0.45 ± 0.01 | 0.47 ± 0.01 | 0.47 ± 0.007 | 0.46 ± 0.009 | 0.44 ± 0.005
Liver
Absolute | 0.91 ± 0.01 | 0.93 ± 0.02 | 0.91 ± 0.03 | 0.91 ± 0.01 | 0.98 ± 0.02 | 0.83 ± 0.03
Relative^b^ | 4.27 ± 0.09 | 4.51 ± 0.10 | 4.21 ± 0.13 | 4.14 ± 0.23 | 4.58 ± 0.07 | 4.49 ± 0.10
Relative^c^ | 1.94 ± 0.05 | 2.06 ± 0.06 | 1.95 ± 0.05 | 1.94 ± 0.05 | 2.14 ± 0.06 | 1.90 ± 0.07

^a^ The data are presented in grams as the mean ± s.e.m. An asterisk (*) denotes significant difference (p < 0.05) from the control.

^b^ Liver weight/body weight × 100.

^c^ Liver weight/brain weight.