# Appendix D Summary of Lesions in Female Mice in the Two-year Drinking Water Study of Glycidamide

Table D-1 Summary of the Incidence of Neoplasms in Female Mice in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | 2 | 2 | 6 | 7 | 32
Natural deaths | 1 | 2 | 2 | 4 | 6
Survivors
Moribund sacrifice | 2 | – | 2 | 5 | 2
Natural deaths | 2 | 2 | – | 1 | –
Terminal sacrifice | 41 | 42 | 38 | 31 | 8
Animals examined microscopically | 47 | 48 | 48 | 48 | 48
Alimentary System
Esophagus | (46) | (48) | (46) | (47) | (45)
Squamous cell carcinoma | – | – | – | 1 (2%) | –
Gallbladder | (45) | (44) | (47) | (44) | (41)
Lymphoma malignant | 1 (2%) | – | – | 1 (2%) | –
Intestine large, cecum | (45) | (44) | (46) | (45) | (42)
Lymphoma malignant | – | – | 1 (2%) | 1 (2%) | 1 (2%)
Intestine large, colon | (45) | (45) | (47) | (45) | (43)
Lymphoma malignant | – | – | – | – | 1 (2%)
Intestine large, rectum | (45) | (45) | (46) | (45) | (43)
Polyp adenomatous | – | – | – | – | 1 (2%)
Sarcoma stromal, metastatic, uterus | – | – | – | – | 1 (2%)
Intestine small, duodenum | (45) | (44) | (46) | (45) | (42)
Adenoma | – | – | – | – | 1 (2%)
Intestine small, ileum | (45) | (44) | (46) | (45) | (42)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Lymphoma malignant | – | 1 (2%) | – | – | –
Intestine small, jejunum | (45) | (44) | (46) | (45) | (42)
Lymphoma malignant | – | – | 1 (2%) | – | –
Liver | (47) | (48) | (47) | (46) | (43)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Hemangiosarcoma | – | – | 1 (2%) | – | –
Hepatocellular adenoma | 4 (9%) | 2 (4%) | 4 (9%) | 2 (4%) | –
Hepatocellular carcinoma | – | 1 (2%) | 2 (4%) | 2 (4%) | 1 (2%)
Histiocytic sarcoma | 1 (2%) | 3 (6%) | – | 1 (2%) | 4 (9%)
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | 2 (4%) | 2 (4%) | 3 (6%) | 1 (2%) | 4 (9%)
Pancreas | (45) | (48) | (47) | (46) | (44)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Lymphoma malignant | 2 (4%) | 1 (2%) | 2 (4%) | 1 (2%) | 3 (7%)
Salivary glands | (45) | (47) | (47) | (47) | (44)
Lymphoma malignant | 1 (2%) | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Stomach, forestomach | (45) | (45) | (47) | (45) | (44)
Lymphoma malignant | – | – | 1 (2%) | – | –
Squamous cell papilloma | 1 (2%) | 1 (2%) | 1 (2%) | 5 (11%) | 9 (20%)
Stomach, glandular | (45) | (45) | (47) | (45) | (43)
Lymphoma malignant | – | – | – | – | 1 (2%)
Cardiovascular System
Blood vessel | (46) | (48) | (47) | (47) | (45)
Lymphoma malignant | – | – | – | – | 1 (2%)
Heart | (46) | (48) | (47) | (47) | (45)
Histiocytic sarcoma | – | 1 (2%) | – | – | 1 (2%)
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | – | – | 1 (2%) | – | –
Endocrine System
Adrenal cortex | (45) | (48) | (47) | (47) | (44)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Lymphoma malignant | – | – | – | – | 3 (7%)
Subcapsular, adenoma | – | – | – | – | 1 (2%)
Adrenal medulla | (45) | (45) | (47) | (47) | (43)
Pheochromocytoma benign | – | – | – | 1 (2%) | –
Pheochromocytoma complex | – | – | – | – | 1 (2%)
Pheochromocytoma malignant | – | 1 (2%) | – | – | –
Islets, pancreatic | (45) | (48) | (47) | (46) | (43)
Lymphoma malignant | – | – | – | 1 (2%) | –
Parathyroid gland | (41) | (45) | (46) | (40) | (39)
Pituitary gland | (45) | (45) | (43) | (47) | (43)
Histiocytic sarcoma | – | 1 (2%) | 1 (2%) | – | –
Lymphoma malignant | – | – | – | – | 1 (2%)
Pars distalis, adenoma | – | 2 (4%) | – | 1 (2%) | 2 (5%)
Thyroid gland | (45) | (47) | (46) | (46) | (44)
General Body System
Tissue NOS | (0) | (0) | (0) | (0) | (1)
Lymphoma malignant | – | – | – | – | 1 (100%)
Genital System
Clitoral gland | (44) | (48) | (47) | (47) | (41)
Lymphoma malignant | – | – | – | – | 1 (2%)
Schwannoma malignant, metastatic, skin | – | – | – | – | 1 (2%)
Squamous cell carcinoma, metastatic, vagina | – | – | – | – | 1 (2%)
Ovary | (45) | (47) | (47) | (46) | (44)
Granulosa cell tumor benign | – | – | – | 1 (2%) | 2 (5%)
Granulosa cell tumor malignant | – | – | – | 2 (4%) | 1 (2%)
Histiocytic sarcoma | – | 1 (2%) | – | 1 (2%) | –
Lymphoma malignant | – | – | – | 1 (2%) | 3 (7%)
Tubulostromal adenoma | – | – | – | 1 (2%) | 2 (5%)
Uterus | (45) | (48) | (47) | (47) | (45)
Adenocarcinoma | – | – | – | – | 2 (4%)
Hemangioma | – | – | – | 1 (2%) | –
Hemangiosarcoma | – | – | – | 1 (2%) | 1 (2%)
Histiocytic sarcoma | – | 1 (2%) | 2 (4%) | 1 (2%) | –
Lymphoma malignant | – | – | 1 (2%) | – | 3 (7%)
Polyp stromal | 1 (2%) | 1 (2%) | – | 3 (6%) | 4 (9%)
Sarcoma stromal | – | – | – | – | 2 (4%)
Endometrium, adenoma | – | – | 1 (2%) | – | 1 (2%)
Vagina | (0) | (0) | (0) | (0) | (1)
Squamous cell carcinoma | – | – | – | – | 1 (100%)
Hematopoietic System
Bone marrow | (46) | (47) | (47) | (45) | (43)
Hemangiosarcoma | 1 (2%) | – | – | – | –
Hemangiosarcoma, metastatic, liver | – | – | 1 (2%) | – | –
Histiocytic sarcoma | 1 (2%) | – | – | 1 (2%) | 2 (5%)
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | – | – | – | – | 1 (2%)
Lymph node | (8) | (2) | (5) | (8) | (12)
Axillary, lymphoma malignant | – | – | – | 1 (13%) | 2 (17%)
Brachial, lymphoma malignant | – | – | – | – | 1 (8%)
Inguinal, lymphoma malignant | 1 (13%) | – | – | 1 (13%) | 1 (8%)
Lumbar, lymphoma malignant | 2 (25%) | 1 (50%) | 3 (60%) | 1 (13%) | 3 (25%)
Lumbar, squamous cell carcinoma, metastatic, vagina | – | – | – | – | 1 (8%)
Mediastinal, histiocytic sarcoma | 1 (13%) | – | – | – | 2 (17%)
Mediastinal, lymphoma malignant | 1 (13%) | – | 1 (20%) | – | 2 (17%)
Pancreatic, fibrous histiocytoma | 1 (13%) | – | – | – | –
Pancreatic, histiocytic sarcoma | – | – | – | – | 1 (8%)
Pancreatic, lymphoma malignant | 2 (25%) | 1 (50%) | – | 2 (25%) | 1 (8%)
Popliteal, lymphoma malignant | – | – | – | – | 1 (8%)
Renal, fibrous histiocytoma | 1 (13%) | – | – | – | –
Renal, histiocytic sarcoma | – | – | – | 1 (13%) | 1 (8%)
Renal, leukemia | 1 (13%) | – | – | – | –
Renal, lymphoma malignant | – | 1 (50%) | 2 (40%) | 4 (50%) | 1 (8%)
Lymph node, mandibular | (46) | (48) | (47) | (47) | (43)
Histiocytic sarcoma | – | 2 (4%) | – | 1 (2%) | 3 (7%)
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | 3 (7%) | 3 (6%) | 4 (9%) | 4 (9%) | 5 (12%)
Lymph node, mesenteric | (43) | (46) | (46) | (47) | (43)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Histiocytic sarcoma | 1 (2%) | 2 (4%) | – | 1 (2%) | 4 (9%)
Lymphoma malignant | 4 (9%) | 4 (9%) | 5 (11%) | 5 (11%) | 5 (12%)
Spleen | (46) | (47) | (47) | (47) | (45)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Hemangiosarcoma | 1 (2%) | – | – | 1 (2%) | 1 (2%)
Histiocytic sarcoma | 2 (4%) | 3 (6%) | – | 1 (2%) | 4 (9%)
Lymphoma malignant | 8 (17%) | 4 (9%) | 4 (9%) | 5 (11%) | 6 (13%)
Thymus | (43) | (44) | (45) | (43) | (37)
Histiocytic sarcoma | – | 1 (2%) | – | 1 (2%) | 1 (3%)
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | 2 (5%) | 3 (7%) | 4 (9%) | 3 (7%) | 3 (8%)
Integumentary System
Mammary gland | (45) | (48) | (47) | (47) | (45)
Adenoacanthoma | – | – | – | 1 (2%) | 8 (18%)
Adenocarcinoma | 1 (2%) | 1 (2%) | 2 (4%) | 9 (19%) | 11 (24%)
Lymphoma malignant | – | – | 1 (2%) | – | 2 (4%)
Skin | (45) | (48) | (47) | (47) | (45)
Lymphoma malignant | – | – | 1 (2%) | – | 1 (2%)
Squamous cell carcinoma | – | – | – | 1 (2%) | –
Squamous cell papilloma | – | – | 1 (2%) | 1 (2%) | –
Ear, basosquamous tumor malignant | – | – | – | – | 1 (2%)
Subcutaneous tissue, fibrosarcoma | – | – | 2 (4%) | 2 (4%) | 8 (18%)
Subcutaneous tissue, fibrosarcoma, multiple | – | 1 (2%) | – | – | 1 (2%)
Subcutaneous tissue, fibrous histiocytoma | – | – | – | 1 (2%) | –
Subcutaneous tissue, sarcoma | – | – | 1 (2%) | 3 (6%) | 3 (7%)
Subcutaneous tissue, Schwannoma malignant | – | – | 1 (2%) | 1 (2%) | 1 (2%)
Musculoskeletal System
Bone | (0) | (0) | (1) | (2) | (1)
Cranium, rhabdomyosarcoma, metastatic, skeletal muscle | – | – | – | 1 (50%) | –
Vertebra, osteosarcoma | – | – | – | – | 1 (100%)
Bone, femur | (46) | (48) | (48) | (48) | (48)
Skeletal muscle | (46) | (48) | (47) | (47) | (45)
Fibrosarcoma, metastatic, skin | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | – | 1 (2%)
Rhabdomyosarcoma | – | – | – | 1 (2%) | –
Sarcoma, metastatic, skin | – | – | – | – | 1 (2%)
Nervous System
Brain, brain stem | (45) | (47) | (47) | (45) | (44)
Histiocytic sarcoma | – | – | 1 (2%) | – | –
Brain, cerebellum | (45) | (47) | (47) | (45) | (44)
Histiocytic sarcoma | – | – | 1 (2%) | – | –
Brain, cerebrum | (45) | (47) | (47) | (45) | (44)
Histiocytic sarcoma | – | – | 1 (2%) | – | –
Peripheral nerve, sciatic | (45) | (47) | (47) | (45) | (44)
Lymphoma malignant | – | – | – | – | 1 (2%)
Spinal cord, cervical | (45) | (44) | (47) | (45) | (43)
Histiocytic sarcoma | – | – | 1 (2%) | – | –
Spinal cord, lumbar | (45) | (45) | (47) | (45) | (43)
Histiocytic sarcoma | – | – | 1 (2%) | – | –
Lymphoma malignant | – | – | – | – | 1 (2%)
Spinal cord, thoracic | (45) | (44) | (47) | (45) | (43)
Histiocytic sarcoma | – | – | 1 (2%) | – | –
Respiratory System
Lung | (46) | (48) | (47) | (47) | (44)
Alveolar/bronchiolar adenoma | 3 (7%) | 5 (10%) | 3 (6%) | 7 (15%) | 7 (16%)
Alveolar/bronchiolar adenoma, multiple | – | – | – | – | 2 (5%)
Alveolar/bronchiolar carcinoma | 1 (2%) | 1 (2%) | – | 1 (2%) | 2 (5%)
Fibrosarcoma, metastatic, skin | – | – | – | – | 1 (2%)
Granular cell tumor malignant, metastatic, ovary | – | – | – | – | 1 (2%)
Histiocytic sarcoma | 1 (2%) | 2 (4%) | – | 1 (2%) | 4 (9%)
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%) | 4 (9%)
Osteosarcoma, metastatic, bone | – | – | – | – | 1 (2%)
Nose | (46) | (46) | (47) | (46) | (45)
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%) | –
Trachea | (45) | (47) | (46) | (46) | (43)
Special Senses System
Eye | (45) | (44) | (47) | (44) | (43)
Lymphoma malignant | – | – | 1 (2%) | – | –
Rhabdomyosarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%) | –
Harderian gland | (45) | (47) | (47) | (46) | (46)
Adenocarcinoma | – | – | 1 (2%) | – | –
Adenoma | 2 (4%) | 18 (38%) | 17 (36%) | 17 (37%) | 27 (59%)
Bilateral, adenoma | – | 1 (2%) | 3 (6%) | 7 (15%) | 13 (28%)
Urinary System
Kidney | (46) | (47) | (47) | (46) | (43)
Histiocytic sarcoma | – | 2 (4%) | – | 1 (2%) | –
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | 2 (4%) | 3 (6%) | 2 (4%) | 1 (2%) | 4 (9%)
Urinary bladder | (45) | (46) | (47) | (46) | (42)
Lymphoma malignant | 1 (2%) | 3 (7%) | 2 (4%) | 1 (2%) | 1 (2%)
Sarcoma stromal, metastatic, uterus | – | – | – | – | 1 (2%)
Systemic Lesions
Multiple organs | (47)^b^ | (48)^b^ | (48)^b^ | (48)^b^ | (48)^b^
Histiocytic sarcoma | 2 (4%) | 3 (6%) | 3 (6%) | 1 (2%) | 4 (8%)
Leukemia | 1 (2%) | – | – | – | –
Lymphoma malignant | 8 (17%) | 5 (10%) | 7 (15%) | 5 (10%) | 6 (13%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 23 | 35 | 34 | 41 | 44
Total primary neoplasms | 33 | 43 | 50 | 80 | 128
Total animals with benign neoplasms | 10 | 26 | 27 | 35 | 42
Total benign neoplasms | 11 | 30 | 30 | 47 | 72
Total animals with malignant neoplasms | 15 | 13 | 19 | 25 | 37
Total malignant neoplasms | 22 | 13 | 20 | 33 | 56
Total animals with metastatic neoplasms | – | – | 1 | 1 | 8
Total metastatic neoplasms | – | – | 1 | 3 | 10

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table D-2 Statistical Analysis of Neoplasms in Female Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 0/45 (0%) | 0/45 (0%) | 0/47 (0%) | 1/47 (2%) | 0/43 (0%)
Adjusted rate^b^ | 0.0% | 0.0% | 0.0% | 2.4% | 0.0%
Terminal rate^c^ | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days)^d^ | – | – | – | 644 | –
Poly-3 test^e^ | P = 0.363 | – | – | P = 0.491 | –
Adrenal Medulla: Malignant Pheochromocytoma
Overall rate | 0/45 (0%) | 1/45 (2%) | 0/47 (0%) | 0/47 (0%) | 0/43 (0%)
Adjusted rate | 0.0% | 2.3% | 0.0% | 0.0% | 0.0%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days) | – | 733 (T) | – | – | –
Poly-3 test | P = 0.450N | P = 0.499 | – | – | –
Adrenal Medulla: Benign and Malignant Pheochromocytoma (Combined)
Overall rate | 0/45 (0%) | 1/45 (2%) | 0/47 (0%) | 1/47 (2%) | 0/43 (0%)
Adjusted rate | 0.0% | 2.3% | 0.0% | 2.4% | 0.0%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days) | – | 733 (T) | – | 644 | –
Poly-3 test | P = 0.567 | P = 0.499 | – | P = 0.491 | –
Harderian Gland: Adenoma
Overall rate | 2/45 (4%) | 19/47 (40%) | 20/47 (43%) | 24/46 (52%) | 40/46 (87%)
Adjusted rate | 4.5% | 41.2% | 44.0% | 54.9% | 93.4%
Terminal rate | 1/41 (2%) | 17/42 (41%) | 15/38 (40%) | 15/31 (48%) | 7/8 (88%)
First incidence (days) | 636 | 537 | 519 | 512 | 394
Poly-3 test | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001***
Harderian Gland: Bilateral Adenoma
Overall rate | 0/45 (0%) | 1/47 (2%) | 3/47 (6%) | 7/46 (15%) | 13/46 (28%)
Adjusted rate | 0.0% | 2.2% | 6.9% | 16.9% | 40.4%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 3/38 (8%) | 5/31 (16%) | 2/8 (25%)
First incidence (days) | – | 733 (T) | 733 (T) | 667 | 498
Poly-3 test | P < 0.001*** | P = 0.504 | P = 0.117 | P = 0.006** | P < 0.001***
Liver: Hepatocellular Adenoma
Overall rate | 4/47 (9%) | 2/48 (4%) | 4/47 (9%) | 2/46 (4%) | 0/43 (0%)
Adjusted rate | 8.8% | 4.4% | 9.1% | 4.9% | 0.0%
Terminal rate | 3/41 (7%) | 2/42 (5%) | 3/38 (8%) | 2/31 (7%) | 0/8 (0%)
First incidence (days) | 722 | 733 (T) | 541 | 733 (T) | –
Poly-3 test | P = 0.143N | P = 0.341N | P = 0.625 | P = 0.393N | P = 0.176N
Liver: Hepatocellular Carcinoma
Overall rate | 0/47 (0%) | 1/48 (2%) | 2/47 (4%) | 2/46 (4%) | 1/43 (2%)
Adjusted rate | 0.0% | 2.2% | 4.5% | 4.9% | 3.9%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 1/38 (3%) | 1/31 (3%) | 0/8 (0%)
First incidence (days) | – | 704 | 586 | 726 | 647
Poly-3 test | P = 0.184 | P = 0.499 | P = 0.230 | P = 0.212 | P = 0.391
Liver: Hepatocellular Adenoma and Carcinoma (Combined)
Overall rate | 4/47 (9%) | 3/48 (6%) | 6/47 (13%) | 4/46 (9%) | 1/43 (2%)
Adjusted rate | 8.8% | 6.6% | 13.4% | 9.9% | 3.9%
Terminal rate | 3/41 (7%) | 2/42 (5%) | 4/38 (11%) | 3/31 (10%) | 0/8 (0%)
First incidence (days) | 722 | 704 | 541 | 726 | 647
Poly-3 test | P = 0.406N | P = 0.503N | P = 0.356 | P = 0.577 | P = 0.395N
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 3/46 (7%) | 5/48 (10%) | 3/47 (6%) | 7/47 (15%) | 9/44 (21%)
Adjusted rate | 6.7% | 11.0% | 6.9% | 16.4% | 31.0%
Terminal rate | 2/41 (5%) | 5/42 (12%) | 3/38 (8%) | 2/31 (7%) | 1/8 (13%)
First incidence (days) | 722 | 733 (T) | 733 (T) | 512 | 498
Poly-3 test | P = 0.002** | P = 0.363 | P = 0.650 | P = 0.139 | P = 0.007**
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 1/46 (2%) | 1/48 (2%) | 0/47 (0%) | 1/47 (2%) | 2/44 (5%)
Adjusted rate | 2.2% | 2.2% | 0.0% | 2.4% | 7.6%
Terminal rate | 1/41 (2%) | 0/42 (0%) | 0/38 (0%) | 1/31 (3%) | 1/8 (13%)
First incidence (days) | 733 (T) | 540 | – | 733 (T) | 659
Poly-3 test | P = 0.166 | P = 0.755N | P = 0.505N | P = 0.744 | P = 0.328
Lung: Alveolar/Bronchiolar Adenoma and Carcinoma (Combined)
Overall rate | 4/46 (9%) | 6/48 (13%) | 3/47 (6%) | 8/47 (17%) | 11/44 (25%)
Adjusted rate | 8.9% | 13.1% | 6.9% | 18.7% | 37.5%
Terminal rate | 3/41 (7%) | 5/42 (12%) | 3/38 (8%) | 3/31 (10%) | 2/8 (25%)
First incidence (days) | 722 | 540 | 733 (T) | 512 | 498
Poly-3 test | P < 0.001*** | P = 0.385 | P = 0.514N | P = 0.155 | P = 0.003**
Mammary Gland: Adenoacanthoma
Overall rate | 0/45 (0%) | 0/48 (0%) | 0/47 (0%) | 1/47 (2%) | 8/45 (18%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.4% | 27.2%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 1/31 (3%) | 1/8 (13%)
First incidence (days) | – | – | – | 733 (T) | 498
Poly-3 test | P < 0.001*** | – | – | P = 0.489 | P < 0.001***
Mammary Gland: Adenocarcinoma
Overall rate | 1/45 (2%) | 1/48 (2%) | 2/47 (4%) | 9/47 (19%) | 11/45 (24%)
Adjusted rate | 2.3% | 2.2% | 4.6% | 21.4% | 36.8%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 2/38 (5%) | 5/31 (16%) | 2/8 (25%)
First incidence (days) | 688 | 733 (T) | 733 (T) | 622 | 477
Poly-3 test | P < 0.001*** | P = 0.755N | P = 0.496 | P = 0.006** | P < 0.001***
Mammary Gland: Adenoacanthoma and Adenocarcinoma (Combined)
Overall rate | 1/45 (2%) | 1/48 (2%) | 2/47 (4%) | 9/47 (19%) | 18/45 (40%)
Adjusted rate | 2.3% | 2.2% | 4.6% | 21.4% | 54.7%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 2/38 (5%) | 5/31 (16%) | 3/8 (38%)
First incidence (days) | 688 | 733 (T) | 733 (T) | 622 | 477
Poly-3 test | P < 0.001*** | P = 0.755N | P = 0.496 | P = 0.006** | P < 0.001***
Ovary: Benign Granulosa Cell Tumor
Overall rate | 0/45 (0%) | 0/47 (0%) | 0/47 (0%) | 1/46 (2%) | 2/44 (5%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.4% | 7.5%
Terminal rate | 0/41 (0%) | 0/41 (0%) | 0/38 (0%) | 0/31 (0%) | 1/8 (13%)
First incidence (days) | – | – | – | 674 | 576
Poly-3 test | P = 0.014* | – | – | P = 0.487 | P = 0.146
Skin: Fibrosarcoma
Overall rate | 0/45 (0%) | 1/48 (2%) | 2/47 (4%) | 2/47 (4%) | 9/45 (20%)
Adjusted rate | 0.0% | 2.2% | 4.6% | 4.7% | 30.4%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 1/38 (3%) | 0/31 (0%) | 1/8 (13%)
First incidence (days) | – | 733 (T) | 701 | 520 | 421
Poly-3 test | P < 0.001*** | P = 0.506 | P = 0.236 | P = 0.229 | P < 0.001***
Skin: Sarcoma
Overall rate | 0/45 (0%) | 0/48 (0%) | 1/47 (2%) | 3/47 (6%) | 3/45 (7%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 7.2% | 10.7%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 1/31 (3%) | 0/8 (0%)
First incidence (days) | – | – | 707 | 667 | 384
Poly-3 test | P = 0.004** | – | P = 0.499 | P = 0.110 | P = 0.059
Skin: Fibrosarcoma and Sarcoma (Combined)
Overall rate | 0/45 (0%) | 1/48 (2%) | 3/47 (6%) | 5/47 (11%) | 12/45 (27%)
Adjusted rate | 0.0% | 2.2% | 6.8% | 11.7% | 38.2%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 1/38 (3%) | 1/31 (3%) | 1/8 (13%)
First incidence (days) | – | 733 (T) | 701 | 520 | 384
Poly-3 test | P < 0.001*** | P = 0.506 | P = 0.118 | P = 0.028* | P < 0.001***
Skin: Squamous Cell Carcinoma
Overall rate | 0/45 (0%) | 0/48 (0%) | 0/47 (0%) | 1/47 (2%) | 0/45 (0%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.4% | 0.0%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 1/31 (3%) | 0/8 (0%)
First incidence (days) | – | – | – | 733 (T) | –
Poly-3 test | P = 0.365 | – | – | P = 0.489 | –
Skin: Squamous Cell Papilloma
Overall rate | 0/45 (0%) | 0/48 (0%) | 1/47 (2%) | 1/47 (2%) | 0/45 (0%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 2.4% | 0.0%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 1/38 (3%) | 1/31 (3%) | 0/8 (0%)
First incidence (days) | – | – | 733 (T) | 733 (T) | –
Poly-3 test | P = 0.431 | – | P = 0.499 | P = 0.489 | –
Skin: Squamous Cell Carcinoma and Papilloma (Combined)
Overall rate | 0/45 (0%) | 0/48 (0%) | 1/47 (2%) | 2/47 (4%) | 0/45 (0%)
Adjusted rate | 0.0% | 0.0% | 2.3% | 4.8% | 0.0%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 1/38 (3%) | 2/31 (7%) | 0/8 (0%)
First incidence (days) | – | – | 733 (T) | 733 (T) | –
Poly-3 test | P = 0.271 | – | P = 0.499 | P = 0.225 | –
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 1/45 (2%) | 1/45 (2%) | 1/47 (2%) | 5/45 (11%) | 9/44 (21%)
Adjusted rate | 2.3% | 2.3% | 2.3% | 12.2% | 30.7%
Terminal rate | 1/41 (2%) | 1/42 (2%) | 1/38 (3%) | 4/31 (13%) | 2/8 (25%)
First incidence (days) | 733 (T) | 733 (T) | 733 (T) | 379 | 384
Poly-3 test | P < 0.001*** | P = 0.759 | P = 0.759 | P = 0.086 | P < 0.001***
Uterus: Stromal Polyp
Overall rate | 1/45 (2%) | 1/48 (2%) | 0/47 (0%) | 3/47 (6%) | 4/45 (9%)
Adjusted rate | 2.3% | 2.2% | 0.0% | 7.1% | 15.0%
Terminal rate | 0/41 (0%) | 1/42 (2%) | 0/38 (0%) | 2/31 (7%) | 3/8 (38%)
First incidence (days) | 688 | 733 (T) | – | 520 | 645
Poly-3 test | P = 0.007** | P = 0.755N | P = 0.502N | P = 0.290 | P = 0.070
Uterus: Stromal Sarcoma
Overall rate | 0/45 (0%) | 0/48 (0%) | 0/47 (0%) | 0/47 (0%) | 2/45 (4%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 7.3%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days) | – | – | – | – | 520
Poly-3 test | P = 0.016* | – | – | – | P = 0.152
All Organs: Fibrous Histiocytoma
Overall rate | 1/47 (2%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%)
Adjusted rate | 2.2% | 0.0% | 0.0% | 2.4% | 0.0%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days) | 559 | – | – | 732 | –
Poly-3 test | P = 0.549N | P = 0.504N | P = 0.509N | P = 0.737 | P = 0.601N
All Organs: Hemangioma
Overall rate | 0/47 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.4% | 0.0%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 1/31 (3%) | 0/8 (0%)
First incidence (days) | – | – | – | 733 (T) | –
Poly-3 test | P = 0.357 | – | – | P = 0.482 | –
All Organs: Hemangiosarcoma
Overall rate | 1/47 (2%) | 0/48 (0%) | 1/48 (2%) | 2/48 (4%) | 2/48 (4%)
Adjusted rate | 2.2% | 0.0% | 2.2% | 4.8% | 7.2%
Terminal rate | 1/41 (2%) | 0/42 (0%) | 0/38 (0%) | 1/31 (3%) | 0/8 (0%)
First incidence (days) | 733 (T) | – | 586 | 621 | 477
Poly-3 test | P = 0.084 | P = 0.501N | P = 0.755 | P = 0.471 | P = 0.338
All Organs: Hemangioma or Hemangiosarcoma
Overall rate | 1/47 (2%) | 0/48 (0%) | 1/48 (2%) | 3/48 (6%) | 2/48 (4%)
Adjusted rate | 2.2% | 0.0% | 2.2% | 7.2% | 7.2%
Terminal rate | 1/41 (2%) | 0/42 (0%) | 0/38 (0%) | 2/31 (7%) | 0/8 (0%)
First incidence (days) | 733 (T) | – | 586 | 621 | 477
Poly-3 test | P = 0.056 | P = 0.501N | P = 0.755 | P = 0.276 | P = 0.338
All Organs: Histiocytic Sarcoma
Overall rate | 2/47 (4%) | 3/48 (6%) | 3/48 (6%) | 1/48 (2%) | 4/48 (8%)
Adjusted rate | 4.4% | 6.6% | 6.7% | 2.4% | 14.4%
Terminal rate | 1/41 (2%) | 2/42 (5%) | 2/38 (5%) | 0/31 (0%) | 1/8 (13%)
First incidence (days) | 708 | 698 | 519 | 644 | 639
Poly-3 test | P = 0.202 | P = 0.497 | P = 0.490 | P = 0.530N | P = 0.153
All Organs: Leukemia (Lymphocytic, Monocytic, Mononuclear, or Undifferentiated)
Overall rate | 1/47 (2%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%)
Adjusted rate | 2.2% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days) | 683 | – | – | – | –
Poly-3 test | P = 0.261N | P = 0.502N | P = 0.508N | P = 0.519N | P = 0.599N
All Organs: Malignant Lymphoma (Histiocytic, Lymphocytic, Mixed, NOS, or Undifferentiated Cell Type)
Overall rate | 8/47 (17%) | 5/48 (10%) | 7/48 (15%) | 5/48 (10%) | 6/48 (13%)
Adjusted rate | 17.5% | 11.0% | 15.6% | 12.0% | 20.3%
Terminal rate | 8/41 (20%) | 5/42 (12%) | 5/38 (13%) | 5/31 (16%) | 2/8 (25%)
First incidence (days) | 733 (T) | 733 (T) | 582 | 733 (T) | 282
Poly-3 test | P = 0.418 | P = 0.280N | P = 0.513N | P = 0.338N | P = 0.501
All Organs: Osteosarcoma
Overall rate | 0/47 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 3.6%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days) | – | – | – | – | 394
Poly-3 test | P = 0.107 | – | – | – | P = 0.406
All Organs: Osteosarcoma or Osteoma
Overall rate | 0/47 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 3.6%
Terminal rate | 0/41 (0%) | 0/42 (0%) | 0/38 (0%) | 0/31 (0%) | 0/8 (0%)
First incidence (days) | – | – | – | – | 394
Poly-3 test | P = 0.107 | – | – | – | P = 0.406
All Organs: Benign Tumors
Overall rate | 10/47 (21%) | 26/48 (54%) | 27/48 (56%) | 35/48 (73%) | 42/48 (88%)
Adjusted rate | 21.7% | 56.0% | 58.8% | 75.7% | 94.6%
Terminal rate | 7/41 (17%) | 24/42 (57%) | 22/38 (58%) | 22/31 (71%) | 7/8 (88%)
First incidence (days) | 636 | 537 | 519 | 379 | 384
Poly-3 test | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001***
All Organs: Malignant Tumors
Overall rate | 15/47 (32%) | 13/48 (27%) | 19/48 (40%) | 25/48 (52%) | 37/48 (77%)
Adjusted rate | 32.2% | 28.2% | 41.1% | 56.7% | 87.1%
Terminal rate | 11/41 (27%) | 10/42 (24%) | 12/38 (32%) | 14/31 (45%) | 6/8 (75%)
First incidence (days) | 559 | 540 | 519 | 520 | 282
Poly-3 test | P < 0.001*** | P = 0.425N | P = 0.251 | P = 0.014* | P < 0.001***
All Organs: Benign or Malignant Tumors
Overall rate | 23/47 (49%) | 35/48 (73%) | 34/48 (71%) | 41/48 (85%) | 44/48 (92%)
Adjusted rate | 48.9% | 74.0% | 71.7% | 87.2% | 96.2%
Terminal rate | 17/41 (42%) | 30/42 (71%) | 25/38 (66%) | 25/31 (81%) | 7/8 (88%)
First incidence (days) | 559 | 537 | 519 | 379 | 282
Poly-3 test | P < 0.001*** | P = 0.010** | P = 0.018* | P < 0.001*** | P < 0.001***

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at the terminal sacrifice.

^d^ T indicates terminal sacrifice.

^e^ Beneath the 0 mM Glycidamide are the p-values associated with the trend test. Beneath the treated groups incidences are the p-values corresponding to pairwise comparisons between the 0 mM Glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

Table D-3 Historical Incidence of Alveolar/Bronchiolar Neoplasms in NCTR Control Female B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Adenoma | Carcinoma | Adenoma or Carcinoma
Sulfamethazine (February 1988) | Diet | 5/182 (2.7%) | 1/182 (0.5%) | 6/182 (3.3%)
Doxylamine (April 1991) | Diet | 3/48 (6.3%) | 0/48 (0.0%) | 3/48 (6.3%)
Tripolidine (June 1991) | Diet | 3/47 (6.4%) | 2/47 (4.3%) | 5/47 (10.6%)
Pyrilamine (July 1991) | Diet | 1/48 (2.1%) | 0/48 (0.0%) | 1/48 (2.1%)
Fumonisin B_1_ (March 1999) | Diet | 2/47 (4.3%) | 0/47 (0.0%) | 2/47 (4.3%)
Malachite Green (June 2001) | Diet | 2/48 (4.2%) | 0/48 (0.0%) | 2/48 (4.2%)
Leucomalachite Green (June 2001) | Diet | 3/47 (6.4%) | 2/47 (4.3%) | 5/47 (10.6%)
Chloral Hydrate (July 2001) | Gavage | 8/143 (5.6%) | 0/143 (0.0%) | 8/143 (5.6%)
Urethane and Ethanol (May 2003) | Drinking Water | 4/48 (8.3%) | 2/48 (4.2%) | 6/48 (12.5%)
Acrylamide (February 2012) | Drinking Water | 1/47 (2.1%) | 1/47 (2.1%) | 2/47 (4.3%)
Aloe vera Whole Leaf (2013) | Drinking Water | 3/45 (6.7%) | 0/45 (0.0%) | 3/45 (6.7%)
Total (%) (All studies) | | 35/750 (4.7%) | 8/750 (1.1%) | 43/750 (5.7%)
Range | | 2.1–8.3% | 0.0–4.3% | 2.1–12.5%
Total (%) (Drinking water studies) | | 8/140 (5.7%) | 3/140 (2.1%) | 11/140 (7.9%)
Range | | 2.1–8.3% | 0–4.2% | 4.3–12.5%

Table D-4 Historical Incidence of Mammary Gland Neoplasms in NCTR Control Female B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Adenocarcinoma | Adenoacanthoma | Adenocarcinoma or Adenoacanthoma
Doxylamine (April 1991) | Diet | 4/47 (8.5%) | 0/47 (0.0%) | 4/47 (8.5%)
Tripolidine (June 1991) | Diet | 0/44 (0.0%) | 0/44 (0.0%) | 0/44 (0.0%)
Pyrilamine (July 1991) | Diet | 0/47 (0.0%) | 0/47 (0.0%) | 0/47 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 1/46 (2.2%) | 0/46 (0.0%) | 1/46 (2.2%)
Malachite Green (June 2001) | Diet | 2/46 (4.3%) | 0/46 (0.0%) | 2/46 (4.3%)
Leucomalachite Green (June 2001) | Diet | 1/46 (2.2%) | 2/46 (4.3%) | 3/46 (6.5%)
Chloral Hydrate (July 2001) | Gavage | 1/133 (0.8%) | 0/133 (0.0%) | 1/133 (0.8%)
Urethane and Ethanol (May 2003) | Drinking Water | 4/47 (8.5%) | 0/47 (0.0%) | 4/47 (8.5%)
Acrylamide (February 2012) | Drinking Water | 0/47 (0.0%) | 0/47 (0.0%) | 0/47 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 5/44 (11.4%) | 0/44 (0.0%) | 5/44 (11.4%)
Total (%) (All studies) | | 18/547 (3.3%) | 2/547 (0.4%) | 20/547 (3.7%)
Range | | 0.0–11.4% | 0.0–4.3% | 0.0–11.4%
Total (%) (Drinking water studies) | | 9/138 (6.5%) | 0/138 (0.0%) | 9/138 (6.5%)
Range | | 0.0–11.4% | 0.0% | 0.0–11.4%

Table D-5 Historical Incidence of Adenoma of the Harderian Gland in NCTR Control Female B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 13/182 (7.1%)
Doxylamine (April 1991) | Diet | 1/48 (2.1%)
Tripolidine (June 1991) | Diet | 2/47 (4.3%)
Fumonisin B_1_ (March 1999) | Diet | 4/46 (8.7%)
Malachite Green (June 2001) | Diet | 3/48 (6.3%)
Leucomalachite Green (June 2001) | Diet | 2/47 (4.3%)
Chloral Hydrate (July 2001) | Gavage | 4/140 (2.9%)
Urethane and Ethanol (May 2003) | Drinking Water | 3/48 (6.3%)
Acrylamide (February 2012) | Drinking Water | 0/45 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 3/43 (7.0%)
Total (%) (All studies) | | 35/694 (5.0%)
Range | | 0.0–8.7%
Total (%) (Drinking water studies) | | 6/136 (4.4%)
Range | | 0.0–7.0%

Table D-6 Historical Incidence of Mescenchymal Skin Tumors in NCTR Control Female B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 0/181 (0.0%)
Doxylamine (April 1991) | Diet | 1/48 (2.1%)
Tripolidine (June 1991) | Diet | 0/46 (0.0%)
Pyrilamine (July 1991) | Diet | 1/48 (2.1%)
Fumonisin B_1_ (March 1999) | Diet | 1/47 (2.1%)
Malachite Green (June 2001) | Diet | 0/48 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/46 (0.0%)
Chloral Hydrate (July 2001) | Gavage | 1/139 (0.7%)
Urethane and Ethanol (May 2003) | Drinking Water | 4/48 (8.3%)
Acrylamide (February 2012) | Drinking Water | 0/48 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 5/44 (11.4%)
Total (%) (All studies) | | 13/743 (1.7%)
Range | | 0.0–11.4%
Total (%) (All studies) | | 9/140 (6.4%)
Range | | 0.0–11.4%

Table D-7 Historical Incidence of Squamous Cell Papilloma or Carcinoma (Combined) of the Forestomach in NCTR Control Female B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 1/178 (0.6%)
Doxylamine (April 1991) | Diet | 0/47 (0.0%)
Tripolidine (June 1991) | Diet | 1/46 (2.2%)
Pyrilamine (July 1991) | Diet | 1/48 (2.1%)
Fumonisin B_1_ (March 1999) | Diet | 0/46 (0.0%)
Malachite Green (June 2001) | Diet | 2/47 (4.3%)
Leucomalachite Green (June 2001) | Diet | 0/46 (0.0%)
Chloral Hydrate (July 2001) | Gavage | 1/139 (0.7%)
Urethane and Ethanol (May 2003) | Drinking Water | 2/48 (4.2%)
Acrylamide (February 2012) | Drinking Water | 4/46 (8.7%)
Aloe vera Whole Leaf (2013) | Drinking Water | 0/43 (0.0%)
Total (%) (All studies) | | 12/734 (1.6%)
Range | | 0.0–8.7%
Total (%) (Drinking water studies) | | 6/137 (4.4%)
Range | | 0.0–8.7%

Table D-8 Historical Incidence of Granulosa Cell Tumors of the Ovary in NCTR Control Female B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Benign | Malignant | Benign or Malignant
Sulfamethazine (February 1988) | Diet | 0/177 (0.0%) | 1/177 (0.6%) | 1/177 (0.6%)
Doxylamine (April 1991) | Diet | 0/47 (0.0%) | 0/47 (0.0%) | 0/47 (0.0%)
Tripolidine (June 1991) | Diet | 0/45 (0.0%) | 0/45 (0.0%) | 0/45 (0.0%)
Pyrilamine (July 1991) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 0/46 (0.0%) | 0/46 (0.0%) | 0/46 (0.0%)
Malachite Green (June 2001) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/46 (0.0%) | 0/46 (0.0%) | 0/46 (0.0%)
Chloral Hydrate (July 2001) | Gavage | 1/141 (0.7%) | 0/141 (0.0%) | 1/141 (0.7%)
Urethane and Ethanol (May 2003) | Drinking Water | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Acrylamide (February 2012) | Drinking Water | 0/46 (0.0%) | 0/46 (0.0%) | 0/46 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 0/44 (0.0%) | 0/44 (0.0%) | 0/44 (0.0%)
Total (%) (All studies) | | 1/736 (0.1%) | 1/736 (0.1%) | 2/736 (0.3%)
Range | | 0.0–0.7% | 0.0–0.6% | 0.0–0.7%
Total (%) (Drinking water studies) | | 0/138 (0.0%) | 0/138 (0.0%) | 0/138 (0.0%)
Range | | 0.0% | 0.0% | 0.0%

Table D-9 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | 2 | 2 | 6 | 7 | 32
Natural death | 1 | 2 | 2 | 4 | 6
Survivors
Moribund sacrifice | 2 | – | 2 | 5 | 2
Natural death | 2 | 2 | – | 1 | –
Terminal sacrifice | 41 | 42 | 38 | 31 | 8
Animals examined microscopically | 47 | 48 | 48 | 48 | 48
Alimentary System
Esophagus | (46) | (48) | (46) | (47) | (45)
Gallbladder | (45) | (44) | (47) | (44) | (41)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | – | –
Intestine large, cecum | (45) | (44) | (46) | (45) | (42)
Hyperplasia, lymphoid | 2 (4%) | – | – | 4 (9%) | 1 (2%)
Intestine large, colon | (45) | (45) | (47) | (45) | (43)
Intestine large, rectum | (45) | (45) | (46) | (45) | (43)
Intestine small, duodenum | (45) | (44) | (46) | (45) | (42)
Hyperplasia, lymphoid | – | – | – | – | 1 (2%)
Intestine small, ileum | (45) | (44) | (46) | (45) | (42)
Hyperplasia, lymphoid | – | – | – | 1 (2%) | –
Inflammation, suppurative | – | 1 (2%) | – | – | –
Ulcer | – | 1 (2%) | – | – | –
Intestine small, jejunum | (45) | (44) | (46) | (45) | (42)
Hyperplasia, lymphoid | – | 1 (2%) | 1 (2%) | 1 (2%) | –
Liver | (47) | (48) | (47) | (46) | (43)
Angiectasis | – | – | 1 (2%) | – | 5 (12%)
Basophilic focus | 2 (4%) | – | 3 (6%) | 1 (2%) | 4 (9%)
Cyst | 3 (6%) | – | – | 1 (2%) | 1 (2%)
Eosinophilic focus | – | 2 (4%) | – | – | –
Eosinophilic focus, multiple | – | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 6 (13%) | 11 (23%) | 3 (6%) | 5 (11%) | 6 (14%)
Hemorrhage | 1 (2%) | – | – | – | –
Infiltration cellular, lymphocyte | 4 (9%) | 3 (6%) | 3 (6%) | 4 (9%) | 2 (5%)
Inflammation, chronic active | 1 (2%) | – | – | 5 (11%) | 1 (2%)
Necrosis | – | – | – | – | 5 (12%)
Tension lipidosis | – | – | – | – | 1 (2%)
Vacuolization cytoplasmic | 1 (2%) | 1 (2%) | 1 (2%) | 3 (7%) | 3 (7%)
Centrilobular, degeneration | – | – | – | – | 1 (2%)
Pancreas | (45) | (48) | (47) | (46) | (44)
Infiltration cellular, lymphocyte | 9 (20%) | 10 (21%) | 10 (21%) | 9 (20%) | 3 (7%)
Necrosis | – | – | – | – | 2 (5%)
Acinus, degeneration | 2 (4%) | 6 (13%) | 3 (6%) | – | 2 (5%)
Duct, dilatation | – | 2 (4%) | – | – | –
Salivary glands | (45) | (47) | (47) | (47) | (44)
Infiltration cellular, lymphocyte | 29 (64%) | 30 (64%) | 28 (60%) | 28 (60%) | 8 (18%)
Stomach, forestomach | (45) | (45) | (47) | (45) | (44)
Cyst epithelial inclusion | – | 1 (2%) | – | – | –
Ulcer | 1 (2%) | – | 1 (2%) | 1 (2%) | 1 (2%)
Epithelium, hyperplasia | 4 (9%) | 4 (9%) | 10 (21%) | 11 (24%) | 5 (11%)
Stomach, glandular | (45) | (45) | (47) | (45) | (43)
Epithelium, hyperplasia | – | – | – | 1 (2%) | –
Cardiovascular System
Blood vessel | (46) | (48) | (47) | (47) | (45)
Heart | (46) | (48) | (47) | (47) | (45)
Cardiomyopathy | – | 1 (2%) | – | – | 1 (2%)
Inflammation, chronic | – | 1 (2%) | – | – | –
Pericardium, inflammation, chronic active | – | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (45) | (48) | (47) | (47) | (44)
Accessory adrenal cortical nodule | – | – | – | 2 (4%) | –
Angiectasis | – | – | – | 1 (2%) | –
Cyst | – | – | – | – | 1 (2%)
Hypertrophy | – | 1 (2%) | 1 (2%) | – | –
Subcapsular, hyperplasia | 45 (100%) | 48 (100%) | 47 (100%) | 46 (98%) | 43 (98%)
Adrenal medulla | (45) | (45) | (47) | (47) | (43)
Islets, pancreatic | (45) | (48) | (47) | (46) | (43)
Hyperplasia | – | 2 (4%) | 3 (6%) | 2 (4%) | –
Parathyroid gland | (41) | (45) | (46) | (40) | (39)
Cyst | 4 (10%) | – | 2 (4%) | 2 (5%) | 2 (5%)
Hyperplasia | – | – | – | – | 1 (3%)
Inflammation, chronic active | – | – | 1 (2%) | – | –
Pituitary gland | (45) | (45) | (43) | (47) | (43)
Pars distalis, cyst | – | 1 (2%) | 1 (2%) | – | –
Pars distalis, hyperplasia | 3 (7%) | – | 2 (5%) | 1 (2%) | 3 (7%)
Thyroid gland | (45) | (47) | (46) | (46) | (44)
Cyst | 1 (2%) | 1 (2%) | – | – | –
Ectopic thymus | 1 (2%) | 2 (4%) | 3 (7%) | 1 (2%) | 1 (2%)
Infiltration cellular, lymphocyte | 1 (2%) | 3 (6%) | – | – | –
Inflammation, chronic active | – | 1 (2%) | – | 1 (2%) | –
Follicle, degeneration | 3 (7%) | 5 (11%) | 7 (15%) | 6 (13%) | 3 (7%)
General Body System
Tissue NOS | (0) | (0) | (0) | (0) | (1)
Genital System
Clitoral Gland | (44) | (48) | (47) | (47) | (41)
Degeneration | 43 (98%) | 48 (100%) | 47 (100%) | 47 (100%) | 36 (88%)
Inflammation, suppurative | 1 (2%) | – | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | – | 1 (2%)
Ovary | (45) | (47) | (47) | (46) | (44)
Angiectasis | 1 (2%) | – | – | 4 (9%) | 1 (2%)
Atrophy | 44 (98%) | 42 (89%) | 46 (98%) | 39 (85%) | 31 (70%)
Cyst | 14 (31%) | 16 (34%) | 23 (49%) | 21 (46%) | 15 (34%)
Hematocyst | – | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | 1 (2%) | 3 (6%) | 2 (4%) | 3 (7%)
Hyperplasia, tubulostromal | – | – | – | – | 1 (2%)
Inflammation, chronic | 1 (2%) | – | – | – | –
Mineralization | 1 (2%) | – | – | – | 1 (2%)
Thrombosis | 1 (2%) | – | 1 (2%) | 1 (2%) | 1 (2%)
Bilateral, cyst | – | 1 (2%) | 2 (4%) | 1 (2%) | 3 (7%)
Uterus | (45) | (48) | (47) | (47) | (45)
Angiectasis | 1 (2%) | 2 (4%) | – | 2 (4%) | 2 (4%)
Fibrosis | – | 1 (2%) | – | – | –
Hemorrhage | – | – | – | 1 (2%) | 1 (2%)
Hydrometra | 1 (2%) | 1 (2%) | – | – | –
Inflammation, suppurative | – | – | 1 (2%) | – | –
Necrosis | – | – | – | – | 1 (2%)
Thrombus | – | 1 (2%) | – | – | 2 (4%)
Endometrium, hyperplasia, cystic | 44 (98%) | 45 (94%) | 47 (100%) | 45 (96%) | 36 (80%)
Endometrium, hyperplasia, glandular, focal | – | – | 1 (2%) | – | –
Vagina | (0) | (0) | (0) | (0) | (1)
Hematopoietic System
Bone marrow | (46) | (47) | (47) | (45) | (43)
Hyperplasia | – | 2 (4%) | 5 (11%) | 6 (13%) | 20 (47%)
Lymph node | (8) | (2) | (5) | (8) | (12)
Lumbar, hyperplasia, lymphoid | 1 (13%) | – | – | 1 (13%) | 2 (17%)
Lumbar, infiltration cellular, histiocyte | – | – | – | – | 1 (8%)
Lumbar, infiltration cellular, plasma cell | – | – | – | – | 1 (8%)
Lumbar, infiltration cellular, polymorphonuclear | – | – | – | 1 (13%) | 1 (8%)
Mediastinal, angiectasis | – | – | – | – | 1 (8%)
Mediastinal, hyperplasia, lymphoid | 1 (13%) | – | 2 (40%) | – | –
Pancreatic, hyperplasia, lymphoid | – | – | – | 1 (13%) | –
Renal, hyperplasia, lymphoid | – | – | – | – | 1 (8%)
Renal, infiltration cellular, plasma cell | – | – | – | – | 1 (8%)
Renal, infiltration cellular, polymorphonuclear | – | 1 (50%) | – | – | 1 (8%)
Lymph node, mandibular | (46) | (48) | (47) | (47) | (43)
Erythrophagocytosis | – | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | – | – | – | –
Hyperplasia, lymphoid | 13 (28%) | 10 (21%) | 8 (17%) | 8 (17%) | –
Infiltration cellular, plasma cell | 3 (7%) | 1 (2%) | 4 (9%) | – | 1 (2%)
Infiltration cellular, polymorphonuclear | 1 (2%) | 2 (4%) | – | – | 1 (2%)
Sinus, dilatation | – | – | – | – | 1 (2%)
Lymph node, mesenteric | (43) | (46) | (46) | (47) | (43)
Angiectasis | – | 2 (4%) | – | 2 (4%) | –
Hemorrhage | – | – | – | – | 1 (2%)
Hyperplasia, lymphoid | 14 (33%) | 7 (15%) | 9 (20%) | 14 (30%) | 5 (12%)
Infiltration cellular, histiocyte | 1 (2%) | – | 1 (2%) | 2 (4%) | –
Infiltration cellular, mast cell | – | – | 1 (2%) | – | –
Infiltration cellular, plasma cell | 2 (5%) | 1 (2%) | – | – | –
Infiltration cellular, polymorphonuclear | – | 1 (2%) | – | – | –
Thrombosis | – | – | – | – | 1 (2%)
Sinus, dilatation | 1 (2%) | – | – | – | –
Spleen | (46) | (47) | (47) | (47) | (45)
Accessory spleen | – | – | 1 (2%) | – | –
Depletion lymphoid | – | – | – | – | 1 (2%)
Hematopoietic cell proliferation | 6 (13%) | 10 (21%) | 11 (23%) | 14 (30%) | 29 (64%)
Hemorrhage | – | – | 1 (2%) | – | –
Hyperplasia, lymphoid | 35 (76%) | 33 (70%) | 35 (74%) | 29 (62%) | 12 (27%)
Necrosis | 1 (2%) | – | – | – | –
Pigmentation | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%) | –
Thymus | (43) | (44) | (45) | (43) | (37)
Angiectasis | 1 (2%) | – | – | – | –
Atrophy | 16 (37%) | 11 (25%) | 15 (33%) | 13 (30%) | 18 (49%)
Hyperplasia, lymphoid | 7 (16%) | 5 (11%) | 9 (20%) | 5 (12%) | 1 (3%)
Mineralization | – | 1 (2%) | 1 (2%) | – | –
Integumentary System
Mammary gland | (45) | (48) | (47) | (47) | (45)
Alveolus, hyperplasia | 1 (2%) | – | – | 2 (4%) | –
Skin | (45) | (48) | (47) | (47) | (45)
Fibrosis | – | – | – | 2 (4%) | –
Inflammation, chronic active | – | – | – | 1 (2%) | –
Musculoskeletal System
Bone | (0) | (0) | (1) | (2) | (1)
Joint, ligament, degeneration | – | – | 1 (100%) | – | –
Bone, femur | (46) | (48) | (48) | (48) | (48)
Callus | – | – | – | – | 1 (2%)
Fibro-osseous lesion | 1 (2%) | – | – | 1 (2%) | –
Skeletal muscle | (46) | (48) | (47) | (47) | (45)
Atrophy | – | – | – | – | 1 (2%)
Nervous System
Brain, brain stem | (45) | (47) | (47) | (45) | (44)
Brain, cerebellum | (45) | (47) | (47) | (45) | (44)
Hemorrhage | – | – | – | – | 1 (2%)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | – | 1 (2%)
Brain, cerebrum | (45) | (47) | (47) | (45) | (44)
Compression | – | – | – | 1 (2%)
Hemorrhage | – | – | – | – | 1 (2%)
Infarct, focal, chronic | – | – | – | – | 1 (2%)
Infiltration cellular, lymphocyte | 3 (7%) | 1 (2%) | – | – | –
Mineralization | 31 (69%) | 36 (77%) | 28 (60%) | 25 (56%) | 22 (50%)
Hippocampus, neuron, depletion | – | – | 1 (2%) | – | –
Peripheral nerve, sciatic | (45) | (47) | (47) | (45) | (44)
Inflammation, acute | – | – | 1 (2%) | – | –
Axon, degeneration | 39 (87%) | 38 (81%) | 38 (81%) | 34 (76%) | 28 (64%)
Spinal cord, cervical | (45) | (44) | (47) | (45) | (43)
Infiltration cellular, lymphocyte | 3 (7%) | – | 1 (2%) | 1 (2%) | –
Axon, degeneration | 4 (9%) | 9 (20%) | 10 (21%) | 9 (20%) | 10 (23%)
Nerve, degeneration | – | – | – | – | 1 (2%)
Spinal cord, lumbar | (45) | (45) | (47) | (45) | (43)
Cyst | – | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | 6 (13%) | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Axon, degeneration | 12 (27%) | 13 (29%) | 13 (28%) | 15 (33%) | 4 (9%)
Nerve, degeneration | 43 (96%) | 43 (96%) | 40 (85%) | 40 (89%) | 24 (56%)
Spinal cord, thoracic | (45) | (44) | (47) | (45) | (43)
Infiltration cellular, lymphocyte | 3 (7%) | – | 1 (2%) | 1 (2%) | –
Axon, degeneration | 35 (78%) | 32 (73%) | 34 (72%) | 34 (76%) | 23 (53%)
Nerve, degeneration | – | 1 (2%) | – | 1 (2%) | –
Respiratory System
Lung | (46) | (48) | (47) | (47) | (44)
Congestion | – | 1 (2%) | – | – | –
Hemorrhage | 2 (4%) | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | – | – | 1 (2%) | 2 (4%) | 3 (7%)
Infiltration cellular, lymphocyte | 1 (2%) | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Inflammation, chronic active | 3 (7%) | 2 (4%) | 1 (2%) | – | –
Alveolar epithelium, hyperplasia | – | 1 (2%) | 2 (4%) | 4 (9%) | 3 (7%)
Nose | (46) | (46) | (47) | (46) | (45)
Amyloid deposition | – | – | 1 (2%) | – | –
Crystals | – | – | 2 (4%) | – | 1 (2%)
Hyaline droplet | 9 (20%) | 3 (7%) | 15 (32%) | 4 (9%) | –
Inflammation, suppurative | – | 1 (2%) | – | – | 1 (2%)
Trachea | (45) | (47) | (46) | (46) | (43)
Atrophy | – | – | – | 1 (2%) | –
Special Senses System
Eye | (45) | (44) | (47) | (44) | (43)
Cataract | 1 (2%) | 2 (5%) | 8 (17%) | 8 (18%) | 9 (21%)
Inflammation, chronic active | – | 1 (2%) | – | – | –
Phthisis bulbi | – | 1 (2%) | – | 1 (2%) | 2 (5%)
Cornea, fibrosis | – | – | – | – | 1 (2%)
Cornea, inflammation, chronic active | – | 2 (5%) | 1 (2%) | 3 (7%) | 5 (12%)
Cornea, ulcer | – | – | – | – | 1 (2%)
Harderian gland | (45) | (47) | (47) | (46) | (46)
Degeneration, cystic | – | – | – | 1 (2%) | –
Fibrosis | – | – | 1 (2%) | 1 (2%) | –
Infiltration cellular, lymphocyte | 3 (7%) | 5 (11%) | 1 (2%) | 2 (4%) | –
Epithelium, hyperplasia | – | 1 (2%) | – | 1 (2%) | –
Urinary System
Kidney | (46) | (47) | (47) | (46) | (43)
Cyst | – | – | – | – | 1 (2%)
Hyaline droplet | – | 1 (2%) | 1 (2%) | – | 3 (7%)
Hydronephrosis | – | – | 1 (2%) | – | 1 (2%)
Infarct | – | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | 23 (50%) | 26 (55%) | 28 (60%) | 19 (41%) | 13 (30%)
Inflammation, chronic | – | – | 1 (2%) | – | –
Metaplasia, osseous | 2 (4%) | 1 (2%) | – | – | –
Nephropathy | 2 (4%) | 2 (4%) | 3 (6%) | 5 (11%) | 5 (12%)
Glomerulus, amyloid deposition | 1 (2%) | – | – | 1 (2%) | –
Urinary bladder | (45) | (46) | (47) | (46) | (42)
Infiltration cellular, lymphocyte | 31 (69%) | 28 (61%) | 34 (72%) | 22 (48%) | 18 (43%)
Lumen, dilatation | – | – | – | 2 (4%) | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.