# Appendix C Summary of Lesions in Male Mice in the Two-year Drinking Water Study of Glycidamide

Table C-1 Summary of the Incidence of Neoplasms in Male Mice in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | – | 4 | 11 | 16 | 11
Natural deaths | 1 | 3 | 2 | 3 | 9
Survivors
Moribund sacrifice | 2 | – | 1 | 2 | 2
Natural deaths | – | – | – | 1 | 1
Terminal sacrifice | 45 | 41 | 34 | 26 | 25
Animals examined microscopically | 48 | 48 | 48 | 48 | –
Alimentary System
Esophagus | (47) | (48) | (47) | (47) | (46)
Gallbladder | (46) | (45) | (46) | (45) | (39)
Lymphoma malignant | – | 1 (2%) | – | – | –
Intestine large, cecum | (47) | (45) | (46) | (44) | (39)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Intestine large, colon | (47) | (45) | (47) | (45) | (39)
Intestine large, rectum | (47) | (45) | (47) | (45) | (39)
Intestine small, duodenum | (47) | (45) | (46) | (44) | (39)
Adenoma | – | – | – | 1 (2%) | –
Lymphoma malignant | – | – | – | 1 (2%) | 1 (3%)
Intestine small, ileum | (47) | (45) | (46) | (44) | (39)
Lymphoma malignant | 2 (4%) | – | – | – | 1 (3%)
Intestine small, jejunum | (47) | (45) | (46) | (44) | (39)
Lymphoma malignant | 1 (2%) | – | 1 (2%) | 1 (2%) | –
Liver | (47) | (47) | (47) | (47) | (48)
Hemangiosarcoma | – | – | 1 (2%) | – | –
Hepatocellular adenoma | 9 (19%) | 1 (2%) | 8 (17%) | 8 (17%) | 10 (21%)
Hepatocellular adenoma, multiple | 1 (2%) | – | – | 4 (9%) | 1 (2%)
Hepatocellular carcinoma | 5 (11%) | 9 (19%) | 6 (13%) | 7 (15%) | 9 (19%)
Hepatocellular carcinoma, multiple | – | 1 (2%) | 1 (2%) | 2 (4%) | 2 (4%)
Hepatocholangiocarcinoma | – | – | – | 1 (2%) | 2 (4%)
Histiocytic sarcoma | 1 (2%) | – | 1 (2%) | 3 (6%) | 2 (4%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | 1 (2%) | – | 2 (4%) | 3 (6%)
Mesentery | (2) | (1) | (0) | (1) | (1)
Fibrous histiocytoma | 1 (50%) | – | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (100%)
Oral mucosa | (0) | (1) | (0) | (0) | (2)
Squamous cell carcinoma | – | – | – | – | 1 (50%)
Squamous cell papilloma | – | – | – | – | 1 (50%)
Pancreas | (47) | (46) | (47) | (47) | (45)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Histiocytic sarcoma | 1 (2%) | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | 1 (2%) | – | 1 (2%) | –
Salivary glands | (47) | (47) | (47) | (46) | (44)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | 1 (2%) | – | – | –
Stomach, forestomach | (47) | (45) | (48) | (45) | (41)
Squamous cell carcinoma | – | – | – | – | 2 (5%)
Squamous cell papilloma | – | 2 (4%) | 3 (6%) | 1 (2%) | 9 (22%)
Squamous cell papilloma, multiple | – | – | – | 1 (2%) | 1 (2%)
Stomach, glandular | (47) | (45) | (46) | (44) | (38)
Tongue | (0) | (0) | (0) | (1) | (0)
Squamous cell carcinoma | – | – | – | 1 (100%) | –
Cardiovascular System
Blood vessel | (47) | (48) | (47) | (47) | (47)
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (2%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | – | 3 (6%)
Heart | (47) | (48) | (47) | (47) | (46)
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (2%)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | 1 (2%) | 2 (4%)
Endocrine System
Adrenal cortex | (47) | (47) | (47) | (45) | (44)
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (2%)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | 1 (2%) | 2 (5%)
Adrenal medulla | (47) | (46) | (47) | (45) | (43)
Leukemia | – | – | – | – | 1 (2%)
Pheochromocytoma benign | 1 (2%) | 1 (2%) | – | – | 1 (2%)
Islets, pancreatic | (47) | (47) | (47) | (47) | (44)
Adenoma | – | – | – | – | 1 (2%)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Lymphoma malignant | – | 1 (2%) | – | – | –
Parathyroid gland | (43) | (48) | (43) | (42) | (42)
Pituitary gland | (45) | (44) | (47) | (42) | (42)
Lymphoma malignant | – | – | – | 1 (2%) | –
Pars distalis, carcinoma | – | – | – | 1 (2%) | –
Thyroid gland | (47) | (48) | (47) | (44) | (43)
Lymphoma malignant | – | 1 (2%) | – | – | –
Follicular cell, carcinoma | – | – | 1 (2%) | – | –
General Body System
Tissue NOS | (0) | (0) | (0) | (1) | (1)
Histiocytic sarcoma | – | – | – | 1 (100%) | –
Thoracic, hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (100%)
Genital System
Epididymis | (47) | (47) | (47) | (46) | (43)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Penis | (0) | (0) | (1) | (0) | (0)
Preputial gland | (47) | (47) | (46) | (46) | (44)
Hemangioma | – | – | 1 (2%) | – | –
Leukemia | – | – | – | – | 1 (2%)
Squamous cell carcinoma | – | – | – | 1 (2%) | –
Prostate | (47) | (47) | (47) | (45) | (41)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | – | 1 (2%)
Seminal vesicle | (47) | (46) | (47) | (45) | (41)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Testes | (47) | (46) | (46) | (46) | (42)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Hematopoietic System
Bone marrow | (47) | (47) | (47) | (46) | (44)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | – | 1 (2%)
Lymph node | (4) | (5) | (2) | (6) | (6)
Axillary, fibrous histiocytoma | 1 (25%) | – | – | – | –
Axillary, lymphoma malignant | – | – | – | – | 1 (17%)
Inguinal, fibrous histiocytoma | 1 (25%) | – | – | – | –
Inguinal, lymphoma malignant | – | 1 (20%) | – | – | 1 (17%)
Lumbar, fibrous histiocytoma | 1 (25%) | – | – | – | –
Lumbar, lymphoma malignant | 1 (25%) | 1 (20%) | – | 1 (17%) | –
Mediastinal, fibrous histiocytoma | 1 (25%) | – | – | – | –
Mediastinal, lymphoma malignant | 1 (25%) | 1 (20%) | – | 1 (17%) | 1 (17%)
Pancreatic, lymphoma malignant | – | – | – | 1 (17%) | 1 (17%)
Renal, histiocytic sarcoma | 1 (25%) | – | – | 1 (17%) | –
Renal, lymphoma malignant | 1 (25%) | 2 (40%) | – | 1 (17%) | 1 (17%)
Lymph node, mandibular | (47) | (47) | (47) | (45) | (43)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Histiocytic sarcoma | 1 (2%) | – | – | – | –
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | 1 (2%) | 1 (2%) | – | 1 (2%) | 2 (5%)
Lymph node, mesenteric | (47) | (46) | (47) | (45) | (42)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Histiocytic sarcoma | 1 (2%) | – | 1 (2%) | 2 (4%) | 1 (2%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | 2 (4%) | 3 (7%) | 2 (4%) | 4 (9%) | 6 (14%)
Spleen | (47) | (47) | (47) | (46) | (44)
Basosquamous tumor malignant, metastatic, skin | – | – | – | – | 1 (2%)
Hemangiosarcoma | 2 (4%) | – | 1 (2%) | 1 (2%) | 2 (5%)
Histiocytic sarcoma | 1 (2%) | – | 1 (2%) | 2 (4%) | 1 (2%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | 1 (2%) | 4 (9%) | 2 (4%) | 4 (9%) | 6 (14%)
Thymus | (43) | (45) | (43) | (39) | (34)
Histiocytic sarcoma | 1 (2%) | – | – | – | –
Lymphoma malignant | 1 (2%) | 3 (7%) | – | 1 (3%) | 5 (15%)
Integumentary System
Mammary gland | (3) | (1) | (0) | (2) | (1)
Skin | (47) | (48) | (47) | (47) | (46)
Basosquamous tumor malignant | – | – | – | – | 2 (4%)
Fibroma | – | 1 (2%) | – | – | –
Fibroma, multiple | – | – | 1 (2%) | – | –
Keratoacanthoma | – | – | – | – | 1 (2%)
Squamous cell carcinoma | – | – | – | – | 2 (4%)
Squamous cell papilloma | – | 1 (2%) | 2 (4%) | 1 (2%) | 8 (17%)
Subcutaneous tissue, fibrosarcoma | 2 (4%) | – | 4 (9%) | 2 (4%) | 3 (7%)
Subcutaneous tissue, fibrous histiocytoma | 1 (2%) | 2 (4%) | – | – | 1 (2%)
Subcutaneous tissue, hemangiosarcoma | – | 1 (2%) | – | – | 1 (2%)
Subcutaneous tissue, sarcoma | – | 1 (2%) | – | 2 (4%) | –
Subcutaneous tissue, schwannoma malignant | – | 1 (2%) | 4 (9%) | 3 (6%) | –
Musculoskeletal System
Bone, femur | (48) | (48) | (48) | (48) | (47)
Skeletal muscle | (48) | (47) | (47) | (47) | (47)
Hemangiosarcoma | 1 (2%) | – | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (2%)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Sarcoma | – | – | – | 1 (2%) | –
Nervous System
Brain, brain stem | (47) | (47) | (46) | (46) | (42)
Leukemia | – | – | – | – | 1 (2%)
Brain, cerebellum | (47) | (47) | (46) | (46) | (42)
Leukemia | – | – | – | – | 1 (2%)
Brain, cerebrum | (47) | (47) | (46) | (46) | (42)
Leukemia | – | – | – | – | 1 (2%)
Peripheral nerve, sciatic | (47) | (47) | (47) | (46) | (42)
Schwannoma malignant, metastatic, skin | – | – | 1 (2%) | – | –
Spinal cord, cervical | (47) | (46) | (46) | (44) | (39)
Leukemia | – | – | – | – | 1 (3%)
Spinal cord, lumbar | (47) | (46) | (46) | (45) | (39)
Leukemia | – | – | – | – | 1 (3%)
Spinal cord, thoracic | (47) | (46) | (46) | (45) | (39)
Leukemia | – | – | – | – | 1 (3%)
Respiratory System
Lung | (47) | (46) | (47) | (47) | (47)
Adenocarcinoma, metastatic, harderian gland | – | – | – | – | 1 (2%)
Alveolar/bronchiolar adenoma | – | 6 (13%) | 5 (11%) | 8 (17%) | 13 (28%)
Alveolar/bronchiolar adenoma, multiple | – | 1 (2%) | 2 (4%) | 5 (11%) | 4 (9%)
Alveolar/bronchiolar carcinoma | – | – | 1 (2%) | – | 2 (4%)
Basosquamous tumor malignant, metastatic, skin | – | – | – | – | 1 (2%)
Fibrosarcoma, metastatic, skin | – | – | 1 (2%) | – | –
Hepatocellular carcinoma, metastatic, liver | 1 (2%) | – | 1 (2%) | 1 (2%) | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | 1 (2%) | 1 (2%)
Histiocytic sarcoma | – | – | 1 (2%) | 3 (6%) | 1 (2%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | 1 (2%) | 2 (4%) | – | 1 (2%) | 3 (6%)
Sarcoma, metastatic, skeletal muscle | – | – | – | 1 (2%) | –
Nose | (47) | (46) | (47) | (47) | (45)
Fibrous histiocytoma | 1 (2%) | – | – | – | –
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (2%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | – | 1 (2%)
Trachea | (47) | (48) | (46) | (46) | (45)
Special Senses System
Eye | (47) | (45) | (46) | (44) | (42)
Harderian gland | (47) | (47) | (47) | (46) | (47)
Adenocarcinoma | – | – | – | – | 1 (2%)
Adenoma | 3 (6%) | 15 (32%) | 19 (40%) | 17 (37%) | 11 (23%)
Leukemia | – | – | – | – | 1 (2%)
Bilateral, adenoma | – | 2 (4%) | 4 (9%) | 15 (33%) | 31 (66%)
Zymbal’s gland | (0) | (0) | (0) | (0) | (1)
Urinary System
Kidney | (47) | (47) | (47) | (46) | (46)
Hepatocholangiocarcinoma, metastatic, liver | – | – | – | – | 1 (2%)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | 1 (2%) | – | 1 (2%) | 2 (4%)
Renal tubule, adenoma | – | – | – | – | 1 (2%)
Renal tubule, carcinoma | – | – | – | – | 2 (4%)
Urinary bladder | (47) | (46) | (47) | (45) | (41)
Hemangioma | – | – | – | – | 1 (2%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | – | – | – | – | 1 (2%)
Transitional epithelium, papilloma | – | – | – | – | 1 (2%)
Systemic Lesions
Multiple organs | (48)^b^ | (48)^b^ | (48)^b^ | (48)^b^ | (48)^b^
Histiocytic sarcoma | 1 (2%) | – | 1 (2%) | 3 (6%) | 3 (6%)
Leukemia | – | – | – | – | 1 (2%)
Lymphoma malignant | 2 (4%) | 4 (8%) | 2 (4%) | 4 (8%) | 7 (15%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 23 | 35 | 41 | 46 | 47
Total primary neoplasms | 38 | 49 | 67 | 90 | 138
Total animals with benign neoplasms | 14 | 23 | 34 | 40 | 43
Total benign neoplasms | 14 | 30 | 45 | 61 | 95
Total animals with malignant neoplasms | 13 | 17 | 21 | 27 | 33
Total malignant neoplasms | 24 | 19 | 22 | 29 | 43
Total animals with metastatic neoplasms | 1 | – | 3 | 3 | 3
Total metastatic neoplasms | 1 | – | 3 | 3 | 12

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table C-2 Statistical Analysis of Neoplasms in Male Mice in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Harderian Gland: Adenoma
Overall rate^a^ | 3/47 (6%) | 17/47 (36%) | 23/47 (49%) | 32/46 (70%) | 42/47 (89%)
Adjusted rate^b^ | 6.4% | 38.3% | 52.1% | 77.3% | 93.4%
Terminal rate^c^ | 3/45 (7%) | 17/41 (42%) | 16/34 (47%) | 20/26 (77%) | 25/25 (100%)
First incidence (days)^d^ | 733 (T) | 726 (T) | 558 | 559 | 530
Poly-3 test^e^ | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001***
Harderian Gland: Adenocarcinoma
Overall rate | 0/47 (0%) | 0/47 (0%) | 0/47 (0%) | 0/46 (0%) | 1/47 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 2.6%
Terminal rate | 0/45 (0%) | 0/41 (0%) | 0/34 (0%) | 0/26 (0%) | 1/25 (4%)
First incidence (days) | – | – | – | – | 733 (T)
Poly-3 test | P = 0.129 | – | – | – | P = 0.460
Harderian Gland: Bilateral Adenoma
Overall rate | 0/47 (0%) | 2/47 (4%) | 4/47 (9%) | 15/46 (33%) | 31/47 (66%)
Adjusted rate | 0.0% | 4.5% | 9.5% | 38.2% | 73.1%
Terminal rate | 0/45 (0%) | 2/41 (5%) | 2/34 (6%) | 9/26 (35%) | 20/25 (80%)
First incidence (days) | – | 733 (T) | 618 | 646 | 530
Poly-3 test | P < 0.001*** | P = 0.226 | P = 0.048* | P < 0.001*** | P < 0.001***
Harderian Gland: Adenoma and Adenocarcinoma (Combined)
Overall rate | 3/47 (6%) | 17/47 (36%) | 23/47 (49%) | 32/46 (70%) | 42/47 (89%)
Adjusted rate | 6.4% | 38.3% | 52.1% | 77.3% | 93.4%
Terminal rate | 3/45 (7%) | 17/41 (42%) | 16/34 (47%) | 20/26 (77%) | 25/25 (100%)
First incidence (days) | 733 (T) | 726 (T) | 558 | 559 | 530
Poly-3 test | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001*** | P < 0.001***
Lung: Alveolar/Bronchiolar Adenoma
Overall rate | 0/47 (0%) | 7/46 (15%) | 7/47 (15%) | 13/47 (28%) | 17/47 (36%)
Adjusted rate | 0.0% | 16.0% | 16.6% | 32.3% | 42.1%
Terminal rate | 0/45 (0%) | 7/41 (17%) | 6/34 (18%) | 8/26 (31%) | 10/25 (40%)
First incidence (days) | – | 726 (T) | 604 | 552 | 530
Poly-3 test | P < 0.001*** | P = 0.006** | P = 0.005** | P < 0.001*** | P < 0.001***
Lung: Alveolar/Bronchiolar Carcinoma
Overall rate | 0/47 (0%) | 0/46 (0%) | 1/47 (2%) | 0/47 (0%) | 2/47 (4%)
Adjusted rate | 0.0% | 0.0% | 2.4% | 0.0% | 5.2%
Terminal rate | 0/45 (0%) | 0/41 (0%) | 1/34 (3%) | 0/26 (0%) | 1/25 (4%)
First incidence (days) | – | – | 733 (T) | – | 669
Poly-3 test | P = 0.058 | – | P = 0.477 | – | P = 0.196
Lung: Alveolar/Bronchiolar Adenoma and Carcinoma (Combined)
Overall rate | 0/47 (0%) | 7/46 (15%) | 8/47 (17%) | 13/47 (28%) | 19/47 (40%)
Adjusted rate | 0.0% | 16.0% | 19.0% | 32.3% | 46.7%
Terminal rate | 0/45 (0%) | 7/41 (17%) | 7/34 (21%) | 8/26 (31%) | 11/25 (44%)
First incidence (days) | – | 726 (T) | 604 | 552 | 530
Poly-3 test | P < 0.001*** | P = 0.006** | P = 0.002** | P < 0.001*** | P < 0.001***
Skin: Squamous Cell Carcinoma
Overall rate | 0/47 (0%) | 0/48 (0%) | 0/47 (0%) | 0/47 (0%) | 2/46 (4%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 5.4%
Terminal rate | 0/45 (0%) | 0/41 (0%) | 0/34 (0%) | 0/26 (0%) | 2/25 (8%)
First incidence (days) | – | – | – | – | 733 (T)
Poly-3 test | P = 0.017* | – | – | – | P = 0.191
Skin: Squamous Cell Papilloma
Overall rate | 0/47 (0%) | 1/48 (2%) | 2/47 (4%) | 1/47 (2%) | 8/46 (17%)
Adjusted rate | 0.0% | 2.2% | 4.8% | 2.6% | 20.7%
Terminal rate | 0/45 (0%) | 1/41 (2%) | 2/34 (6%) | 1/26 (4%) | 4/25 (16%)
First incidence (days) | – | 733 (T) | 733 (T) | 733 (T) | 574
Poly-3 test | P < 0.001*** | P = 0.493 | P = 0.213 | P = 0.462 | P = 0.001**
Skin: Squamous Cell Carcinoma and Papilloma (Combined)
Overall rate^a^ | 0/47 (0%) | 1/48 (2%) | 2/47 (4%) | 1/47 (2%) | 9/46 (20%)
Adjusted rate^b^ | 0.0% | 2.2% | 4.8% | 2.6% | 23.3%
Terminal rate^c^ | 0/45 (0%) | 1/41 (2%) | 2/34 (6%) | 1/26 (4%) | 5/25 (20%)
First incidence (days)^d^ | – | 733 (T) | 733 (T) | 733 (T) | 574
Poly-3 test^e^ | P < 0.001*** | P = 0.493 | P = 0.213 | P = 0.462 | P < 0.001***
Stomach (Forestomach): Squamous Cell Carcinoma
Overall rate | 0/47 (0%) | 0/45 (0%) | 0/48 (0%) | 0/45 (0%) | 2/41 (5%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 5.8%
Terminal rate | 0/45 (0%) | 0/41 (0%) | 0/34 (0%) | 0/26 (0%) | 2/25 (8%)
First incidence (days) | – | – | – | – | 726 (T)
Poly-3 test | P = 0.014* | – | – | – | P = 0.176
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 0/47 (0%) | 2/45 (4%) | 3/48 (6%) | 2/45 (4%) | 10/41 (24%)
Adjusted rate | 0.0% | 4.7% | 7.2% | 5.3% | 27.6%
Terminal rate | 0/45 (0%) | 2/41 (5%) | 2/34 (6%) | 2/26 (8%) | 5/25 (20%)
First incidence (days) | – | 733 (T) | 701 | 733 (T) | 530
Poly-3 test | P < 0.001*** | P = 0.218 | P = 0.100 | P = 0.193 | P < 0.001***
Stomach (Forestomach): Squamous Cell Carcinoma and Papilloma (Combined)
Overall rate | 0/47 (0%) | 2/45 (4%) | 3/48 (6%) | 2/45 (4%) | 12/41 (29%)
Adjusted rate | 0.0% | 4.7% | 7.2% | 5.3% | 33.1%
Terminal rate | 0/45 (0%) | 2/41 (5%) | 2/34 (6%) | 2/26 (8%) | 7/25 (28%)
First incidence (days) | – | 733 (T) | 701 | 733 (T) | 530
Poly-3 test | P < 0.001*** | P = 0.218 | P = 0.100 | P = 0.193 | P < 0.001***
All Organs: Fibrous Histiocytoma
Overall rate | 2/48 (4%) | 2/48 (4%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 4.3% | 4.4% | 0.0% | 0.0% | 2.6%
Terminal rate | 1/45 (2%) | 1/41 (2%) | 0/34 (0%) | 0/26 (0%) | 0/25 (0%)
First incidence (days) | 694 | 701 | – | – | 586
Poly-3 test | P = 0.341N | P = 0.680 | P = 0.264N | P = 0.283N | P = 0.567N
All Organs: Hemangioma
Overall rate | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 2.4% | 0.0% | 2.6%
Terminal rate | 0/45 (0%) | 0/41 (0%) | 1/34 (3%) | 0/26 (0%) | 0/25 (0%)
First incidence (days) | – | – | 733 (T) | – | 659
Poly-3 test | P = 0.260 | – | P = 0.477 | – | P = 0.461
All Organs: Hemangiosarcoma
Overall rate | 2/48 (4%) | 1/48 (2%) | 2/48 (4%) | 1/48 (2%) | 3/48 (6%)
Adjusted rate | 4.3% | 2.2% | 4.8% | 2.6% | 7.8%
Terminal rate | 2/45 (4%) | 1/41 (2%) | 1/34 (3%) | 1/26 (4%) | 2/25 (8%)
First incidence (days) | 733 (T) | 733 (T) | 716 | 733 (T) | 669
Poly-3 test | P = 0.248 | P = 0.513N | P = 0.653 | P = 0.566N | P = 0.411
All Organs: Hemangiosarcoma or Hemangioma
Overall rate | 2/48 (4%) | 1/48 (2%) | 3/48 (6%) | 1/48 (2%) | 4/48 (8%)
Adjusted rate | 4.3% | 2.2% | 7.2% | 2.6% | 10.3%
Terminal rate | 2/45 (4%) | 1/41 (2%) | 2/34 (6%) | 1/26 (4%) | 2/25 (8%)
First incidence (days) | 733 (T) | 733 (T) | 716 | 733 (T) | 659
Poly-3 test | P = 0.135 | P = 0.513N | P = 0.449 | P = 0.566N | P = 0.255
All Organs: Histiocytic Sarcoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 1/48 (2%) | 3/48 (6%) | 3/48 (6%)
Adjusted rate | 2.1% | 0.0% | 2.4% | 7.6% | 7.7%
Terminal rate | 1/45 (2%) | 0/41 (0%) | 0/34 (0%) | 1/26 (4%) | 1/25 (4%)
First incidence (days) | 733 (T) | – | 558 | 563 | 530
Poly-3 test | P = 0.042* | P = 0.507N | P = 0.738 | P = 0.248 | P = 0.244
All Organs: Leukemia (Lymphocytic, Monocytic, Mononuclear, or Undifferentiated)
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 2.6%
Terminal rate | 0/45 (0%) | 0/41 (0%) | 0/34 (0%) | 0/26 (0%) | 0/25 (0%)
First incidence (days) | – | – | – | – | 472
Poly-3 test | P = 0.130 | – | – | – | P = 0.463
All Organs: Malignant Lymphoma (Histiocytic, Lymphocytic, Mixed, NOS, or Undifferentiated Cell Type)
Overall rate | 2/48 (4%) | 4/48 (8%) | 2/48 (4%) | 4/48 (8%) | 7/48 (15%)
Adjusted rate | 4.3% | 8.6% | 4.7% | 10.0% | 17.2%
Terminal rate | 1/45 (2%) | 2/41 (5%) | 1/34 (3%) | 1/26 (4%) | 2/25 (8%)
First incidence (days) | 715 | 400 | 604 | 413 | 388
Poly-3 test | P = 0.022* | P = 0.332 | P = 0.655 | P = 0.266 | P = 0.049*
All Organs: Benign Tumors
Overall rate | 14/48 (29%) | 23/48 (48%) | 34/48 (71%) | 40/48 (83%) | 43/48 (90%)
Adjusted rate | 29.9% | 50.9% | 76.0% | 91.6% | 95.4%
Terminal rate | 14/45 (31%) | 23/41 (56%) | 25/34 (74%) | 24/26 (93%) | 25/25 (100%)
First incidence (days) | 733 (T) | 726 (T) | 558 | 497 | 530
Poly-3 test | P < 0.001*** | P = 0.030* | P < 0.001*** | P < 0.001*** | P < 0.001***
All Organs: Malignant Tumors
Overall rate | 13/48 (27%) | 17/48 (35%) | 21/48 (44%) | 27/48 (56%) | 33/48 (69%)
Adjusted rate | 27.6% | 35.6% | 46.5% | 59.4% | 71.2%
Terminal rate | 11/45 (24%) | 11/41 (27%) | 12/34 (35%) | 11/26 (43%) | 13/25 (52%)
First incidence (days) | 694 | 400 | 387 | 352 | 388
Poly-3 test | P < 0.001*** | P = 0.272 | P = 0.047* | P = 0.001** | P < 0.001***
All Organs: Benign or Malignant Tumors
Overall rate | 23/48 (48%) | 35/48 (73%) | 41/48 (85%) | 46/48 (96%) | 47/48 (98%)
Adjusted rate | 48.9% | 73.3% | 88.4% | 98.8% | 100.0%
Terminal rate | 21/45 (47%) | 29/41 (71%) | 29/34 (85%) | 26/26 (100%) | 25/25 (100%)
First incidence (days) | 694 | 400 | 387 | 352 | 388
Poly-3 test | P < 0.001*** | P = 0.011* | P < 0.001*** | P < 0.001*** | P < 0.001***

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at the terminal sacrifice.

^d^ T indicates terminal sacrifice.

^e^ Beneath the 0 mM Glycidamide are the p-values associated with the trend test. Beneath the treated groups incidences are the p-values corresponding to pairwise comparisons between the 0 mM Glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

Table C-3 Historical Incidence of Harderian Gland Neoplasms in NCTR Control Male B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Adenoma
Sulfamethazine (February 1988) | Diet | 15/184 (8.2%)
Doxylamine (April 1991) | Diet | 1/48 (2.1%)
Triprolidine (June 1991) | Diet | 0/48 (0.0%)
Pyrilamine (July 1991) | Diet | 2/47 (4.3%)
Fumonisin B_1_ (March 1999) | Diet | 1/46 (2.2%)
Chloral Hydrate (July 2001) | Gavage | 4/48 (8.3%)
Chloral Hydrate (October 2002) | Gavage | 5/47 (10.6%)
Urethane and Ethanol (May 2003) | Drinking Water | 3/47 (6.4%)
Acrylamide (February 2012) | Drinking Water | 2/46 (4.3%)
Aloe vera Whole Leaf (2013) | Drinking Water | 3/48 (6.3%)
Total (%) (All studies) | | 36/609 (5.9%)
Range | | 0.0–10.6%
Total (%) (Drinking water studies) | | 8/141 (5.7%)
Range | | 4.3–6.4%

Table C-4 Historical Incidence of Alveolar/Bronchiolar Neoplasms in NCTR Control Male B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Adenoma | Carcinoma | Adenoma or Carcinoma
Sulfamethazine (February 1988) | Diet | 25/186 (13.4%) | 3/186 (1.6%) | 28/186 (15.1%)
Doxylamine (April 1991) | Diet | 9/48 (18.8%) | 0/48 (0.0%) | 9/48 (18.8%)
Triprolidine (June 1991) | Diet | 9/48 (18.8%) | 2/48 (4.2%) | 11/48 (22.9%)
Pyrilamine (July 1991) | Diet | 5/47 (10.6%) | 0/47 (0.0%) | 5/47 (10.6%)
Fumonisin B_1_ (March 1999) | Diet | 6/48 (12.5%) | 0/48 (0.0%) | 6/48 (12.5%)
Chloral Hydrate (July 2001) | Gavage | 4/48 (8.3%) | 4/48 (8.3%) | 8/48 (16.7%)
Chloral Hydrate (October 2002) | Gavage | 13/48 (27.1%) | 2/48 (4.2%) | 15/48 (31.3%)
Urethane and Ethanol (May 2003) | Drinking Water | 4/48 (8.3%) | 1/48 (2.1%) | 5/48 (10.4%)
Acrylamide (February 2012) | Drinking Water | 5/47 (10.6%) | 2/47 (4.3%) | 6/47 (12.8%)
Aloe vera Whole Leaf (2013) | Drinking Water | 3/48 (6.3%) | 3/48 (6.3%) | 6/48 (12.5%)
Total (%) (All studies) | | 83/616 (13.5%) | 17/616 (2.8%) | 99/616 (16.1%)
Range | | 6.3–27.1% | 0.0–8.3% | 10.4–31.3%
Total (%) (Drinking water studies) | | 12/143 (8.4%) | 6/143 (4.2%) | 17/143 (11.9%)
Range | | 6.3–10.6% | 2.1–6.3% | 10.4–12.8%

Table C-5 Historical Incidence of Squamous Cell Papilloma or Carcinoma (Combined) of the Forestomach in NCTR Control Male B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 1/179 (0.6%)
Doxylamine (April 1991) | Diet | 0/47 (0.0%)
Triprolidine (June 1991) | Diet | 0/48 (0.0%)
Pyrilamine (July 1991) | Diet | 0/46 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 1/47 (2.1%)
Chloral Hydrate (July 2001) | Gavage | 0/48 (0.0%)
Chloral Hydrate (October 2002) | Gavage | 0/43 (0.0%)
Urethane and Ethanol (May 2003) | Drinking Water | 0/46 (0.0%)
Acrylamide (February 2012) | Drinking Water | 0/46 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 0/47 (0.0%)
Total (%) (All studies) | | 2/597 (0.3%)
Range | | 0.0–2.1%
Total (%) (Drinking water studies) | | 0/137 (0.0%)
Range | | 0.0%

Table C-6 Historical Incidence of Malignant Lymphoma in NCTR Control Male B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 10/187 (5.3%)
Doxylamine (April 1991) | Diet | 5/48 (10.4%)
Triprolidine (June 1991) | Diet | 3/48 (6.3%)
Pyrilamine (July 1991) | Diet | 3/47 (6.4%)
Fumonisin B_1_ (March 1999) | Diet | 5/48 (10.4%)
Chloral Hydrate (July 2001) | Gavage | 5/48 (10.4%)
Chloral Hydrate (October 2002) | Gavage | 5/48 (10.4%)
Urethane and Ethanol (May 2003) | Drinking Water | 9/48 (18.8%)
Acrylamide (February 2012) | Drinking Water | 4/48 (8.3%)
Aloe vera Whole Leaf (2013) | Drinking Water | 4/48 (8.3%)
Total (%) (All studies) | | 53/618 (8.6%)
Range | | 5.3–10.4%
Total (%) (Drinking water studies) | | 17/144 (11.8%)
Range | | 8.3–18.8%

Table C-7 Historical Incidence of Squamous Cell Papilloma or Carcinoma (Combined) of the Skin in NCTR Control Male B6C3F1/Nctr Mice

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 0/183 (0.0%)
Doxylamine (April 1991) | Diet | 0/47 (0.0%)
Triprolidine (June 1991) | Diet | 0/48 (0.0%)
Pyrilamine (July 1991) | Diet | 0/47 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 0/48 (0.0%)
Chloral Hydrate (July 2001) | Gavage | 0/47 (0.0%)
Chloral Hydrate (October 2002) | Gavage | 0/48 (0.0%)
Urethane and Ethanol (May 2003) | Drinking Water | 0/47 (0.0%)
Acrylamide (February 2012) | Drinking Water | 1/47 (2.1%)
Aloe vera Whole Leaf (2013) | Drinking Water | 0/48 (0.0%)
Total (%) (All studies) | | 1/610 (0.2%)
Range | | 0.0–2.1%
Total (%) (Drinking water studies) | | 1/42 (0.7%)
Range | | 0.0–2.1%

Table C-8 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | – | 4 | 11 | 16 | 11
Natural death | 1 | 3 | 2 | 3 | 9
Survivors
Moribund sacrifice | 2 | – | 1 | 2 | 2
Natural death | – | – | – | 1 | 1
Terminal sacrifice | 45 | 41 | 34 | 26 | 25
Animals examined microscopically | 48 | 48 | 48 | 48 | 48
Alimentary System
Esophagus | (47) | (48) | (47) | (47) | (46)
Gallbladder | (46) | (45) | (46) | (45) | (39)
Infiltration cellular, lymphocyte | – | – | – | 1 (2%) | –
Intestine large, cecum | (47) | (45) | (46) | (44) | (39)
Hyperplasia, lymphoid | 1 (2%) | 3 (7%) | 4 (9%) | 4 (9%) | 2 (5%)
Intestine large, colon | (47) | (45) | (47) | (45) | (39)
Intestine large, rectum | (47) | (45) | (47) | (45) | (39)
Intestine small, duodenum | (47) | (45) | (46) | (44) | (39)
Epithelium, hyperplasia | – | – | – | – | 1 (3%)
Intestine small, ileum | (47) | (45) | (46) | (44) | (39)
Hyperplasia, lymphoid | – | 1 (2%) | – | – | 2 (5%)
Intestine small, jejunum | (47) | (45) | (46) | (44) | (39)
Hyperplasia, lymphoid | 1 (2%) | 1 (2%) | – | – | 1 (3%)
Epithelium, hyperplasia | – | – | 1 (2%) | – | –
Liver | (47) | (47) | (47) | (47) | (48)
Angiectasis | – | – | – | – | 1 (2%)
Basophilic focus | – | – | 2 (4%) | 4 (9%) | 2 (4%)
Basophilic focus, multiple | – | – | – | – | 1 (2%)
Cyst | – | – | – | 1 (2%) | –
Eosinophilic focus | – | – | – | – | 2 (4%)
Hematopoietic cell proliferation | 2 (4%) | 1 (2%) | 2 (4%) | – | 1 (2%)
Infiltration cellular, lymphocyte | 2 (4%) | 1 (2%) | 1 (2%) | 3 (6%) | –
Infiltration cellular, polymorphonuclear | – | – | – | – | 1 (2%)
Inflammation, suppurative | – | 1 (2%) | – | – | –
Inflammation, chronic active | 1 (2%) | 3 (6%) | – | 1 (2%) | 1 (2%)
Mineralization | – | – | – | 1 (2%) | –
Mixed cell focus | – | – | 1 (2%) | – | –
Necrosis | – | 3 (6%) | 1 (2%) | 3 (6%) | 3 (6%)
Tension lipidosis | – | 1 (2%) | – | 1 (2%) | –
Vacuolization cytoplasmic | 2 (4%) | – | 1 (2%) | 1 (2%) | –
Bile duct, hyperplasia | 1 (2%) | – | – | – | –
Kupffer cell, hyperplasia | – | – | – | – | 1 (2%)
Oval cell, hyperplasia | 1 (2%) | – | – | – | 1 (2%)
Mesentery | (2) | (1) | (0) | (1) | (1)
Hemorrhage | – | 1 (100%) | – | – | –
Fat, necrosis | 1 (50%) | – | – | 1 (100%) | –
Oral mucosa | (0) | (1) | (0) | (0) | (2)
Pancreas | (47) | (46) | (47) | (47) | (45)
Cyst | – | – | – | 1 (2%) | –
Infiltration cellular, lymphocyte | 7 (15%) | 3 (7%) | – | 1 (2%) | 3 (7%)
Acinus, degeneration | 4 (9%) | 1 (2%) | 4 (9%) | 6 (13%) | 3 (7%)
Duct, dilatation | – | – | – | – | 2 (4%)
Salivary glands | (47) | (47) | (47) | (46) | (44)
Infiltration cellular, lymphocyte | 26 (55%) | 22 (47%) | 20 (43%) | 17 (37%) | 18 (41%)
Stomach, forestomach | (47) | (45) | (48) | (45) | (41)
Cyst epithelial inclusion | – | – | 2 (4%) | – | –
Ulcer | – | 1 (2%) | – | – | –
Epithelium, hyperplasia | 5 (11%) | 2 (4%) | 5 (10%) | 5 (11%) | 12 (29%)
Serosa, necrosis | – | – | – | 1 (2%) | –
Stomach, glandular | (47) | (45) | (46) | (44) | (38)
Epithelium, hyperplasia | – | 1 (2%) | – | – | 1 (3%)
Tongue | (0) | (0) | (0) | (1) | (0)
Cardiovascular System
Blood vessel | (47) | (48) | (47) | (47) | (47)
Heart | (47) | (48) | (47) | (47) | (46)
Infiltration cellular, polymorphonuclear | – | – | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (47) | (47) | (47) | (45) | (44)
Accessory adrenal cortical nodule | – | 1 (2%) | 2 (4%) | 2 (4%) | –
Subcapsular, hyperplasia | 43 (91%) | 38 (81%) | 45 (96%) | 39 (87%) | 36 (82%)
Adrenal Medulla | (47) | (46) | (47) | (45) | (43)
Hyperplasia | 1 (2%) | – | – | – | –
Islets, pancreatic | (47) | (47) | (47) | (47) | (44)
Hyperplasia | 1 (2%) | 2 (4%) | – | 2 (4%) | 2 (5%)
Infiltration cellular, lymphocyte | – | – | – | 1 (2%) | –
Parathyroid gland | (43) | (48) | (43) | (42) | (42)
Cyst | 2 (5%) | – | 1 (2%) | 1 (2%) | 2 (5%)
Pituitary gland | (45) | (44) | (47) | (42) | (42)
Pars distalis, cyst | 1 (2%) | – | 2 (4%) | – | 1 (2%)
Thyroid gland | (47) | (48) | (47) | (44) | (43)
Cyst | – | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | 1 (2%) | – | – | – | –
Follicle, degeneration | 2 (4%) | 4 (8%) | 2 (4%) | 2 (5%) | 4 (9%)
General Body System
Tissue NOS | (0) | (0) | (0) | (1) | (1)
Genital System
Epididymis | (47) | (47) | (47) | (46) | (43)
Exfoliated germ cell | – | – | 1 (2%) | – | 1 (2%)
Hypospermia | 2 (4%) | – | 3 (6%) | – | 3 (7%)
Infiltration cellular, lymphocyte | – | 1 (2%) | – | – | –
Infiltration cellular, polymorphonuclear | – | – | – | – | 1 (2%)
Inflammation, chronic | – | 1 (2%) | 2 (4%) | – | 3 (7%)
Inflammation, chronic active | 1 (2%) | – | – | – | –
Spermatocele | – | – | – | – | 1 (2%)
Penis | (0) | (0) | (1) | (0) | (0)
Inflammation, chronic active | – | – | 1 (100%) | – | –
Ulcer | – | – | 1 (100%) | – | –
Preputial gland | (47) | (47) | (46) | (46) | (44)
Cyst | 3 (6%) | 2 (4%) | 5 (11%) | 1 (2%) | 4 (9%)
Degeneration | 4 (9%) | 10 (21%) | 5 (11%) | 12 (26%) | 9 (20%)
Hyperkeratosis | 1 (2%) | 1 (2%) | 1 (2%) | – | –
Infiltration cellular, lymphocyte | 3 (6%) | – | 1 (2%) | 4 (9%) | 1 (2%)
Inflammation, suppurative | – | 5 (11%) | 2 (4%) | 3 (7%) | 7 (16%)
Inflammation, chronic active | 1 (2%) | 1 (2%) | – | – | 2 (5%)
Duct, dilatation | – | – | 1 (2%) | – | 4 (9%)
Prostate | (47) | (47) | (47) | (45) | (41)
Inflammation, suppurative | – | – | 1 (2%) | – | –
Inflammation, chronic active | – | – | – | – | 1 (2%)
Epithelium, hyperplasia | – | – | – | – | 1 (2%)
Seminal vesicle | (47) | (46) | (47) | (45) | (41)
Atrophy | – | – | – | 1 (2%) | –
Lumen, dilatation | – | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Testes | (47) | (46) | (46) | (46) | (42)
Mineralization | – | – | – | 1 (2%) | –
Seminiferous tubule, degeneration | 2 (4%) | – | 3 (7%) | 2 (4%) | 5 (12%)
Hematopoietic System
Bone marrow | (47) | (47) | (47) | (46) | (44)
Hyperplasia | 3 (6%) | 3 (6%) | 5 (11%) | 5 (11%) | 8 (18%)
Lymph node | (4) | (5) | (2) | (6) | (6)
Axillary, hyperplasia, lymphoid | – | 1 (20%) | 1 (50%) | – | 1 (17%)
Iliac, hyperplasia, lymphoid | – | – | – | 1 (17%) | 1 (17%)
Iliac, infiltration cellular, polymorphonuclear | – | – | – | – | 1 (17%)
Inguinal, hyperplasia, lymphoid | – | – | 1 (50%) | 2 (33%) | 1 (17%)
Inguinal, infiltration cellular, plasma cell | – | – | – | – | 1 (17%)
Lumbar, hyperplasia, lymphoid | 1 (25%) | – | 1 (50%) | – | –
Lumbar, infiltration cellular, polymorphonuclear | – | – | – | – | 1 (17%)
Mediastinal, hyperplasia, lymphoid | 1 (25%) | – | – | 1 (17%) | –
Renal, hyperplasia, lymphoid | 1 (25%) | – | – | – | 1 (17%)
Renal, infiltration cellular, polymorphonuclear | – | – | – | – | 1 (17%)
Lymph node, mandibular | (47) | (47) | (47) | (45) | (43)
Hyperplasia, lymphoid | 7 (15%) | 4 (9%) | 5 (11%) | 10 (22%) | 7 (16%)
Infiltration cellular, histiocyte | – | – | – | 1 (2%) | 2 (5%)
Infiltration cellular, mast cell | – | – | 1 (2%) | 1 (2%) | 2 (5%)
Infiltration cellular, plasma cell | 1 (2%) | – | 1 (2%) | 3 (7%) | 4 (9%)
Infiltration cellular, polymorphonuclear | – | – | – | – | 1 (2%)
Pigmentation | – | – | 1 (2%) | – | 1 (2%)
Sinus, dilatation | – | – | – | – | 1 (2%)
Lymph node, mesenteric | (47) | (46) | (47) | (45) | (42)
Angiectasis | 9 (19%) | 5 (11%) | 3 (6%) | 5 (11%) | 3 (7%)
Hematopoietic cell proliferation | – | – | – | – | 4 (10%)
Hemorrhage | 5 (11%) | 12 (26%) | 4 (9%) | 4 (9%) | 9 (21%)
Hyperplasia, lymphoid | 25 (53%) | 12 (26%) | 21 (45%) | 16 (36%) | 12 (29%)
Infiltration cellular, histiocyte | 5 (11%) | 4 (9%) | 3 (6%) | 5 (11%) | 5 (12%)
Infiltration cellular, mast cell | – | 2 (4%) | 1 (2%) | – | 2 (5%)
Infiltration cellular, polymorphonuclear | 1 (2%) | – | – | – | 1 (2%)
Sinus, dilatation | – | 1 (2%) | – | – | 1 (2%)
Spleen | (47) | (47) | (47) | (46) | (44)
Congestion | – | – | – | – | 1 (2%)
Depletion lymphoid | – | – | – | 2 (4%) | –
Hematopoietic cell proliferation | 6 (13%) | 6 (13%) | 12 (26%) | 14 (30%) | 17 (39%)
Hyperplasia, lymphoid | 34 (72%) | 31 (66%) | 22 (47%) | 22 (48%) | 23 (52%)
Inflammation, granulomatous | – | – | 1 (2%) | – | –
Necrosis | – | – | – | 1 (2%) | –
Pigmentation | – | – | – | – | 1 (2%)
Thymus | (43) | (45) | (43) | (39) | (34)
Atrophy | 28 (65%) | 25 (56%) | 17 (40%) | 21 (54%) | 16 (47%)
Hyperplasia, lymphoid | – | – | 1 (2%) | 1 (3%) | –
Integumentary System
Mammary gland | (3) | (1) | (0) | (2) | (1)
Skin | (47) | (48) | (47) | (47) | (46)
Fibrosis | – | 1 (2%) | – | 1 (2%) | –
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%) | 1 (2%)
Metaplasia, osseous | 1 (2%) | – | – | – | –
Mineralization | – | – | – | 1 (2%) | –
Ulcer | – | – | – | – | 1 (2%)
Epithelium, hyperplasia | – | – | 1 (2%) | – | 1 (2%)
Sebaceous gland, hyperplasia | – | – | – | 1 (2%) | –
Musculoskeletal System
Bone, femur | (48) | (48) | (48) | (48) | (47)
Skeletal muscle | (48) | (47) | (47) | (47) | (47)
Degeneration | – | – | – | 1 (2%) | –
Nervous System
Brain, brain stem | (47) | (47) | (46) | (46) | (42)
Brain, cerebellum | (47) | (47) | (46) | (46) | (42)
Hemorrhage | – | – | 1 (2%) | – | –
Brain, cerebrum | (47) | (47) | (46) | (46) | (42)
Cyst | – | 1 (2%) | – | – | –
Mineralization | 33 (70%) | 30 (64%) | 32 (70%) | 29 (63%) | 20 (48%)
Meninges, arteritis | 1 (2%) | – | – | – | –
Peripheral nerve, sciatic | (47) | (47) | (47) | (46) | (42)
Axon, degeneration | 36 (77%) | 37 (79%) | 30 (64%) | 30 (65%) | 32 (76%)
Spinal cord, cervical | (47) | (46) | (46) | (44) | (39)
Axon, degeneration | 8 (17%) | 8 (17%) | 3 (7%) | 11 (25%) | 12 (31%)
Nerve, degeneration | – | – | 1 (2%) | – | –
Spinal cord, lumbar | (47) | (46) | (46) | (45) | (39)
Axon, degeneration | 9 (19%) | 10 (22%) | 4 (9%) | – | 1 (3%)
Nerve, degeneration | 39 (83%) | 41 (89%) | 37 (80%) | 35 (78%) | 34 (87%)
Spinal cord, thoracic | (47) | (46) | (46) | (45) | (39)
Axon, degeneration | 37 (79%) | 28 (61%) | 23 (50%) | 24 (53%) | 26 (67%)
Nerve, degeneration | 1 (2%) | 1 (2%) | 1 (2%) | – | –
Respiratory System
Lung | (47) | (46) | (47) | (47) | (47)
Congestion | – | – | 1 (2%) | – | –
Hemorrhage | – | – | – | – | 1 (2%)
Infiltration cellular, histiocyte | – | 1 (2%) | – | 1 (2%) | 4 (9%)
Infiltration cellular, lymphocyte | – | – | 1 (2%) | – | –
Inflammation, chronic | – | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | – | 1 (2%) | 4 (9%) | 3 (6%) | 6 (13%)
Alveolus, infiltration cellular, histiocyte | – | – | – | – | 1 (2%)
Nose | (47) | (46) | (47) | (47) | (45)
Amyloid deposition | – | – | 1 (2%) | – | –
Crystals | – | – | 2 (4%) | 1 (2%) | 1 (2%)
Foreign body | – | – | – | 1 (2%) | –
Hyaline droplet | 13 (28%) | 6 (13%) | 11 (23%) | 2 (4%) | 1 (2%)
Inflammation, suppurative | – | 1 (2%) | – | 1 (2%) | 1 (2%)
Trachea | (47) | (48) | (46) | (46) | (45)
Special Senses System
Eye | (47) | (45) | (46) | (44) | (42)
Cataract | 1 (2%) | 3 (7%) | 7 (15%) | 8 (18%) | 17 (40%)
Cornea, inflammation, chronic | – | – | – | – | 1 (2%)
Cornea, inflammation, chronic active | – | – | 2 (4%) | – | 7 (17%)
Cornea, ulcer | – | – | 1 (2%) | – | 3 (7%)
Harderian gland | (47) | (47) | (47) | (46) | (47)
Cyst | – | – | – | – | 1 (2%)
Infiltration cellular, lymphocyte | 4 (9%) | – | 1 (2%) | – | –
Epithelium, hyperplasia | – | 1 (2%) | 2 (4%) | 2 (4%) | 1 (2%)
Zymbal’s gland | (0) | (0) | (0) | (0) | (1)
Keratin cyst | – | – | – | – | 1 (100%)
Urinary System
Kidney | (47) | (47) | (47) | (46) | (46)
Autolysis | – | – | – | 1 (2%) | 1 (2%)
Cyst | 1 (2%) | – | – | – | –
Degeneration | – | – | – | – | 1 (2%)
Hyaline droplet | – | – | 1 (2%) | 3 (7%) | 2 (4%)
Hydronephrosis | 1 (2%) | – | – | – | 1 (2%)
Infarct | 1 (2%) | – | – | 1 (2%) | 1 (2%)
Infiltration cellular, lymphocyte | 20 (43%) | 12 (26%) | 19 (40%) | 8 (17%) | 9 (20%)
Infiltration cellular, polymorphonuclear | – | – | – | – | 1 (2%)
Inflammation, chronic | 1 (2%) | – | – | – | –
Nephropathy | 15 (32%) | 18 (38%) | 14 (30%) | 12 (26%) | 16 (35%)
Urinary bladder | (47) | (46) | (47) | (45) | (41)
Infiltration cellular, lymphocyte | 7 (15%) | 4 (9%) | 3 (6%) | 3 (7%) | 1 (2%)
Infiltration cellular, polymorphonuclear | – | – | – | – | 1 (2%)
Inflammation, suppurative | – | – | – | – | 1 (2%)
Lumen, dilatation | 3 (6%) | 2 (4%) | 3 (6%) | 1 (2%) | 2 (5%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.