# Appendix B Summary of Lesions in Female Rats in the Two-year Drinking Water Study of Glycidamide

Table B-1 Summary of the Incidence of Neoplasms in Female Rats in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | 7 | 15 | 11 | 20 | 40
Natural deaths | 2 | – | 4 | 3 | 3
Survivors
Moribund sacrifice | 3 | 6 | 5 | 8 | 3
Natural deaths | 1 | 1 | 1 | – | –
Terminal sacrifice | 35 | 26 | 27 | 17 | 2
Animals examined microscopically | 48 | 48 | 48 | 48 | 48
Alimentary System
Esophagus | (48) | (48) | (48) | (48) | (48)
Intestine large, cecum | (46) | (48) | (44) | (45) | (45)
Adenoma | 1 (2%) | – | – | – | –
Leukemia mononuclear | – | 1 (2%) | – | 1 (2%) | –
Lymphoma malignant | – | – | – | 1 (2%) | –
Intestine large, colon | (46) | (48) | (44) | (45) | (45)
Adenoma | – | – | 1 (2%) | – | –
Intestine large, rectum | (46) | (48) | (45) | (45) | (45)
Sarcoma, metastatic, clitoral gland | – | – | – | 1 (2%) | –
Schwannoma malignant | – | – | 1 (2%) | – | –
Intestine small, duodenum | (46) | (48) | (45) | (45) | (45)
Adenocarcinoma | – | 1 (2%) | – | – | –
Leiomyoma | – | 1 (2%) | 1 (2%) | – | –
Intestine small, ileum | (46) | (48) | (44) | (45) | (45)
Leukemia mononuclear | – | – | – | – | 2 (4%)
Intestine small, jejunum | (46) | (48) | (45) | (44) | (44)
Sarcoma, metastatic, uterus | – | 1 (2%) | – | – | –
Liver | (48) | (48) | (48) | (48) | (48)
Hepatocellular adenoma, multiple | 1 (2%) | – | – | – | –
Leukemia mononuclear | 14 (29%) | 11 (23%) | 21 (44%) | 19 (40%) | 27 (56%)
Mesentery | (4) | (4) | (1) | (9) | (5)
Leukemia mononuclear | – | – | – | 1 (11%) | 1 (20%)
Lymphoma malignant | – | – | – | 1 (11%) | –
Oral mucosa | (1) | (2) | (5) | (4) | (9)
Squamous cell carcinoma | – | – | – | 1 (25%) | 2 (22%)
Squamous cell papilloma | 1 (100%) | 1 (50%) | 2 (40%) | – | 4 (44%)
Pancreas | (48) | (48) | (48) | (48) | (48)
Leukemia mononuclear | 2 (4%) | 2 (4%) | 4 (8%) | 5 (10%) | 4 (8%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Sarcoma, metastatic, uterus | – | 1 (2%) | – | – | –
Salivary glands | (48) | (48) | (48) | (48) | (48)
Leukemia mononuclear | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Stomach, forestomach | (48) | (48) | (48) | (47) | (46)
Lymphoma malignant | – | – | – | 1 (2%) | –
Squamous cell papilloma | – | 1 (2%) | – | – | 3 (7%)
Stomach, glandular | (47) | (48) | (45) | (46) | (46)
Adenoma | – | – | – | – | 1 (2%)
Leukemia mononuclear | 1 (2%) | – | 1 (2%) | 1 (2%) | –
Lymphoma malignant | – | – | – | 1 (2%) | –
Tongue | (0) | (1) | (1) | (3) | (4)
Squamous cell carcinoma | – | – | – | – | 1 (25%)
Squamous cell papilloma | – | 1 (100%) | – | 1 (33%) | –
Cardiovascular System
Blood Vessel | (48) | (48) | (48) | (48) | (48)
Leukemia mononuclear | 1 (2%) | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%)
Heart | (48) | (48) | (48) | (48) | (48)
Leukemia mononuclear | 5 (10%) | 4 (8%) | 8 (17%) | 8 (17%) | 10 (21%)
Schwannoma malignant | 2 (4%) | 1 (2%) | 4 (8%) | 2 (4%) | 1 (2%)
Endocrine System
Adrenal cortex | (48) | (48) | (48) | (48) | (48)
Adenoma | – | – | 1 (2%) | – | –
Carcinoma | 1 (2%) | – | – | – | –
Leukemia mononuclear | 2 (4%) | 2 (4%) | 4 (8%) | 2 (4%) | 5 (10%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Adrenal medulla | (47) | (48) | (47) | (47) | (48)
Leukemia mononuclear | 2 (4%) | 5 (10%) | 5 (11%) | 4 (9%) | 7 (15%)
Pheochromocytoma benign | 2 (4%) | 1 (2%) | 1 (2%) | 4 (9%) | 2 (4%)
Pheochromocytoma complex | – | – | – | – | 1 (2%)
Pheochromocytoma malignant | – | – | 1 (2%) | 1 (2%) | –
Bilateral, pheochromocytoma benign | 1 (2%) | – | – | – | –
Islets, pancreatic | (48) | (48) | (48) | (48) | (47)
Adenoma | – | 1 (2%) | – | – | –
Leukemia mononuclear | – | 1 (2%) | – | 1 (2%) | –
Lymphoma malignant | – | – | – | 1 (2%) | –
Parathyroid gland | (48) | (45) | (48) | (47) | (46)
Pituitary gland | (47) | (48) | (47) | (46) | (48)
Leukemia mononuclear | 1 (2%) | 2 (4%) | 2 (4%) | 4 (9%) | 5 (10%)
Pars distalis, adenoma | 32 (68%) | 36 (75%) | 32 (68%) | 27 (59%) | 24 (50%)
Pars distalis, carcinoma | 2 (4%) | 2 (4%) | 2 (4%) | – | –
Thyroid gland | (48) | (48) | (46) | (46) | (47)
Leukemia mononuclear | 1 (2%) | – | – | 2 (4%) | 1 (2%)
C-cell, adenoma | 1 (2%) | 3 (6%) | 6 (13%) | 4 (9%) | 2 (4%)
C-cell, adenoma, multiple | 1 (2%) | 1 (2%) | – | – | –
C-cell, carcinoma | 1 (2%) | – | – | – | 1 (2%)
Follicular cell, adenoma | – | 3 (6%) | 3 (7%) | 1 (2%) | 5 (11%)
Follicular cell, carcinoma | – | – | 2 (4%) | 3 (7%) | 2 (4%)
Follicular cell, carcinoma, multiple | – | – | – | – | 1 (2%)
General Body System
Tissue NOS | (0) | (1) | (0) | (0) | (0)
Sarcoma, metastatic, uterus | – | 1 (100%) | – | – | –
Genital System
Clitoral gland | (48) | (48) | (48) | (48) | (47)
Adenoma | 6 (13%) | 3 (6%) | 6 (13%) | 3 (6%) | 5 (11%)
Carcinoma | 4 (8%) | 6 (13%) | 7 (15%) | 11 (23%) | 13 (28%)
Leukemia mononuclear | 2 (4%) | 2 (4%) | – | 2 (4%) | 2 (4%)
Sarcoma, deep invasion | – | – | – | 1 (2%) | –
Squamous cell carcinoma | 2 (4%) | – | – | – | –
Squamous cell papilloma | – | – | – | 1 (2%) | 2 (4%)
Bilateral, carcinoma | – | – | – | – | 1 (2%)
Ovary | (48) | (48) | (48) | (48) | (48)
Granulosa cell tumor malignant | 1 (2%) | – | – | – | –
Leukemia mononuclear | 3 (6%) | 1 (2%) | 6 (13%) | 3 (6%) | 4 (8%)
Uterus | (48) | (48) | (48) | (48) | (48)
Adenoma | – | – | – | 1 (2%) | 1 (2%)
Deciduoma benign | 1 (2%) | – | – | – | –
Leukemia mononuclear | 2 (4%) | – | 1 (2%) | 3 (6%) | 2 (4%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Polyp stromal | 9 (19%) | 10 (21%) | 12 (25%) | 13 (27%) | 10 (21%)
Polyp stromal, multiple | 1 (2%) | 1 (2%) | – | – | –
Sarcoma | – | 1 (2%) | – | 1 (2%) | –
Sarcoma stromal | 1 (2%) | – | 2 (4%) | 1 (2%) | 2 (4%)
Bilateral, polyp stromal | 1 (2%) | – | 1 (2%) | 1 (2%) | 1 (2%)
Vagina | (3) | (3) | (4) | (5) | (1)
Sarcoma, metastatic, clitoral gland | – | – | – | 1 (20%) | –
Sarcoma stromal | – | – | – | – | 1 (100%)
Hematopoietic System
Bone marrow | (48) | (48) | (46) | (47) | (47)
Leukemia mononuclear | 5 (10%) | 7 (15%) | 10 (22%) | 11 (23%) | 11 (23%)
Lymph node | (5) | (9) | (15) | (12) | (18)
Leukemia mononuclear | – | – | – | – | 2 (11%)
Lymphoma malignant | – | – | – | 1 (8%) | –
Axillary, leukemia mononuclear | 1 (20%) | 1 (11%) | 1 (7%) | 3 (25%) | –
Brachial, leukemia mononuclear | – | 1 (11%) | – | – | –
Cervical, carcinoma, metastatic, thyroid gland | – | – | – | – | 1 (6%)
Cervical, leukemia mononuclear | 1 (20%) | 1 (11%) | – | – | 1 (6%)
Iliac, leukemia mononuclear | – | – | – | 1 (8%) | –
Inguinal, leukemia mononuclear | – | 1 (11%) | – | – | 1 (6%)
Lumbar, leukemia mononuclear | 2 (40%) | 3 (33%) | 2 (13%) | 6 (50%) | 3 (17%)
Mediastinal, leukemia mononuclear | 2 (40%) | 4 (44%) | 5 (33%) | 4 (33%) | 3 (17%)
Mediastinal, lymphoma malignant | – | – | – | 1 (8%) | –
Pancreatic, leukemia mononuclear | 2 (40%) | 5 (56%) | 6 (40%) | 5 (42%) | 6 (33%)
Pancreatic, lymphoma malignant | – | – | – | 1 (8%) | –
Renal, leukemia mononuclear | 2 (40%) | 2 (22%) | 5 (33%) | 3 (25%) | 2 (11%)
Lymph node, mandibular | (48) | (48) | (47) | (47) | (47)
Leukemia mononuclear | 5 (10%) | 6 (13%) | 10 (21%) | 12 (26%) | 15 (32%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Osteosarcoma, metastatic, nose | – | – | – | 1 (2%) | –
Lymph node, mesenteric | (47) | (48) | (47) | (48) | (48)
Leukemia mononuclear | 6 (13%) | 7 (15%) | 12 (26%) | 14 (29%) | 17 (35%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Sarcoma, metastatic, uterus | – | 1 (2%) | – | – | –
Spleen | (48) | (48) | (48) | (48) | (48)
Leukemia mononuclear | 14 (29%) | 11 (23%) | 21 (44%) | 19 (40%) | 27 (56%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Osteosarcoma, metastatic, nose | – | – | – | 1 (2%) | –
Thymus | (45) | (47) | (45) | (45) | (44)
Leukemia mononuclear | 2 (4%) | 3 (6%) | 3 (7%) | 4 (9%) | 6 (14%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Thymoma benign | – | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (48) | (48) | (48) | (48) | (48)
Adenocarcinoma | 1 (2%) | – | 2 (4%) | 2 (4%) | 2 (4%)
Adenoma | 2 (4%) | – | 1 (2%) | – | 3 (6%)
Adenoma, multiple | – | – | – | – | 1 (2%)
Fibroadenoma | 9 (19%) | 15 (31%) | 16 (33%) | 10 (21%) | 13 (27%)
Fibroadenoma, multiple | 7 (15%) | 11 (23%) | 19 (40%) | 23 (48%) | 23 (48%)
Leukemia mononuclear | – | 1 (2%) | – | – | –
Skin | (48) | (48) | (48) | (48) | (48)
Basal cell carcinoma | 1 (2%) | – | – | – | –
Squamous cell carcinoma | – | – | – | – | 1 (2%)
Subcutaneous tissue, fibroma | 1 (2%) | – | – | 1 (2%) | –
Subcutaneous tissue, lipoma | – | 2 (4%) | 1 (2%) | – | –
Musculoskeletal System
Bone | (0) | (1) | (1) | (0) | (0)
Cranium, meningioma malignant, metastatic, brain, cerebrum | – | 1 (100%) | – | – | –
Bone, femur | (48) | (48) | (48) | (48) | (48)
Chondrosarcoma | – | 1 (2%) | – | – | –
Skeletal muscle | (48) | (48) | (48) | (48) | (48)
Rhabdomyosarcoma | – | 1 (2%) | – | – | –
Sarcoma, metastatic, clitoral gland | – | – | – | 1 (2%) | –
Nervous System
Brain, brain stem | (48) | (48) | (47) | (48) | (48)
Carcinoma, metastatic, pituitary gland | 2 (4%) | 2 (4%) | 2 (4%) | – | –
Leukemia mononuclear | – | 1 (2%) | 3 (6%) | 3 (6%) | 4 (8%)
Brain, cerebellum | (48) | (48) | (47) | (48) | (48)
Astrocytoma malignant | – | – | – | 1 (2%) | –
Granular cell tumor benign | – | – | – | 1 (2%) | –
Histiocytic sarcoma | – | – | – | – | 1 (2%)
Leukemia mononuclear | 1 (2%) | – | 3 (6%) | 3 (6%) | 2 (4%)
Meningioma malignant, metastatic, brain, cerebrum | – | 1 (2%) | – | – | –
Brain, cerebrum | (48) | (48) | (48) | (48) | (48)
Astrocytoma malignant | – | – | – | – | 1 (2%)
Carcinoma, metastatic, pituitary gland | – | – | 1 (2%) | – | –
Glioma malignant | – | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | – | – | 5 (10%) | 4 (8%) | 3 (6%)
Meningioma malignant | – | 1 (2%) | – | – | –
Peripheral nerve, sciatic | (48) | (48) | (48) | (48) | (48)
Leukemia mononuclear | – | – | 1 (2%) | 1 (2%) | –
Spinal cord, cervical | (48) | (48) | (48) | (48) | (48)
Leukemia mononuclear | – | – | 3 (6%) | 2 (4%) | 1 (2%)
Spinal cord, lumbar | (48) | (48) | (47) | (48) | (48)
Leukemia mononuclear | – | – | 1 (2%) | 2 (4%) | –
Spinal cord, thoracic | (48) | (48) | (47) | (48) | (48)
Leukemia mononuclear | – | 1 (2%) | – | 1 (2%) | 1 (2%)
Respiratory System
Lung | (48) | (48) | (48) | (48) | (48)
Alveolar/bronchiolar adenoma | – | – | 1 (2%) | – | –
Carcinoma, metastatic, Zymbal’s gland | 1 (2%) | – | – | – | –
Leukemia mononuclear | 5 (10%) | 7 (15%) | 11 (23%) | 11 (23%) | 15 (31%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Sarcoma, metastatic, uterus | – | 1 (2%) | – | – | –
Nose | (48) | (48) | (48) | (48) | (47)
Adenoma | – | – | – | – | 1 (2%)
Leukemia mononuclear | 1 (2%) | – | – | – | –
Osteosarcoma | – | – | – | 1 (2%) | –
Nasopharyngeal duct, squamous cell carcinoma | – | – | – | – | 1 (2%)
Trachea | (48) | (48) | (47) | (47) | (48)
Special Senses System
Eye | (46) | (47) | (45) | (45) | (45)
Leukemia mononuclear | 1 (2%) | – | 1 (2%) | – | –
Harderian gland | (48) | (48) | (46) | (47) | (47)
Leukemia mononuclear | 1 (2%) | – | 1 (2%) | – | –
Zymbal’s gland | (1) | (0) | (0) | (0) | (2)
Carcinoma | 1 (100%) | – | – | – | 2 (100%)
Urinary System
Kidney | (48) | (48) | (48) | (47) | (48)
Leukemia mononuclear | 3 (6%) | 2 (4%) | 5 (10%) | 4 (9%) | 6 (13%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Urinary bladder | (48) | (48) | (48) | (47) | (47)
Leukemia mononuclear | – | 1 (2%) | – | 1 (2%) | 1 (2%)
Sarcoma stromal, metastatic, uterus | – | – | 1 (2%) | – | –
Transitional epithelium, papilloma | – | – | – | – | 1 (2%)
Systemic Lesions
Multiple organs | (48)^b^ | (48)^b^ | (48)^b^ | (48)^b^ | (48)^b^
Histiocytic sarcoma | – | – | – | – | 1 (2%)
Leukemia mononuclear | 14 (29%) | 11 (23%) | 21 (44%) | 19 (40%) | 27 (56%)
Lymphoma malignant | – | – | – | 1 (2%) | –
Neoplasm Summary
Total animals with primary neoplasms^c^ | 45 | 48 | 46 | 46 | 48
Total primary neoplasms | 108 | 116 | 147 | 137 | 164
Total animals with benign neoplasms | 40 | 47 | 42 | 40 | 44
Total benign neoplasms | 77 | 91 | 105 | 91 | 102
Total animals with malignant neoplasms | 22 | 20 | 31 | 34 | 44
Total malignant neoplasms | 31 | 25 | 42 | 46 | 62
Total animals with metastatic neoplasms | 2 | 4 | 3 | 2 | 1
Total metastatic neoplasms | 3 | 9 | 4 | 5 | 1

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table B-2 Statistical Analysis of Neoplasms in Female Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 3/47 (6%) | 1/48 (2%) | 1/47 (2%) | 4/47 (9%) | 2/48 (4%)
Adjusted rate^b^ | 7.2% | 2.5% | 2.6% | 11.4% | 8.0%
Terminal rate^c^ | 3/34 (9%) | 1/26 (4%) | 1/26 (4%) | 2/17 (12%) | 1/2 (50%)
First incidence (days)^d^ | 736 (T) | 737 (T) | 736 (T) | 717 | 506
Poly-3 test^e^ | P = 0.245 | P = 0.320N | P = 0.330N | P = 0.405 | P = 0.627
Brain (Cerebellum): Malignant Astrocytoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/47 (0%) | 1/48 (2%) | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.8% | 0.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 1/17 (6%) | 0/2 (0%)
First incidence (days) | – | – | – | 737 (T) | –
Poly-3 test | P = 0.363 | – | – | P = 0.461 | –
Brain (Cerebrum): Malignant Astrocytoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 4.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | – | – | – | 520
Poly-3 test | P = 0.106 | – | – | – | P = 0.397
Clitoral Gland: Adenoma
Overall rate | 6/48 (13%) | 3/48 (6%) | 6/48 (13%) | 3/48 (6%) | 5/47 (11%)
Adjusted rate | 13.9% | 7.5% | 14.9% | 8.4% | 19.2%
Terminal rate | 5/35 (14%) | 3/26 (12%) | 6/27 (22%) | 1/17 (6%) | 0/2 (0%)
First incidence (days) | 665 | 736 (T) | 736 (T) | 697 | 465
Poly-3 test | P = 0.340 | P = 0.278N | P = 0.570 | P = 0.346N | P = 0.409
Clitoral Gland: Carcinoma
Overall rate | 4/48 (8%) | 6/48 (13%) | 7/48 (15%) | 11/48 (23%) | 14/47 (30%)
Adjusted rate | 9.3% | 14.5% | 17.1% | 30.0% | 45.5%
Terminal rate | 4/35 (11%) | 3/26 (12%) | 5/27 (19%) | 6/17 (35%) | 1/2 (50%)
First incidence (days) | 736 (T) | 570 | 513 | 480 | 374
Poly-3 test | P < 0.001*** | P = 0.345 | P = 0.233 | P = 0.017* | P < 0.001***
Clitoral Gland: Squamous Cell Carcinoma
Overall rate | 2/48 (4%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/47 (0%)
Adjusted rate | 4.7% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate | 2/35 (6%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | 737 (T) | – | – | – | –
Poly-3 test | P = 0.111N | P = 0.252N | P = 0.252N | P = 0.283N | P = 0.387N
Clitoral Gland: Squamous Cell Papilloma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 2/47 (4%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.8% | 8.3%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 1/17 (6%) | 1/2 (50%)
First incidence (days) | – | – | – | 736 (T) | 620
Poly-3 test | P = 0.013* | – | – | P = 0.461 | P = 0.136
Clitoral Gland: Adenoma, Carcinoma, and Squamous Cell Carcinoma and Papilloma (Combined)
Overall rate | 11/48 (23%) | 9/48 (19%) | 13/48 (27%) | 14/48 (29%) | 20/47 (43%)
Adjusted rate | 25.5% | 21.8% | 31.7% | 38.0% | 60.3%
Terminal rate | 10/35 (29%) | 6/26 (23%) | 11/27 (41%) | 8/17 (47%) | 2/2 (100%)
First incidence (days) | 665 | 570 | 513 | 480 | 374
Poly-3 test | P < 0.001*** | P = 0.442N | P = 0.347 | P = 0.165 | P = 0.001**
Heart: Malignant Schwannoma
Overall rate | 2/48 (4%) | 1/48 (2%) | 4/48 (8%) | 2/48 (4%) | 1/48 (2%)
Adjusted rate | 4.6% | 2.5% | 9.8% | 5.6% | 4.1%
Terminal rate | 1/35 (3%) | 1/26 (4%) | 2/27 (7%) | 1/17 (6%) | 0/2 (0%)
First incidence (days) | 665 | 736 (T) | 555 | 660 | 645
Poly-3 test | P = 0.509 | P = 0.525N | P = 0.311 | P = 0.622 | P = 0.680N
Liver: Hepatocellular Adenoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%)
Adjusted rate | 2.3% | 0.0% | 0.0% | 0.0% | 0.0%
Terminal rate | 1/35 (3%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | 736 (T) | – | – | – | –
Poly-3 test | P = 0.265N | P = 0.513N | P = 0.513N | P = 0.539N | P = 0.606N
Mammary Gland: Adenoma
Overall rate | 2/48 (4%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 4/48 (8%)
Adjusted rate | 4.6% | 0.0% | 2.5% | 0.0% | 15.7%
Terminal rate | 1/35 (3%) | 0/26 (0%) | 1/27 (4%) | 0/17 (0%) | 1/2 (50%)
First incidence (days) | 714 | – | 737 (T) | – | 550
Poly-3 test | P = 0.050 | P = 0.252N | P = 0.524N | P = 0.284N | P = 0.144
Mammary Gland: Adenocarcinoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 2/48 (4%) | 2/48 (4%) | 2/48 (4%)
Adjusted rate | 2.3% | 0.0% | 4.9% | 5.6% | 8.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 1/27 (4%) | 1/17 (6%) | 0/2 (0%)
First incidence (days) | 579 | – | 555 | 522 | 550
Poly-3 test | P = 0.102 | P = 0.516N | P = 0.478 | P = 0.435 | P = 0.324
Mammary Gland: Fibroadenoma
Overall rate | 16/48 (33%) | 26/48 (54%) | 35/48 (73%) | 33/48 (69%) | 36/48 (75%)
Adjusted rate | 35.9% | 59.4% | 81.4% | 85.4% | 90.7%
Terminal rate | 10/35 (29%) | 15/26 (58%) | 22/27 (82%) | 17/17 (100%) | 2/2 (100%)
First incidence (days) | 549 | 483 | 548 | 584 | 403
Poly-3 test | P < 0.001*** | P = 0.019* | P < 0.001*** | P < 0.001*** | P < 0.001***
Mammary Gland: Adenocarcinoma and Fibroadenoma (Combined)
Overall rate | 17/48 (35%) | 26/48 (54%) | 36/48 (75%) | 34/48 (71%) | 36/48 (75%)
Adjusted rate | 37.7% | 59.4% | 82.7% | 86.5% | 90.7%
Terminal rate | 10/35 (29%) | 15/26 (58%) | 22/27 (82%) | 17/17 (100%) | 2/2 (100%)
First incidence (days) | 549 | 483 | 548 | 522 | 403
Poly-3 test | P < 0.001*** | P = 0.029* | P < 0.001*** | P < 0.001*** | P < 0.001***
Oral Mucosa: Squamous Cell Carcinoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 2/48 (4%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.8% | 7.8%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 1/17 (6%) | 0/2 (0%)
First incidence (days) | – | – | – | 737 (T) | 421
Poly-3 test | P = 0.015* | – | – | P = 0.461 | P = 0.145
Oral Mucosa: Squamous Cell Papilloma
Overall rate | 1/48 (2%) | 1/48 (2%) | 2/48 (4%) | 0/48 (0%) | 4/48 (8%)
Adjusted rate | 2.3% | 2.5% | 5.0% | 0.0% | 15.3%
Terminal rate | 1/35 (3%) | 0/26 (0%) | 2/27 (7%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | 737 (T) | 670 | 736 (T) | – | 520
Poly-3 test | P = 0.045* | P = 0.747 | P = 0.477 | P = 0.539N | P = 0.070
Tongue: Squamous Cell Carcinoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 4.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | – | – | – | 574
Poly-3 test | P = 0.105 | – | – | – | P = 0.397
Tongue: Squamous Cell Papilloma
Overall rate | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%)
Adjusted rate | 0.0% | 2.5% | 0.0% | 2.8% | 0.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | 693 | – | 584 | –
Poly-3 test | P = 0.548 | P = 0.488 | – | P = 0.464 | –
Oral Mucosa and Tongue (Combined): Squamous Cell Carcinoma and Papilloma (Combined)
Overall rate | 1/48 (2%) | 2/48 (4%) | 2/48 (4%) | 2/48 (4%) | 7/48 (15%)
Adjusted rate | 2.3% | 4.9% | 5.0% | 5.6% | 25.0%
Terminal rate | 1/35 (3%) | 0/26 (0%) | 2/27 (7%) | 1/17 (6%) | 0/2 (0%)
First incidence (days) | 737 (T) | 670 | 736 (T) | 584 | 421
Poly-3 test | P = 0.001** | P = 0.481 | P = 0.477 | P = 0.437 | P = 0.005**
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 32/47 (68%) | 36/48 (75%) | 32/47 (68%) | 27/46 (59%) | 24/48 (50%)
Adjusted rate | 73.2% | 80.5% | 74.6% | 68.7% | 70.8%
Terminal rate | 26/34 (77%) | 20/26 (77%) | 21/27 (78%) | 11/17 (65%) | 2/2 (100%)
First incidence (days) | 572 | 519 | 513 | 435 | 374
Poly-3 test | P = 0.243N | P = 0.277 | P = 0.540 | P = 0.414N | P = 0.509N
Stomach (Forestomach): Squamous Cell Papilloma
Overall rate | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 0/47 (0%) | 3/46 (7%)
Adjusted rate | 0.0% | 2.5% | 0.0% | 0.0% | 12.4%
Terminal rate | 0/35 (0%) | 1/26 (4%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | 736 (T) | – | – | 504
Poly-3 test | P = 0.015* | P = 0.487 | – | – | P = 0.048*
Thyroid Gland: C-Cell Adenoma
Overall rate | 2/48 (4%) | 4/48 (8%) | 6/46 (13%) | 4/46 (9%) | 2/47 (4%)
Adjusted rate | 4.7% | 9.8% | 15.3% | 11.4% | 8.1%
Terminal rate | 2/35 (6%) | 2/26 (8%) | 5/27 (19%) | 2/17 (12%) | 0/2 (0%)
First incidence (days) | 737 (T) | 610 | 682 | 670 | 571
Poly-3 test | P = 0.358 | P = 0.313 | P = 0.104 | P = 0.249 | P = 0.485
Thyroid Gland: C-Cell Carcinoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 0/46 (0%) | 0/46 (0%) | 1/47 (2%)
Adjusted rate | 2.3% | 0.0% | 0.0% | 0.0% | 4.1%
Terminal rate | 1/35 (3%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | 736 (T) | – | – | – | 705
Poly-3 test | P = 0.447 | P = 0.513N | P = 0.519N | P = 0.542N | P = 0.618
Thyroid Gland: Follicular Cell Adenoma
Overall rate | 0/48 (0%) | 3/48 (6%) | 3/46 (7%) | 1/46 (2%) | 5/47 (11%)
Adjusted rate | 0.0% | 7.4% | 7.6% | 2.9% | 19.3%
Terminal rate | 0/35 (0%) | 1/26 (4%) | 2/27 (7%) | 0/17 (0%) | 1/2 (50%)
First incidence (days) | – | 652 | 555 | 716 | 465
Poly-3 test | P = 0.017* | P = 0.109 | P = 0.104 | P = 0.459 | P = 0.007**
Thyroid Gland: Follicular Cell Carcinoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 2/46 (4%) | 3/46 (7%) | 3/47 (6%)
Adjusted rate | 0.0% | 0.0% | 5.1% | 8.6% | 12.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 3/17 (18%) | 0/2 (0%)
First incidence (days) | – | – | 634 | 737 (T) | 596
Poly-3 test | P = 0.006** | – | P = 0.219 | P = 0.085 | P = 0.051
Thyroid Gland: Follicular Cell Adenoma and Carcinoma (Combined)
Overall rate | 0/48 (0%) | 3/48 (6%) | 5/46 (11%) | 4/46 (9%) | 8/47 (17%)
Adjusted rate | 0.0% | 7.4% | 12.5% | 11.5% | 29.9%
Terminal rate | 0/35 (0%) | 1/26 (4%) | 2/27 (7%) | 3/17 (18%) | 1/2 (50%)
First incidence (days) | – | 652 | 555 | 716 | 465
Poly-3 test | P < 0.001*** | P = 0.109 | P = 0.025* | P = 0.037* | P < 0.001***
Uterus: Stromal Polyp
Overall rate | 11/48 (23%) | 11/48 (23%) | 13/48 (27%) | 14/48 (29%) | 11/48 (23%)
Adjusted rate | 25.2% | 26.3% | 31.4% | 38.1% | 38.1%
Terminal rate | 9/35 (26%) | 7/26 (27%) | 8/27 (30%) | 8/17 (47%) | 0/2 (0%)
First incidence (days) | 572 | 570 | 513 | 584 | 453
Poly-3 test | P = 0.086 | P = 0.550 | P = 0.345 | P = 0.155 | P = 0.184
Uterus: Stromal Sarcoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 2/48 (4%) | 1/48 (2%) | 2/48 (4%)
Adjusted rate | 2.3% | 0.0% | 4.9% | 2.8% | 7.8%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 1/27 (4%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | 721 | – | 619 | 364 | 453
Poly-3 test | P = 0.152 | P = 0.514N | P = 0.480 | P = 0.721 | P = 0.332
Zymbal’s Gland: Carcinoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 2/48 (4%)
Adjusted rate | 2.3% | 0.0% | 0.0% | 0.0% | 7.8%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | 686 | – | – | – | 343
Poly-3 test | P = 0.134 | P = 0.514N | P = 0.514N | P = 0.540N | P = 0.332
All Organs: Histiocytic Sarcoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 0.0% | 4.1%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | – | – | – | 704
Poly-3 test | P = 0.105 | – | – | – | P = 0.394
All Organs: Leukemia (Mononuclear)
Overall rate | 14/48 (29%) | 11/48 (23%) | 21/48 (44%) | 19/48 (40%) | 27/48 (56%)
Adjusted rate | 30.6% | 25.5% | 47.4% | 47.9% | 72.6%
Terminal rate | 8/35 (23%) | 3/26 (12%) | 10/27 (37%) | 7/17 (42%) | 1/2 (50%)
First incidence (days) | 432 | 508 | 373 | 456 | 435
Poly-3 test | P < 0.001*** | P = 0.382N | P = 0.076 | P = 0.076 | P < 0.001***
All Organs: Malignant Lymphoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.8% | 0.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | – | – | 435 | –
Poly-3 test | P = 0.356 | – | – | P = 0.466 | –
All Organs: Osteosarcoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.8% | 0.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | – | – | 526 | –
Poly-3 test | P = 0.357 | – | – | P = 0.465 | –
All Organs: Osteosarcoma or Osteoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 2.8% | 0.0%
Terminal rate | 0/35 (0%) | 0/26 (0%) | 0/27 (0%) | 0/17 (0%) | 0/2 (0%)
First incidence (days) | – | – | – | 526 | –
Poly-3 test | P = 0.357 | – | – | P = 0.465 | –
All Organs: Benign Neoplasms
Overall rate | 40/48 (83%) | 47/48 (98%) | 42/48 (88%) | 40/48 (83%) | 44/48 (92%)
Adjusted rate | 87.9% | 99.3% | 93.6% | 94.5% | 97.9%
Terminal rate | 32/35 (91%) | 26/26 (100%) | 26/27 (96%) | 17/17 (100%) | 2/2 (100%)
First incidence (days) | 549 | 483 | 513 | 435 | 374
Poly-3 test | P = 0.089 | P = 0.018* | P = 0.260 | P = 0.201 | P = 0.048*
All Organs: Malignant Neoplasms
Overall rate | 22/48 (46%) | 20/48 (42%) | 31/48 (65%) | 34/48 (71%) | 44/48 (92%)
Adjusted rate | 47.5% | 44.8% | 67.1% | 75.7% | 96.4%
Terminal rate | 14/35 (40%) | 9/26 (35%) | 16/27 (59%) | 11/17 (65%) | 2/2 (100%)
First incidence (days) | 432 | 483 | 373 | 364 | 343
Poly-3 test | P < 0.001*** | P = 0.481N | P = 0.042* | P = 0.004** | P < 0.001***
All Organs: Benign or Malignant Neoplasms
Overall rate | 45/48 (94%) | 48/48 (100%) | 46/48 (96%) | 46/48 (96%) | 48/48 (100%)
Adjusted rate | 93.8% | 100.0% | 97.3% | 99.2% | 100.0%
Terminal rate | 32/35 (92%) | 26/26 (100%) | 26/27 (96%) | 17/17 (100%) | 2/2 (100%)
First incidence (days) | 432 | 483 | 373 | 364 | 343
Poly-3 test | P = 0.083 | P = 0.119 | P = 0.364 | P = 0.180 | P = 0.119

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at the terminal sacrifice.

^d^ T indicates terminal sacrifice.

^e^ Beneath the 0 mM Glycidamide are the p-values associated with the trend test. Beneath the treated (0.0875, 0.175, 0.35, and 0.70 mM Glycidamide) group incidences are the p-values corresponding to pairwise comparisons between the 0 mM Glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

Table B-3 Historical Incidence of Thyroid Gland Follicular Cell Neoplasms in NCTR Control Female F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Adenoma | Carcinoma | Adenoma or Carcinoma
Sulfamethazine (February 1988) | Diet | 5/170 (2.9%) | 0/170 (0.0%) | 5/170 (2.9%)
Gentian Violet (November 1988) | Diet | 1/159 (0.6%) | 0/159 (0.0%) | 1/159 (0.6%)
Doxylamine (April 1991) | Diet | 0/47 (0.0%) | 0/47 (0.0%) | 0/47 (0.0%)
Triprolidine (June 1991) | Diet | 1/45 (2.2%) | 0/45 (0.0%) | 1/45 (2.2%)
Pyrilamine (July 1991) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Malachite Green (June 2001) | Diet | 0/46 (0.0%) | 0/46 (0.0%) | 0/46 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/46 (0.0%) | 0/46 (0.0%) | 0/46 (0.0%)
Acrylamide (February 2012) | Drinking Water | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Total (%) (All studies) | | 7/705 (0.1%) | 0/705 (0.0%) | 7/705 (0.1%)
Range | | 0.0–2.9% | 0.0% | 0.0–2.9%
Total (%) (Drinking water studies) | | 0/96 (0.0%) | 0/96 (0.0%) | 0/96 (0.0%)
Range | | 0.0% | 0.0% | 0.0%

Table B-4 Historical Incidence of Carcinoma of the Clitoral Gland in NCTR Control Female F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Doxylamine (April 1991) | Diet | 3/46 (6.5%)
Triprolidine (June 1991) | Diet | 0/46 (0.0%)
Pyrilamine (July 1991) | Diet | 3/45 (6.7%)
Fumonisin B_1_ (March 1999) | Diet | 1/41 (2.4%)
Malachite Green (June 2001) | Diet | 5/48 (10.4%)
Leucomalachite Green (June 2001) | Diet | 2/47 (4.3%)
Acrylamide (February 2012) | Drinking Water | 1/48 (2.1%)
Aloe vera Whole Leaf (2013) | Drinking Water | 3/48 (6.3%)
Total (%) (All studies) | | 18/369 (4.9%)
Range | | 0.0–10.4%
Total (%) (Drinking water studies) | | 4/96 (4.2%)
Range | | 2.1–6.3%

Table B-5 Historical Incidence of Fibroadenoma of the Mammary Gland in NCTR Control Female F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 48/177 (27.1%)
Gentian Violet (November 1988) | Diet | 65/169 (38.5%)
Doxylamine (April 1991) | Diet | 19/48 (39.6%)
Triprolidine (June 1991) | Diet | 15/46 (32.6%)
Pyrilamine (July 1991) | Diet | 20/47 (42.6%)
Fumonisin B_1_ (March 1999) | Diet | 18/47 (38.3%)
Malachite Green (June 2001) | Diet | 15/46 (32.6%)
Leucomalachite Green (June 2001) | Diet | 20/48 (41.7%)
Acrylamide (February 2012) | Drinking Water | 16/48 (33.3%)
Aloe vera Whole Leaf (2013) | Drinking Water | 12/47 (25.5%)
Total (%) (All studies) | | 248/723 (34.3%)
Range | | 25.5–42.6%
Total (%) (Drinking water studies) | | 28/95 (29.5%)
Range | | 25.5–33.3%

Table B-6 Historical Incidence of Neoplasms of the Oral Cavity in NCTR Control Female F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Papilloma or Squamous Cell Papilloma | Squamous Cell Carcinoma | Papilloma, Squamous Cell Papilloma, or Squamous Cell Carcinoma
Sulfamethazine (February 1988) | Diet | 0/179 (0.0%) | 0/179 (0.0%) | 0/179 (0.0%)
Gentian Violet (November 1988) | Diet | 1/167 (0.6%) | 0/167 (0.0%) | 1/167 (0.6%)
Doxylamine (April 1991) | Diet | –^a^ | –^a^ | –^a^
Triprolidine (June 1991) | Diet | – | – | –
Pyrilamine (July 1991) | Diet | 1/48 (2.1%) | 0/48 (0.0%) | 1/48 (2.1%)
Fumonisin B_1_ (March 1999) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Malachite Green (June 2001) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Acrylamide (February 2012) | Drinking Water | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Total (%) (All studies) | | 2/634 (0.3%) | 0/634 (0.0%) | 2/634 (0.3%)
Range | | 0.0–2.1% | 0.0% | 0.0–2.1%
Total (%) (Drinking water studies) | | 0/96 (0.0%) | 0/96 (0.0%) | 0/96 (0.0%)
Range | | 0.0% | 0.0% | 0.0%

^a^ Not reported.

Table B-7 Historical Incidence of Squamous Cell Papilloma or Carcinoma (Combined) of the Forestomach in NCTR Control Female F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 0/179 (0.0%)
Gentian Violet (November 1988) | Diet | 0/165 (0.0%)
Doxylamine (April 1991) | Diet | 0/47 (0.0%)
Triprolidine (June 1991) | Diet | 0/48 (0.0%)
Pyrilamine (July 1991) | Diet | 0/48 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 0/48 (0.0%)
Malachite Green (June 2001) | Diet | 0/48 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/48 (0.0%)
Acrylamide (February 2012) | Drinking Water | 0/48 (0.0%)
Aloe vera Whole Leaf (2013) | Drinking Water | 1/48 (2.1%)
Total (%) (All studies) | | 1/727 (0.1%)
Range | | 0.0–2.1%
Total (%) (Drinking water studies) | | 1/96 (1.0%)
Range | | 0.0–2.1%

Table B-8 Historical Incidence of Mononuclear Cell Leukemia in NCTR Control Female F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 67/179 (37.4%)
Gentian Violet (November 1988) | Diet | 77/171 (45.0%)
Doxylamine (April 1991) | Diet | 13/48 (27.1%)
Triprolidine (June 1991) | Diet | 12/48 (25.0%)
Pyrilamine (July 1991) | Diet | 6/48 (12.5%)
Fumonisin B_1_ (March 1999) | Diet | 13/48 (27.1%)
Malachite Green (June 2001) | Diet | 19/48 (39.6%)
Leucomalachite Green (June 2001) | Diet | 17/48 (35.4%)
Acrylamide (February 2012) | Drinking Water | 10/48 (20.8%)
Aloe vera Whole Leaf (2013) | Drinking Water | 10/48 (20.8%)
Total (%) (All studies) | | 244/734 (33.2%)
Range | | 12.5–45.0%
Total (%) (Drinking water studies) | | 20/96 (20.8%)
Range | | 20.8%

Table B-9 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | 7 | 15 | 11 | 20 | 40
Natural death | 2 | – | 4 | 3 | 3
Survivors
Moribund sacrifice | 3 | 6 | 5 | 8 | 3
Natural death | 1 | 1 | 1 | – | –
Terminal sacrifice | 35 | 26 | 27 | 17 | 2
Animals examined microscopically | 48 | 48 | 48 | 48 | 48
Alimentary System
Esophagus | (48) | (48) | (48) | (48) | (48)
Lumen, dilatation | – | – | – | 1 (2%) | –
Intestine large, cecum | (46) | (48) | (44) | (45) | (45)
Ulcer | 1 (2%) | – | – | – | –
Lumen, dilatation | – | 1 (2%) | – | – | 1 (2%)
Intestine large, colon | (46) | (48) | (44) | (45) | (45)
Goblet cell, hyperplasia | 1 (2%) | – | – | – | –
Intestine large, rectum | (46) | (48) | (45) | (45) | (45)
Intestine small, duodenum | (46) | (48) | (45) | (45) | (45)
Intestine small, ileum | (46) | (48) | (44) | (45) | (45)
Infiltration cellular, lymphocyte | 1 (2%) | – | – | – | –
Pigmentation | 1 (2%) | – | – | – | –
Intestine small, jejunum | (46) | (48) | (45) | (44) | (44)
Infiltration cellular, lymphocyte | – | – | – | – | 1 (2%)
Liver | (48) | (48) | (48) | (48) | (48)
Angiectasis | – | – | 1 (2%) | – | 1 (2%)
Basophilic focus | – | 2 (4%) | 2 (4%) | 2 (4%) | 4 (8%)
Basophilic focus, multiple | 41 (85%) | 38 (79%) | 36 (75%) | 35 (73%) | 32 (67%)
Clear cell focus | 2 (4%) | – | – | 1 (2%) | –
Congestion | 1 (2%) | 1 (2%) | – | – | –
Deformity | 7 (15%) | 4 (8%) | 4 (8%) | 5 (10%) | 7 (15%)
Degeneration, cystic | 3 (6%) | 2 (4%) | 3 (6%) | 2 (4%) | –
Eosinophilic focus | 5 (10%) | 8 (17%) | 5 (10%) | 4 (8%) | 4 (8%)
Eosinophilic focus, multiple | 2 (4%) | 3 (6%) | – | 4 (8%) | –
Granuloma | 3 (6%) | 3 (6%) | – | 1 (2%) | –
Hematopoietic cell proliferation | 1 (2%) | – | 1 (2%) | 1 (2%) | 2 (4%)
Hemorrhage | – | – | – | – | 1 (2%)
Hepatodiaphragmatic nodule | 2 (4%) | – | – | 2 (4%) | 1 (2%)
Hypertrophy | – | – | 1 (2%) | – | –
Infiltration cellular, lymphocyte | – | 1 (2%) | – | 2 (4%) | –
Inflammation, chronic active | 19 (40%) | 14 (29%) | 18 (38%) | 13 (27%) | 8 (17%)
Mitotic alteration | – | 1 (2%) | – | – | –
Mixed cell focus | 10 (21%) | 7 (15%) | 6 (13%) | 3 (6%) | 2 (4%)
Mixed cell focus, multiple | 8 (17%) | 8 (17%) | 6 (13%) | 5 (10%) | 3 (6%)
Necrosis | 2 (4%) | 8 (17%) | 1 (2%) | – | 3 (6%)
Pigmentation | 2 (4%) | 4 (8%) | 1 (2%) | – | 1 (2%)
Thrombosis | – | – | – | 2 (4%) | 1 (2%)
Vacuolization cytoplasmic | 15 (31%) | 11 (23%) | 18 (38%) | 12 (25%) | 7 (15%)
Bile duct, hyperplasia | 16 (33%) | 19 (40%) | 25 (52%) | 15 (31%) | 15 (31%)
Hepatocyte, degeneration | 4 (8%) | 6 (13%) | 3 (6%) | 3 (6%) | 4 (8%)
Hepatocyte, hyperplasia | – | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Mesentery | (4) | (4) | (1) | (9) | (5)
Cyst | – | – | – | 1 (11%) | –
Infiltration cellular, lymphocyte | – | – | – | 1 (11%) | –
Fat, necrosis | 4 (100%) | 4 (100%) | 1 (100%) | 7 (78%) | 5 (100%)
Oral Mucosa | (1) | (2) | (5) | (4) | (9)
Epithelium, hyperplasia | – | 1 (50%) | 3 (60%) | 3 (75%) | 3 (33%)
Pancreas | (48) | (48) | (48) | (48) | (48)
Cyst | – | – | – | – | 1 (2%)
Necrosis | – | – | – | 2 (4%) | –
Acinus, degeneration | 21 (44%) | 18 (38%) | 17 (35%) | 19 (40%) | 13 (27%)
Salivary glands | (48) | (48) | (48) | (48) | (48)
Infiltration cellular, lymphocyte | 1 (2%) | – | – | – | –
Stomach, forestomach | (48) | (48) | (48) | (47) | (46)
Edema | – | – | – | – | 1 (2%)
Fibrosis | 1 (2%) | – | – | – | –
Inflammation, chronic active | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%) | 2 (4%)
Necrosis | – | – | 1 (2%) | – | 1 (2%)
Ulcer | – | 2 (4%) | 1 (2%) | 2 (4%) | –
Epithelium, hyperplasia | 3 (6%) | 3 (6%) | 2 (4%) | 2 (4%) | 6 (13%)
Stomach, glandular | (47) | (48) | (45) | (46) | (46)
Necrosis | 1 (2%) | 1 (2%) | – | – | 1 (2%)
Pigmentation | 1 (2%) | – | – | – | –
Epithelium, degeneration | – | – | – | – | 1 (2%)
Tongue | (0) | (1) | (1) | (3) | (4)
Inflammation, suppurative | – | – | – | 1 (33%) | –
Keratin cyst | – | – | – | 1 (33%) | –
Epithelium, hyperplasia | – | – | – | 1 (33%) | 1 (25%)
Cardiovascular System
Blood vessel | (48) | (48) | (48) | (48) | (48)
Heart | (48) | (48) | (48) | (48) | (48)
Cardiomyopathy | 40 (83%) | 39 (81%) | 38 (79%) | 33 (69%) | 31 (65%)
Thrombosis | – | 3 (6%) | 2 (4%) | 1 (2%) | 1 (2%)
Endocardium, hyperplasia | – | 1 (2%) | – | – | –
Ventricle, dilatation | – | 1 (2%) | – | – | 1 (2%)
Endocrine System
Adrenal cortex | (48) | (48) | (48) | (48) | (48)
Accessory adrenal cortical nodule | – | – | – | 3 (6%) | 1 (2%)
Angiectasis | 2 (4%) | 3 (6%) | 2 (4%) | 2 (4%) | –
Congestion | 1 (2%) | – | – | – | –
Cyst | – | – | 1 (2%) | – | –
Degeneration, cystic | 3 (6%) | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Hemorrhage | 1 (2%) | – | – | – | –
Hyperplasia | 1 (2%) | 1 (2%) | – | 2 (4%) | 2 (4%)
Hypertrophy | 4 (8%) | – | 4 (8%) | – | –
Pigmentation | – | – | 1 (2%) | – | –
Vacuolization cytoplasmic | 12 (25%) | 13 (27%) | 12 (25%) | 17 (35%) | 22 (46%)
Adrenal medulla | (47) | (48) | (47) | (47) | (48)
Hyperplasia | 3 (6%) | 1 (2%) | 4 (9%) | 2 (4%) | –
Necrosis | – | – | – | – | 1 (2%)
Islets, pancreatic | (48) | (48) | (48) | (48) | (47)
Hyperplasia | – | 1 (2%) | – | 2 (4%) | –
Parathyroid gland | (48) | (45) | (48) | (47) | (46)
Hyperplasia | 2 (4%) | – | 2 (4%) | – | 3 (7%)
Pituitary gland | (47) | (48) | (47) | (46) | (48)
Pars distalis, angiectasis | – | – | – | – | 1 (2%)
Pars distalis, cyst | 3 (6%) | 3 (6%) | 1 (2%) | 1 (2%) | 5 (10%)
Pars distalis, hyperplasia | 11 (23%) | 7 (15%) | 12 (26%) | 14 (30%) | 20 (42%)
Pars intermedia, cyst | – | – | – | 1 (2%)
Pars intermedia, hyperplasia | – | – | – | 1 (2%) | 1 (2%)
Pars intermedia, Rathke’s Cleft, Degeneration | – | – | – | 1 (2%) | –
Thyroid gland | (48) | (48) | (46) | (46) | (47)
Cyst | – | – | – | 1 (2%) | –
Infiltration cellular, polymorphonuclear | 1 (2%) | – | – | – | –
C-cell, hyperplasia | 31 (65%) | 27 (56%) | 24 (52%) | 16 (35%) | 19 (40%)
Follicular cell, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
General Body System
Tissue NOS | (0) | (1) | (0) | (0) | (0)
Genital System
Clitoral gland | (48) | (48) | (48) | (48) | (47)
Fibrosis | – | – | – | 1 (2%) | –
Hyperkeratosis | – | – | – | – | 1 (2%)
Infiltration cellular, lymphocyte | 1 (2%) | – | 1 (2%) | 1 (2%) | 1 (2%)
Inflammation, suppurative | 16 (33%) | 13 (27%) | 17 (35%) | 20 (42%) | 13 (28%)
Inflammation, chronic | – | 1 (2%) | – | – | –
Inflammation, chronic active | 5 (10%) | 5 (10%) | 8 (17%) | – | 4 (9%)
Necrosis | – | 2 (4%) | – | – | –
Acinus, degeneration | 16 (33%) | 21 (44%) | 15 (31%) | 16 (33%) | 10 (21%)
Duct, ectasia | 25 (52%) | 21 (44%) | 25 (52%) | 17 (35%) | 19 (40%)
Epithelium, hyperplasia | 4 (8%) | 2 (4%) | 2 (4%) | 1 (2%) | 4 (9%)
Ovary | (48) | (48) | (48) | (48) | (48)
Atrophy | 44 (92%) | 46 (96%) | 44 (92%) | 46 (96%) | 47 (98%)
Cyst | 3 (6%) | 2 (4%) | 2 (4%) | 2 (4%) | 1 (2%)
Bilateral, cyst | – | – | – | 1 (2%) | –
Uterus | (48) | (48) | (48) | (48) | (48)
Angiectasis | – | – | 1 (2%) | – | –
Cyst | 2 (4%) | 4 (8%) | 5 (10%) | 5 (10%) | 4 (8%)
Decidual reaction | – | – | – | – | 1 (2%)
Hemorrhage | 1 (2%) | – | 1 (2%) | – | 1 (2%)
Cervix, fibrosis | – | 1 (2%) | – | 3 (6%) | 1 (2%)
Endometrium, hyperplasia, cystic | 11 (23%) | 17 (35%) | 14 (29%) | 14 (29%) | 23 (48%)
Lumen, dilatation | 6 (13%) | 3 (6%) | 6 (13%) | 3 (6%) | 3 (6%)
Vagina | (3) | (3) | (4) | (5) | (1)
Fibrosis | – | – | – | 1 (20%) | –
Inflammation, suppurative | – | 1 (33%) | – | – | –
Prolapse | – | – | 1 (25%) | – | 1 (100%)
Lumen, dilatation | 3 (100%) | 3 (100%) | 3 (75%) | 4 (80%) | –
Mucocyte, hyperplasia | 2 (67%) | – | – | – | –
Hematopoietic System
Bone marrow | (48) | (48) | (46) | (47) | (47)
Atrophy | – | – | – | 1 (2%) | 1 (2%)
Hyperplasia | 2 (4%) | 6 (13%) | 7 (15%) | 8 (17%) | 14 (30%)
Lymph node | (5) | (9) | (15) | (12) | (18)
Lumbar, hyperplasia, lymphoid | – | 1 (11%) | 1 (7%) | 1 (8%) | 1 (6%)
Lumbar, infiltration cellular, plasma cell | – | – | 1 (7%) | 1 (8%) | 1 (6%)
Lumbar, sinus, dilatation | – | – | – | 1 (8%) | 2 (11%)
Mediastinal, fibrosis | – | 1 (11%) | – | – | –
Mediastinal, hemorrhage | – | 1 (11%) | 1 (7%) | – | –
Mediastinal, hyperplasia, lymphoid | – | – | 1 (7%) | – | 1 (6%)
Mediastinal, pigmentation | – | 1 (11%) | 1 (7%) | – | –
Mediastinal, sinus, dilatation | – | 1 (11%) | – | – | –
Pancreatic, hyperplasia, lymphoid | 1 (20%) | – | – | 1 (8%) | 1 (6%)
Pancreatic, infiltration cellular, histiocyte | – | – | 1 (7%) | 1 (8%) | –
Pancreatic, infiltration cellular, plasma cell | – | – | – | – | 1 (6%)
Pancreatic, sinus, dilatation | – | – | 2 (13%) | – | –
Renal, hemorrhage | 1 (20%) | – | – | – | –
Renal, hyperplasia, lymphoid | – | – | – | – | 2 (11%)
Renal, infiltration, cellular, histiocyte | – | – | 1 (7%) | 1 (8%) | 1 (6%)
Renal, infiltration, cellular, plasma cell | – | – | – | – | 1 (6%)
Renal, sinus, dilatation | 1 (20%) | – | 2 (13%) | – | –
Sinus, thoracic, dilatation | – | – | – | 1 (8%) | –
Thoracic, hemorrhage | – | – | – | 1 (8%) | –
Thoracic, infiltration cellular, histiocyte | – | – | – | 1 (8%) | –
Lymph node, mandibular | (48) | (48) | (47) | (47) | (47)
Hemorrhage | – | 1 (2%) | 1 (2%) | – | 2 (4%)
Hyperplasia, lymphoid | 6 (13%) | 4 (8%) | 7 (15%) | 4 (9%) | 9 (19%)
Infiltration cellular, plasma cell | 22 (46%) | 16 (33%) | 18 (38%) | 20 (43%) | 16 (34%)
Sinus, dilatation | 3 (6%) | 5 (10%) | 3 (6%) | 5 (11%) | 6 (13%)
Lymph node, mesenteric | (47) | (48) | (47) | (48) | (48)
Erythrophagocytosis | – | 1 (2%) | – | – | –
Hemorrhage | 1 (2%) | 2 (4%) | – | 4 (8%) | 2 (4%)
Hyperplasia, lymphoid | 10 (21%) | 6 (13%) | 6 (13%) | 5 (10%) | 10 (21%)
Infiltration cellular, histiocyte | – | – | – | – | 1 (2%)
Infiltration cellular, mast cell | – | – | 1 (2%) | 1 (2%) | –
Infiltration cellular, plasma cell | 2 (4%) | 4 (8%) | 6 (13%) | 4 (8%) | 6 (13%)
Sinus, dilatation | 2 (4%) | 2 (4%) | – | – | 1 (2%)
Spleen | (48) | (48) | (48) | (48) | (48)
Accessory spleen | – | 1 (2%) | – | 1 (2%) | –
Congestion | – | – | 1 (2%) | – | –
Depletion lymphoid | – | – | – | – | 1 (2%)
Fibrosis | 1 (2%) | 3 (6%) | 3 (6%) | 5 (10%) | 5 (10%)
Hematopoietic cell proliferation | 14 (29%) | 15 (31%) | 9 (19%) | 16 (33%) | 11 (23%)
Hemorrhage | 1 (2%) | – | 1 (2%) | 2 (4%) | –
Hyperplasia, lymphoid | 1 (2%) | 3 (6%) | – | 2 (4%) | –
Hyperplasia, stromal | – | – | 1 (2%) | – | –
Necrosis | 1 (2%) | – | 1 (2%) | 1 (2%) | 2 (4%)
Pigmentation | 36 (75%) | 34 (71%) | 20 (42%) | 21 (44%) | 14 (29%)
Thymus | (45) | (47) | (45) | (45) | (44)
Atrophy | 43 (96%) | 44 (94%) | 41 (91%) | 40 (89%) | 40 (91%)
Cyst | – | – | – | – | 1 (2%)
Cyst, multilocular | – | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (48) | (48) | (48) | (48) | (48)
Abscess | – | 1 (2%) | – | – | –
Galactocele | 7 (15%) | 8 (17%) | 12 (25%) | 9 (19%) | 3 (6%)
Inflammation, chronic active | – | 1 (2%) | – | – | –
Lactation | 11 (23%) | 10 (21%) | 3 (6%) | 2 (4%) | 2 (4%)
Alveolus, hyperplasia | 10 (21%) | 6 (13%) | 2 (4%) | 1 (2%) | 1 (2%)
Skin | (48) | (48) | (48) | (48) | (48)
Abscess | – | 1 (2%) | – | – | –
Cyst epithelial inclusion | 1 (2%) | – | 2 (4%) | – | 2 (4%)
Hemorrhage | – | – | – | 1 (2%) | –
Infiltration cellular, plasma cell | – | 1 (2%) | – | – | –
Inflammation, suppurative | 3 (6%) | 3 (6%) | – | 3 (6%) | 2 (4%)
Inflammation, chronic active | – | 1 (2%) | – | 2 (4%) | –
Ulcer | 3 (6%) | 2 (4%) | 1 (2%) | 4 (8%) | 1 (2%)
Epithelium, hyperplasia | 3 (6%) | 2 (4%) | – | 2 (4%) | 1 (2%)
Musculoskeletal System
Bone | (0) | (1) | (1) | (0) | (0)
Bone, femur | (48) | (48) | (48) | (48) | (48)
Fibrous osteodystrophy | – | 3 (6%) | – | – | –
Osteopetrosis | – | – | – | 3 (6%) | –
Skeletal muscle | (48) | (48) | (48) | (48) | (48)
Nervous System
Brain, brain stem | (48) | (48) | (47) | (48) | (48)
Compression | 10 (21%) | 10 (21%) | 12 (26%) | 6 (13%) | 11 (23%)
Hemorrhage | 2 (4%) | 1 (2%) | 3 (6%) | – | –
Brain, cerebellum | (48) | (48) | (47) | (48) | (48)
Gliosis | – | – | 1 (2%) | 2 (4%) | 1 (2%)
Hemorrhage | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Ventricle, dilatation | 1 (2%) | – | – | – | –
Brain, cerebrum | (48) | (48) | (48) | (48) | (48)
Cyst | – | – | – | 1 (2%) | –
Gliosis | – | – | 3 (6%) | 2 (4%) | 3 (6%)
Hemorrhage | 1 (2%) | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%)
Necrosis | – | – | – | – | 1 (2%)
Ventricle, dilatation | 4 (8%) | 2 (4%) | 2 (4%) | – | –
Ventricle, hemorrhage | – | – | 1 (2%) | – | –
Peripheral nerve, sciatic | (48) | (48) | (48) | (48) | (48)
Axon, degeneration | 27 (56%) | 24 (50%) | 32 (67%) | 32 (67%) | 20 (42%)
Spinal cord, cervical | (48) | (48) | (48) | (48) | (48)
Gliosis | – | – | – | 1 (2%) | –
Hemorrhage | 1 (2%) | – | – | – | –
Inflammation, chronic active | 1 (2%) | – | – | – | –
Axon, degeneration | 32 (67%) | 19 (40%) | 25 (52%) | 14 (29%) | 14 (29%)
Nerve, degeneration | 2 (4%) | 3 (6%) | 3 (6%) | 1 (2%) | –
Spinal cord, lumbar | (48) | (48) | (47) | (48) | (48)
Gliosis | – | – | 2 (4%) | – | 1 (2%)
Axon, degeneration | 5 (10%) | 6 (13%) | 5 (11%) | 6 (13%) | 9 (19%)
Meninges, hyperplasia | – | – | – | 1 (2%) | –
Meninges, infiltration cellular, histiocyte | – | – | 1 (2%) | – | –
Nerve, degeneration | 35 (73%) | 35 (73%) | 35 (74%) | 30 (63%) | 23 (48%)
Nerve, gliosis | 1 (2%) | – | – | – | –
Nerve, hyperplasia | – | 1 (2%) | – | – | –
Neuron, degeneration | – | – | – | – | 1 (2%)
Spinal cord, thoracic | (48) | (48) | (47) | (48) | (48)
Hemorrhage | – | – | 1 (2%) | – | –
Mineralization | – | 1 (2%) | – | – | –
Axon, degeneration | 29 (60%) | 26 (54%) | 18 (38%) | 17 (35%) | 18 (38%)
Meninges, hyperplasia | – | – | 1 (2%) | 1 (2%) | –
Meninges, infiltration cellular, histiocyte | – | – | – | 1 (2%) | –
Nerve, degeneration | 8 (17%) | 7 (15%) | 8 (17%) | 8 (17%) | 2 (4%)
Respiratory System
Lung | (48) | (48) | (48) | (48) | (48)
Congestion | – | – | – | – | 2 (4%)
Fibrosis | – | 1 (2%) | – | – | –
Hemorrhage | 1 (2%) | – | – | – | –
Infiltration cellular, histiocyte | 24 (50%) | 25 (52%) | 24 (50%) | 20 (42%) | 9 (19%)
Inflammation, chronic active | – | – | 1 (2%) | – | –
Necrosis | – | – | – | – | 1 (2%)
Pigmentation | – | 1 (2%) | – | – | –
Polyarteritis | – | – | – | – | 1 (2%)
Alveolar epithelium, hyperplasia | 3 (6%) | 1 (2%) | 3 (6%) | 1 (2%) | 4 (8%)
Nose | (48) | (48) | (48) | (48) | (47)
Foreign body | – | – | – | 1 (2%) | –
Hyaline droplet | 5 (10%) | 6 (13%) | 2 (4%) | 5 (10%) | 2 (4%)
Inflammation, suppurative | 1 (2%) | 1 (2%) | 2 (4%) | 4 (8%) | 1 (2%)
Inflammation, chronic active | 2 (4%) | – | – | 1 (2%) | 1 (2%)
Goblet cell, hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | 3 (6%) | 2 (4%)
Trachea | (48) | (48) | (47) | (47) | (48)
Inflammation, suppurative | 1 (2%) | – | – | – | –
Necrosis | 1 (2%) | – | – | – | –
Ulcer | 1 (2%) | – | – | – | –
Special Senses System
Eye | (46) | (47) | (45) | (45) | (45)
Cataract | – | – | – | 1 (2%) | 2 (4%)
Inflammation, suppurative | 1 (2%) | – | – | – | –
Bilateral, cataract | – | – | 1 (2%) | – | –
Bilateral, retina, degeneration | 5 (11%) | 4 (9%) | 3 (7%) | 2 (4%) | 2 (4%)
Retina, degeneration | 7 (15%) | 7 (15%) | 6 (13%) | 6 (13%) | 4 (9%)
Harderian gland | (48) | (48) | (46) | (47) | (47)
Infiltration cellular, lymphocyte | 8 (17%) | 5 (10%) | 1 (2%) | 2 (4%) | 8 (17%)
Inflammation, chronic | 1 (2%) | – | – | – | –
Inflammation, chronic active | – | – | – | 1 (2%) | –
Pigmentation | – | – | 1 (2%) | – | –
Acinus, degeneration | – | – | 1 (2%) | – | –
Epithelium, hyperplasia | – | – | – | 1 (2%) | –
Zymbal’s gland | (1) | (0) | (0) | (0) | (2)
Urinary System
Kidney | (48) | (48) | (48) | (47) | (48)
Cyst | – | – | – | 1 (2%) | –
Hyaline droplet | 1 (2%) | 2 (4%) | 2 (4%) | 1 (2%) | 2 (4%)
Infarct | – | – | – | 1 (2%) | –
Mineralization | 34 (71%) | 33 (69%) | 29 (60%) | 36 (77%) | 30 (63%)
Nephropathy | 43 (90%) | 39 (81%) | 38 (79%) | 32 (68%) | 25 (52%)
Pigmentation | – | – | – | 1 (2%) | 3 (6%)
Urinary Bladder | (48) | (48) | (48) | (47) | (47)
Infiltration cellular, histiocyte | – | – | – | – | 1 (2%)
Lumen, dilatation | – | – | 2 (4%) | – | 1 (2%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.