# Appendix A Summary of Lesions in Male Rats in the Two-year Drinking Water Study of Glycidamide

Table A-1 Summary of the Incidence of Neoplasms in Male Rats in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | 16 | 13 | 24 | 26 | 36
Natural deaths | 4 | 10 | 4 | 2 | 1
Survivors
Moribund sacrifice | 7 | 5 | 4 | 10 | 7
Natural deaths | – | 2 | 1 | 2 | 2
Terminal sacrifice | 21 | 18 | 15 | 7 | 2
Other | – | – | – | 1 | –
Animals examined microscopically | 48 | 48 | 48 | 47 | 48
Alimentary System
Esophagus | (48) | (47) | (48) | (47) | (48)
Intestine large, cecum | (45) | (37) | (43) | (42) | (46)
Leukemia mononuclear | 1 (2%) | – | – | 2 (5%) | –
Intestine large, colon | (46) | (38) | (44) | (43) | (45)
Adenocarcinoma | – | 1 (3%) | – | – | –
Leukemia mononuclear | – | – | – | 1 (2%) | 1 (2%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Intestine large, rectum | (46) | (37) | (44) | (44) | (45)
Intestine small, duodenum | (46) | (37) | (43) | (43) | (46)
Leukemia mononuclear | – | – | – | 1 (2%) | 1 (2%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Intestine small, ileum | (45) | (37) | (43) | (43) | (45)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia mononuclear | – | – | – | 1 (2%) | 1 (2%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Serosa, schwannoma malignant | – | – | 1 (2%) | – | –
Intestine small, jejunum | (45) | (36) | (43) | (43) | (45)
Adenocarcinoma | – | – | – | 1 (2%) | –
Leiomyoma | – | – | – | 1 (2%) | –
Liver | (47) | (47) | (48) | (47) | (47)
Hepatocellular adenoma | 1 (2%) | – | – | – | 2 (4%)
Hepatocellular adenoma, multiple | – | 1 (2%) | – | – | –
Histiocytic sarcoma | – | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 20 (43%) | 24 (51%) | 26 (54%) | 27 (57%) | 30 (64%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesentery | (3) | (8) | (6) | (9) | (4)
Adenocarcinoma, metastatic, intestine small, jejunum | – | – | – | 1 (11%) | –
Hemangioma | – | 1 (13%) | – | – | –
Leukemia mononuclear | 1 (33%) | 4 (50%) | – | 3 (33%) | 1 (25%)
Lipoma | 1 (33%) | – | – | – | –
Mesothelioma malignant | – | – | – | 1 (11%) | 2 (50%)
Oral mucosa | (4) | (3) | (2) | (6) | (7)
Squamous cell carcinoma | 1 (25%) | – | 1 (50%) | 1 (17%) | –
Squamous cell papilloma | 1 (25%) | 1 (33%) | – | 2 (33%) | 3 (43%)
Pancreas | (48) | (44) | (47) | (46) | (48)
Leukemia mononuclear | 1 (2%) | 5 (11%) | 2 (4%) | 5 (11%) | 5 (10%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | – | 1 (2%) | 3 (6%)
Sarcoma | 1 (2%) | – | – | – | –
Acinar cell, adenoma | – | 1 (2%) | 1 (2%) | – | –
Salivary glands | (48) | (44) | (48) | (46) | (47)
Leukemia mononuclear | 2 (4%) | 1 (2%) | – | 2 (4%) | –
Lymphoma malignant | – | – | 1 (2%) | – | –
Schwannoma malignant | – | – | – | – | 1 (2%)
Stomach, forestomach | (46) | (46) | (46) | (47) | (47)
Leukemia mononuclear | – | – | – | 2 (4%) | –
Lymphoma malignant | – | – | 1 (2%) | – | –
Stomach, glandular | (46) | (38) | (44) | (44) | (46)
Leukemia mononuclear | 1 (2%) | 1 (3%) | – | 2 (5%) | 2 (4%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Tongue | (0) | (1) | (1) | (2) | (6)
Squamous cell carcinoma | – | – | 1 (100%) | – | –
Squamous cell papilloma | – | 1 (100%) | – | 1 (50%) | 4 (67%)
Cardiovascular System
Blood vessel | (48) | (48) | (48) | (47) | (48)
Leukemia mononuclear | – | – | 1 (2%) | 5 (11%) | 3 (6%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | 1 (2%) | – | –
Heart | (48) | (48) | (48) | (47) | (48)
Histiocytic sarcoma | – | – | – | – | 1 (2%)
Leukemia mononuclear | 12 (25%) | 18 (38%) | 14 (29%) | 16 (34%) | 24 (50%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | 1 (2%) | – | –
Schwannoma malignant | 2 (4%) | 3 (6%) | 3 (6%) | 7 (15%) | 8 (17%)
Endocrine System
Adrenal cortex | (47) | (47) | (48) | (47) | (47)
Histiocytic sarcoma | – | – | – | – | 1 (2%)
Leukemia mononuclear | 3 (6%) | 5 (11%) | – | 2 (4%) | 8 (17%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | – | – | 1 (2%)
Adrenal medulla | (46) | (47) | (48) | (47) | (48)
Leukemia mononuclear | 4 (9%) | 9 (19%) | 6 (13%) | 11 (23%) | 8 (17%)
Pheochromocytoma benign | 8 (17%) | 10 (21%) | 13 (27%) | 3 (6%) | 7 (15%)
Pheochromocytoma complex | 2 (4%) | 1 (2%) | – | – | –
Pheochromocytoma malignant | 4 (9%) | 1 (2%) | 4 (8%) | – | 2 (4%)
Bilateral, pheochromocytoma benign | 2 (4%) | 1 (2%) | 1 (2%) | 5 (11%) | 2 (4%)
Islets, pancreatic | (48) | (45) | (48) | (45) | (48)
Adenoma | 4 (8%) | 2 (4%) | 2 (4%) | 1 (2%) | 1 (2%)
Carcinoma | 1 (2%) | – | – | – | –
Leukemia mononuclear | – | – | – | 2 (4%) | 1 (2%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Parathyroid gland | (48) | (47) | (47) | (45) | (48)
Pituitary gland | (47) | (46) | (48) | (47) | (47)
Leukemia mononuclear | 5 (11%) | 9 (20%) | 4 (8%) | 6 (13%) | 3 (6%)
Pars distalis, adenoma | 28 (60%) | 22 (48%) | 31 (65%) | 21 (45%) | 19 (40%)
Pars distalis, adenoma, multiple | – | 1 (2%) | – | – | 1 (2%)
Pars distalis, carcinoma | – | – | – | 1 (2%) | –
Pars intermedia, adenoma | 1 (2%) | 1 (2%) | – | – | –
Thyroid gland | (47) | (42) | (48) | (47) | (46)
Leukemia mononuclear | 1 (2%) | – | – | – | –
Lymphoma malignant | – | – | 1 (2%) | – | –
C-cell, adenoma | 4 (9%) | – | 1 (2%) | – | 1 (2%)
C-cell, carcinoma | 1 (2%) | 2 (5%) | 1 (2%) | 1 (2%) | –
Follicular cell, adenoma | 2 (4%) | 1 (2%) | 3 (6%) | 3 (6%) | 7 (15%)
Follicular cell, adenoma, multiple | – | – | – | – | 1 (2%)
Follicular cell, carcinoma | – | 2 (5%) | 3 (6%) | 1 (2%) | 5 (11%)
General Body System
Tissue NOS | (2) | (0) | (1) | (1) | (1)
Histiocytic sarcoma | – | – | – | 1 (100%) | –
Leukemia mononuclear | 1 (50%) | – | – | – | –
Schwannoma malignant | – | – | 1 (100%) | – | –
Mediastinum, leukemia mononuclear | – | – | – | – | 1 (100%)
Thoracic, sarcoma | 1 (50%) | – | – | – | –
Genital System
Coagulating gland | (0) | (0) | (0) | (0) | (1)
Epididymis | (48) | (45) | (48) | (47) | (47)
Leukemia mononuclear | – | – | – | 1 (2%) | –
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | 1 (2%) | 3 (6%) | 10 (21%) | 17 (36%)
Adventitia, schwannoma malignant | – | – | 1 (2%) | – | –
Preputial gland | (48) | (48) | (48) | (47) | (48)
Adenoma | 2 (4%) | | 5 (10%) | 3 (6%) | 2 (4%)
Carcinoma | 6 (13%) | 1 (2%) | 2 (4%) | 6 (13%) | 4 (8%)
Hemangioma | – | – | – | 1 (2%) | –
Leukemia mononuclear | 3 (6%) | – | 1 (2%) | 2 (4%) | 1 (2%)
Schwannoma malignant | – | – | – | – | 1 (2%)
Squamous cell carcinoma | 6 (13%) | 5 (10%) | 4 (8%) | 4 (9%) | 3 (6%)
Squamous cell papilloma | – | 1 (2%) | – | – | –
Prostate | (47) | (47) | (48) | (47) | (48)
Adenoma | 1 (2%) | 1 (2%) | – | 3 (6%) | 1 (2%)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia mononuclear | 2 (4%) | 2 (4%) | – | 2 (4%) | –
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | – | 1 (2%) | 1 (2%)
Seminal vesicle | (47) | (38) | (46) | (46) | (47)
Leukemia mononuclear | – | – | – | 1 (2%) | –
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | – | 1 (2%) | 2 (4%)
Adventitia, sarcoma | 1 (2%) | – | – | – | –
Testes | (48) | (47) | (48) | (47) | (48)
Leukemia mononuclear | – | – | – | 1 (2%) | –
Mesothelioma malignant | – | 1 (2%) | 3 (6%) | 6 (13%) | 13 (27%)
Bilateral, interstitial cell, adenoma | 22 (46%) | 17 (36%) | 17 (35%) | 21 (45%) | 10 (21%)
Interstitial cell, adenoma | 11 (23%) | 17 (36%) | 16 (33%) | 13 (28%) | 17 (35%)
Hematopoietic System
Bone marrow | (47) | (40) | (45) | (46) | (46)
Histiocytic sarcoma | – | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 14 (30%) | 18 (45%) | 16 (36%) | 17 (37%) | 23 (50%)
Lymph node | (17) | (19) | (19) | (23) | (23)
Leukemia mononuclear | 1 (6%) | 1 (5%) | – | – | –
Axillary, leukemia mononuclear | 3 (18%) | 2 (11%) | 1 (5%) | 5 (22%) | 1 (4%)
Brachial, leukemia mononuclear | – | 1 (5%) | – | – | –
Cervical, leukemia mononuclear | – | – | – | 1 (4%) | –
Lumbar, leukemia mononuclear | 5 (29%) | 7 (37%) | 5 (26%) | 5 (22%) | 4 (17%)
Lumbar, squamous cell carcinoma, metastatic, preputial gland | 1 (6%) | – | – | – | –
Mediastinal, histiocytic sarcoma | – | – | – | 1 (4%) | –
Mediastinal, leukemia mononuclear | 7 (41%) | 8 (42%) | 4 (21%) | 7 (30%) | 7 (30%)
Mediastinal, lymphoma malignant | – | – | 1 (5%) | – | –
Pancreatic, histiocytic sarcoma | – | – | – | 1 (4%) | –
Pancreatic, leukemia mononuclear | 7 (41%) | 10 (53%) | 5 (26%) | 9 (39%) | 11 (48%)
Pancreatic, lymphoma malignant | – | – | 1 (5%) | – | –
Renal, histiocytic sarcoma | – | – | – | 1 (4%) | –
Renal, leukemia mononuclear | 6 (35%) | 5 (26%) | 5 (26%) | 8 (35%) | 4 (17%)
Thoracic, leukemia mononuclear | – | – | – | – | 1 (4%)
Lymph node, mandibular | (48) | (45) | (48) | (47) | (47)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia mononuclear | 14 (29%) | 17 (38%) | 17 (35%) | 16 (34%) | 21 (45%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Follicular, carcinoma, metastatic, thyroid gland | – | 1 (2%) | – | – | –
Lymph node, mesenteric | (48) | (46) | (46) | (46) | (47)
Histiocytic sarcoma | – | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 16 (33%) | 19 (41%) | 20 (43%) | 20 (43%) | 22 (47%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Spleen | (48) | (47) | (48) | (47) | (47)
Histiocytic sarcoma | – | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 21 (44%) | 25 (53%) | 26 (54%) | 27 (57%) | 31 (66%)
Mesothelioma malignant | – | – | – | – | 2 (4%)
Thymus | (43) | (38) | (43) | (42) | (43)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia mononuclear | 3 (7%) | 3 (8%) | 3 (7%) | 7 (17%) | 4 (9%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Integumentary System
Mammary gland | (45) | (42) | (45) | (44) | (42)
Adenocarcinoma | 2 (4%) | – | – | 1 (2%) | –
Adenoma | – | – | 1 (2%) | – | –
Fibroadenoma | 4 (9%) | 6 (14%) | 3 (7%) | 5 (11%) | 6 (14%)
Fibroadenoma, multiple | – | – | – | 2 (5%) | –
Leukemia mononuclear | 1 (2%) | – | – | 1 (2%) | –
Skin | (48) | (48) | (48) | (47) | (48)
Basal cell adenoma | 1 (2%) | – | 2 (4%) | 1 (2%) | –
Keratoacanthoma | 1 (2%) | 1 (2%) | – | 1 (2%) | 2 (4%)
Leukemia mononuclear | 1 (2%) | – | – | 1 (2%) | –
Squamous cell papilloma | – | – | – | – | 2 (4%)
Ear, squamous cell papilloma | – | – | – | 1 (2%) | –
Sebaceous gland, adenoma | – | 1 (2%) | – | – | –
Subcutaneous tissue, fibroma | 2 (4%) | – | 1 (2%) | 1 (2%) | 4 (8%)
Subcutaneous tissue, lipoma | – | – | 1 (2%) | 1 (2%) | –
Subcutaneous tissue, schwannoma malignant | – | – | 1 (2%) | 1 (2%) | –
Musculoskeletal System
Bone | (1) | (0) | (2) | (3) | (1)
Cranium, osteoma | – | – | – | 1 (33%) | 1 (100%)
Humerus, osteosarcoma | – | – | 1 (50%) | – | –
Vertebra, leukemia mononuclear | – | – | – | 1 (33%) | –
Bone, femur | (48) | (48) | (48) | (47) | (48)
Skeletal muscle | (48) | (48) | (48) | (47) | (48)
Mesothelioma malignant | – | – | – | – | 2 (4%)
Nervous System
Brain, brain stem | (48) | (48) | (48) | (47) | (48)
Histiocytic sarcoma | 1 (2%) | – | – | – | –
Leukemia mononuclear | 1 (2%) | 8 (17%) | 3 (6%) | 4 (9%) | 1 (2%)
Brain, cerebellum | (48) | (48) | (48) | (47) | (48)
Histiocytic sarcoma | 1 (2%) | – | – | – | –
Leukemia mononuclear | 2 (4%) | 7 (15%) | 5 (10%) | 5 (11%) | 2 (4%)
Brain, cerebrum | (48) | (48) | (48) | (47) | (48)
Glioma malignant | 1 (2%) | – | – | – | –
Histiocytic sarcoma | 1 (2%) | – | – | – | –
Leukemia mononuclear | 2 (4%) | 7 (15%) | 5 (10%) | 4 (9%) | –
Meninges, lymphoma malignant | – | – | 1 (2%) | – | –
Peripheral nerve, sciatic | (48) | (48) | (48) | (47) | (48)
Spinal cord, cervical | (47) | (46) | (48) | (47) | (48)
Leukemia mononuclear | 2 (4%) | 2 (4%) | 5 (10%) | 4 (9%) | –
Spinal cord, lumbar | (47) | (46) | (48) | (47) | (48)
Leukemia mononuclear | 2 (4%) | 2 (4%) | 5 (10%) | 5 (11%) | –
Spinal cord, thoracic | (47) | (46) | (48) | (47) | (48)
Leukemia mononuclear | – | 1 (2%) | 3 (6%) | 1 (2%) | –
Respiratory System
Lung | (48) | (47) | (48) | (47) | (47)
Alveolar/bronchiolar adenoma | – | 1 (2%) | – | – | 1 (2%)
Carcinoma, metastatic, thyroid gland | – | – | – | 1 (2%) | –
Carcinoma, metastatic, Zymbal’s gland | – | – | – | 1 (2%) | –
Histiocytic sarcoma | – | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 13 (27%) | 21 (45%) | 17 (35%) | 19 (40%) | 22 (47%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | 1 (2%) | – | –
Osteosarcoma, metastatic, bone | – | – | 1 (2%) | – | –
Pheochromocytoma malignant, metastatic, adrenal medulla | 1 (2%) | – | – | – | –
Alveolar epithelium, alveolar/bronchiolar adenoma | – | – | – | – | 1 (2%)
Nose | (48) | (45) | (47) | (45) | (48)
Osteosarcoma | – | – | – | 1 (2%) | –
Mucosa, squamous cell carcinoma | – | – | 1 (2%) | – | –
Trachea | (48) | (43) | (48) | (47) | (47)
Special Senses System
Ear | (0) | (0) | (1) | (1) | (0)
Neural crest tumor | – | – | 1 (100%) | 1 (100%) | –
Eye | (45) | (38) | (43) | (44) | (45)
Leukemia mononuclear | – | – | – | 1 (2%) | –
Melanoma malignant | – | – | – | 1 (2%) | –
Harderian gland | (47) | (47) | (48) | (46) | (48)
Leukemia mononuclear | 1 (2%) | – | 1 (2%) | 1 (2%) | –
Zymbal’s gland | (0) | (0) | (3) | (2) | (3)
Carcinoma | – | – | 3 (100%) | 2 (100%) | 3 (100%)
Urinary System
Kidney | (46) | (44) | (47) | (47) | (47)
Histiocytic sarcoma | – | – | – | 1 (2%) | –
Leukemia mononuclear | 7 (15%) | 11 (25%) | 7 (15%) | 12 (26%) | 10 (21%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | – | 1 (2%) | 2 (4%)
Urethra | (0) | (0) | (0) | (0) | (1)
Urinary bladder | (48) | (43) | (48) | (47) | (47)
Leukemia mononuclear | – | – | – | 3 (6%) | 1 (2%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | – | – | – | 1 (2%)
Transitional epithelium, papilloma | 1 (2%) | – | – | – | –
Systemic Lesions
Multiple organs | (48)^b^ | (48)^b^ | (48)^b^ | (47)^b^ | (48)^b^
Histiocytic sarcoma | 1 (2%) | – | – | 1 (2%) | 1 (2%)
Leukemia mononuclear | 21 (44%) | 26 (54%) | 27 (56%) | 27 (57%) | 31 (65%)
Lymphoma malignant | – | – | 1 (2%) | – | –
Mesothelioma malignant | – | 1 (2%) | 4 (8%) | 10 (21%) | 17 (35%)
Neoplasm Summary
Total animals with primary neoplasms^c^ | 48 | 47 | 48 | 47 | 47
Total primary neoplasms | 148 | 131 | 159 | 158 | 171
Total animals with benign neoplasms | 44 | 44 | 46 | 43 | 42
Total benign neoplasms | 97 | 88 | 98 | 91 | 95
Total animals with malignant neoplasms | 33 | 32 | 41 | 41 | 45
Total malignant neoplasms | 51 | 43 | 60 | 66 | 76
Total animals with metastatic neoplasms | 2 | 1 | 1 | 3 | –
Total metastatic neoplasms | 2 | 1 | 1 | 3 | –
Total animals with neoplasms uncertain-benign or malignant | – | – | 1 | 1 | –
Total uncertain neoplasms | – | – | 1 | 1 | –

^a^ Number of animals examined microscopically at the site and the number of animals with neoplasm.

^b^ Number of animals with any tissue examined microscopically.

^c^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-2 Statistical Analysis of Neoplasms in Male Rats in the Two-year Drinking Water Study of Glycidamide

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | | 0.70 mM
Adrenal Medulla: Benign Pheochromocytoma
Overall rate^a^ | 10/46 (22%) | 11/47 (23%) | 14/48 (29%) | 8/47 (17%) | | 9/48 (19%)
Adjusted rate^b^ | 26.4% | 28.7% | 37.8% | 23.1% | | 30.6%
Terminal rate^c^ | 6/21 (29%) | 4/18 (22%) | 9/15 (60%) | 2/7 (29%) | | 1/2 (50%)
First incidence (days)^d^ | 522 | 468 | 577 | 634 | | 543
Poly-3 test^e^ | P = 0.531 | P = 0.513 | P = 0.204 | P = 0.478N | | P = 0.457
Adrenal Medulla: Benign Pheochromocytoma, Bilateral
Overall rate | 2/46 (4%) | 1/47 (2%) | 1/48 (2%) | 5/47 (11%) | | 2/48 (4%)
Adjusted rate | 5.4% | 2.7% | 2.8% | 14.7% | | 7.3%
Terminal rate | 1/21 (5%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 725 | 574 | 730 | 676 | | 554
Poly-3 test | P = 0.169 | P = 0.502N | P = 0.508N | P = 0.180 | | P = 0.584
Adrenal Medulla: Malignant Pheochromocytoma
Overall rate | 4/46 (9%) | 1/47 (2%) | 4/48 (8%) | 0/47 (0%) | | 2/48 (4%)
Adjusted rate | 10.6% | 2.8% | 10.9% | 0.0% | | 7.4%
Terminal rate | 2/21 (10%) | 0/18 (0%) | 1/15 (7%) | 0/7 (0%) | | 1/2 (50%)
First incidence (days) | 522 | 715 | 639 | – | | 662
Poly-3 test | P = 0.316N | P = 0.190N | P = 0.629 | P = 0.076N | | P = 0.502N
Brain (Cerebrum): Malignant Glioma
Overall rate | 1/48 (2%) | 0/48 (0%) | 0/48 (0%) | 0/47 (0%) | | 0/48 (0%)
Adjusted rate | 2.6% | 0.0% | 0.0% | 0.0% | | 0.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | 725 | – | – | – | | –
Poly-3 test | P = 0.305N | P = 0.509N | P = 0.510N | P = 0.525N | | P = 0.568N
Heart: Malignant Schwannoma
Overall rate | 2/48 (4%) | 3/48 (6%) | 3/48 (6%) | 7/47 (15%) | | 8/48 (17%)
Adjusted rate | 5.3% | 8.3% | 8.3% | 19.6% | | 26.4%
Terminal rate | 2/21 (10%) | 2/18 (11%) | 3/15 (20%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 736 (T) | 715 | 737 (T) | 550 | | 439
Poly-3 test | P = 0.002** | P = 0.481 | P = 0.478 | P = 0.061 | | P = 0.015*
Mammary Gland: Fibroadenoma
Overall rate | 4/45 (9%) | 6/42 (14%) | 3/45 (7%) | 7/44 (16%) | | 6/42 (14%)
Adjusted rate | 10.9% | 18.3% | 8.8% | 21.3% | | 22.0%
Terminal rate | 2/21 (10%) | 4/15 (27%) | 1/14 (7%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 702 | 674 | 449 | 632 | | 446
Poly-3 test | P = 0.125 | P = 0.297 | P = 0.540N | P = 0.195 | | P = 0.197
Oral Mucosa: Squamous Cell Carcinoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 1/48 (2%) | 1/47 (2%) | | 0/48 (0%)
Adjusted rate | 2.6% | 0.0% | 2.8% | 3.0% | | 0.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | 725 | – | 729 | 634 | | –
Poly-3 test | P = 0.489N | P = 0.509N | P = 0.751 | P = 0.735 | | P = 0.568N
Oral Mucosa: Squamous Cell Papilloma
Overall rate | 1/48 (2%) | 1/48 (2%) | 0/48 (0%) | 2/47 (4%) | | 3/48 (6%)
Adjusted rate | 2.6% | 2.7% | 0.0% | 5.9% | | 10.9%
Terminal rate | 1/21 (5%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 737 (T) | 640 | – | 585 | | 623
Poly-3 test | P = 0.050* | P = 0.754 | P = 0.509N | P = 0.462 | | P = 0.201
Tongue: Squamous Cell Carcinoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/47 (0%) | | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 2.7% | 0.0% | | 0.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | – | 497 | – | | –
Poly-3 test | P = 0.649N | – | P = 0.494 | – | | –
Tongue: Squamous Cell Papilloma
Overall rate | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 1/47 (2%) | | 4/48 (8%)
Adjusted rate | 0.0% | 2.7% | 0.0% | 3.0% | | 14.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | – | 648 | – | 737 (T) | | 516
Poly-3 test | P = 0.003** | P = 0.493 | – | P = 0.475 | | P = 0.031*
Oral Mucosa and Tongue (Combined): Squamous Cell Carcinoma and Papilloma
Overall rate | 2/48 (4%) | 2/48 (4%) | 2/48 (4%) | 3/47 (6%) | | 7/48 (15%)
Adjusted rate | 5.3% | 5.4% | 5.4% | 8.8% | | 23.9%
Terminal rate | 1/21 (5%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 725 | 640 | 497 | 585 | | 516
Poly-3 test | P = 0.005** | P = 0.686 | P = 0.685 | P = 0.454 | | P = 0.030*
Pancreas: Acinar Cell Adenoma
Overall rate | 0/48 (0%) | 1/44 (2%) | 1/47 (2%) | 0/46 (0%) | | 0/48 (0%)
Adjusted rate | 0.0% | 2.9% | 2.8% | 0.0% | | 0.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 1/15 (7%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | 648 | 737 (T) | – | | –
Poly-3 test | P = 0.435N | P = 0.484 | P = 0.486 | – | | –
Pancreatic Islets: Adenoma
Overall rate | 4/48 (8%) | 2/45 (4%) | 2/48 (4%) | 1/45 (2%) | | 1/48 (2%)
Adjusted rate | 10.6% | 5.7% | 5.4% | 3.1% | | 3.7%
Terminal rate | 3/21 (14%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | 733 | 640 | 577 | 577 | | 723
Poly-3 test | P = 0.180N | P = 0.367N | P = 0.346N | P = 0.227N | | P = 0.299N
Pancreatic Islets: Carcinoma
Overall rate | 1/48 (2%) | 0/45 (0%) | 0/48 (0%) | 0/45 (0%) | | 0/48 (0%)
Adjusted rate | 2.6% | 0.0% | 0.0% | 0.0% | | 0.0%
Terminal rate | 1/21 (5%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | 737 (T) | – | – | – | | –
Poly-3 test | P = 0.309N | P = 0.516N | P = 0.509N | P = 0.535N | | P = 0.568N
Pancreatic Islets: Adenoma and Carcinoma (Combined)
Overall rate | 5/48 (10%) | 2/45 (4%) | 2/48 (4%) | 1/45 (2%) | | 1/48 (2%)
Adjusted rate | 13.2% | 5.7% | 5.4% | 3.1% | | 3.7%
Terminal rate | 4/21 (19%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2% (0%)
First incidence (days) | 733 | 640 | 577 | 577 | | 723
Poly-3 test | P = 0.114N | P = 0.240N | P = 0.222N | P = 0.138N | | P = 0.200N
Pituitary Gland (Pars Distalis): Adenoma
Overall rate | 28/47 (60%) | 23/46 (50%) | 31/48 (65%) | 21/47 (45%) | | 20/47 (43%)
Adjusted rate | 69.1% | 58.0% | 75.0% | 54.7% | | 60.5%
Terminal rate | 14/20 (70%) | 9/18 (50%) | 11/15 (73%) | 4/7 (57%) | | 2/2 (100%)
First incidence (days) | 402 | 476 | 505 | 573 | | 439
Poly-3 test | P = 0.204N | P = 0.197N | P = 0.352 | P = 0.120N | | P = 0.282N
Preputial Gland: Adenoma
Overall rate | 2/48 (4%) | 0/48 (0%) | 5/48 (10%) | 3/47 (6%) | | 2/48 (4%)
Adjusted rate | 5.3% | 0.0% | 13.7% | 8.8% | | 7.4%
Terminal rate | 2/21 (10%) | 0/18 (0%) | 3/15 (20%) | 0/7 (0%) | | 0/2 0%)
First incidence (days) | 736 (T) | – | 652 | 676 | | 660
Poly-3 test | P = 0.295 | P = 0.246N | P = 0.197 | P = 0.452 | | P = 0.568
Preputial Gland: Carcinoma
Overall rate | 6/48 (13%) | 1/48 (2%) | 2/48 (4%) | 6/47 (13%) | | 4/48 (8%)
Adjusted rate | 15.8% | 2.7% | 5.4% | 17.0% | | 13.7%
Terminal rate | 4/21 (19%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 702 | 632 | 534 | 550 | | 428
Poly-3 test | P = 0.275 | P = 0.059N | P = 0.138N | P = 0.570 | | P = 0.542N
Preputial Gland: Squamous Cell Carcinoma
Overall rate | 6/48 (13%) | 5/48 (10%) | 4/48 (8%) | 4/47 (9%) | | 3/48 (6%)
Adjusted rate | 15.1% | 13.1% | 10.9% | 11.6% | | 10.6%
Terminal rate | 1/21 (5%) | 0/18 (0%) | 1/15 (7%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 527 | 466 | 577 | 585 | | 534
Poly-3 test | P = 0.347N | P = 0.528N | P = 0.418N | P = 0.460N | | P = 0.430N
Prostate: Adenoma
Overall rate | 1/47 (2%) | 1/47 (2%) | 0/48 (0%) | 3/47 (6%) | | 1/48 (2%)
Adjusted rate | 2.7% | 2.8% | 0.0% | 8.9% | | 3.7%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 733 | 558 | – | 682 | | 723
Poly-3 test | P = 0.276 | P = 0.752 | P = 0.508N | P = 0.266 | | P = 0.680
Skin (Subcutaneous Tissue): Fibroma
Overall rate | 2/48 (4%) | 0/48 (0%) | 1/48 (2%) | 1/47 (2%) | | 4/48 (8%)
Adjusted rate | 5.3% | 0.0% | 2.8% | 2.9% | | 14.1%
Terminal rate | 2/21 (10%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | 736 (T) | – | 682 | 577 | | 555
Poly-3 test | P = 0.043* | P = 0.246N | P = 0.515N | P = 0.538N | | P = 0.215
Testes (Interstitial Cell): Adenoma
Overall rate | 33/48 (69%) | 34/47 (72%) | 33/48 (69%) | 34/47 (72%) | | 27/48 (56%)
Adjusted rate | 77.6% | 80.5% | 76.9% | 80.5% | | 75.0%
Terminal rate | 17/21 (81%) | 15/18 (83%) | 13/15 (87%) | 7/7 (100%) | | 2/2 (100%)
First incidence (days) | 486 | 466 | 497 | 487 | | 428
Poly-3 test | P = 0.417N | P = 0.477 | P = 0.576N | P = 0.474 | | P = 0.498N
Testes (Bilateral/Interstitial Cell): Adenoma
Overall rate | 22/48 (46%) | 17/47 (36%) | 17/48 (35%) | 21/47 (45%) | | 10/48 (21%)
Adjusted rate | 55.4% | 44.3% | 43.9% | 56.0% | | 34.2%
Terminal rate | 15/21 (71%) | 11/18 (61%) | 8/15 (53%) | 5/7 (71%) | | 1/2 (50%)
First incidence (days) | 564 | 514 | 549 | 556 | | 518
Poly-3 test | P = 0.154N | P = 0.215N | P = 0.202N | P = 0.572 | | P = 0.056N
Testes: Malignant Mesothelioma
Overall rate | 0/48 (0%) | 1/47 (2%) | 3/48 (6%) | 6/47 (13%) | | 13/48 (27%)
Adjusted rate | 0.0% | 2.8% | 8.3% | 17.5% | | 40.5%
Terminal rate | 0/21 (0%) | 1/18 (6%) | 1/15 (7%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | – | 736 (T) | 686 | 634 | | 473
Poly-3 test | P < 0.001*** | P = 0.490 | P = 0.110 | P = 0.010** | | P < 0.001***
Epididymis: Malignant Mesothelioma
Overall rate | 0/48 (0%) | 1/45 (2%) | 3/48 (6%) | 10/47 (21%) | | 17/47 (36%)
Adjusted rate | 0.0% | 2.9% | 8.3% | 28.2% | | 51.6%
Terminal rate | 0/21 (0%) | 1/18 (6%) | 1/15 (7%) | 2/7 (29%) | | 1/2 (50%)
First incidence (days) | – | 736 (T) | 686 | 556 | | 473
Poly-3 test | P < 0.001*** | P = 0.483 | P = 0.110 | P < 0.001*** | | P < 0.001***
Testes and Epididymis (Combined): Malignant Mesothelioma
Overall rate | 0/48 (0%) | 1/48 (2%) | 3/48 (6%) | 10/47 (21%) | | 17/48 (35%)
Adjusted rate | 0.0% | 2.8% | 8.3% | 28.2% | | 51.4%
Terminal rate | 0/21 (0%) | 1/18 (6%) | 1/15 (7%) | 2/7 (29%) | | 1/2 (50%)
First incidence (days) | – | 736 (T) | 686 | 556 | | 473
Poly-3 test | P < 0.001*** | P = 0.491 | P = 0.110 | P < 0.001*** | | P < 0.001***
Thyroid Gland: C-Cell Adenoma
Overall rate | 4/47 (9%) | 0/42 (0%) | 1/48 (2%) | 0/47 (0%) | | 1/46 (2%)
Adjusted rate | 10.4% | 0.0% | 2.8% | 0.0% | | 3.8%
Terminal rate | 2/21 (10%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | 481 | – | 725 | – | | 439
Poly-3 test | P = 0.190N | P = 0.077N | P = 0.198N | P = 0.079N | | P = 0.311N
Thyroid Gland: C-Cell Carcinoma
Overall rate | 1/47 (2%) | 2/42 (5%) | 1/48 (2%) | 1/47 (2%) | | 0/46 (0%)
Adjusted rate | 2.7% | 5.8% | 2.7% | 3.0% | | 0.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | 708 | 624 | 518 | 676 | | –
Poly-3 test | P = 0.283N | P = 0.470 | P = 0.757 | P = 0.737 | | P = 0.572N
Thyroid Gland: Follicular Cell Adenoma
Overall rate | 2/47 (4%) | 1/42 (2%) | 3/48 (6%) | 3/47 (6%) | | 8/46 (17%)
Adjusted rate | 5.4% | 3.0% | 8.1% | 8.9% | | 28.4%
Terminal rate | 1/21 (5%) | 1/18 (6%) | 1/15 (7%) | 2/7 (29%) | | 1/2 (50%)
First incidence (days) | 724 | 737 (T) | 549 | 635 | | 520
Poly-3 test | P < 0.001*** | P = 0.534N | P = 0.494 | P = 0.454 | | P = 0.011*
Thyroid Gland: Follicular Cell Carcinoma
Overall rate | 0/47 (0%) | 2/42 (5%) | 3/48 (6%) | 1/47 (2%) | | 5/46 (11%)
Adjusted rate | 0.0% | 5.8% | 8.2% | 3.0% | | 18.3%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 2/15 (13%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | 683 | 536 | 603 | | 540
Poly-3 test | P = 0.014* | P = 0.217 | P = 0.114 | P = 0.481 | | P = 0.011*
Thyroid Gland: Follicular Cell Adenoma and Carcinoma (Combined)
Overall rate | 2/47 (4%) | 3/42 (7%) | 6/48 (13%) | 4/47 (9%) | | 13/46 (28%)
Adjusted rate | 5.4% | 8.8% | 16.0% | 11.7% | | 43.8%
Terminal rate | 1/21 (5%) | 1/18 (6%) | 3/15 (20%) | 2/7 (29%) | | 1/2 (50%)
First incidence (days) | 724 | 683 | 536 | 603 | | 520
Poly-3 test | P < 0.001*** | P = 0.460 | P = 0.130 | P = 0.295 | | P < 0.001***
Zymbal’s Gland: Carcinoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 3/48 (6%) | 2/47 (4%) | | 3/48 (6%)
Adjusted rate | 0.0% | 0.0% | 8.2% | 5.8% | | 10.4%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | – | 602 | 418 | | 473
Poly-3 test | P = 0.029* | – | P = 0.111 | P = 0.216 | | P = 0.076
All Organs: Hemangioma
Overall rate | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 1/47 (2%) | | 0/48 (0%)
Adjusted rate | 0.0% | 2.8% | 0.0% | 2.9% | | 0.0%
Terminal rate | 0/21 (0%) | 1/18 (6%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | 737 (T) | – | 573 | | –
Poly-3 test | P = 0.641 | P = 0.491 | – | P = 0.478 | | –
All Organs: Hemangiosarcoma or Hemangioma
Overall rate | 0/48 (0%) | 1/48 (2%) | 0/48 (0%) | 1/47 (2%) | | 0/48 (0%)
Adjusted rate | 0.0% | 2.8% | 0.0% | 2.9% | | 0.0%
Terminal rate | 0/21 (0%) | 1/18 (6%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | 737 (T) | – | 573 | | –
Poly-3 test | P = 0.641 | P = 0.491 | – | P = 0.478 | | –
All Organs: Histiocytic Sarcoma
Overall rate | 1/48 (2%) | 0/48 (0%) | 0/48 (0%) | 1/47 (2%) | | 1/48 (2%)
Adjusted rate | 2.6% | 0.0% | 0.0% | 3.0% | | 3.7%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | 633 | – | – | 737 (T) | | 568
Poly-3 test | P = 0.333 | P = 0.510N | P = 0.511N | P = 0.731 | | P = 0.680
All Organs: Leukemia (Mononuclear)
Overall rate | 21/48 (44%) | 26/48 (54%) | 27/48 (56%) | 27/47 (57%) | | 31/48 (65%)
Adjusted rate | 49.4% | 60.2% | 65.5% | 65.3% | | 76.1%
Terminal rate | 7/21 (33%) | 7/18 (39%) | 8/15 (53%) | 3/7 (43%) | | 1/2 (50%)
First incidence (days) | 481 | 468 | 505 | 484 | | 410
Poly-3 test | P = 0.008** | P = 0.211 | P = 0.093 | P = 0.097 | | P = 0.006**
All Organs: Malignant Lymphoma (Histiocytic, Lymphocytic, Mixed, NOS, or Undifferentiated Cell Type)
Overall rate | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 0/47 (0%) | | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 2.8% | 0.0% | | 0.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | – | 682 | – | | –
Poly-3 test | P = 0.650N | – | P = 0.492 | – | | –
All Organs: Mesothelioma (Benign, Malignant, NOS)
Overall rate | 0/48 (0%) | 1/48 (2%) | 4/48 (8%) | 10/47 (21%) | | 17/48 (35%)
Adjusted rate | 0.0% | 2.8% | 11.0% | 28.2% | | 51.4%
Terminal rate | 0/21 (0%) | 1/18 (6%) | 2/15 (13%) | 2/7 (29%) | | 1/2 (50%)
First incidence (days) | – | 736 (T) | 686 | 556 | | 473
Poly-3 test | P < 0.001*** | P = 0.491 | P = 0.054 | P < 0.001*** | | P < 0.001***
All Organs: Osteoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 0/48 (0%) | 1/47 (2%) | | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 0.0% | 3.0% | | 3.7%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | – | – | – | 737 (T) | | 676
Poly-3 test | P = 0.098 | – | – | P = 0.475 | | P = 0.434
All Organs: Osteosarcoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 1/47 (2%) | | 0/48 (0%)
Adjusted rate | 0.0% | 0.0% | 2.7% | 3.0% | | 0.0%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 0/7 (0%) | | 0/2 (0%)
First incidence (days) | – | – | 506 | 634 | | –
Poly-3 test | P = 0.524 | – | P = 0.494 | P = 0.477 | | –
All Organs: Osteosarcoma or Osteoma
Overall rate | 0/48 (0%) | 0/48 (0%) | 1/48 (2%) | 2/47 (4%) | | 1/48 (2%)
Adjusted rate | 0.0% | 0.0% | 2.7% | 5.9% | | 3.7%
Terminal rate | 0/21 (0%) | 0/18 (0%) | 0/15 (0%) | 1/7 (14%) | | 0/2 (0%)
First incidence (days) | – | – | 506 | 634 | | 676
Poly-3 test | P = 0.124 | – | P = 0.494 | P = 0.212 | | P = 0.434
All Organs: Benign Neoplasms
Overall rate | 44/48 (92%) | 44/48 (92%) | 46/48 (96%) | 43/47 (92%) | | 42/48 (88%)
Adjusted rate | 95.0% | 95.8% | 97.7% | 95.8% | | 95.5%
Terminal rate | 20/21 (95%) | 17/18 (94%) | 15/15 (100%) | 7/7 (100%) | | 2/2 (100%)
First incidence (days) | 402 | 466 | 449 | 487 | | 428
Poly-3 test | P = 0.589N | P = 0.637 | P = 0.430 | P = 0.645 | | P = 0.685
All Organs: Malignant Neoplasms
Overall rate | 33/48 (69%) | 32/48 (67%) | 41/48 (85%) | 41/47 (87%) | | 45/48 (94%)
Adjusted rate | 73.1% | 70.7% | 89.7% | 89.2% | | 97.4%
Terminal rate | 12/21 (57%) | 8/18 (44%) | 13/15 (87%) | 6/7 (86%) | | 2/2 (100%)
First incidence (days) | 481 | 466 | 497 | 418 | | 410
Poly-3 test | P < 0.001*** | P = 0.488N | P = 0.030* | P = 0.037* | | P < 0.001***
All Organs: Benign or Malignant Neoplasms
Overall rate | 48/48 (100%) | 47/48 (98%) | 48/48 (100%) | 47/47 (100%) | | 47/48 (98%)
Adjusted rate | 100.0% | 99.8% | 100.0% | 100.0% | | 99.7%
Terminal rate | 21/21 (100%) | 18/18 (100%) | 15/15 (100%) | 7/7 (100%) | | 2/2 (100%)
First incidence (days) | 402 | 466 | 449 | 418 | | 410
Poly-3 test | P = 0.998N | P = 1.000N | – | – | | P = 1.000N

^a^ Number of animals with neoplasm per number of animals examined microscopically.

^b^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Observed incidence at the terminal sacrifice.

^d^ T indicates terminal sacrifice.

^e^ Beneath the 0 mM Glycidamide are the p-values associated with the trend test. Beneath the treated (0.0875, 0.175, 0.35, and 0.70 mM Glycidamide) group incidences are the p-values corresponding to pairwise comparisons between the 0 mM Glycidamide group and the treated groups. The Poly-3 test accounts for differential mortality in animals that do not reach the terminal sacrifice. An N indicates a negative trend or decreased tumor incidence.

Table A-3 Historical Incidence of Thyroid Gland Follicular Cell Neoplasms in NCTR Control Male F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Adenoma | Carcinoma | Adenoma or Carcinoma
Sulfamethazine (February 1988) | Diet | 0/170 (0.0%) | 0/170 (0.0%) | 0/170 (0.0%)
Gentian Violet (November 1988) | Diet | 1/163 (0.6%) | 0/163 (0.0%) | 1/163 (0.6%)
Doxylamine (April 1991) | Diet | 1/48 (2.1%) | 0/48 (0.0%) | 1/48 (2.1%)
Triprolidine (June 1991) | Diet | 0/40 (0.0%) | 0/40 (0.0%) | 0/40 (0.0%)
Pyrilamine (July 1991) | Diet | 0/42 (0.0%) | 0/42 (0.0%) | 0/42 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/47 (0.0%) | 0/47 (0.0%) | 0/47 (0.0%)
Acrylamide (February 2012) | Drinking water | 0/47 (0.0%) | 1/47 (2.1%) | 1/47 (2.1%)
Aloe vera Whole Leaf (2013) | Drinking water | 2/48 (4.2%) | 0/48 (0.0%) | 2/48 (4.2%)
Total (%) (All studies) | | 4/653 (0.6%) | 1/653 (0.2%) | 5/653 (0.8%)
Range | | 0.0–4.2% | 0.0–2.1% | 0.0–4.2%
Total (%) (Drinking water studies) | | 2/95 (2.1%) | 1/95 (1.1%) | 3/95 (3.2%)
Range | | 0.0–4.2% | 0.0–2.1% | 2.1–4.2%

Table A-4 Historical Incidence of Malignant Mesothelioma (All Sites) in NCTR Control Male F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 11/179 (6.1%)
Gentian Violet (November 1988) | Diet | 6/180 (3.3%)
Doxylamine (April 1991) | Diet | 2/48 (4.2%)
Triprolidine (June 1991) | Diet | 3/47 (6.4%)
Pyrilamine (July 1991) | Diet | 2/48 (4.2%)
Fumonisin B_1_ (March 1999) | Diet | 3/48 (6.3%)
Leucomalachite Green (June 2001) | Diet | 2/48 (4.2%)
Acrylamide (February 2012) | Drinking water | 2/48 (4.2%)
Aloe vera Whole Leaf (2013) | Drinking water | 0/48 (0.0%)
Total (%) (All studies) | | 31/694 (4.5%)
Range | | 0.0–6.4%
Total (%) (Drinking water studies) | | 2/96 (2.1%)
Range | | 0.0–4.2%

Table A-5 Historical Incidence of Malignant Schwannoma of the Heart in NCTR Control Male F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 0/179 (0.0%)
Gentian Violet (November 1988) | Diet | 0/179 (0.0%)
Doxylamine (April 1991) | Diet | 0/48 (0.0%)
Triprolidine (June 1991) | Diet | 0/47 (0.0%)
Pyrilamine (July 1991) | Diet | 0/48 (0.0%)
Fumonisin B_1_ (March 1999) | Diet | 0/48 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/48 (0.0%)
Acrylamide (February 2012) | Drinking water | 1/48 (2.1%)
Aloe vera Whole Leaf (2013) | Drinking water | 1/48 (2.1%)
Total (%) (All studies) | | 2/693 (0.3%)
Range | | 0.0–2.1%
Total (%) (Drinking water studies) | | 2/96 (2.1%)
Range | | 2.1%

Table A-6 Historical Incidence of Mononuclear Cell Leukemia in NCTR Control Male F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Sulfamethazine (February 1988) | Diet | 62/179 (34.6%)
Gentian Violet (November 1988) | Diet | 104/180 (57.8%)
Doxylamine (April 1991) | Diet | 18/48 (37.5%)
Triprolidine (June 1991) | Diet | 17/47 (36.2%)
Pyrilamine (July 1991) | Diet | 15/48 (31.3%)
Fumonisin B_1_ (March 1999) | Diet | 24/48 (50.0%)
Leucomalachite Green (June 2001) | Diet | 29/48 (60.4%)
Acrylamide (February 2012) | Drinking water | 31/48 (64.6%)
Aloe vera Whole Leaf (2013) | Drinking water | 27/48 (56.3%)
Total (%) (All studies) | | 327/694 (47.1%)
Range | | 31.3–64.6%
Total (%) (Drinking water studies) | | 58/96 (60.4%)
Range | | 56.3–64.6%

Table A-7 Historical Incidence of Neoplasms of the Oral Cavity in NCTR Control Male F344/N Nctr Rats

Study (Report Date) | Route of Administration | Incidence in Controls
Study (Report Date) | Route of Administration | Papilloma or Squamous Cell Papilloma | Squamous Cell Carcinoma | Papilloma, Squamous Cell Papilloma, or Squamous Cell Carcinoma
Sulfamethazine (February 1988) | Diet | 0/179 (0.0%) | 0/179 (0.0%) | 0/179 (0.0%)
Gentian Violet (November 1988) | Diet | 0/178 (0.0%) | 1/178 (0.6%) | 1/178 (0.6%)
Doxylamine (April 1991) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Triprolidine (June 1991) | Diet | 1/47 (2.1%) | 0/47 (0.0%) | 1/47 (2.1%)
Pyrilamine (July 1991) | Diet | –^a^ | –^a^ | –^a^
Fumonisin B_1_ (March 1999) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Leucomalachite Green (June 2001) | Diet | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Acrylamide (February 2012) | Drinking water | 1/48 (2.1%) | 0/48 (0.0%) | 1/48 (2.1%)
Aloe vera Whole Leaf (2013) | Drinking water | 0/48 (0.0%) | 0/48 (0.0%) | 0/48 (0.0%)
Total (%) (All studies) | | 2/644 (0.3%) | 1/644 (0.2%) | 3/644 (0.5%)
Range | | 0.0–2.1% | 0.0–0.6% | 0.0–2.1%
Total (%) (Drinking water studies) | | 1/96 (1.0%) | 0/96 (0.0%) | 1/96 (1.0%)
Range | | 0.0–2.1% | 0.0% | 0.0–2.1%

^a^ Not reported.

Table A-8 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Two-year Drinking Water Study of Glycidamide^a^

| 0 mM | 0.0875 mM | 0.175 mM | 0.35 mM | 0.70 mM
Disposition Summary
Animals initially in study | 48 | 48 | 48 | 48 | 48
Early deaths
Moribund sacrifice | 16 | 13 | 24 | 26 | 36
Natural deaths | 4 | 10 | 4 | 2 | 1
Survivors
Moribund sacrifice | 7 | 5 | 4 | 10 | 7
Natural deaths | – | 2 | 1 | 2 | 2
Terminal sacrifice | 21 | 18 | 15 | 7 | 2
Other | – | – | – | 1 | –
Animals examined microscopically | 48 | 48 | 48 | 47 | 48
Alimentary System
Esophagus | (48) | (47) | (48) | (47) | (48)
Inflammation, suppurative | – | – | – | 1 (2%) | –
Ulcer | – | – | – | 1 (2%) | –
Intestine large, cecum | (45) | (37) | (43) | (42) | (46)
Hyperplasia, lymphoid | – | – | – | 1 (2%) | –
Lumen, dilatation | – | – | – | 1 (2%) | –
Intestine large, colon | (46) | (38) | (44) | (43) | (45)
Hyperplasia, lymphoid | 1 (2%) | – | – | – | –
Intestine large, rectum | (46) | (37) | (44) | (44) | (45)
Edema | 1 (2%) | – | – | – | –
Intestine small, duodenum | (46) | (37) | (43) | (43) | (46)
Inflammation, chronic active | – | 1 (3%) | – | – | –
Necrosis | – | 1 (3%) | – | – | –
Epithelium, hyperplasia | – | 1 (3%) | – | 1 (2%) | –
Intestine small, ileum | (45) | (37) | (43) | (43) | (45)
Hyperplasia, lymphoid | – | – | – | – | 2 (4%)
Epithelium, hyperplasia | – | – | – | 1 (2%) | –
Intestine small, jejunum | (45) | (36) | (43) | (43) | (45)
Bacterium | – | 1 (3%) | – | – | –
Hyperplasia, lymphoid | – | – | – | – | 1 (2%)
Inflammation, chronic active | – | 1 (3%) | – | – | –
Necrosis | – | 1 (3%) | – | – | –
Liver | (47) | (47) | (48) | (47) | (47)
Angiectasis | 1 (2%) | – | – | – | 1 (2%)
Basophilic focus | 6 (13%) | 1 (2%) | 6 (13%) | 7 (15%) | 2 (4%)
Basophilic focus, multiple | 10 (21%) | 8 (17%) | 5 (10%) | 1 (2%) | 2 (4%)
Clear cell focus | 2 (4%) | 2 (4%) | – | – | 1 (2%)
Congestion | – | – | 1 (2%) | 1 (2%) | 1 (2%)
Deformity | 3 (6%) | 4 (9%) | 3 (6%) | 4 (9%) | 3 (6%)
Degeneration, cystic | 16 (34%) | 20 (43%) | 21 (44%) | 13 (28%) | 21 (45%)
Eosinophilic focus | 10 (21%) | 6 (13%) | 9 (19%) | 5 (11%) | 3 (6%)
Eosinophilic focus, multiple | 7 (15%) | 5 (11%) | 5 (10%) | 2 (4%) | 2 (4%)
Granuloma | 1 (2%) | – | – | – | –
Hemorrhage | – | – | 1 (2%) | – | –
Hepatodiaphragmatic nodule | – | 1 (2%) | – | 1 (2%) | 1 (2%)
Hypertrophy | – | 1 (2%) | – | – | –
Infiltration cellular, lymphocyte | – | – | – | 1 (2%) | 1 (2%)
Infiltration cellular, polymorphonuclear | – | 1 (2%) | – | – | –
Inflammation, chronic active | 7 (15%) | 5 (11%) | 7 (15%) | 4 (9%) | 2 (4%)
Mineralization | – | – | – | 1 (2%) | –
Mixed cell focus | 1 (2%) | 2 (4%) | 2 (4%) | 2 (4%) | 2 (4%)
Necrosis | 1 (2%) | 5 (11%) | 2 (4%) | 7 (15%) | 5 (11%)
Pigmentation | 3 (6%) | 5 (11%) | 6 (13%) | 5 (11%) | 3 (6%)
Thrombosis | 1 (2%) | 2 (4%) | – | – | 2 (4%)
Vacuolization cytoplasmic | 17 (36%) | 15 (32%) | 14 (29%) | 12 (26%) | 12 (26%)
Bile duct, hyperplasia | 39 (83%) | 38 (81%) | 39 (81%) | 38 (81%) | 36 (77%)
Biliary tract, fibrosis | – | 1 (2%) | 1 (2%) | 1 (2%) | –
Hepatocyte, degeneration | 2 (4%) | 6 (13%) | 6 (13%) | 10 (21%) | 8 (17%)
Hepatocyte, hyperplasia | 1 (2%) | 1 (2%) | 2 (4%) | – | –
Oval cell, hyperplasia | – | – | 1 (2%) | – | 1 (2%)
Mesentery | (3) | (8) | (6) | (9) | (4)
Hemorrhage | – | – | 1 (17%) | – | –
Pigmentation | – | – | 1 (17%) | – | –
Fat, necrosis | 2 (67%) | 6 (75%) | 6 (100%) | 7 (78%) | 1 (25%)
Oral Mucosa | (4) | (3) | (2) | (6) | (7)
Foreign body | – | – | 1 (50%) | – | –
Keratin cyst | – | – | – | 1 (17%) | 1 (14%)
Epithelium, hyperplasia | 2 (50%) | 2 (67%) | 1 (50%) | 3 (50%) | 2 (29%)
Epithelium, hyperplasia, basal cell | – | – | – | – | 1 (14%)
Pancreas | (48) | (44) | (47) | (46) | (48)
Angiectasis | – | – | – | – | 1 (2%)
Inflammation, chronic active | 1 (2%) | – | – | – | –
Polyarteritis | – | 1 (2%) | – | – | –
Vacuolization cytoplasmic | – | – | 1 (2%) | – | –
Acinar cell, hyperplasia | – | – | 1 (2%) | 1 (2%) | –
Acinus, degeneration | 25 (52%) | 30 (68%) | 19 (40%) | 25 (54%) | 23 (48%)
Salivary glands | (48) | (44) | (48) | (46) | (47)
Stomach, Forestomach | (46) | (46) | (46) | (47) | (47)
Edema | 1 (2%) | – | – | – | –
Inflammation, chronic active | – | 3 (7%) | 2 (4%) | 3 (6%) | –
Ulcer | – | 3 (7%) | 2 (4%) | 5 (11%) | –
Epithelium, hyperplasia | 4 (9%) | 6 (13%) | 3 (7%) | 9 (19%) | 2 (4%)
Stomach, glandular | (46) | (38) | (44) | (44) | (46)
Edema | 1 (2%) | – | – | – | –
Inflammation, suppurative | – | – | 1 (2%) | – | –
Inflammation, chronic active | 2 (4%) | – | 3 (7%) | 1 (2%) | –
Necrosis | 5 (11%) | 3 (8%) | 2 (5%) | 2 (5%) | 4 (9%)
Pigmentation | 1 (2%) | 2 (5%) | 1 (2%) | 1 (2%) | 1 (2%)
Ulcer | 1 (2%) | 1 (3%) | 2 (5%) | – | 1 (2%)
Epithelium, degeneration | – | – | 1 (2%) | 1 (2%) | –
Epithelium, hyperplasia | 2 (4%) | – | – | – | 1 (2%)
Tongue | (0) | (1) | (1) | (2) | (6)
Inflammation, suppurative | – | 1 (100%) | – | – | –
Epithelium, hyperplasia | – | – | – | 1 (50%) | –
Cardiovascular System
Blood vessel | (48) | (48) | (48) | (47) | (48)
Heart | (48) | (48) | (48) | (47) | (48)
Cardiomyopathy | 37 (77%) | 37 (77%) | 36 (75%) | 31 (66%) | 34 (71%)
Congestion | – | – | – | 1 (2%) | 1 (2%)
Metaplasia, osseous | – | 1 (2%) | – | – | 2 (4%)
Mineralization | 1 (2%) | 2 (4%) | 1 (2%) | – | –
Pigmentation | 1 (2%) | – | – | – | –
Thrombosis | 10 (21%) | 14 (29%) | 14 (29%) | 8 (17%) | 9 (19%)
Atrium, dilatation | 2 (4%) | 2 (4%) | 1 (2%) | – | 2 (4%)
Ventricle, dilatation | – | – | 2 (4%) | 2 (4%) | 1 (2%)
Endocrine System
Adrenal cortex | (47) | (47) | (48) | (47) | (47)
Accessory adrenal cortical nodule | – | – | 1 (2%) | 3 (6%)
Atrophy | – | – | – | – | 1 (2%)
Degeneration, cystic | – | 1 (2%) | – | – | 1 (2%)
Hyperplasia | 3 (6%) | – | – | 1 (2%) | –
Hypertrophy | 1 (2%) | – | 2 (4%) | 1 (2%) | 3 (6%)
Metaplasia, osseous | – | – | 1 (2%) | 1 (2%) | –
Thrombosis | – | – | – | – | 1 (2%)
Vacuolization cytoplasmic | 26 (55%) | 27 (57%) | 31 (65%) | 28 (60%) | 34 (72%)
Adrenal Medulla | (46) | (47) | (48) | (47) | (48)
Hyperplasia | 13 (28%) | 11 (23%) | 7 (15%) | 5 (11%) | 6 (13%)
Necrosis | – | 1 (2%) | – | – | –
Islets, pancreatic | (48) | (45) | (48) | (45) | (48)
Fibrosis | – | 1 (2%) | – | – | –
Hyperplasia | – | 4 (9%) | 2 (4%) | 2 (4%) | 3 (6%)
Parathyroid gland | (48) | (47) | (47) | (45) | (48)
Hyperplasia | 5 (10%) | 10 (21%) | 6 (13%) | 3 (7%) | 7 (15%)
Pituitary gland | (47) | (46) | (48) | (47) | (47)
Hemorrhage | – | – | – | 1 (2%) | –
Inflammation, suppurative | – | – | – | 1 (2%) | –
Pars distalis, angiectasis | 1 (2%) | 1 (2%) | – | – | –
Pars distalis, cyst | 2 (4%) | – | 3 (6%) | 1 (2%) | 3 (6%)
Pars Distalis, hyperplasia | 10 (21%) | 10 (22%) | 6 (13%) | 10 (21%) | 8 (17%)
Pars intermedia, cyst | – | 1 (2%) | – | – | –
Pars nervosa, Rathke’s cleft, degeneration | – | 2 (4%) | – | – | –
Thyroid gland | (47) | (42) | (48) | (47) | (46)
Cyst | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%) | –
C-cell, hyperplasia | 14 (30%) | 16 (38%) | 18 (38%) | 18 (38%) | 14 (30%)
Follicular cell, hyperplasia | – | 2 (5%) | 3 (6%) | – | 4 (9%)
General Body System
Tissue NOS | (2) | (0) | (1) | (1) | (1)
Genital System
Coagulating gland | (0) | (0) | (0) | (0) | (1)
Inflammation, suppurative | – | – | – | – | 1 (100%)
Necrosis | – | – | – | – | 1 (100%)
Epithelium, hyperplasia | – | – | – | – | 1 (100%)
Epididymis | (48) | (45) | (48) | (47) | (47)
Exfoliated germ cell | – | 1 (2%) | 2 (4%) | 3 (6%) | 4 (9%)
Hypospermia | 36 (75%) | 29 (64%) | 31 (65%) | 31 (66%) | 24 (51%)
Epithelium, degeneration | 31 (65%) | 25 (56%) | 27 (56%) | 28 (60%) | 18 (38%)
Preputial gland | (48) | (48) | (48) | (47) | (48)
Cyst | – | – | 1 (2%) | – | 1 (2%)
Fibrosis | – | – | – | – | 2 (4%)
Hemorrhage | 1 (2%) | – | – | – | –
Hyperkeratosis | – | – | – | 1 (2%) | 2 (4%)
Infiltration cellular, plasma cell | – | 1 (2%) | – | – | –
Inflammation, suppurative | 21 (44%) | 27 (56%) | 25 (52%) | 24 (51%) | 18 (38%)
Inflammation, chronic active | 14 (29%) | 7 (15%) | 9 (19%) | 8 (17%) | 10 (21%)
Necrosis | 1 (2%) | – | – | 1 (2%) | 1 (2%)
Acinus, degeneration | 24 (50%) | 25 (52%) | 25 (52%) | 26 (55%) | 22 (46%)
Duct, ectasia | 25 (52%) | 24 (50%) | 24 (50%) | 23 (49%) | 17 (35%)
Epithelium, hyperplasia | – | – | 2 (4%) | – | 2 (4%)
Prostate | (47) | (47) | (48) | (47) | (48)
Cyst multilocular | 1 (2%) | – | – | – | 2 (4%)
Infiltration cellular, lymphocyte | – | – | 1 (2%) | – | –
Inflammation, suppurative | 23 (49%) | 24 (51%) | 29 (60%) | 21 (45%) | 22 (46%)
Inflammation, chronic active | 11 (23%) | 6 (13%) | 8 (17%) | 8 (17%) | 7 (15%)
Necrosis | – | 1 (2%) | – | – | 1 (2%)
Acinus, degeneration | 1 (2%) | – | – | 1 (2%) | –
Epithelium, hyperplasia | 8 (17%) | 7 (15%) | 6 (13%) | 8 (17%) | 3 (6%)
Seminal vesicle | (47) | (38) | (46) | (46) | (47)
Atrophy | 27 (57%) | 17 (45%) | 25 (54%) | 27 (59%) | 18 (38%)
Inflammation, suppurative | – | – | – | – | 1 (2%)
Necrosis | – | – | – | – | 1 (2%)
Epithelium, hyperplasia | – | – | – | – | 2 (4%)
Lumen, dilatation | 2 (4%) | 1 (3%) | 3 (7%) | 1 (2%) | –
Testes | (48) | (47) | (48) | (47) | (48)
Cyst | 1 (2%) | – | – | – | –
Polyarteritis | 2 (4%) | – | 1 (2%) | – | –
Interstitial cell, hyperplasia | 7 (15%) | 3 (6%) | 8 (17%) | 6 (13%) | 11 (23%)
Seminiferous tubule, degeneration | 38 (79%) | 35 (74%) | 36 (75%) | 38 (81%) | 41 (85%)
Hematopoietic System
Bone marrow | (47) | (40) | (45) | (46) | (46)
Atrophy | – | 4 (10%) | 1 (2%) | 1 (2%) | –
Hyperplasia | 6 (13%) | 4 (10%) | 10 (22%) | 12 (26%) | 10 (22%)
Lymph node | (17) | (19) | (19) | (23) | (23)
Inguinal, hyperplasia, lymphoid | – | – | – | 1 (4%) | –
Inguinal, infiltration cellular, plasma cell | – | – | – | 1 (4%) | –
Lumbar, hyperplasia, lymphoid | – | – | – | 1 (4%) | 1 (4%)
Lumbar, infiltration cellular, plasma cell | – | – | 1 (5%) | – | 1 (4%)
Lumbar, sinus, dilatation | – | 2 (11%) | 2 (11%) | 1 (4%) | 2 (9%)
Mediastinal, hemorrhage | – | 1 (5%) | – | 2 (9%) | 2 (9%)
Mediastinal, hyperplasia, lymphoid | – | – | – | – | 1 (4%)
Mediastinal, pigmentation | – | – | 1 (5%) | – | –
Mediastinal, sinus, dilatation | 1 (6%) | 2 (11%) | 3 (16%) | 2 (9%) | 3 (13%)
Pancreatic, hemorrhage | – | – | – | – | 1 (4%)
Pancreatic, hyperplasia, lymphoid | 1 (6%) | 1 (5%) | 1 (5%) | 1 (4%) | 1 (4%)
Pancreatic, infiltration cellular, plasma cell | 1 (6%) | – | – | – | –
Pancreatic, sinus, dilatation | – | 1 (5%) | 1 (5%) | 2 (9%) | 2 (9%)
Renal, hemorrhage | – | 1 (5%) | – | – | –
Renal, hyperplasia, lymphoid | 1 (6%) | – | – | – | 2 (9%)
Renal, infiltration cellular, histiocyte | 1 (6%) | – | – | –
Renal, infiltration cellular, plasma cell | – | – | 3 (16%) | – | –
Renal, pigmentation | 1 (6%) | – | – | – | 1 (4%)
Renal, sinus, dilatation | 5 (29%) | 1 (5%) | 5 (26%) | 2 (9%) | 3 (13%)
Sinus, dilatation | – | 1 (5%) | – | – | –
Lymph node, mandibular | (48) | (45) | (48) | (47) | (47)
Hemorrhage | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%) | –
Hyperplasia, lymphoid | 7 (15%) | 6 (13%) | 6 (13%) | 7 (15%) | 11 (23%)
Infiltration cellular, plasma cell | 27 (56%) | 21 (47%) | 21 (44%) | 20 (43%) | 19 (40%)
Infiltration cellular, polymorphonuclear | – | 1 (2%) | – | – | –
Sinus, dilatation | 15 (31%) | 10 (22%) | 9 (19%) | 6 (13%) | 6 (13%)
Lymph node, mesenteric | (48) | (46) | (46) | (46) | (47)
Angiectasis | – | – | 1 (2%) | – | –
Hemorrhage | – | 1 (2%) | 1 (2%) | 1 (2%) | 3 (6%)
Hyperplasia, lymphoid | 15 (31%) | 9 (20%) | 11 (24%) | 12 (26%) | 10 (21%)
Infiltration cellular, histiocyte | – | – | 1 (2%) | – | 1 (2%)
Infiltration cellular, plasma cell | 8 (17%) | 6 (13%) | 2 (4%) | 1 (2%) | 1 (2%)
Metaplasia, osseous | – | – | 1 (2%) | – | –
Sinus, dilatation | 3 (6%) | 2 (4%) | 2 (4%) | 5 (11%) | 5 (11%)
Spleen | (48) | (47) | (48) | (47) | (47)
Accessory spleen | 1 (2%) | 3 (6%) | – | 1 (2%) | 3 (6%)
Congestion | 3 (6%) | 3 (6%) | 3 (6%) | 2 (4%) | 2 (4%)
Depletion lymphoid | – | – | 1 (2%) | 1 (2%) | 1 (2%)
Developmental malformation | 1 (2%) | – | – | – | –
Fibrosis | 6 (13%) | 10 (21%) | 13 (27%) | 13 (28%) | 11 (23%)
Hematopoietic cell proliferation | 4 (8%) | 4 (9%) | 6 (13%) | 8 (17%) | 7 (15%)
Hemorrhage | – | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%)
Hyperplasia, lymphoid | 3 (6%) | 2 (4%) | 2 (4%) | – | 1 (2%)
Hyperplasia, stromal | – | – | 1 (2%) | – | 1 (2%)
Necrosis | 1 (2%) | 3 (6%) | 1 (2%) | 1 (2%) | 1 (2%)
Pigmentation | 19 (40%) | 17 (36%) | 15 (31%) | 13 (28%) | 9 (19%)
Red pulp, hyperplasia | 1 (2%) | – | – | – | –
Thymus | (43) | (38) | (43) | (42) | (43)
Atrophy | 40 (93%) | 37 (97%) | 41 (95%) | 34 (81%) | 40 (93%)
Hemorrhage | – | 1 (3%) | – | – | –
Integumentary System
Mammary gland | (45) | (42) | (45) | (44) | (42)
Fibrosis | – | – | – | 1 (2%) | 1 (2%)
Galactocele | 4 (9%) | 4 (10%) | 5 (11%) | 4 (9%) | 6 (14%)
Lactation | 12 (27%) | 8 (19%) | 17 (38%) | 6 (14%) | 7 (17%)
Alveolus, hyperplasia | 2 (4%) | 1 (2%) | 4 (9%) | 1 (2%) | 1 (2%)
Duct, dilatation | 1 (2%) | – | – | – | –
Skin | (48) | (48) | (48) | (47) | (48)
Cyst epithelial inclusion | 3 (6%) | 1 (2%) | 3 (6%) | 5 (11%) | 4 (8%)
Fibrosis | 2 (4%) | 1 (2%) | – | 2 (4%) | 2 (4%)
Hyperkeratosis | 1 (2%) | 2 (4%) | – | 1 (2%) | –
Infiltration cellular, plasma cell | 1 (2%) | – | – | – | –
Inflammation, suppurative | – | – | – | 1 (2%) | –
Inflammation, chronic | – | – | – | 1 (2%) | –
Inflammation, chronic active | 1 (2%) | 1 (2%) | 1 (2%) | – | 1 (2%)
Necrosis | 1 (2%) | – | – | – | 1 (2%)
Ulcer | 1 (2%) | – | – | – | –
Epithelium, hyperplasia | – | 2 (4%) | – | 1 (2%) | 1 (2%)
Sebaceous gland, hyperplasia | – | – | – | – | 1 (2%)
Musculoskeletal System
Bone | (1) | (0) | (2) | (3) | (1)
Cranium, deformity | – | – | 1 (50%) | 1 (33%) | –
Vertebra, fracture | 1 (100%) | – | – | – | –
Bone, femur | (48) | (48) | (48) | (47) | (48)
Fibrous osteodystrophy | – | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%)
Osteopetrosis | – | 2 (4%) | – | 1 (2%) | –
Skeletal muscle | (48) | (48) | (48) | (47) | (48)
Nervous System
Brain, brain stem | (48) | (48) | (48) | (47) | (48)
Compression | 15 (31%) | 10 (21%) | 13 (27%) | 8 (17%) | 9 (19%)
Gliosis | – | 1 (2%) | – | – | 3 (6%)
Hemorrhage | 1 (2%) | 2 (4%) | 1 (2%) | 1 (2%) | 1 (2%)
Necrosis | – | 1 (2%) | – | – | –
Brain, cerebellum | (48) | (48) | (48) | (47) | (48)
Hemorrhage | – | – | 1 (2%) | 1 (2%) | 1 (2%)
Infiltration cellular, polymorphonuclear | – | – | – | 1 (2%) | –
Ventricle, dilatation | 2 (4%) | 1 (2%) | 3 (6%) | 1 (2%) | –
Brain, cerebrum | (48) | (48) | (48) | (47) | (48)
Compression | – | – | – | 1 (2%) | –
Gliosis | – | – | – | – | 2 (4%)
Hemorrhage | – | – | 1 (2%) | – | 1 (2%)
Mineralization | – | – | 2 (4%) | 1 (2%) | –
Meninges, hemorrhage | 1 (2%) | – | – | – | –
Ventricle, dilatation | 6 (13%) | 2 (4%) | 4 (8%) | 3 (6%) | –
Peripheral nerve, sciatic | (48) | (48) | (48) | (47) | (48)
Axon, degeneration | 31 (65%) | 22 (46%) | 26 (54%) | 28 (60%) | 28 (58%)
Spinal cord, cervical | (47) | (46) | (48) | (47) | (48)
Cyst | – | – | 1 (2%) | – | –
Gliosis | – | – | – | – | 1 (2%)
Hemorrhage | 2 (4%) | – | 1 (2%) | 1 (2%) | –
Mineralization | – | – | – | – | 1 (2%)
Axon, degeneration | 25 (53%) | 19 (41%) | 23 (48%) | 28 (60%) | 27 (56%)
Spinal cord, lumbar | (47) | (46) | (48) | (47) | (48)
Gliosis | 1 (2%) | – | – | – | –
Mineralization | – | – | – | – | 2 (4%)
Axon, degeneration | 5 (11%) | 7 (15%) | 4 (8%) | 2 (4%) | 5 (10%)
Nerve, degeneration | 36 (77%) | 26 (57%) | 29 (60%) | 32 (68%) | 26 (54%)
Nerve, gliosis | 2 (4%) | 2 (4%) | – | – | 1 (2%)
Spinal cord, thoracic | (47) | (46) | (48) | (47) | (48)
Hemorrhage | – | – | – | 1 (2%) | –
Mineralization | – | – | – | – | 1 (2%)
Axon, degeneration | 23 (49%) | 22 (48%) | 25 (52%) | 30 (64%) | 27 (56%)
Nerve, degeneration | 5 (11%) | 8 (17%) | 3 (6%) | 4 (9%) | 5 (10%)
Respiratory System
Lung | (48) | (47) | (48) | (47) | (47)
Congestion | 1 (2%) | – | – | – | –
Foreign body | – | – | – | – | 1 (2%)
Hemorrhage | 2 (4%) | – | – | 1 (2%) | 2 (4%)
Infiltration cellular, histiocyte | 12 (25%) | 4 (9%) | 8 (17%) | 5 (11%) | 15 (32%)
Infiltration cellular, lymphocyte | – | – | – | – | 1 (2%)
Inflammation, suppurative | – | – | 1 (2%) | – | –
Inflammation, granulomatous | – | – | – | 1 (2%) | 1 (2%)
Inflammation, chronic | – | – | – | 1 (2%) | –
Mineralization | – | – | 1 (2%) | – | –
Pigmentation | 2 (4%) | 2 (4%) | 3 (6%) | – | 2 (4%)
Alveolar epithelium, hyperplasia | 1 (2%) | 1 (2%) | 1 (2%) | 1 (2%) | 5 (11%)
Bronchus, inflammation, suppurative | – | – | – | 1 (2%) | –
Endothelium, hyperplasia | – | – | – | – | 1 (2%)
Nose | (48) | (45) | (47) | (45) | (48)
Inflammation, suppurative | 3 (6%) | 5 (11%) | 1 (2%) | 4 (9%) | 2 (4%)
Inflammation, chronic active | 1 (2%) | 2 (4%) | – | – | 1 (2%)
Goblet cell, hyperplasia | – | 1 (2%) | – | 1 (2%) | 2 (4%)
Nasopharyngeal duct, hyperkeratosis | – | – | – | 1 (2%) | –
Nasopharyngeal duct, inflammation, suppurative | – | – | – | 1 (2%) | –
Trachea | (48) | (43) | (48) | (47) | (47)
Special Senses System
Ear | (0) | (0) | (1) | (1) | (0)
Eye | (45) | (38) | (43) | (44) | (45)
Cataract | 1 (2%) | 1 (3%) | – | 1 (2%) | –
Phthisis bulbi | 1 (2%) | 1 (3%) | – | – | –
Bilateral, cataract | 1 (2%) | – | – | – | –
Bilateral, retina, degeneration | 8 (18%) | 3 (8%) | 5 (12%) | 7 (16%) | 5 (11%)
Cornea, inflammation, suppurative | – | – | – | 1 (2%) | –
Cornea, necrosis | – | – | – | 1 (2%) | –
Cornea, ulcer | – | – | – | 1 (2%) | –
Retina, degeneration | 4 (9%) | 5 (13%) | 2 (5%) | 2 (5%) | 4 (9%)
Sclera, metaplasia, osseous | 2 (4%) | 4 (11%) | 2 (5%) | – | –
Harderian gland | (47) | (47) | (48) | (46) | (48)
Infiltration cellular, lymphocyte | 1 (2%) | 3 (6%) | – | – | –
Inflammation, chronic | 1 (2%) | – | – | – | –
Inflammation, chronic active | – | – | 1 (2%) | 1 (2%) | –
Necrosis | – | – | – | – | 1 (2%)
Acinus, degeneration | – | – | 1 (2%) | 1 (2%) | –
Epithelium, hyperplasia | 1 (2%) | – | – | – | 1 (2%)
Zymbal’s gland | (0) | (0) | (3) | (2) | (3)
Inflammation, suppurative | – | – | – | 1 (50%) | –
Urinary System
Kidney | (46) | (44) | (47) | (47) | (47)
Cyst | 1 (2%) | – | – | 1 (2%) | 1 (2%)
Hyaline droplet | – | – | – | 3 (6%) | 1 (2%)
Hydronephrosis | 1 (2%) | 1 (2%) | – | – | 2 (4%)
Necrosis | 1 (2%) | – | – | – | –
Nephropathy | 46 (100%) | 40 (91%) | 46 (98%) | 45 (96%) | 44 (94%)
Pigmentation | – | – | 1 (2%) | 3 (6%) | 2 (4%)
Transitional epithelium, hyperplasia | 1 (2%) | – | 1 (2%) | 2 (4%) | –
Urethra | (0) | (0) | (0) | (0) | (1)
Urinary bladder | (48) | (43) | (48) | (47) | (47)
Hemorrhage | – | – | – | 1 (2%) | –
Inflammation, chronic | 1 (2%) | – | – | – | –
Lumen, dilatation | 5 (10%) | 5 (12%) | 2 (4%) | 5 (11%) | 5 (11%)
Transitional epithelium, hyperplasia | – | – | 1 (2%) | 1 (2%) | 2 (4%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.