# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-587

Report Series: NTP Technical Report Series

Report Series Number: 587

Official citation: National Toxicology Program (NTP). 2014. NTP technical report on the toxicology studies of tetrabromobisphenol A (CASRN 79-94-7) in F344/NTac rats and B6C3F1/N mice and toxicology and carcinogenesis studies of tetrabromobisphenol A in Wistar Han [Crl:WI(Han)] rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 587.