# References

1 Ashford RD Ashford’s dictionary of industrial chemicals. London, England: Wavelength Publications Ltd; 1994. p. 868.
2 Hazardous Substances Data Bank (HSDB). 2,2′-,6,6′-Tetrabromo-4,4′ isopropylidenediphenol tetrabromobisphenol-A. The National Library of Medicine TOXNET System; 2011. http://toxnet.nlm.nih.gov/cgi-bin/sis/search/f?./temp/~pLZPGP:1
3 International Programme on Chemical Safety (IPCS). Tetrabromobisphenol A and derivatives. Geneva, Switzerland: World Health Organization; 1995. Environmental Health Criteria 172. http://www.inchem.org/documents/ehc/ehc/ehc172.htm
4 United States Environmental Protection Agency (USEPA). Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information. CAS No. 79-94-7, Phenol, 4,4′-(1-methylethylidene)bis[2,6-dibromo-]. 2006. https://cfpub.epa.gov/iursearch/2006_iur_companyinfo.cfm?chemid=6379&outchem=both [Accessed: May 2013]
5 Bromine Science and Environmental Forum (BSEF) End-of-life management of plastics containing brominated flame retardants. Brussels, Belgium: Factsheet; 2007.
6 Bastos PM Eriksson J Green N Bergman Å A standardized method for assessment of oxidative transformations of brominated phenols in water. Chemosphere. 2008;70(7):1196–1202. 10.1016/j.chemosphere.2007.08.019 17897700
7 Law RJ Bersuder P Allchin CR Barry J Levels of the flame retardants hexabromocyclododecane and tetrabromobisphenol A in the blubber of harbor porpoises (Phocoena phocoena) stranded or bycaught in the U.K., with evidence for an increase in HBCD concentrations in recent years. Environ Sci Technol. 2006;40(7):2177–2183. 10.1021/es052416o 16646450
8 Bromine Science and Environmental Forum (BSEF) Brominated flame retardant. Tetrabromo-bisphenol A for printed circuit boards and ABS plastics. Brussels, Belgium: Factsheet; 2012.
9 Birnbaum LS Staskal DF Brominated flame retardants: cause for concern? Environ Health Perspect. 2004;112(1):9–17. 10.1289/ehp.6559 14698924
10 Talsness CE Andrade AJ Kuriyama SN Taylor JA vom Saal FS Components of plastic: experimental studies in animals and relevance for human health. Philos Trans R Soc Lond B Biol Sci. 2009;364(1526):2079–2096. 10.1098/rstb.2008.0281 19528057
11 Carignan CC Abdallah MA-E Wu N Heiger-Bernays W McClean MD Harrad S Webster TF Predictors of tetrabromobisphenol-A (TBBP-A) and hexabromocyclododecanes (HBCD) in milk from Boston mothers. Environ Sci Technol. 2012;46(21):12146–12153. 10.1021/es302638d 22998345
12 de Wit CA Herzke D Vorkamp K Brominated flame retardants in the Arctic environment—trends and new candidates. Sci Total Environ. 2010;408(15):2885–2918. 10.1016/j.scitotenv.2009.08.037 19815253
13 United States Environmental Protection Agency (USEPA). HPV data summary and test plan for phenol, 4,4′ isopropylidenebis[2,6-dibromo]. 2005. https://www.epa.gov/HPV/pubs/summaries/phenolis/c13460rt3.pdf [Accessed: May 2013]
14 Qu G Liu A Wang T Zhang C Fu J Yu M Sun J Zhu N Li Z Wei G Identification of tetrabromobisphenol A allyl ether and tetrabromobisphenol A 2,3-dibromopropyl ether in the ambient environment near a manufacturing site and in mollusks at a coastal region. Environ Sci Technol. 2013;47(9):4760–4767. 10.1021/es3049916 23550727
15 Iasur-Kruh L Ronen Z Arbeli Z Nejidat A Characterization of an enrichment culture debrominating tetrabromobisphenol A and optimization of its activity under anaerobic conditions. J Appl Microbiol. 2010;109(2):707–715. 10.1111/j.1365-2672.2010.04699.x 20202021
16 de Wit CA An overview of brominated flame retardants in the environment. Chemosphere. 2002;46(5):583–624. 10.1016/S0045-6535(01)00225-9 11999784
17 Yang S Wang S Liu H Yan Z Tetrabromobisphenol A Tissue distribution in fish, and seasonal variation in water and sediment of Lake Chaohu, China. Environ Sci Pollut Res Int. 2012;19(9):4090–4096. 10.1007/s11356-012-1023-9 22825637
18 Ni HG Zeng H Tao S Zeng EY Environmental and human exposure to persistent halogenated compounds derived from e-waste in China. Environ Toxicol Chem. 2010;29(6):1237–1247. 10.1002/etc.160 20821565
19 Hakk H Letcher RJ Metabolism in the toxicokinetics and fate of brominated flame retardants—a review. Environ Int. 2003;29(6):801–828. 10.1016/S0160-4120(03)00109-0 12850098
20 McCormick JM Paiva MS Häggblom MM Cooper KR White LA Embryonic exposure to tetrabromobisphenol A and its metabolites, bisphenol A and tetrabromobisphenol A dimethyl ether disrupts normal zebrafish (Danio rerio) development and matrix metalloproteinase expression. Aquat Toxicol. 2010;100(3):255–262. 10.1016/j.aquatox.2010.07.019 20728951
21 European Food Safety Authority (EFSA) Panel on contaminants in the food chain. Scientific opinion on tetrabromobisphenol A (TBBPA) and its derivatives in food. EFSA J. 2011;9:2477–2537.10.2903/j.efsa.2011.2477
22 United States Environmental Protection Agency (USEPA) Toxics Release Inventory reporting requirements. 2012. https://yosemite.epa.gov/r10/owcm.nsf/ea6b351e337b08a288256b5800612787/d3d1d36b3e1a32d48825681d008358ce!OpenDocument [Accessed: June 2013]
23 Hakk H Larsen G Bergman A Örn U Metabolism, excretion and distribution of the flame retardant tetrabromobisphenol-A in conventional and bile-duct cannulated rats. Xenobiotica. 2000;30(9):881–890. 10.1080/004982500433309 11055266
24 Kuester RK Sólyom AM Rodriguez VP Sipes IG The effects of dose, route, and repeated dosing on the disposition and kinetics of tetrabromobisphenol A in male F-344 rats. Toxicol Sci. 2007;96(2):237–245. 10.1093/toxsci/kfm006 17234645
25 Knudsen GA, Sanders JM, Sadik AM, Birnbaum LS. 2013. Disposition and kinetics of tetrabromobisphenol A (TBBPA) in female Wistar-Han rats. In: The Sixth International Symposium On Flame Retardants.
26 Kang MJ Kim JH Shin S Choi JH Lee SK Kim HS Kim ND Kang GW Jeong HG Kang W Nephrotoxic potential and toxicokinetics of tetrabromobisphenol A in rat for risk assessment. J Toxicol Environ Health A. 2009;72(21-22):1439–1445. 10.1080/15287390903212907 20077216
27 Schauer UM Völkel W Dekant W Toxicokinetics of tetrabromobisphenol A in humans and rats after oral administration. Toxicol Sci. 2006;91(1):49–58. 10.1093/toxsci/kfj132 16481339
28 Fini JB Riu A Debrauwer L Hillenweck A Le Mével S Chevolleau S Boulahtouf A Palmier K Balaguer P Cravedi JP Parallel biotransformation of tetrabromobisphenol A in Xenopus laevis and mammals: xenopus as a model for endocrine perturbation studies. Toxicol Sci. 2012;125(2):359–367. 10.1093/toxsci/kfr312 22086976
29 Zalko D Prouillac C Riu A Perdu E Dolo L Jouanin I Canlet C Debrauwer L Cravedi J-P Biotransformation of the flame retardant tetrabromo-bisphenol A by human and rat sub-cellular liver fractions. Chemosphere. 2006;64(2):318–327. 10.1016/j.chemosphere.2005.12.053 16473389
30 Chignell CF Han S-K Mouithys-Mickalad A Sik RH Stadler K Kadiiska MB EPR studies of in vivo radical production by 3,3′,5,5′-tetrabromobisphenol A (TBBPA) in the Sprague-Dawley rat. Toxicol Appl Pharmacol. 2008;230(1):17–22. 10.1016/j.taap.2008.01.035 18342900
31 Szymańska JA Sapota A Frydrych B The disposition and metabolism of tetrabromobisphenol-A after a single i.p. dose in the rat. Chemosphere. 2001;45(4-5):693–700. 10.1016/S0045-6535(01)00015-7 11680765
32 Arbeli Z Ronen Z Díaz-Báez MC Reductive dehalogenation of tetrabromobisphenol-A by sediment from a contaminated ephemeral streambed and an enrichment culture. Chemosphere. 2006;64(9):1472–1478. 10.1016/j.chemosphere.2005.12.069 16497360
33 Knudsen GA Jacobs LM Kuester RK Sipes IG Absorption, distribution, metabolism and excretion of intravenously and orally administered tetrabromobisphenol A [2,3-dibromopropyl ether] in male Fischer-344 rats. Toxicology. 2007;237(1-3):158–167. 10.1016/j.tox.2007.05.006 17582672
34 Hagmar L Sjödin A Höglund P Thuresson K Rylander L Bergman A Biological half-lives of polybrominated diphenyl ethers and tetrabromobisphenol A in exposed workers. Organohalogen Compd. 2000;47:198–201.
35 Jakobsson K Thuresson K Rylander L Sjödin A Hagmar L Bergman A Exposure to polybrominated diphenyl ethers and tetrabromobisphenol A among computer technicians. Chemosphere. 2002;46(5):709–716. 10.1016/S0045-6535(01)00235-1 11999794
36 Thomsen C Leknes H Lundanes E Becher G A new method for determination of halogenated flame retardants in human milk using solid-phase extraction. J Anal Toxicol. 2002;26(3):129–137. 10.1093/jat/26.3.129 11991528
37 Hayama T Yoshida H Onimaru S Yonekura S Kuroki H Todoroki K Nohta H Yamaguchi M Determination of tetrabromobisphenol A in human serum by liquid chromatography-electrospray ionization tandem mass spectrometry. J Chromatogr B Analyt Technol Biomed Life Sci. 2004;809(1):131–136. 10.1016/j.jchromb.2004.06.013 15282103
38 Johnson-Restrepo B Adams DH Kannan K Tetrabromobisphenol A TBBPA) and hexabromocyclododecanes (HBCDs) in tissues of humans, dolphins, and sharks from the United States. Chemosphere. 2008;70(11):1935–1944. 10.1016/j.chemosphere.2007.10.002 18037156
39 Registry of Toxic Effects of Chemical Substances (RTECS). Phenol, 4,4′-(1-methylethylidene) bis(2,6 dibromo-), CAS registry number 79-94-7. Bethesda, MD: National Library of Medicine; 2011. https://www.expub.com/Members/DocumentViewer.aspx?key=6792746&pc=172281D091B640f39AAA7AD75B2E04C6&st=fts
40 United States Environmental Protection Agency (USEPA). Flame retardants in printed circuit boards, Draft report. 2008. https://www.epa.gov/dfe
41 European Chemicals Bureau (ECB). European Union Risk Assessment Report: 2,2′-,6,6′-Tetrabromo-4,4′ isopropylidenediphenol (tetrabromobisphenol-A or TBBP-A). Part II: Human Health. Luxembourg: Institute for Health and Consumer Protection, European Chemicals Bureau, European Commission Joint Research Centre; 2006. 4th Priority List, Vol. 63. https://europa.eu/index_en.htm
42 Saegusa Y Fujimoto H Woo GH Inoue K Takahashi M Mitsumori K Hirose M Nishikawa A Shibutani M Developmental toxicity of brominated flame retardants, tetrabromobisphenol A and 1,2,5,6,9,10-hexabromocyclododecane, in rat offspring after maternal exposure from mid-gestation through lactation. Reprod Toxicol. 2009;28(4):456–467. 10.1016/j.reprotox.2009.06.011 19577631
43 Van der Ven LT Van de Kuil T Verhoef A Verwer CM Lilienthal H Leonards PE Schauer UM Canton RF Litens S De Jong FH Endocrine effects of tetrabromobisphenol-A (TBBPA) in Wistar rats as tested in a one-generation reproduction study and a subacute toxicity study. Toxicology. 2008;245(1-2):76–89. 10.1016/j.tox.2007.12.009 18255212
44 Germer S Piersma AH van der Ven L Kamyschnikow A Fery Y Schmitz H-J Schrenk D Subacute effects of the brominated flame retardants hexabromocyclododecane and tetrabromobisphenol A on hepatic cytochrome P450 levels in rats. Toxicology. 2006;218(2-3):229–236. 10.1016/j.tox.2005.10.019 16325980
45 Szymańska JA Piotrowski JK Frydrych B Hepatotoxicity of tetrabromobisphenol-A: effects of repeated dosage in rats. Toxicology. 2000;142(2):87–95. 10.1016/S0300-483X(99)00108-0 10685508
46 Fukuda N Ito Y Yamaguchi M Mitumori K Koizumi M Hasegawa R Kamata E Ema M Unexpected nephrotoxicity induced by tetrabromobisphenol A in newborn rats. Toxicol Lett. 2004;150(2):145–155. 10.1016/j.toxlet.2004.01.001 15093670
47 Eriksson P Jakobsson E Fredriksson A Brominated flame retardants: A novel class of developmental neurotoxicants in our environment? Environ Health Perspect. 2001;109(9):903–908. 10.1289/ehp.01109903 11673118
48 Viberg H Eriksson P Differences in neonatal neurotoxicity of brominated flame retardants, PBDE 99 and TBBPA, in mice. Toxicology. 2011;289(1):59–65. 10.1016/j.tox.2011.07.010 21820030
49 Nakajima A Saigusa D Tetsu N Yamakuni T Tomioka Y Hishinuma T Neurobehavioral effects of tetrabromobisphenol A, a brominated flame retardant, in mice. Toxicol Lett. 2009;189(1):78–83. 10.1016/j.toxlet.2009.05.003 19463927
50 Saegusa Y Fujimoto H Woo GH Ohishi T Wang L Mitsumori K Nishikawa A Shibutani M Transient aberration of neuronal development in the hippocampal dentate gyrus after developmental exposure to brominated flame retardants in rats. Arch Toxicol. 2012;86(9):1431–1442. 10.1007/s00204-012-0824-4 22415764
51 Williams AL DeSesso JM The potential of selected brominated flame retardants to affect neurological development. J Toxicol Environ Health B Crit Rev. 2010;13(5):411–448. 10.1080/10937401003751630 20582854
52 Samuelsen M Olsen C Holme JA Meussen-Elholm E Bergmann A Hongslo JK Estrogen-like properties of brominated analogs of bisphenol A in the MCF-7 human breast cancer cell line. Cell Biol Toxicol. 2001;17(3):139–151. 10.1023/A:1011974012602 11693576
53 Kitamura S Suzuki T Sanoh S Kohta R Jinno N Sugihara K Yoshihara S Fujimoto N Watanabe H Ohta S Comparative study of the endocrine-disrupting activity of bisphenol A and 19 related compounds. Toxicol Sci. 2005;84(2):249–259. 10.1093/toxsci/kfi074 15635150
54 Uhnáková B Ludwig R Pěknicová J Homolka LLL Šulc M Petříčková A Elzeinová F Pelantová H Monti D Biodegradation of tetrabromobisphenol A by oxidases in basidiomycetous fungi and estrogenic activity of the biotransformation products. Bioresour Technol. 2011;102(20):9409–9415. 10.1016/j.biortech.2011.07.036 21865031
55 Hamers T Kamstra JH Sonneveld E Murk AJ Kester MH Andersson PL Legler J Brouwer A In vitro profiling of the endocrine-disrupting potency of brominated flame retardants. Toxicol Sci. 2006;92(1):157–173. 10.1093/toxsci/kfj187 16601080
56 Li J Ma M Wang Z In vitro profiling of endocrine disrupting effects of phenols. Toxicol In Vitro. 2010;24(1):201–207. 10.1016/j.tiv.2009.09.008 19765641
57 Meerts IA van Zanden JJ Luijks EA van Leeuwen-Bol I Marsh G Jakobsson E Bergman Å Brouwer A Potent competitive interactions of some brominated flame retardants and related compounds with human transthyretin in vitro. Toxicol Sci. 2000;56(1):95–104. 10.1093/toxsci/56.1.95 10869457
58 Kitamura S Jinno N Ohta S Kuroki H Fujimoto N Thyroid hormonal activity of the flame retardants tetrabromobisphenol A and tetrachlorobisphenol A. Biochem Biophys Res Commun. 2002;293(1):554–559. 10.1016/S0006-291X(02)00262-0 12054637
59 Hendriks HS van Kleef RG van den Berg M Westerink RH Multiple novel modes of action involved in the in vitro neurotoxic effects of tetrabromobisphenol-A. Toxicol Sci. 2012;128(1):235–246. 10.1093/toxsci/kfs136 22547355
60 Mariussen E Fonnum F The effect of brominated flame retardants on neurotransmitter uptake into rat brain synaptosomes and vesicles. Neurochem Int. 2003;43(4-5):533–542. 10.1016/S0197-0186(03)00044-5 12742101
61 Reistad T Mariussen E Fonnum F The effect of a brominated flame retardant, tetrabromobisphenol-A, on free radical formation in human neutrophil granulocytes: the involvement of the MAP kinase pathway and protein kinase C. Toxicol Sci. 2005;83(1):89–100. 10.1093/toxsci/kfh298 15456914
62 Reistad T Mariussen E Ring A Fonnum F In vitro toxicity of tetrabromobisphenol-A on cerebellar granule cells: cell death, free radical formation, calcium influx and extracellular glutamate. Toxicol Sci. 2007;96(2):268–278. 10.1093/toxsci/kfl198 17205976
63 Watanabe W Shimizu T Sawamura R Hino A Konno K Hirose A Kurokawa M Effects of tetrabromobisphenol A, a brominated flame retardant, on the immune response to respiratory syncytial virus infection in mice. Int Immunopharmacol. 2010;10(4):393–397. 10.1016/j.intimp.2009.12.014 20074668
64 Hurd T Whalen MM Tetrabromobisphenol A decreases cell-surface proteins involved in human natural killer (NK) cell-dependent target cell lysis. J Immunotoxicol. 2011;8(3):219–227. 10.3109/1547691X.2011.580437 21623697
65 Kibakaya EC Stephen K Whalen MM Tetrabromobisphenol A has immunosuppressive effects on human natural killer cells. J Immunotoxicol. 2009;6(4):285–292. 10.3109/15476910903258260 19908946
66 Lilienthal H Verwer CM van der Ven LT Piersma AH Vos JG Exposure to tetrabromobisphenol A (TBBPA) in Wistar rats: neurobehavioral effects in offspring from a one-generation reproduction study. Toxicology. 2008;246(1):45–54. 10.1016/j.tox.2008.01.007 18295390
67 Tada Y Fujitani T Yano N Takahashi H Yuzawa K Ando H Kubo Y Nagasawa A Ogata A Kamimura H Effects of tetrabromobisphenol A, brominated flame retardant, in ICR mice after prenatal and postnatal exposure. Food Chem Toxicol. 2006;44(8):1408–1413. 10.1016/j.fct.2006.03.006 16716481
68 Zatecka E Ded L Elzeinova F Kubatova A Dorosh A Margaryan H Dostalova P Peknicova J Effect of tetrabrombisphenol A on induction of apoptosis in the testes and changes in expression of selected testicular genes in CD1 mice. Reprod Toxicol. 2013;35:32–39. 10.1016/j.reprotox.2012.05.095 22677475
69 Kuiper RV Cantón RF Leonards PEG Jenssen BM Dubbeldam M Wester PW van den Berg M Vos JG Vethaak AD Long-term exposure of European flounder (Platichthys flesus) to the flame-retardants tetrabromobisphenol A (TBBPA) and hexabromocyclododecane (HBCD). Ecotoxicol Environ Saf. 2007;67(3):349–360. 10.1016/j.ecoenv.2006.12.001 17258806
70 Thomas P The endocrine system. In: deGiulio RT Hinton DEeditors. The Toxicology of Fishes. Boca Raton (FL): CRC Press; 2008. p. 457–488.10.1201/9780203647295.ch10
71 Chan WK Chan KM Disruption of the hypothalamic-pituitary-thyroid axis in zebrafish embryo-larvae following waterborne exposure to BDE-47, TBBPA and BPA. Aquat Toxicol. 2012;108:106–111. 10.1016/j.aquatox.2011.10.013 22100034
72 De Wit M Keil D Remmerie N van der Ven K van den Brandhof EJ Knapen D Witters E De Coen W Molecular targets of TBBPA in zebrafish analysed through integration of genomic and proteomic approaches. Chemosphere. 2008;74(1):96–105. 10.1016/j.chemosphere.2008.09.030 18976794
73 Shi H Qian L Guo S Zhang X Liu J Cao Q Teratogenic effects of tetrabromobisphenol A on Xenopus tropicalis embryos. Comp Biochem Physiol C Toxicol Pharmacol. 2010;152(1):62–68. 10.1016/j.cbpc.2010.02.013 20188212
74 Zalko D Antignac J-P Riu A Cariou R Berrebi A Perdu E Debrauwer L Balaguer P Cravedi J-P Le Bizec B Major results from French research programs on brominated flame retardants. Organohalogen Compd. 2007;69:674–677.
75 Cariou R Antignac J-P Zalko D Berrebi A Cravedi J-P Maume D Marchand P Monteau F Riu A Andre F Exposure assessment of French women and their newborns to tetrabromobisphenol-A: occurrence measurements in maternal adipose tissue, serum, breast milk and cord serum. Chemosphere. 2008;73(7):1036–1041. 10.1016/j.chemosphere.2008.07.084 18790516
76 Kawashiro Y Fukata H Omori-Inoue M Kubonoya K Jotaki T Takigami H Sakai S Mori C Perinatal exposure to brominated flame retardants and polychlorinated biphenyls in Japan. Endocr J. 2008;55(6):1071–1084. 10.1507/endocrj.K08E-155 18719292
77 Mortelmans K Haworth S Lawlor T Speck W Tainer B Zeiger E Salmonella mutagenicity tests: II. Results from the testing of 270 chemicals. Environ Mutagen. 1986;8 Suppl 7:1–119. 10.1002/em.2860080802 3516675
78 King-Herbert A Thayer K NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006;34(6):802–805. 10.1080/01926230600935938 17162538
79 Battelle Columbus Operations. Biochemical toxicology report: Hepatic CYP1A1, CYP2B1, CYP1A2, and UDP GT activities for the 14-week gavage toxicity study of tetrabromobisphenol A (TBP) in B6C3F1 mice (G823512-C). Columbus, OH: Battelle Columbus Operations; 2006. Battelle Study No. G823512-C.
80 Battelle Columbus Operations. Biochemical toxicology report: Hepatic CYP1A1, CYP2B1, CYP1A2, and UDP GT activities for the 14-week gavage toxicity study of tetrabromobisphenol A (TBP) in Fischer F344/NTac rats (G823512-B). Columbus, OH: Battelle Columbus Operations; 2006. Battelle Study No. G823512-B.
81 Rutten AAJJL Falke HE Catsburg JF Wortelboer HM Blaauboer BJ Doorn L van Leeuwen FXR Theelen R Rietjens IMCM Interlaboratory comparison of microsomal ethoxyresorufin and pentoxyresorufin O-dealkylation determinations: standardization of assay conditions. Arch Toxicol. 1992;66(4):237–244. 10.1007/BF02307168 1514921
82 Liu G Gelboin HV Myers MJ Role of cytochrome P450 IA2 in acetanilide 4-hydroxylation as determined with cDNA expression and monoclonal antibodies. Arch Biochem Biophys. 1991;284(2):400–406. 10.1016/0003-9861(91)90315-A 1989524
83 DeVito MJ Maier WE Diliberto JJ Birnbaum LS Comparative ability of various PCBs, PCDFs, and TCDD to induce cytochrome P450 1A1 and 1A2 activity following 4 weeks of treatment. Fundam Appl Toxicol. 1993;20(1):125–130. 10.1006/faat.1993.1015 8432423
84 DeVito MJ Beebe LE Menache M Birnbaum LS Relationship between CYP1A enzyme activities and protein levels in rats treated with 2,3,7,8-tetrachlorodibenzo-p-dioxin. J Toxicol Environ Health. 1996;47(4):379–394. 10.1080/009841096161717 8600290
85 Hood A Klaassen CD Differential effects of microsomal enzyme inducers on in vitro thyroxine (T(4)) and triiodothyronine (T(3)) glucuronidation. Toxicol Sci. 2000;55(1):78–84. 10.1093/toxsci/55.1.78 10788562
86 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
87 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
88 McConnell EE Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986;76(2):283–289. 3456066
89 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958;53:457–481. 10.1080/01621459.1958.10501452
90 Cox D Regression models and life-tables. J R Stat Soc B. 1972;34:187–220.
91 Tarone RE Tests for trend in life table analysis. Biometrika. 1975;62(3):679–690.10.1093/biomet/62.3.679
92 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988;44(2):417–431. 10.2307/2531856 3390507
93 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989;12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
94 Piegorsch W, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, England: CRC Press; 1997.
95 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986;46(9):4372–4378. 3731095
96 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993;49(3):793–801. 10.2307/2532200 8241374
97 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
98 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121.10.1080/01621459.1955.10501294
99 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
100 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
101 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
102 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
103 Dunn OJ Multiple comparison using RANK sums. Technometrics. 1964;6:241–252.10.1080/00401706.1964.10490181
104 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1-2):133–145.10.1093/biomet/41.1-2.133
105 Dixon WJ Massey FJ Introduction to statistical analysis. New York: McGraw-Hill; 1957.10.2307/2332898
106 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
107 Haseman JK Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992;26(2):191–200.10.1177/009286159202600210
108 Haseman JKData analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharm. 1995; 21(1):52-59. 10.1006/rtph.1995.1009
109 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992;20(1):52–60. 10.1177/019262339202000107 1411131
110 Code of Federal Regulations (CFR). 21:Part 58.
111 Schmid W The micronucleus test. Mutat Res. 1975;31(1):9–15. 10.1016/0165-1161(75)90058-8 48190
112 Heddle JA Hite M Kirkhart B Mavournin K MacGregor JT Newell GW Salamone MF The induction of micronuclei as a measure of genotoxicity. A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1983;123(1):61–118. 10.1016/0165-1110(83)90047-7 6888413
113 Miller JA Miller EC Origins of Human Cancer. Cold Spring Harbor (NY): Cold Spring Harbor Laboratory; 1977. Ultimate chemical carcinogens as reactive mutagenic electrophiles; p. 605–627.
114 Straus DS Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981;67(2):233–241. 7021938
115 Crawford BD Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA Flamm WG Lorentzen RJeditors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton (NJ): Princeton Scientific Publishing Co., Inc.; 1985. p. 13–59.
116 Ashby J Tennant RW Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the U.S. NTP. Mutat Res. 1991;257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
117 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987;236(4804):933–941. 10.1126/science.3554512 3554512
118 Zeiger E Haseman JK Shelby MD Margolin BH Tennant RW Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: confirmation of earlier results with 41 additional chemicals. Environ Mol Mutagen. 1990;16 Suppl 18:1–14. 10.1002/em.2850160502 2091921
119 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993;21(2):160–179. 10.1002/em.2850210210 8444144
120 Shelby MD Witt KL Comparison of results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995;25(4):302–313. 10.1002/em.2850250407 7607185
121 Witt KL Knapton A Wehr CM Hook GJ Mirsalis J Shelby MD MacGregor JTMicronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
122 Cooke PS Porcelli J Hess RA Induction of increased testis growth and sperm production in adult rats by neonatal administration of the goitrogen propylthiouracil (PTU): the critical period. Biol Reprod. 1992;46(1):146–154. 10.1095/biolreprod46.1.146 1547312
123 Kirkwood TB Kowald A Network theory of aging. Exp Gerontol. 1997;32(4-5):395–399. 10.1016/S0531-5565(96)00171-4 9315444
124 Kirkwood TB Kowald A The free-radical theory of ageing—older, wiser and still alive: modelling positional effects of the primary targets of ROS reveals new support. BioEssays. 2012;34(8):692–700. 10.1002/bies.201200014 22641614
125 Rahman K Studies on free radicals, antioxidants, and co-factors. Clin Interv Aging. 2007;2(2):219–236. 18044138
126 Salmon AB Richardson A Perez VI Update on the oxidative stress theory of aging: does oxidative stress play a role in aging or healthy aging? Free Radic Biol Med. 2010;48(5):642–655. 10.1016/j.freeradbiomed.2009.12.015 20036736
127 Salmon AB Oxidative stress in the etiology of age-associated decline in glucose metabolism. Longev Healthspan. 2012;1:7. 10.1186/2046-2395-1-7 24764512
128 Odicino F Pecorelli S Zigliani L Creasman WT History of the FIGO cancer staging system. Int J Gynaecol Obstet. 2008;101(2):205–210. 10.1016/j.ijgo.2007.11.004 18199437
129 Jemal A Siegel R Ward E Hao Y Xu J Thun MJ Cancer statistics, 2009. CA Cancer J Clin. 2009;59(4):225–249. 10.3322/caac.20006 19474385
130 Bartels PH Garcia FA Trimble CL Kauderer J Curtin J Lim PC Hess LM Silverberg S Zaino RJ Yozwiak M Karyometry in atypical endometrial hyperplasia: A gynecologic oncology group study. Gynecol Oncol. 2012;125(1):129–135. 10.1016/j.ygyno.2011.12.422 22155796
131 van der Zee M Jia Y Wang Y Heijmans-Antonissen C Ewing PC Franken P DeMayo FJ Lydon JP Burger CW Fodde R Alterations in Wnt-beta-catenin and Pten signalling play distinct roles in endometrial cancer initiation and progression. J Pathol. 2013;230(1):48–58. 10.1002/path.4160 23288720
132 Kurman RJ Kaminski PF Norris HJThe behavior of endometrial hyperplasia. A long-term study of “untreated” hyperplasia in 170 patients. Cancer. 1985; 56(2):403-412. 10.1002/1097-0142(19850715)56:2<403::AID-CNCR2820560233>3.0.CO;2-X
133 Beller U Benedet JL Creasman WT Ngan HY Quinn MA Maisonneuve P Pecorelli S Odicino F Heintz AP Carcinoma of the vagina. FIGO 26th annual report on the results of treatment in gynecological cancer. Int J Gynaecol Obstet. 2006;95 Suppl 1:S29–S42. 10.1016/S0020-7292(06)60029-5 17161165
134 Beller U Quinn MA Benedet JL Creasman WT Ngan HY Maisonneuve P Pecorelli S Odicino F Heintz AP Carcinoma of the vulva. FIGO 26th annual report on the results of treatment in gynecological cancer. Int J Gynaecol Obstet. 2006;95 Suppl 1:S7–S27. 10.1016/S0020-7292(06)60028-3 17161169
135 Quinn MA Benedet JL Odicino F Maisonneuve P Beller U Creasman WT Heintz AP Ngan HY Pecorelli S Carcinoma of the cervix uteri. FIGO 26th annual report on the results of treatment in gynecological cancer. Int J Gynaecol Obstet. 2006;95 Suppl 1:S43–S103. 10.1016/S0020-7292(06)60030-1 17161167
136 Odicino F Tisi G Rampinelli F Miscioscia R Sartori E Pecorelli S New development of the FIGO staging system. Gynecol Oncol. 2007;107(1) Suppl 1:S8–S9. 10.1016/j.ygyno.2007.07.018 17761268
137 van den Brink-Knol H van Esch E Spontaneous malignant mixed Mullerian tumor in a Wistar rat: A case report including immunohistochemistry. Vet Pathol. 2010;47(6):1105–1110. 10.1177/0300985810374840 20587687
138 Kanthan R Senger JL Diudea D Malignant mixed Mullerian tumors of the uterus: histopathological evaluation of cell cycle and apoptotic regulatory proteins. World J Surg Oncol. 2010;8:60. 10.1186/1477-7819-8-60 20642852
139 Voutsadakis IA Epithelial to mesenchymal transition in the pathogenesis of uterine malignant mixed Mullerian tumours: the role of ubiquitin proteasome system and therapeutic opportunities. Clin Transl Oncol. 2012;14(4):243–253. 10.1007/s12094-012-0792-4 22484631
140 Gupta N Dudding N Smith JH Eight cases of malignant mixed Mullerian tumor (carcinosarcoma) of the uterus: findings in SurePath cervical cytology. Diagn Cytopathol. 2014;42(2):165–169. 10.1002/dc.22910 22865798
141 McCluggage WG Malignant biphasic uterine tumours: carcinosarcomas or metaplastic carcinomas? J Clin Pathol. 2002;55(5):321–325. 10.1136/jcp.55.5.321 11986333
142 Carthew P Edwards RE Nolan BM Martin EA Heydon RT White IN Tucker MJ Tamoxifen induces endometrial and vaginal cancer in rats in the absence of endometrial hyperplasia. Carcinogenesis. 2000;21(4):793–797. 10.1093/carcin/21.4.793 10753217
143 International Agency for Research on Cancer (IARC) A. Vol. 100. Lyon, France: IARC; 2012. (IARC monographs on the evaluation of carcinogenic risks to humans. Pharmaceuticals: A review of human carcinogens).
144 Lévy-Bimbot M Major G Courilleau D Blondeau JP Lévi Y Tetrabromobisphenol-A disrupts thyroid hormone receptor alpha function in vitro: use of fluorescence polarization to assay corepressor and coactivator peptide binding. Chemosphere. 2012;87(7):782–788. 10.1016/j.chemosphere.2011.12.080 22277881
145 Malarkey DE Hoenerhoff M Maronpot RR Chapter 5, Carcinogenesis: Mechanisms and manifestations. In: Haschek WM Rousseaux CG Wallig MAeditors. Haschek and Rousseaux’s Handbook of Toxicologic Pathology. 3rd ed. Boston: Academic Press; 2013. p. 107–146.10.1016/B978-0-12-415759-0.00005-4
146 Blagosklonny MV p53 from complexity to simplicity: mutant p53 stabilization, gain-of-function, and dominant-negative effect. FASEB J. 2000;14(13):1901–1907. 10.1096/fj.99-1078rev 11023974
147 Rivlin N Brosh R Oren M Rotter V Mutations in the p53 tumor suppressor gene: important milestones at the various steps of tumorigenesis. Genes Cancer. 2011;2(4):466–474. 10.1177/1947601911408889 21779514
148 Muller PA Vousden KH p53 mutations in cancer. Nat Cell Biol. 2013;15(1):2–8. 10.1038/ncb2641 23263379
149 Wang D Weghorst CM Calvert RJ Stoner GD Mutation in the p53 tumor suppressor gene in rat esophageal papillomas induced by N-nitrosomethylbenzylamine. Carcinogenesis. 1996;17(4):625–630. 10.1093/carcin/17.4.625 8625469
150 Caron de Fromentel C Soussi T TP53 tumor suppressor gene: A model for investigating human mutagenesis. Genes Chromosomes Cancer. 1992;4(1):1–15. 10.1002/gcc.2870040102 1377002
151 Jacks T Remington L Williams BO Schmitt EM Halachmi S Bronson RT Weinberg RA Tumor spectrum analysis in p53-mutant mice. Curr Biol. 1994;4(1):1–7. 10.1016/S0960-9822(00)00002-6 7922305
152 Barbin A Froment O Boivin S Marion MJ Belpoggi F Maltoni C Montesano R p53 gene mutation pattern in rat liver tumors induced by vinyl chloride. Cancer Res. 1997;57(9):1695–1698. 9135010
153 Vähäkangas KH Castrén K Welsh JA Single-strand conformation polymorphism analysis of mutations in exons 4-8 of the TP53 gene. Methods Mol Med. 2001;49:15–27. 21370130
154 Liu FS Molecular carcinogenesis of endometrial cancer. Taiwan J Obstet Gynecol. 2007;46(1):26–32. 10.1016/S1028-4559(08)60102-3 17389185
155 Oreskovic S Babic D Kalafatic D Barisic D Beketic-Oreskovic L A significance of immunohistochemical determination of steroid receptors, cell proliferation factor Ki-67 and protein p53 in endometrial carcinoma. Gynecol Oncol. 2004;93(1):34–40. 10.1016/j.ygyno.2003.12.038 15047211
156 Llobet D Pallares J Yeramian A Santacana M Eritja N Velasco A Dolcet X Matias-Guiu X Molecular pathology of endometrial carcinoma: practical aspects from the diagnostic and therapeutic viewpoints. J Clin Pathol. 2009;62(9):777–785. 10.1136/jcp.2008.056101 18977806
157 Zannoni GF Vellone VG Arena V Prisco MG Scambia G Carbone A Gallo D Does high-grade endometrioid carcinoma (grade 3 FIGO) belong to type I or type II endometrial cancer? A clinical-pathological and immunohistochemical study. Virchows Arch. 2010;457(1):27–34. 10.1007/s00428-010-0939-z 20552366
158 Zeiger E Identification of rodent carcinogens and noncarcinogens using genetic toxicity tests: Premises, promises, and performance. Regul Toxicol Pharmacol. 1998;28(2):85–95. 10.1006/rtph.1998.1234 9927558
159 Takahashi M Dinse GE Foley JF Hardisty JF Maronpot RR Comparative prevalence, multiplicity, and progression of spontaneous and vinyl carbamate-induced liver lesions in five strains of male mice. Toxicol Pathol. 2002;30(5):599–605. 10.1080/01926230290105776 12371669
160 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of benzofuran (CAS No. 271-89-6) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1989. Technical Report Series No. 370. NIH Publication No. 90-2825.
161 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of ethylene thiourea (CAS: 96-45-7) in F344 rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1992. Technical Report Series No. 388. NIH Publication No. 92-2843.
162 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of o-nitroanisole (CAS No. 91-23-6) in F344 rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Technical Report Series No. 416. NIH Publication No. 93-3147.
163 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of coumarin (CAS No. 91-64-5) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Technical Report Series No. 422. NIH Publication No. 93-3153.
164 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of oxazepam (CAS No. 604-75-1) in Swiss-Webster and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1993. Technical Report Series No. 443. NIH Publication No. 93-3359.
165 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of methylphenidate hydrochloride (CAS No. 298-59-9) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1995. Technical Report Series No. 439. NIH Publication No. 93-3153.
166 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of 1-amino-2,4-dibromoanthraquinone (CAS No. 81-49-2) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 383. NIH Publication No. 96-2838.
167 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of pyridine (CAS No. 110-86-1) in F344/N rats, Wistar rats, and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. Technical Report Series No. 470. NIH Publication No. 00-3960.
168 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of primidone (CAS No. 125-33-7) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2000. Technical Report Series No. 476. NIH Publication No. 00-3966.
169 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of goldenseal root powder (Hydrastis Canadensis) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2010. Technical Report Series No. 562. NIH Publication No. 10-5903.
170 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of Ginkgo biloba extract (CAS No. 90045-36-6) in F344/N rats and B6C3F1/N mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2013. Technical Report Series No. 578. NIH Publication No. 13-5920.
171 Koenig H Goldstone A Blume G Lu CY Testosterone-mediated sexual dimorphism of mitochondria and lysosomes in mouse kidney proximal tubules. Science. 1980;209(4460):1023–1026. 10.1126/science.7403864 7403864
172 Lax SF Molecular genetic pathways in various types of endometrial carcinoma: from a phenotypical to a molecular-based classification. Virchows Arch. 2004;444(3):213–223. 10.1007/s00428-003-0947-3 14747944
173 Leonard SL Knobil E β-Glucuronidase activity in the rat uterus. Endocrinology. 1950;47(5):331–337. 10.1210/endo-47-5-331 14793497
174 Doerge DR Twaddle NC Vanlandingham M Fisher JW Pharmacokinetics of bisphenol A in neonatal and adult Sprague-Dawley rats. Toxicol Appl Pharmacol. 2010;247(2):158–165. 10.1016/j.taap.2010.06.008 20600215
175 Raftogianis R Creveling C Weinshilboum R Weisz JEstrogen metabolism by conjugation. J Natl Cancer Inst Monogr. 2000; (27):113-124. 10.1093/oxfordjournals.jncimonographs.a024234
176 Hamers T Kamstra JH Sonneveld E Murk AJ Visser TJ Van Velzen MJ Brouwer A Bergman Å Biotransformation of brominated flame retardants into potentially endocrine-disrupting metabolites, with special attention to 2,2′,4,4′-tetrabromodiphenyl ether (BDE-47). Mol Nutr Food Res. 2008;52(2):284–298. 10.1002/mnfr.200700104 18161906
177 Kester MH Bulduk S van Toor H Tibboel D Meinl W Glatt H Falany CN Coughtrie MW Schuur AG Brouwer A Potent inhibition of estrogen sulfotransferase by hydroxylated metabolites of polyhalogenated aromatic hydrocarbons reveals alternative mechanism for estrogenic activity of endocrine disrupters. J Clin Endocrinol Metab. 2002;87(3):1142–1150. 10.1210/jcem.87.3.8311 11889178
178 Gosavi RA Knudsen GA Birnbaum LS Pedersen LC Mimicking of estradiol binding by flame retardants and their metabolites: A crystallographic analysis. Environ Health Perspect. 2013;121(10):1194–1199. 10.1289/ehp.1306902 23959441
179 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256
180 The Aldrich Library of 13C and H1 FT-NMR Spectra. 1st ed. Vol. 1. Milwaukee, WI: Aldrich Chemical Company, Inc.; 1993. p. 323 (B).
181 The Aldrich library of FT-IR spectra. 2nd ed. Vol. 2. Milwaukee, WI: Aldrich Chemical Company; 1997. p. 1908 (B).