# Conclusions

Under the conditions of these 2-year gavage studies, there was equivocal evidence of carcinogenic activity^a^ of tetrabromobisphenol A in male Wistar Han rats based on the occurrence of testicular adenoma. There was clear evidence of carcinogenic activity of tetrabromobisphenol A in female Wistar Han rats based on increased incidences of uterine epithelial tumors (predominantly uterine adenocarcinoma). There was some evidence of carcinogenic activity of tetrabromobisphenol A in male B6C3F1/N mice based on increased incidences of hepatoblastoma. The increased incidences of large intestine neoplasms and hemangiosarcoma (all organs) may have been related to chemical administration. There was no evidence of carcinogenic activity of tetrabromobisphenol A in female B6C3F1/N mice administered 250 or 500 mg/kg.

a See [underlined: Explanation of Levels of Evidence of Carcinogenic Activity.] See summary of the peer review panel comments and the public discussion on this Technical Report in Appendix N.

Administration of tetrabromobisphenol A resulted in increased incidences of non-neoplastic lesions of the uterus and ovary in female rats, the liver and kidney in male mice, and the forestomach in male and female mice.