# Discussion

These tetrabromobisphenol A rodent studies were performed to evaluate the toxic and carcinogenic potential of this widely used flame retardant. 3-month studies were conducted in F344/NTac rats and B6C3F1/N mice, and 2-year studies were conducted in Wistar Han rats and B6C3F1/N mice. A special 3-month interim evaluation using Wistar Han rats was conducted as part of the 2-year study in order to compare the results in this rat strain with those from the 3-month F344/NTac rat study.

In the 3-month tetrabromobisphenol A studies, there was no treatment-related mortality in F344/NTac rats or B6C3F1/N mice, and final mean body weights of dosed groups were similar to those of the vehicle controls. Liver weights of 500 and 1,000 mg/kg male mice and male and female rats and 1,000 mg/kg female mice were increased (increases of 9% to 14%). Increases in liver CYP2B (PROD) activity were seen at 500 and 1,000 mg/kg and treatment-related decreases in thyroxine (T_4_) concentration were seen in male and female rats. There were no treatment-related lesions in rats or mice in the 3-month studies other than an increase in the incidences of renal tubule cytoplasmic alteration in 500 and 1,000 mg/kg male mice. The results of the 3-month interim evaluation in the 2-year Wistar Han rat study (vehicle control and 1,000 mg/kg groups) were similar to those in the 3-month F344/NTac rat study, where there was no treatment-related mortality, mean body weights in the treated groups were similar to those of the vehicle control groups, and there were no treatment related lesions. Liver weights at 1,000 mg/kg were 4% to 7% greater than those of the vehicle controls.

Thyroid hormones have been shown to play an integral role in testicular development^122^ and also to affect ovarian follicular maturation,^10^ although, in the current NTP studies, there was no evidence for a tetrabromobisphenol A-associated disruption of reproductive evaluations in the 3-month studies. In addition, although in vitro studies suggest tetrabromobisphenol A could increase estrogen activity, reproductive studies with tetrabromobisphenol A have not demonstrated a significant estrogen-mediated response (e.g., accelerated vaginal opening) consistent with either estrogen receptor agonist activity or increased circulating estrogen levels due to inhibition of estradiol sulfation.

The high dose selected for the 2-year rat and mouse studies was 1,000 mg/kg because, although there were some increases in liver weights and alterations in clinical pathology endpoints in rats and/or mice in the 3-month studies, these effects were not considered to be severe enough to compromise the conduct of a 2-year study.

In the 2-year studies, survival of male and female Wistar Han rats in the treated groups was comparable to the vehicle controls. Survival of 1,000 mg/kg male and female mice and final mean body weight of 1,000 mg/kg female mice were reduced. While gastrointestinal toxic lesions were not present at 3 months in mice, gastrointestinal toxicity was found in treated mice in the 2-year study, although the severities of the lesions did not increase with dose. The ability of tetrabromobisphenol A to cause oxidative damage^30^ may have contributed to this toxicity. The reduced capacity of animals to repair oxidative damage as they age may account for the occurrence of gastrointestinal toxicity at 2 years but not at 3 months.^123-127^

There was tetrabromobisphenol A carcinogenic activity in the uterus of female rats and the liver of male mice. The occurrence of testicular tumors in male rats and large intestine tumors and hemangiosarcoma in male mice may have been related to tetrabromobisphenol A administration. Chemical induction of uterine tumors in rats was considered to be an important finding, not present in most of the previous NTP 2-year chemical carcinogenesis studies.

No treatment-related lesions were found in the uterus at 3 months in the F344/NTac rat, Wistar Han rat, or B6C3F1/N mouse, but treatment-related neoplastic and non-neoplastic uterine lesions were found in the 2-year Wistar Han rat study. These lesions included increased incidences of atypical endometrium hyperplasia, uterine adenocarcinoma, and malignant mixed Müllerian tumor. The occurrence of uterine epithelial tumors (predominantly adenocarcinoma) was considered to be clear evidence for carcinogenic activity because the incidences of malignant uterine epithelial tumors were significantly increased in the 500 and 1,000 mg/kg groups by pairwise comparison and by the trend test (P < 0.001). In addition, the incidences of the malignant uterine eithelial tumors exceeded the historical control ranges in all treatment groups. The predominant tumor type in rats was uterine adenocarcinoma, which is also the predominant uterine tumor type in humans.^128,129^

The initial uterine neoplastic findings in the 2-year Wistar Han study were based on the traditional NTP histopathology review of a transverse section through each uterine horn 0.5 cm from the cervix of the uterus. Cervix and vagina were not present in the original transverse review, except in several cases where a large mass was identified during necropsy. The extended residual tissue review involved trimming, embedding, and sectioning the remaining uterine tissue, cervix, and vagina longitudinally. The reasons for the residual longitudinal review were 1) a need to determine the site of origin for the cervical and vaginal tumors, 2) the need to have a complete review of cervices for stromal hyperplasia and stromal fibrosis, and 3) to look for additional neoplasms. In this residual longitudinal review, additional non-neoplastic and neoplastic uterine lesions were found that supported the initial findings. In several cases, the additional neoplasms were found in an animal already diagnosed with uterine cancer during the original transverse review. During the residual longitudinal review, atypical endometrial hyperplasia was diagnosed that was not present in the original transverse sections. This is a potentially preneoplastic lesion and the increased incidences in all treated groups were statistically significant. Cystic endometrial hyperplasia was also identified in the original transverse and residual longitudinal reviews. In the original transverse review, this appeared to be a treatment-related lesion, however, after the residual longitudinal review, additional lesions were identified in all groups, and the differences were no longer statistically significant.

Morphologically similar atypical endometrial hyperplasia has been diagnosed in women and rats. In women, this is considered a preneoplastic lesion and is diagnosed as simple or complex, depending on the architectural changes in the lesion.^130,131^ In both types, there are atypical changes in glandular cells, including cell stratification, tufting, loss of nuclear polarity, enlarged nuclei, and an increase in mitotic activity. These changes are similar to those seen in cancer cells, but atypical hyperplasia does not show invasion into the surrounding connective tissue. Most cases of atypical hyperplasia in women result from high levels of estrogens with insufficient levels of progesterone-like hormones. Risk factors include obesity, polycystic ovary syndrome, estrogen producing tumors (e.g., granulosa cell tumor), and some estrogen replacement therapies. Atypical endometrial hyperplasia is considered a significant risk factor for the development or coexistence of endometrial cancer. Among patients with atypical endometrial hyperplasia, 22% will eventually develop cancer.^132^

The occurrence of uterine adenocarcinomas was supported by increases in the incidences of uterine adenomas, significant by the trend statistic (P = 0.010). Uterine adenomas were well-circumscribed endometrium masses with no evidence of invasion into the myometrium. In contrast, uterine adenocarcinomas were less well-circumscribed than adenomas and showed evidence of invasion into the myometrium in some cases and metastasis to other tissues (e.g., lung). Uterine tumor metastases were found in the intestine, liver, mesentery, pancreas, glandular stomach, adrenal cortex, lymph nodes, spleen, thymus, skeletal muscle, lung, kidney, and urinary bladder. In humans, uterine endometrial carcinomas may be staged according to tumor size, involvement of adjacent organ systems (e.g., vagina), and involvement of nonadjacent tissues and lymph nodes.^133-136^

The malignant mixed Müllerian cell tumors seen in Wistar Han rats treated with tetrabromobisphenol A are uncommon tumors thought to arise from a pluripotent Müllerian duct cell.^137^ Dysregulation of the cell cycle and apoptotic regulatory proteins have been reported to be involved in malignant mixed Müllerian tumor neoplasia.^138^ In humans, these tumors account for about 5% of all malignant tumors derived from the body of the uterus, and they are highly malignant and associated with a poor prognosis.^139,140^ Risk factors are similar to those of adenocarcinomas and include obesity, exogenous estrogen therapies, nulliparity, tamoxifen therapy, and pelvic irradiation. There are two types of malignant mixed Müllerian cell tumors that can display differentiation along multiple pathways^137^: the homologous type contains a sarcomatous component that is made up of tissues found in the uterus such as endometrial, fibrous, or smooth muscle tissues; the heterologous type is made up of tissue not found in the uterus such as cartilage, skeletal muscle, or bone. Both types were seen in this study. For statistical analysis, malignant mixed Müllerian cell tumors were combined with the uterine adenomas and adenocarcinomas because, based on our knowledge of histogenesis of this tumor from the human literature, the epithelial component is considered to be the “driving force” of the tumor and the mesenchymal component is considered to be derived from the epithelial component. Evidence for this histogenesis theory includes clinical, histopathologic, immunohistochemical, ultrastructural, tissue culture, and molecular data.^141^ As an example, the behavior of human malignant mixed Müllerian cell tumors is more related to the type and grade of the epithelium rather than the mesenchymal component. For this reason, treatments are generally aimed at the epithelial component. Moreover, metastases tend to be the epithelial component, as they all were in this study.

The Wistar Han rat is responsive to chemical induction of uterine tumors by other chemicals. Tamoxifen treatment (given on days 2 to 5 after birth at 1 mg/kg body weight per day) caused uterine adenocarcinomas in Wistar Han rats at 24 to 35 months.^142^ This induction of uterine tumors in the Wistar Han rat by tamoxifen has been confirmed by the finding that tamoxifen treatment caused uterine adenocarcinomas in humans; the IARC has classified tamoxifen as a Group 1 carcinogen (carcinogenic to humans).^143^

Tetrabromobisphenol A may interfere with complex gene regulation systems.^144^ Alterations in proto-oncogenes, tumor suppressor genes, apoptosis genes, and DNA repair genes are central to the process of carcinogenesis, and the study of these alterations has revealed mechanistic insights into the process of chemical carcinogenesis.^145^ Chemical exposure (or exposure to chemical metabolites) may induce direct alterations in DNA, leading to chemical-DNA adduct formation, or may induce mutations indirectly through secondary mechanisms such as oxidative stress, cytotoxicity, or regenerative proliferation. Changes in the frequency or type of DNA mutation in chemically exposed animals may reveal chemical-related alterations that may drive carcinogenesis, or promote endogenous tumorigenic events.

The Tp53 tumor suppressor gene is responsible for cell cycle checkpoint maintenance, apoptosis, and genomic stability.^146^ Tp53 mutation results in the generation of a mutant protein that has lost normal tumor suppressor function and has additional oncogenic properties including promotion of cell survival and increased cell proliferation.^147^ Loss of cell cycle checkpoint control due to Tp53 mutation also results in inadequate DNA repair, which contributes to the generation of additional mutations in the genome. A number of “hot spot” regions in the central DNA binding domain of human Tp53 are more prone to mutational events,^147,148^ and the location and type of mutation in corresponding regions of the rat Tp53 gene (exons 5 to 8) are commonly used to study chemical-induced carcinogenesis and may reflect exposure to specific carcinogens.^149^

Alterations in Tp53 signaling due to mutation or dysregulation of the Tp53 signaling pathway are important events in the pathogenesis of many different types of cancer in rodents and humans, including aggressive endometrial cancer.^148,150-154^ Tp53 mutations in human endometrial cancer are associated with advanced disease and a poor prognosis.^154^ They occur at a high rate in high grade tumors (80% to 90%)^154-157^ and are thought to possibly occur as a late event in the development of aggressive endometrial cancer.

In the current study, NTP’s primary objective was to evaluate spontaneous adenocarcinomas and adenocarcinomas from tetrabromobisphenol A-dosed rats for alterations in the frequencies of Tp53 mutations to determine if the incidences of these mutations in treated rats difered from spontaneous tumors (Appendix M). Exons 5 to 8 of the rat Tp53 gene were examined for mutations in spontaneous uterine adenocarcinomas and adenocarcinomas from tetrabromobisphenol A-dosed rats. A statistically significant increase in the incidence of Tp53 mutations was observed in uterine adenocarcinomas from tetrabromobisphenol A-dosed rats compared to spontaneous tumors from control rats (P < 0.05). There was no difference between the mutation spectra of spontaneous tumors and those from tetrabromobisphenol A-dosed animals although two treated rats harbored multiple Tp53 mutations per tumor.

The increased incidence of Tp53 mutations observed in uterine adenocarcinomas from tetrabromobisphenol A-dosed rats compared to spontaneous tumors suggests that uterine carcinogenesis in tetrabromobisphenol A-dosed animals may be at least partly driven by alterations in the Tp53 signaling pathway. It is unclear whether or not tetrabromobisphenol A exposure induced a direct genotoxic event leading to Tp53 mutations, or if the increased incidence of mutations was a result of a secondary nongenotoxic event. Tetrabromobisphenol A was not mutagenic in bacterial studies^77^ nor did it induce chromosomal damage in the form of micronuclei in progenitor red blood cells in the bone marrow (Appendix E). Although positive results in bacterial mutagenicity assays and rodent micronucleus tests are highly predictive of rodent carcinogenicity, negative results in these assays are not good predictors of noncarcinogenicity.^117,121,158^

The incidences of testicular interstitial cell adenoma occurred with a significant positive trend in male Wistar Han rats (0 mg/kg, 0/50; 250 mg/kg, 0/50; 500 mg/kg, 1/50; 1,000 mg/kg, 3/50), and the incidence at the high dose exceeded the historical control incidence for all routes (4/150). However, the incidence in the vehicle control group was at the low end of the historical control range for this tumor and the incidence in the high dose group was only one greater than that in some of the historical studies; thus, these tumors were considered to be equivocal evidence for carcinogenic activity.

The incidences of hepatoblastoma in 250 and 500 mg/kg male mice were significantly greater than that in the concurrent vehicle controls and exceeded the historical control ranges both for corn oil gavage and for all routes of administration. In addition, there was supportive evidence from increased incidences of liver foci and multiple hepatocellular adenomas in treated groups of male mice. Hepatocellular adenoma, hepatocellular carcinoma, and hepatoblastoma are considered to represent a biological and morphological continuum.^159^ Hepatoblastomas are uncommon spontaneous neoplasms that may occur after chemical administration (primarily in mice) and have previously been seen as a treatment-related effect in mice in several NTP studies (benzofuran, ethylene thiourea, o-nitroanisole, coumarin, oxazepam, methyl-phenidate hydrochloride, 1-amino-2,4-dibromoanthra-quinone, pyridine, primidone, goldenseal root powder, and Ginkgo biloba extract).^160-170^ The incidences of hepatoblastoma in this study were considered some evidence of carcinogenic activity, but not clear evidence, because the combined incidences of hepatocellular carcinomas and hepatoblastomas were significant only in the 250 mg/kg group and the trend test was not significant.

The incidences of renal tubule cytoplasmic alteration were increased in the treated groups of male mice in the 2-year study. Cytoplasmic alteration of the renal tubule is a lesion that is defined as the reduction or loss of normal vacuoles in the proximal tubules of the outer cortex in male mice. These vacuoles have been shown to be autophagic vacuoles.^171^ They are part of the normal sequestration and degradation of organelles and membrane trafficking and recycling in the renal proximal tubule cells. This morphologic sexual dimorphism of the mouse kidney is also accompanied by an enzymatic dimorphism. A greater kidney acid hydrolase activity is correlated with an expansive lysosomal-vacuolar system in the proximal tubule cells of male mice. This sexual dimorphism has been shown to be dependent on endogenous testosterone. Following orchiectomy, there is a marked decrease in kidney enzymes and urinary excretion of hydrolases and protein. Even greater increases in kidney enzymes, lysosomal enzymuria, and proteinuria have been induced in female mice and orchiectomized male mice by testosterone administration. Thus, testosterone stimulates RNA and protein synthesis, modulates the structural and functional properties of mitochondria, and increases the activity of the lysosomal-vacuolar system in proximal tubule cells by augmenting intracellular autophagy.

The combined occurrence of large intestine tumors (cecum or colon) in male mice (one cecum carcinoma, one colon carcinoma, and one colon adenoma) at 500 mg/kg was considered to be equivocal evidence of carcinogenic activity because the occurrence of these intestinal tumors was significant by the trend statistic (P = 0.039), and the incidence in the 500 mg/kg group exceeded the historical control ranges for corn oil gavage studies and for all routes of administration. The occurrence of these intestinal tumors was not considered to be some evidence of a carcinogenic effect because the increased incidence of these tumors at 500 mg/kg was low, there was no supportive evidence of a carcinogenic effect in the female mice, and the increase at 500 mg/kg was not significant by the pairwise Poly-3 statistic.

The occurrence of hemangiosarcoma (all organs) in male mice was considered to be equivocal evidence of a carcinogenic effect because the increased incidence at 500 mg/kg was significant and the trend test for incidences of this tumor was significant. This was not considered to be some evidence for a carcinogenic effect because the incidence of hemangiosarcoma in the vehicle controls was at the low end of the historical control ranges for corn oil gavage studies and all routes of administration (2%-18% for corn oil gavage studies and 2%-18% for all routes of administration) and the incidence at 500 mg/kg (16%) was within both historical control ranges.

In the current 2-year study, the incidences of bone fibro-osseous lesion, a background lesion in female mice, were significantly decreased in treated groups of females. These decreases may have occurred, in part, due to the early deaths of 1,000 mg/kg mice from gastrointestinal toxicity and/or decreased incidences of cystic ovarian lesions that could have altered the hormonal status of the dosed females. The etiology of fibro-osseous lesion is unknown but it is more prevalent in females and an association with cystic ovaries and cystic endometrial hyperplasia suggests that there may have been an altered estrogen or sex hormone status in the dosed females.

Uterine tumors have been attributed to both estrogenic and nonestrogenic effects.^172^ In the current study, the occurrence of uterine tumors may be related to both the ability of tetrabromobisphenol A-derived metabolites to disrupt hormone signaling and the potential of tetrabromobisphenol A to cause oxidative damage.^30,61,62^ Glucuronidases in the uterus or other organs^173,174^ may work to release free tetrabromobisphenol A from its conjugated form, thus increasing the potential for free radical formation at target sites. Conjugation is the major biotransformation pathway for tetrabromobisphenol A in rodents and this pathway is shared by estrogen and its potentially genotoxic catechol metabolite.^175^ Competition for glucuronosyltransferases and/or sulfotransferases by tetrabromobisphenol A could result in higher circulating levels of estrogen and increased formation of estrogen-derived reactive species, especially following exposure to high concentrations of the chemical. Either process may contribute to tumorigenesis in the uterus.

Tetrabromobisphenol A may disrupt endocrine signaling through direct interaction with endocrine receptors or indirectly, through binding to estradiolsulfotransferase, thereby preventing sulfation of estradiol and its subsequent elimination.^55,176^ Tetrabromobisphenol A has a low IC_50_ (12 to 33 nM) sulfotransferase enzyme (SULT1E1) inhibition level.^177^ Crystallography studies show that tetrabromobisphenol A can bind to SULT1E1 and that the phenolic ring is critical for stable binding.^178^