# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-587.

## Three-month Study in F344/NTac Rats

All core study rats survived to the end of the study (Table 2). The final mean body weights and mean body weight gains of dosed groups of males and females were similar to those of the vehicle control groups (Table 2 and Figure 3). No clinical findings related to tetrabromobisphenol A administration were observed.

Table 2 Survival and Body Weights of F344/NTac Rats in the Three-month Gavage Study of Tetrabromobisphenol A^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 86 ± 3 | 345 ± 5 | 259 ± 5
10 | 10/10 | 85 ± 3 | 354 ± 6 | 269 ± 5 | 103
50 | 10/10 | 85 ± 3 | 350 ± 7 | 265 ± 8 | 101
100 | 10/10 | 85 ± 3 | 352 ± 7 | 267 ± 5 | 102
500 | 10/10 | 85 ± 3 | 339 ± 5 | 254 ± 3 | 98
1,000 | 10/10 | 84 ± 2 | 337 ± 6 | 253 ± 6 | 98
Female
0 | 10/10 | 81 ± 2 | 185 ± 2 | 104 ± 2
10 | 10/10 | 81 ± 2 | 189 ± 4 | 108 ± 3 | 102
50 | 10/10 | 81 ± 2 | 191 ± 2 | 110 ± 3 | 103
100 | 10/10 | 82 ± 3 | 186 ± 5 | 104 ± 4 | 100
500 | 10/10 | 82 ± 2 | 189 ± 4 | 107 ± 4 | 102
1,000 | 10/10 | 82 ± 2 | 187 ± 3 | 106 ± 2 | 101

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for F344/NTac Rats Administered Tetrabromobisphenol A by Gavage for Three Months

Assays for total thyroxine (T_4_) and thyroid stimulating hormone (TSH) were conducted on days 4 and 23 and at week 14; for total triiodothyronine (T_3_), assays were conducted on day 23 and at week 14 (Table F-1). Consistent, progressive, and dose-related decreases in total T_4_ concentrations occurred in 500 and 1,000 mg/kg males and females; this effect was observed with less consistency in the 100 mg/kg groups. On day 4, T_4_ was decreased by approximately 30% in the 1,000 mg/kg animals; by week 14, it was decreased by approximately 45%. The decreases in T_4_ were not accompanied by decreases in T_3_ concentrations or increases in TSH concentrations.

On day 23 and at week 14, the hematology findings suggested small (≤10%) decreases in the estimators of the circulating red cell mass in 500 and 1,000 mg/kg males and females (Table F-1). The erythron decrease was evidenced by decreases in hematocrit values, hemoglobin concentrations, and erythrocyte counts. The greatest magnitude of the decreases, approximately 10%, occurred in 1,000 mg/kg males on day 23. By week 14, there was some amelioration in the severity of the erythron decrease (≤5%) in the 500 and 1,000 mg/kg groups. The erythrocytes were of normal size and hemoglobin content and no changes in reticulocyte counts were observed.

Serum concentrations of total bile acids, a marker of hepatic function/injury and cholestasis, demonstrated transient increases (twofold or greater) in 500 and 1,000 mg/kg males and females on day 4; the effect had essentially resolved by day 23 (Table F-1). However, another marker of cholestasis, alkaline phosphatase, demonstrated little to no change on day 4. Thus, it would appear the transient increases in bile acid concentrations were probably not related to a cholestatic event, but rather a transient effect on hepatic function involving bile acid metabolism. At week 14, markers of hepatocellular injury, serum activities of alanine aminotransferase and sorbitol dehydrogenase, generally demonstrated decreases in males and females administered 100 mg/kg or greater.

Decreases in cytochrome P450 enzyme and UDP-glucuronosyl transferase activities were seen on day 23 and at week 14 in dosed groups of males and females (Table G-1); however no liver enzyme changes were considered to be biologically significant with the exception of 4- to 23-fold increases over the vehicle control value in 7-pentoxyresorufin-O-dealkylase (PROD) activities in 500 and 1,000 mg/kg males and females at week 14. The increased levels indicated some disturbance of liver function, but this was not accompanied by treatment-related liver lesions.

There were significant increases in the absolute and relative liver weights of 500 and 1,000 mg/kg males and females (Table H-1). Significant decreases occurred in the absolute and relative spleen weights of 500 and 1,000 mg/kg males and the absolute thymus weight of 1,000 mg/kg males.

There were no significant differences between the reproductive organ weights or sperm parameters of dosed and vehicle control groups of male rats (Table I-1). Dosed females exhibited a slight but significant increase in time in extended estrus compared to females in the vehicle control group (Table I-2 and Table I-3). This effect was minimal and manifested as a slight increase in the frequency of rats exhibiting 2 sequential days of estrus (compared to proestrus followed by estrus) (Figure I-1). Nevertheless, the rats were exhibiting normal duration cycles. Therefore, tetrabromobisphenol A was not considered to exhibit the potential to be a reproductive toxicant in male or female F344/NTac rats under the conditions of these studies.

No treatment-related histopathologic lesions were observed in F344/NTac rats in the 3-month study.

Dose Selection Rationale: The 3-month F344/NTac rat results were used to set doses for the 2-year study. There were no chemical-related effects on mortality, body weights, or lesion incidences in the 3-month study in F344/NTac rats. Chemical-related effects on organ weights, thyroid hormones, hematology parameters, and liver enzymes were not considered severe enough to compromise survival in the 2-year study. Therefore, doses selected for the 2-year gavage study in Wistar Han rats were 250, 500, and 1,000 mg/kg. The highest dose that could be administered by gavage was 1,000 mg/kg. Because NTP switched the laboratory rat strain from the F344/NTac rat to the Wistar Han rat after the tetrabromobisphenol A 3-month studies were conducted, a 3-month interim evaluation was added to the 2-year Wistar Han rat study.

## Two-year Study in Wistar Han Rats

### Survival

Estimates of 2-year survival probabilities for male and female rats are shown in Table 3 and in the Kaplan-Meier survival curves (Figure 4). Survival of dosed groups was similar to that of the vehicle control groups.

Table 3 Survival of Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation^a^ | 10 | 0 | 0 | 10
Accidental deaths^a^ | 1 | 0 | 0 | 3
Moribund | 14 | 18 | 8 | 6
Natural deaths | 2 | 4 | 4 | 2
Animals surviving to study termination | 33^e^ | 28 | 38 | 39
Percent probability of survival at end of study^b^ | 67 | 56 | 76 | 83
Mean survival (days)^c^ | 642 | 669 | 697 | 688
Survival analysis^d^ | P = 0.021N | P = 0.496 | P = 0.357N | P = 0.096N
Female
Animals initially in study | 60 | 50 | 50 | 60
Three-month interim evaluation^a^ | 10 | 0 | 0 | 10
Accidental deaths^a^ | 3 | 0 | 0 | 4
Moribund | 8 | 14 | 15 | 10
Natural deaths | 4 | 2 | 6 | 3
Animals surviving to study termination | 35^e^ | 34 | 29 | 33^e^
Percent probability of survival at end of study | 72 | 68 | 58 | 72
Mean survival (days) | 678 | 685 | 645 | 672
Survival analysis | P = 0.943 | P = 0.732 | P = 0.111 | P = 1.000

^a^ Censored from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal kill); does not include interim evaluation animals.

^d^ The result of the life table trend test^91^ is in the vehicle control column, and the results of the life table pairwise comparisons^90^ with the vehicle controls are in the dosed group columns. A negative trend or lower mortality in a dose group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

Figure 4

Kaplan-Meier Survival Curves for Wistar Han Rats Administered Tetrabromobisphenol A by Gavage for Two Years

### Organ Weights

At the 3-month interim evaluation, the absolute and relative thymus weights of 1,000 mg/kg rats were significantly less than those of the vehicle control groups and the relative liver weights of these dosed groups were significantly greater than those of the vehicle controls (Table H-2).

### Body Weights and Clinical Findings

The mean body weights of 500 and 1,000 mg/kg males were generally at least 10% less than those of the vehicle control group after week 25; body weights of dosed groups of female rats were similar to those of the vehicle controls throughout the study (Table 4 and Table 5; Figure 5). There were no clinical findings related to tetrabromobisphenol A administration.

Table 4 Mean Body Weights and Survival of Male Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A

Day | Vehicle Control | | | 250 mg/kg | | | 500 mg/kg | | | 1,000 mg/kg
Day | Av. Wt. (g) | No. of Survivors | | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 162 | 60 | | 161 | 99 | 50 | 161 | 99 | 50 | 161 | 99 | 60
8 | 207 | 59 | | 207 | 100 | 50 | 205 | 99 | 50 | 206 | 99 | 60
15 | 246 | 59 | | 248 | 101 | 50 | 242 | 99 | 50 | 245 | 100 | 60
22 | 275 | 59 | | 273 | 99 | 50 | 265 | 97 | 50 | 268 | 97 | 60
29 | 299 | 59 | | 296 | 99 | 50 | 290 | 97 | 50 | 291 | 98 | 60
36 | 321 | 59 | | 317 | 99 | 49 | 309 | 96 | 50 | 312 | 97 | 60
43 | 337 | 59 | | 333 | 99 | 49 | 327 | 97 | 50 | 330 | 98 | 60
50 | 350 | 59 | | 349 | 100 | 49 | 341 | 98 | 50 | 345 | 99 | 60
57 | 361 | 59 | | 365 | 101 | 49 | 357 | 99 | 50 | 359 | 99 | 60
64 | 374 | 59 | | 374 | 100 | 49 | 364 | 97 | 50 | 366 | 98 | 60
71 | 384 | 59 | | 382 | 100 | 49 | 374 | 98 | 50 | 376 | 98 | 60
78 | 393 | 59 | | 394 | 100 | 49 | 384 | 98 | 50 | 386 | 98 | 60
85 | 404 | 59 | | 409 | 101 | 49 | 397 | 98 | 50 | 397 | 98 | 60
113 | 436 | 49^a^ | | 421 | 97 | 49 | 404 | 93 | 50 | 401 | 92 | 50^a^
141 | 461 | 49 | | 440 | 96 | 49 | 420 | 91 | 50 | 421 | 91 | 50
169 | 474 | 49 | | 455 | 96 | 49 | 432 | 91 | 50 | 431 | 91 | 50
197 | 491 | 48 | | 470 | 96 | 49 | 444 | 90 | 50 | 444 | 90 | 50
225 | 504 | 48 | | 482 | 96 | 49 | 455 | 90 | 50 | 455 | 90 | 50
253 | 519 | 46 | | 493 | 95 | 49 | 465 | 90 | 50 | 461 | 89 | 50
281 | 532 | 46 | | 504 | 95 | 49 | 476 | 89 | 50 | 468 | 88 | 50
309 | 547 | 46 | | 518 | 95 | 49 | 487 | 89 | 50 | 481 | 88 | 50
337 | 560 | 46 | | 528 | 94 | 49 | 497 | 89 | 50 | 489 | 87 | 50
365 | 566 | 46 | | 534 | 94 | 49 | 504 | 89 | 50 | 493 | 87 | 50
393 | 579 | 46 | | 549 | 95 | 49 | 511 | 88 | 49 | 498 | 86 | 49
421 | 593 | 46 | | 564 | 95 | 48 | 526 | 89 | 49 | 517 | 87 | 49
449 | 605 | 46 | | 579 | 96 | 48 | 545 | 90 | 49 | 533 | 88 | 48
477 | 612 | 45 | | 590 | 97 | 48 | 556 | 91 | 49 | 540 | 88 | 48
505 | 620 | 42 | | 599 | 97 | 46 | 562 | 91 | 49 | 546 | 88 | 47
533 | 630 | 40 | | 604 | 96 | 45 | 569 | 90 | 48 | 552 | 88 | 45
561 | 642 | 39 | | 615 | 96 | 44 | 579 | 90 | 48 | 566 | 88 | 44
589 | 642 | 38 | | 615 | 96 | 44 | 577 | 90 | 46 | 566 | 88 | 44
617 | 644 | 38 | | 609 | 94 | 42 | 586 | 91 | 45 | 576 | 89 | 41
645 | 640 | 36 | | 613 | 96 | 38 | 590 | 92 | 41 | 574 | 90 | 41
673 | 656 | 35 | | 606 | 92 | 36 | 597 | 91 | 39 | 588 | 90 | 39
701 | 663 | 33 | | 615 | 93 | 30 | 599 | 90 | 39 | 584 | 88 | 39
Mean for Weeks
1–13 | 316 | – | | 316 | 100 | – | 309 | 98 | – | 311 | 98 | –
14–52 | 503 | – | | 479 | 95 | – | 453 | 90 | – | 450 | 89 | –
53–101 | 623 | – | | 592 | 95 | – | 562 | 90 | – | 549 | 88 | –

^a^ Interim evaluation occurred during week 13.

Table 5 Mean Body Weights and Survival of Female Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A

Day | Vehicle Control | | 250 mg/kg | | | 500 mg/kg | | | 1,000 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 136 | 60 | 137 | 101 | 50 | 136 | 100 | 50 | 135 | 100 | 60
8 | 157 | 60 | 157 | 100 | 50 | 157 | 100 | 50 | 156 | 99 | 60
15 | 172 | 60 | 173 | 101 | 50 | 176 | 102 | 50 | 175 | 102 | 60
22 | 185 | 60 | 184 | 100 | 50 | 184 | 100 | 50 | 183 | 99 | 60
29 | 195 | 60 | 196 | 101 | 50 | 194 | 100 | 50 | 194 | 99 | 60
36 | 204 | 60 | 203 | 100 | 50 | 202 | 99 | 50 | 200 | 99 | 60
43 | 209 | 60 | 209 | 100 | 50 | 209 | 100 | 50 | 207 | 99 | 60
50 | 215 | 60 | 216 | 100 | 50 | 218 | 101 | 50 | 216 | 100 | 60
57 | 218 | 60 | 221 | 101 | 50 | 224 | 102 | 50 | 223 | 102 | 60
64 | 224 | 60 | 225 | 100 | 50 | 228 | 102 | 50 | 226 | 101 | 60
71 | 227 | 60 | 226 | 100 | 50 | 231 | 102 | 50 | 229 | 101 | 60
78 | 229 | 60 | 232 | 101 | 50 | 232 | 101 | 50 | 230 | 101 | 60
85 | 233 | 60 | 239 | 102 | 50 | 240 | 103 | 50 | 239 | 103 | 60
113 | 240 | 50^a^ | 245 | 102 | 50 | 245 | 102 | 50 | 243 | 101 | 50^a^
141 | 249 | 50 | 254 | 102 | 50 | 251 | 101 | 50 | 247 | 99 | 50
169 | 254 | 50 | 258 | 102 | 50 | 256 | 101 | 50 | 252 | 99 | 50
197 | 258 | 50 | 264 | 102 | 50 | 260 | 101 | 50 | 256 | 99 | 49
225 | 263 | 50 | 269 | 102 | 50 | 263 | 100 | 50 | 259 | 98 | 49
253 | 268 | 50 | 274 | 102 | 50 | 268 | 100 | 49 | 262 | 98 | 49
281 | 276 | 50 | 280 | 102 | 50 | 271 | 99 | 49 | 267 | 97 | 49
309 | 283 | 50 | 287 | 102 | 50 | 279 | 99 | 49 | 272 | 96 | 49
337 | 292 | 50 | 294 | 101 | 50 | 283 | 97 | 47 | 277 | 95 | 49
365 | 297 | 47 | 299 | 101 | 49 | 288 | 97 | 47 | 284 | 96 | 49
393 | 301 | 47 | 308 | 102 | 48 | 294 | 98 | 46 | 289 | 96 | 49
421 | 309 | 47 | 315 | 102 | 48 | 301 | 97 | 46 | 297 | 96 | 49
449 | 317 | 47 | 327 | 103 | 48 | 311 | 98 | 46 | 306 | 97 | 47
477 | 326 | 46 | 335 | 103 | 48 | 315 | 97 | 45 | 312 | 96 | 46
505 | 334 | 46 | 344 | 103 | 47 | 326 | 97 | 43 | 320 | 96 | 45
533 | 339 | 46 | 353 | 104 | 46 | 329 | 97 | 40 | 329 | 97 | 44
561 | 347 | 42 | 365 | 105 | 45 | 339 | 98 | 38 | 344 | 99 | 43
589 | 352 | 42 | 372 | 106 | 44 | 344 | 98 | 37 | 351 | 100 | 43
617 | 361 | 41 | 378 | 105 | 43 | 352 | 98 | 35 | 357 | 99 | 39
645 | 361 | 41 | 382 | 106 | 41 | 355 | 98 | 31 | 364 | 101 | 37
673 | 370 | 37 | 392 | 106 | 37 | 363 | 98 | 31 | 374 | 101 | 37
701 | 375 | 37 | 403 | 107 | 36 | 368 | 98 | 30 | 375 | 100 | 33
Mean for Weeks
1–13 | 200 | – | 201 | 101 | – | 202 | 101 | – | 201 | 101 | –
14–52 | 265 | – | 269 | 102 | – | 264 | 100 | – | 259 | 98 | –
53–101 | 338 | – | 352 | 104 | – | 330 | 98 | – | 331 | 98 | –

^a^ Interim evaluation occurred during week 13.

Figure 5

Growth Curves for Wistar Han Rats Administered Tetrabromobisphenol A by Gavage for Two Years

#### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or non-neoplastic lesions of the uterus, testis, and ovary. Summaries of the incidences of neoplasms and non-neoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix A for male rats and Appendix B for female rats.

No treatment-related lesions occurred in 1,000 mg/kg rats at the 3-month interim evaluation.

Uterus: Neoplasms occurred in all dosed groups of females in the original transverse review of the uterus; some vehicle control females also had uterine neoplasms (Table 6, Table B-1, and Table B-2). Statistical evaluations were performed for primary tumors identified in the original transverse review, the residual longitudinal review, and the combined original transverse and residual longitudinal reviews. Tumor types were evaluated for statistical significance either individually or combined according to epithelial origin (adenoma, adenocarcinoma, or malignant mixed Müllerian tumor) or mesenchymal origin (stromal polyp, stromal sarcoma, or leiomyosarcoma). For adenoma, there was a positive trend in the original transverse review. For adenocarcinoma, there was a positive trend in the original transverse review and positive trends and significantly increased incidences in the 500 and 1,000 mg/kg groups in the residual longitudinal review and the combined reviews. For the combination of adenoma, adenocarcinoma, or malignant mixed Müllerian tumor there were positive trends and significantly increased incidences in the 500 and 1,000 mg/kg groups in both reviews and when the reviews were combined.

Table 6 Incidences of Neoplasms and Non-neoplastic Lesions of the Uterus in Female Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Original Transverse Review
Number Necropsied | 50 | 50 | 50 | 50
Endometrium, Hyperplasia, Cystic^a^ | 8 (2.1)^b^ | 13 (1.5) | 11 (2.0) | 18* (1.9)
Adenoma^c^
Overall rate^d^ | 0/50 (0%) | 0/50 (0%) | 3/50 (6%) | 4/50 (8%)
Adjusted rate^e^ | 0.0% | 0.0% | 7.8% | 9.4%
Terminal rate^f^ | 0/34 (0%) | 0/34 (0%) | 3/29 (10%) | 2/33 (6%)
First incidence (days) | –^h^ | – | 728 (T) | 625
Poly-3 test^g^ | P = 0.010 | –^i^ | P = 0.100 | P = 0.059
Adenocarcinoma, Multiple | 1 | 0 | 1 | 0
Adenocarcinoma (includes multiple)^j^
Overall rate | 3/50 (6%) | 3/50 (6%) | 8/50 (6%) | 9/50 (18%)
Adjusted rate | 7.0% | 6.7% | 19.8% | 20.9%
Terminal rate | 2/34 (6%) | 0/34 (0%) | 4/29 (14%) | 5/33 (15%)
First incidence (days) | 713 | 548 | 321 | 607
Poly-3 test | P = 0.016 | P = 0.644N | P = 0.078 | P = 0.058
Malignant Mixed Müllerian Tumor^c^ | 0 | 4 | 0 | 2
Adenoma, Adenocarcinoma, or Malignant Mixed Müllerian Tumor^j^
Overall rate | 3/50 (6%) | 7/50 (14%) | 11/50 (22%) | 13/50 (26%)
Adjusted rate | 7.0% | 15.4% | 27.3% | 29.9%
Terminal rate | 2/34 (6%) | 1/34 (3%) | 7/29 (24%) | 7/33 (21%)
First incidence (days) | 713 | 548 | 321 | 607
Poly-3 test | P = 0.003 | P = 0.181 | P = 0.013 | P = 0.005
Residual Longitudinal Review
Number Necropsied | 50 | 50 | 50 | 50
Endometrium, Hyperplasia, Cystic | 23 | 30 | 28 | 31
Endometrium, Hyperplasia, Atypical | 2 | 13** | 11** | 13**
Adenoma | 3 | 2 | 1 | 3
Adenocarcinoma (includes multiple)
Overall rate | 4/50 (8%) | 9/50 (18%) | 15/50 (30%) | 15/50 (30%)
Adjusted rate | 9.3% | 19.9% | 36.4% | 33.8%
Terminal rate | 3/34 (9%) | 4/34 (12%) | 9/29 (31%) | 10/33 (30%)
First incidence (days) | 713 | 548 | 321 | 442
Poly-3 test | P = 0.003 | P = 0.137 | P = 0.002 | P = 0.005
Malignant Mixed Müllerian Tumor | 0 | 0 | 0 | 1
Adenoma, Adenocarcinoma, or Malignant Mixed Müllerian Tumor
Overall rate | 6/50 (12%) | 10/50 (20%) | 16/50 (32%) | 16/50 (32%)
Adjusted rate | 13.9% | 22.1% | 38.8% | 35.8%
Terminal rate | 3/34 (9%) | 5/34 (15%) | 10/29 (35%) | 10/33 (30%)
First incidence (days) | 668 | 548 | 321 | 442
Poly-3 test | P = 0.008 | P = 0.237 | P = 0.007 | P = 0.015
Original Transverse and Residual Longitudinal Reviews (Combined)
Number Necropsied | 50 | 50 | 50 | 50
Endometrium, Hyperplasia, Cystic | 24 | 31 | 30 | 32
Endometrium, Hyperplasia, Atypical | 2 | 13** | 11** | 13**
Adenoma | 3 | 2 | 4 | 6
Adenocarcinoma (includes multiple)
Overall rate | 4/50 (8%) | 10/50 (20%) | 15/50 (30%) | 16/50 (32%)
Adjusted rate | 9.3% | 22.0% | 36.4% | 35.9%
Terminal rate | 3/34 (9%) | 4/34 (12%) | 9/29 (31%) | 10/33 (30%)
First incidence (days) | 713 | 548 | 321 | 442
Poly-3 test | P = 0.002 | P = 0.089 | P = 0.002 | P = 0.002
Malignant Mixed Müllerian Tumor | 0 | 4 | 0 | 2
Adenoma, Adenocarcinoma, or Malignant Mixed Müllerian Tumor
Overall rate | 6/50 (12%) | 11/50 (22%) | 16/50 (32%) | 19/50 (38%)
Adjusted rate | 13.9% | 24.2% | 38.8% | 42.2%
Terminal rate | 3/34 (9%) | 5/34 (15%) | 10/29 (35%) | 11/33 (33%)
First incidence (days) | 668 | 548 | 321 | 442
Poly-3 test | P < 0.001 | P = 0.168 | P = 0.007 | P = 0.002

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

(T) Terminal kill

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^c^ Historical control incidence for 2-year studies (all routes): 0/150.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill. A lower incidence in a dose group is indicated by N.

^h^ Not applicable; no neoplasms in animal group.

^i^ Value of statistic cannot be computed.

^j^ Historical control incidence for 2-year studies (all routes): 7/150 (includes one endometrium carcinoma).

Adenomas were generally solitary, well delineated lesions composed of a collection of endometrial glands that were typical in appearance, with little to no compression of surrounding tissue and no invasion of the adjacent endometrium or myometrium. The glands were lined by a single layer of well-differentiated cuboidal to columnar epithelium without stratification and surrounded by a delicate fibrous stroma. Occasionally adenomas were present on a broad stalk and projected in the uterine lumen.

Adenocarcinomas were often quite large, completely obliterating the normal uterine architecture. Some also invaded distant organs, including the intestines, liver, mesentery, pancreas, adrenal gland, ovary, lymph node, spleen, thymus, subcutaneous tissue, skeletal muscle, lung, and kidney. Histologically, masses were characterized by enlarged pleomorphic epithelial cells arranged as solid nests, cords, papillary, or acinar structures, within or supported by a fibrovascular stroma (Figure 9 and Figure 10). There was moderate to marked cellular pleomorphism and atypia. The epithelium was anaplastic in some cases with stratification of multiple cell layers forming solid sheets of epithelial cells that extended through the uterine wall. Large areas of necrosis and suppurative inflammation were also associated with larger tumors. Proliferation of fibroblasts and formation of thick stroma were present in many cases. If there was more than one adenocarcinoma and the tumors were clearly independent, distinct, and not connected, then a diagnosis of multiple adenocarcinoma was made.

Figure 9

Normal Uterus in a Vehicle Control Female Wistar Han Rat in the Two-year Gavage Study of Tetrabromobisphenol A (H&E)

Note the normal simple tubular endometrial glands (arrows).

Figure 10

Uterine Adenocarcinoma in a Female Wistar Han Rat Administered 250 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

Cords and acinar structures are lined by one or multiple cell layers of pleomorphic neoplastic cells. The cells are cuboidal to columnar with varying amounts of slightly basophilic cytoplasm. Cell nuclei are centrally to basally located, round to oval, with multiple prominent nucleoli. Inflammation and cell debris are common within the fibrous stroma.

An increased incidence of point mutations in the rat Tp53 gene was observed in uterine adenocarcinomas from tetrabromobisphenol A-exposed animals (10/16; 63%) compared to spontaneous uterine adenocarcinomas in control animals (1/9; 11%). Additionally, uterine adenocarcinomas from two rats exposed to tetrabromobisphenol A harbored multiple mutations. The results are presented in Appendix M.

Malignant mixed Müllerian tumors were composed of a mixture of neoplastic epithelial and neoplastic mesenchymal cells (Figure 11). Cytokeratin and vimentin immunohistochemical stains were used to better characterize these lesions (Figure 12 and Figure 13). Cytokeratin staining revealed neoplastic epithelial elements with granular cytoplasmic staining; however, these positive cells were admixed with neoplastic mesenchymal cells that showed positive cytoplasmic staining with vimentin. Stained serial sections showed that some individual neoplastic cells were biphasic and stained with both cytokeratin and vimentin. All tumors were very large and infiltrative, composed of areas with glandular formation and also areas with a more solid growth pattern. In the areas of glandular formation, these tumors were similar to adenocarcinomas in morphology. In the areas with a more solid growth pattern, the neoplastic cells were arranged in sheets, streams, and/or interweaving bundles. In these areas, individual neoplastic cells were large and pleomorphic with large round to elongate nuclei with an open chromatin pattern and a single prominent magenta nucleolus. Bizarre mitotic figures were frequent. One malignant mixed Müllerian tumor had areas of neoplastic bone formation (heterologous type). Tumors in four animals in the 250 mg/kg group had extensive metastases to the liver, mesentery, pancreas, stomach, ovary, spleen, subcutaneous tissue, lung, and kidney.

Figure 11

Malignant Mixed Müllerian Tumor in the Uterus of a Female Wistar Han Rat Administered 250 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

This area of the neoplasm has a more solid pattern than an adenocarcinoma with a mixture of both neoplastic epithelial cells and neoplastic mesenchymal cells. The neoplastic cells are disorganized. Individual neoplastic cells are atypical with variation in size and shape and have pleomorphic nuclei containing vesicular chromatin.

Figure 12

Malignant Mixed Müllerian Tumor in the Uterus of a Female Wistar Han Rat Administered 250 mg/kg Tetrabromobisphenol A by Gavage for Two Years

A subset of the neoplastic cells show cytokeratin-positive cytoplasmic staining. Cytokeratin antibody is an immunohistochemical stain for cells of epithelial origin.

Figure 13

Malignant Mixed Müllerian Tumor in the Uterus of a Female Wistar Han Rat Administered 250 mg/kg Tetrabromobisphenol A by Gavage for Two Years

A subset of the neoplastic cells show vimentin-positive cytoplasmic staining. Vimentin antibody is an immunohistochemical stain for cells of mesenchymal origin.

In the original transverse review, the incidences of cystic endometrial hyperplasia were increased in all dosed groups of females, and the increase in the 1,000 mg/kg group was significant (Table 6 and Table B-4). In the residual longitudinal review, additional incidences of cystic endometrial hyperplasia were found and the treatment-related effect was not supported when the reviews were combined. A new and potentially preneoplastic lesion of endometrial atypical hyperplasia was identified in all dose groups during the residual longitudinal review of the uterus (Figure 14 to Figure 18).

Figure 14

Uterus from a Female Wistar Han Rat Administered 250 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

Note the focal cluster of endometrial glands with atypical hyperplasia (arrow).

Cystic endometrial hyperplasia was diagnosed when there were three or more dilated glands. Microscopically, a single layer of normal appearing endometrial epithelium, either cuboidal or columnar, lined affected glands. In earlier stages, the glands were lined by more crowded epithelial cells and associated with a neutrophilic infiltrate. This lesion was diagnosed as minimal severity when approximately three to five dilated glands were present with little to no distortion or extension into the uterine lumen. Mild cystic endometrial hyperplasia was diagnosed when greater than five dilated glands were present and bulged into, but did not fill, the uterine lumen. In mild hyperplasia, dilated glands were larger than those noted in cases with minimal severity and some glandular crowding and reduction in surrounding stroma was noted. Diagnoses of moderate severity involved increases in glandular density with extension and filling of the entire uterine lumen in most cases. The diameter of the dilated glands often varied in size from small to greater than half the size of the uterine lumen.

Uterus endometrium atypical hyperplasia was not present in the cross sections of originally examined tissues but was only diagnosed in the longitudinal tissues. The lesion affected either glandular epithelium or uterine surface epithelium, and occasionally both types occurred together. Clusters of enlarged glands separated by little to no stroma characterized this lesion. Affected glands were lined by very tall, stratified, disorganized epithelium that piled up to six cell layers thick in some cases. Epithelial cells lining affected glands often displayed loss of nuclear polarization, karyomegaly, mitoses, and cellular pleomorphism. The thickened epithelium frequently projected into glandular lumens forming multiple thickened infoldings and projections. Despite the atypical features, these proliferative lesions were not considered adenomas as they did not form a distinct mass or compress the surrounding uterine architecture. Morphologic features were different in areas of atypia affecting the surface epithelium. The papillary type consisted of numerous small branching projections of epithelium that extended into the uterine lumen, occasionally on small fibrovascular stalks. Epithelial blebbing and loss of nuclear polarization were noted.

Testis: The incidences of interstitial cell adenoma were slightly increased in 500 and 1,000 mg/kg males, and the incidence in the 1,000 mg/kg group exceeded the historical control incidence for all routes of administration (Table 7, Table A-1, Table A-2, and Table A-3). Atrophy of the testicular germinal epithelium was identified in seven treated males, and the severity of the lesion increased with increasing dose (Table 7 and Table A-4). Affected testes were shrunken with a convoluted tunica albuginea. Approximately 50% to 90% of seminiferous tubules were affected in most cases. Seminiferous tubules were small, thin, and widely separated by pale eosinophilic fluid (edema). Interstitial cells appeared prominent. Seminiferous tubules were lined by low flattened epithelium with lumens devoid of spermatozoa.

Table 7 Incidences of Neoplasms and Non-neoplastic Lesions of the Testis and Ovary in Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Testis^a^ | 50 | 50 | 50 | 50
Germinal Epithelium, Atrophy^b^ | 0 | 4 (2.8)^c^ | 1 (3.0) | 2 (3.5)
Interstitial Cell, Adenoma, Bilateral | 0 | 0 | 1 | 0
Interstitial Cell, Adenoma (includes bilateral)^d^
Overall rate^e^ | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%)
Adjusted rate^f^ | 0.0% | 0.0% | 2.2% | 6.8%
Terminal rate^g^ | 0/33 (0%) | 0/28 (0%) | 1/38 (3%) | 3/39 (8%)
First incidence (days) | –^i^ | – | 727 (T) | 727 (T)
Poly-3 test^h^ | P = 0.023 | –^j^ | P = 0.526 | P = 0.138
Female
Ovary | 50 | 49 | 50 | 49
Rete Ovarii, Cyst | 1 | 0 | 6* | 6*

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

(T) Terminal kill.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for 2-year studies (all routes): 4/150.

^e^ Number of animals with neoplasm per number of animals with testis examined microscopically.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Observed incidence at terminal kill.

^h^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^i^ Not applicable; no neoplasms in animal group.

^j^ Value of statistic cannot be computed.

The testicular interstitial cell adenomas were characterized as a mass of proliferating interstitial cells with prominent cystic spaces that caused compression of adjacent seminiferous tubules. The four animals with adenomas (three unilateral and one bilateral) had tumors that ranged from small (an area of about one sixth of the testis) to large (effacing about 70% of the testis). The neoplastic cells had distinct cell borders, were larger and paler than normal interstitial cells, and contained eosinophilic, finely vacuolated cytoplasm, round nuclei with stippled chromatin, and a single prominent magenta nucleolus. The cystic spaces were filled with pale eosinophilic material and clear vacuoles were present around the periphery. There was a scant and sometimes inapparent fibrovascular stroma. Invasion of the capsule was not a feature.

Ovary: The incidences of rete ovarii cyst were significantly increased in 500 and 1,000 mg/kg females (Table 7 and Table B-4).

## Mice

### Three-month Study

All mice survived to the end of the study (Table 8). The final mean body weights and mean body weight gains of dosed groups of males and females were similar to those of the vehicle control groups (Table 8 and Figure 6). No clinical findings related to tetrabromobisphenol A administration were observed.

Table 8 Survival and Body Weights of Mice in the Three-month Gavage Study of Tetrabromobisphenol A^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.6 ± 0.4 | 37.4 ± 0.9 | 14.8 ± 0.9 | –
10 | 10/10 | 22.3 ± 0.4 | 34.7 ± 0.7 | 12.4 ± 0.6 | 93
50 | 10/10 | 22.6 ± 0.3 | 38.4 ± 0.6 | 15.8 ± 0.6 | 103
100 | 10/10 | 22.8 ± 0.4 | 36.2 ± 1.0 | 13.4 ± 0.9 | 97
500 | 10/10 | 22.8 ± 0.5 | 37.1 ± 0.9 | 14.2 ± 0.8 | 99
1,000 | 10/10 | 22.8 ± 0.4 | 35.2 ± 1.2 | 12.4 ± 1.2 | 94
Female
0 | 10/10 | 18.4 ± 0.3 | 27.5 ± 0.6 | 9.1 ± 0.6 | –
10 | 10/10 | 18.4 ± 0.3 | 29.3 ± 1.0 | 10.9 ± 0.8 | 106
50 | 10/10 | 18.5 ± 0.3 | 28.6 ± 0.7 | 10.1 ± 0.5 | 104
100 | 10/10 | 18.3 ± 0.3 | 26.2 ± 0.7 | 7.8 ± 0.5 | 95
500 | 10/10 | 18.5 ± 0.3 | 29.2 ± 0.7 | 10.7 ± 0.6 | 106
1,000 | 10/10 | 18.4 ± 0.3 | 27.7 ± 0.6 | 9.4 ± 0.6 | 101

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant

by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

No changes in hematology parameters were attributable to the administration of tetrabromobisphenol A (Table F-2).

Acetanilide-4-hydroxylase, 7-ethoxyresorufin-O-deeth-ylase, and PROD activities in the liver of 500 and 1,000 mg/kg males were significantly less (30% to 40%) than those of the vehicle controls at the end of the study; in 1,000 mg/kg females, PROD activity was significantly decreased (30%) at week 14 (Table G-2). These effects were less pronounced in mice than in rats in the 3-month study.

Compared to those of the vehicle controls, absolute and relative liver weights were significantly increased in 500 mg/kg males and 1,000 mg/kg males and females; absolute and relative spleen weights in 1,000 mg/kg males were also significantly increased (Table H-3). Absolute and relative kidney weights were significantly decreased in 1,000 mg/kg male mice.

Tetrabromobisphenol A did not exhibit the potential to be a reproductive toxicant in B6C3F1/N mice under the conditions of these studies (Table I-4, Table I-5, and Table I-6; Figure I-2).

Figure 6

Growth Curves for Mice Administered Tetrabromobisphenol A by Gavage for Three Months

Significantly increased incidences of renal tubule cytoplasmic alteration occurred in 500 and 1,000 mg/kg male mice, and the severity of the lesion in the 1,000 mg/kg group was greater than that in the 500 mg/kg group (Table 9). Renal tubule cytoplasmic alteration was characterized by a decrease or absence of the normal vacuoles present in the cortical proximal tubules.

Table 9 Incidences of Cytoplasmic Alteration of the Kidney in Male Mice in the Three-month Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 10 mg/kg | 50 mg/kg | 100 mg/kg | 500 mg/kg | 1,000 mg/kg
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Renal Tubule, Cytoplasmic Alteration^a^ | 0 | 0 | 0 | 0 | 10** (1.0)^b^ | 10** (2.0)

** Significantly different (P ≤ 0.01) from the vehicle control group by the Fisher exact test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Dose Selection Rationale: No effects on mortality, body weights, or hematology parameters were observed in the 3-month study. Chemical-related effects on liver enzyme activities, organ weights, and kidney lesion incidences were not expected to cause increased mortality in a 2-year study. Therefore, doses selected for the 2-year gavage study in mice were 250, 500, and 1,000 mg/kg.

## Two-year Study

### Survival

Estimates of 2-year survival probabilities for male and female mice are shown in Table 10 and in the Kaplan-Meier survival curves (Figure 7). Survival of 1,000 mg/kg males and females was significantly less than that of the vehicle control groups. Increased mortality was seen as early as 6 months into the study and coincided with the initial divergence of body weight gain in the 1,000 mg/kg females. Analysis of the pathology findings suggests that decreased survival may have been due in part to gastrointestinal toxicity, although the severities of the various gastrointestinal lesions in the high dose groups were not always increased over those in the other dosed groups.

Table 10 Survival of Mice in the Two-year Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^a^ | 0 | 0 | 0 | 1
Moribund | 9 | 10 | 6 | 12
Natural deaths | 8 | 14 | 5 | 25
Animals surviving to study termination | 33^e^ | 26^e^ | 39 | 12
Percent probability of survival at end of study^b^ | 66 | 50 | 78 | 25
Mean survival (days)^c^ | 687 | 678 | 702 | 577
Survival analysis^d^ | P < 0.001 | P = 0.200 | P = 0.260N | P < 0.001
Female
Animals initially in study | 50 | 50 | 50 | 50
Accidental death^a^ | 0 | 0 | 0 | 1
Moribund | 6 | 8 | 3 | 7
Natural deaths | 4 | 11 | 11 | 38
Animals surviving to study termination | 40 | 31 | 36 | 4
Percent probability of survival at end of study | 80 | 62 | 72 | 8
Mean survival (days) | 711 | 703 | 695 | 413
Survival analysis | P < 0.001 | P = 0.081 | P = 0.421 | P < 0.001

^a^ Censored from survival analyses.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and terminal kill).

^d^ The result of the life table trend test^91^ is in the vehicle control column, and the results of the life table pairwise comparisons^90^ with the vehicle controls are in the dosed group columns. A lower mortality in a dose group is indicated by N.

^e^ Includes one animal that died during the last week of the study.

### Body Weights and Clinical Findings

The mean body weights of 1,000 mg/kg females were 10% to 25% less than those of the vehicle controls after week 25 (Figure 8; Table 11 and Table 12). Body weights of all dosed groups of males and of 250 and 500 mg/kg females were generally similar to those of the vehicle control groups throughout the study. No clinical findings related to chemical exposure were observed.

Table 11 Mean Body Weights and Survival of Male Mice in the Two-year Gavage Study of Tetrabromobisphenol A

Day | Vehicle Control | | 250 mg/kg | | | 500 mg/kg | | 1,000 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 22.2 | 50 | 22.2 | 100 | 50 | 22.1 | 100 | 50 | 22.2 | 100 | 50
8 | 23.5 | 50 | 23.7 | 101 | 50 | 23.5 | 100 | 50 | 23.7 | 101 | 50
15 | 25.1 | 50 | 25.3 | 101 | 50 | 25.0 | 100 | 50 | 25.1 | 100 | 50
22 | 26.2 | 50 | 26.5 | 101 | 50 | 26.3 | 101 | 50 | 26.0 | 99 | 50
29 | 27.8 | 50 | 28.1 | 101 | 50 | 27.7 | 100 | 50 | 27.3 | 98 | 50
36 | 29.8 | 50 | 29.8 | 100 | 50 | 29.2 | 98 | 50 | 28.7 | 96 | 50
43 | 31.0 | 50 | 30.8 | 99 | 50 | 30.3 | 98 | 50 | 29.9 | 96 | 50
50 | 32.9 | 50 | 32.7 | 99 | 50 | 32.0 | 97 | 50 | 31.4 | 96 | 50
57 | 34.2 | 50 | 34.0 | 99 | 50 | 33.1 | 97 | 50 | 32.4 | 95 | 50
64 | 35.2 | 50 | 35.3 | 101 | 50 | 34.2 | 97 | 50 | 33.3 | 95 | 50
71 | 36.1 | 50 | 36.1 | 100 | 50 | 34.9 | 97 | 50 | 33.9 | 94 | 50
78 | 37.8 | 50 | 37.4 | 99 | 50 | 36.4 | 96 | 50 | 35.3 | 93 | 50
85 | 37.8 | 50 | 38.0 | 100 | 50 | 37.0 | 98 | 50 | 35.5 | 94 | 50
113 | 40.7 | 50 | 41.3 | 102 | 50 | 39.6 | 97 | 50 | 38.6 | 95 | 50
141 | 42.2 | 50 | 43.0 | 102 | 50 | 40.6 | 96 | 50 | 40.0 | 95 | 49
169 | 45.7 | 50 | 46.5 | 102 | 50 | 44.6 | 98 | 50 | 43.2 | 95 | 49
197 | 48.5 | 50 | 50.2 | 104 | 50 | 48.0 | 99 | 50 | 45.5 | 94 | 49
225 | 50.4 | 50 | 52.0 | 103 | 50 | 50.1 | 99 | 50 | 47.2 | 94 | 48
253 | 51.3 | 50 | 52.4 | 102 | 50 | 52.2 | 102 | 50 | 49.2 | 96 | 47
281 | 52.8 | 50 | 54.1 | 102 | 50 | 54.6 | 103 | 50 | 52.4 | 99 | 47
309 | 54.5 | 50 | 55.7 | 102 | 50 | 56.8 | 104 | 50 | 54.7 | 100 | 47
337 | 54.9 | 50 | 55.7 | 102 | 50 | 56.9 | 104 | 50 | 55.4 | 101 | 47
365 | 55.2 | 50 | 57.1 | 103 | 50 | 57.5 | 104 | 50 | 56.4 | 102 | 46
393 | 54.2 | 49 | 56.7 | 105 | 50 | 56.4 | 104 | 50 | 54.8 | 101 | 45
421 | 54.8 | 49 | 57.3 | 105 | 49 | 57.6 | 105 | 50 | 54.6 | 100 | 42
449 | 55.7 | 48 | 57.3 | 103 | 48 | 58.0 | 104 | 50 | 55.9 | 100 | 41
477 | 55.8 | 48 | 57.6 | 103 | 47 | 58.4 | 105 | 50 | 57.6 | 103 | 38
505 | 54.0 | 47 | 56.2 | 104 | 47 | 57.1 | 106 | 50 | 55.8 | 104 | 36
533 | 55.3 | 46 | 56.1 | 101 | 46 | 57.5 | 104 | 48 | 56.1 | 101 | 32
561 | 55.2 | 45 | 55.7 | 101 | 45 | 57.3 | 104 | 46 | 57.2 | 104 | 28
589 | 55.7 | 45 | 56.0 | 101 | 44 | 58.4 | 105 | 44 | 57.6 | 104 | 27
617 | 53.7 | 44 | 56.0 | 104 | 39 | 57.4 | 107 | 43 | 56.1 | 105 | 23
645 | 53.1 | 38 | 54.9 | 103 | 38 | 56.8 | 107 | 43 | 54.9 | 103 | 22
673 | 51.8 | 36 | 54.0 | 104 | 34 | 55.2 | 107 | 42 | 53.5 | 103 | 19
701 | 51.2 | 34 | 55.5 | 108 | 30 | 56.3 | 110 | 41 | 53.7 | 105 | 16
Mean for Weeks
1–13 | 30.7 | – | 30.8 | 100 | – | 30.1 | 98 | – | 29.6 | 96 | –
14–52 | 49.0 | – | 50.1 | 102 | – | 49.3 | 101 | – | 47.4 | 97 | –
53–101 | 54.3 | – | 56.2 | 103 | – | 57.2 | 105 | – | 55.7 | 103 | –

Table 12 Mean Body Weights and Survival of Female Mice in the Two-year Gavage Study of Tetrabromobisphenol A

Day | Vehicle Control | | 250 mg/kg | | | 500 mg/kg | | | 1,000 mg/kg
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | | Wt. (% of Controls) | No. of Survivors
1 | 17.7 | 50 | 17.8 | 101 | 50 | 17.7 | 100 | 50 | | 17.5 | 99 | 50
8 | 17.8 | 50 | 18.2 | 102 | 50 | 18.3 | 103 | 50 | | 18.3 | 103 | 50
15 | 18.9 | 50 | 19.1 | 101 | 50 | 19.1 | 101 | 50 | | 19.4 | 102 | 50
22 | 20.0 | 50 | 20.2 | 101 | 50 | 20.0 | 100 | 50 | | 20.1 | 101 | 50
29 | 20.7 | 50 | 20.8 | 100 | 50 | 20.8 | 101 | 50 | | 20.8 | 101 | 50
36 | 21.7 | 50 | 22.0 | 102 | 50 | 22.1 | 102 | 50 | | 22.2 | 102 | 50
43 | 22.7 | 50 | 23.3 | 103 | 50 | 23.4 | 103 | 50 | | 23.0 | 102 | 50
50 | 23.7 | 50 | 24.4 | 103 | 50 | 24.8 | 105 | 50 | | 24.2 | 102 | 50
57 | 25.2 | 50 | 25.4 | 101 | 50 | 25.9 | 103 | 50 | | 25.2 | 100 | 50
64 | 25.5 | 50 | 25.8 | 101 | 50 | 26.3 | 103 | 50 | | 25.1 | 98 | 50
71 | 26.0 | 50 | 26.2 | 101 | 50 | 26.6 | 102 | 50 | | 25.9 | 100 | 50
78 | 27.1 | 50 | 27.0 | 100 | 50 | 27.7 | 102 | 50 | | 26.7 | 98 | 50
85 | 27.1 | 50 | 27.1 | 100 | 50 | 27.9 | 103 | 50 | | 26.7 | 98 | 50
113 | 30.0 | 50 | 30.1 | 101 | 50 | 31.1 | 104 | 50 | | 29.8 | 100 | 50
141 | 32.5 | 50 | 32.9 | 101 | 50 | 33.6 | 104 | 50 | | 31.4 | 97 | 49
169 | 36.2 | 50 | 36.6 | 101 | 50 | 36.9 | 102 | 50 | | 33.7 | 93 | 48
197 | 39.1 | 50 | 39.4 | 101 | 50 | 39.4 | 101 | 50 | | 35.4 | 90 | 47
225 | 43.3 | 50 | 43.3 | 100 | 50 | 42.8 | 99 | 50 | | 37.4 | 86 | 44
253 | 45.0 | 50 | 45.5 | 101 | 50 | 45.1 | 100 | 50 | | 39.2 | 87 | 39
281 | 49.2 | 50 | 49.1 | 100 | 50 | 48.5 | 99 | 50 | | 41.6 | 85 | 37
309 | 53.0 | 50 | 52.2 | 99 | 50 | 51.5 | 97 | 50 | | 42.5 | 80 | 34
337 | 55.7 | 50 | 55.3 | 99 | 50 | 54.6 | 98 | 50 | | 44.7 | 80 | 32
365 | 57.4 | 50 | 57.2 | 100 | 50 | 56.4 | 98 | 50 | | 44.2 | 77 | 25
393 | 57.4 | 50 | 57.5 | 100 | 50 | 56.5 | 98 | 50 | | 44.1 | 77 | 21
421 | 57.1 | 50 | 59.3 | 104 | 50 | 57.2 | 100 | 50 | | 46.1 | 81 | 21
449 | 61.5 | 49 | 62.6 | 102 | 50 | 60.0 | 98 | 50 | | 45.6 | 74 | 18
477 | 63.3 | 49 | 64.0 | 101 | 50 | 61.4 | 97 | 50 | | 47.1 | 74 | 18
505 | 64.2 | 49 | 65.3 | 102 | 50 | 62.7 | 98 | 47 | | 49.2 | 77 | 16
533 | 64.0 | 49 | 63.5 | 99 | 49 | 60.4 | 95 | 46 | | 48.4 | 76 | 13
561 | 64.8 | 49 | 65.2 | 101 | 47 | 62.0 | 96 | 45 | | 48.8 | 75 | 10
589 | 66.5 | 48 | 66.2 | 100 | 47 | 62.8 | 95 | 45 | | 50.7 | 76 | 10
617 | 65.6 | 47 | 65.1 | 99 | 46 | 60.0 | 92 | 45 | | 49.3 | 75 | 10
645 | 64.7 | 46 | 65.3 | 101 | 43 | 60.6 | 94 | 41 | | 48.9 | 76 | 8
673 | 63.2 | 44 | 63.1 | 100 | 41 | 58.4 | 92 | 39 | | 52.5 | 83 | 6
701 | 63.4 | 43 | 63.7 | 101 | 38 | 58.6 | 92 | 37 | | 54.7 | 86 | 4
Mean for Weeks
1–13 | 22.6 | – | 22.9 | 101 | – | 23.1 | 102 | – | | 22.7 | 100 | –
14–52 | 42.7 | – | 42.7 | 100 | – | 42.6 | 100 | – | | 37.3 | 87 | –
53–101 | 62.6 | – | 62.9 | 100 | – | 59.8 | 96 | – | | 48.4 | 77 | –

Figure 7

Kaplan-Meier Survival Curves for Mice Administered Tetrabromobisphenol A by Gavage for Two Years

Figure 8

Growth Curves for Mice Administered Tetrabromobisphenol A by Gavage for Two Years

### Pathology and Statistical Analyses

This section describes the statistically significant or biologically noteworthy changes in the incidences of hemangioma and hemangiosarcoma and of neoplasms and/or non-neoplastic lesions of the liver, large intestine, kidney, forestomach, bone, and ovary. Due to early mortality, data for neoplasms are not presented for the 1,000 mg/kg groups in this section. Summaries of the incidences of neoplasms and non-neoplastic lesions, statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the neoplasms mentioned in this section are presented in Appendix C for male mice and Appendix D for female mice.

Liver: The incidence of multiple hepatocellular adenoma was significantly increased in 500 mg/kg males (Table I-3 and Table C-1). The incidences of hepatoblastoma and of hepatocellular carcinoma or hepatoblastoma (combined) were significantly increased in 250 mg/kg males; the incidences of hemangiosarcoma were slightly increased in 250 and 500 mg/kg males (Table 13, Table C-1, and Table C-2). The incidences of hepatoblastoma in the 250 and 500 mg/kg groups exceeded the historical control ranges for corn oil gavage studies and all routes of administration in male B6C3F1/N mice (Table 13 and Table C-3). The incidences of clear cell focus in 500 mg/kg males and eosinophilic focus in 250 and 500 mg/kg males were significantly increased; the incidence of mixed cell focus was increased in 500 mg/kg males, though not significantly (Table 13 and Table C-4).

Table 13 Incidences of Neoplasms and Non-neoplastic Lesions of the Liver in Male Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg
Number Examined Microscopically | 50 | 50 | 50
Clear Cell Focus^b^ | 11 | 10 | 25**
Eosinophilic Focus | 20 | 33** | 40**
Mixed Cell Focus | 7 | 8 | 12
Hemangiosarcoma | 0 | 4 | 3
Hepatocellular Adenoma, Multiple | 12 | 20 | 28*
Hepatocellular Adenoma (includes multiple)^c^ | 32 | 33 | 38
Hepatocellular Carcinoma, Multiple | 2 | 4 | 5
Hepatocellular Carcinoma (includes multiple)^d^ | 11 | 15 | 17
Hepatocellular Adenoma or Hepatocellular Carcinoma | 39 | 39 | 43
Hepatoblastoma^e^
Overall rate^f^ | 2/50 (4%) | 11/50 (22%) | 8/50 (16%)
Adjusted rate^g^ | 4.6% | 25.6% | 17.6%
Terminal rate^h^ | 1/33 (3%) | 7/25 (28%) | 7/39 (18%)
First incidence (days) | 619 | 535 | 722
Poly-3 test^i^ | P = 0.065 | P = 0.006 | P = 0.052
Hepatocellular Carcinoma or Hepatoblastoma^j^
Overall rate | 12/50 (24%) | 24/50 (48%) | 20/50 (40%)
Adjusted rate | 26.8% | 52.8% | 41.5%
Terminal rate | 7/33 (21%) | 12/25 (48%) | 12/39 (31%)
First incidence (days) | 521 | 535 | 513
Poly-3 test | P = 0.099 | P = 0.008 | P = 0.099
Hepatocellular Adenoma, Hepatocellular
Carcinoma, or Hepatoblastoma | 39 | 42 | 43

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Due to early mortality, data for the 1,000 mg/kg group are not presented.

^b^ Number of animals with lesion.

^c^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 145/250 (58.0% ± 5.1%), range 52%-64%; all routes: 594/949 (62.6% ± 9.1%), range 48%-78%.

^d^ Historical incidence for corn oil gavage studies: 87/250 (34.8% ± 10.9%), range 22%-44%; all routes: 348/949 (36.7% ± 11.4%), range 22%-56%.

^e^ Historical incidence for corn oil gavage studies: 9/250 (3.6% ± 2.6%), range 0%-6%; all routes: 40/949 (4.2% ± 3.5%), range 0%-12%.

^f^ Number of animals with neoplasm per number of animals with liver examined microscopically.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal kill.

^i^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^j^ Historical incidence for corn oil gavage studies: 93/250 (37.2% ± 10.0%), range 24%-48%; all routes: 371/949 (39.1% ± 11.6%), range 22%-54%.

Hepatocellular adenomas were generally solitary, well-circumscribed lesions occupying an area greater than one liver lobule and causing distinct compression of adjacent parenchyma. They were either solid masses or composed of irregular hepatic plates, one to three cell layers thick. The hepatic plates at the margins impinged at sharp angles to the surrounding normal hepatic plates. An absence of normal lobular architecture was common. Central veins and portal tracts were rare and sometimes trapped within the expanding mass near the periphery. The sinusoids were either compressed or dilated and angiectasis was occasionally present; they were composed of well-differentiated hepatocytes that were variable in size. The tinctorial characteristics of the cytoplasm were variable, and could be eosinophilic, basophilic, clear, vacuolated, or a combination thereof. Cellular atypia was rare and mitoses were variable.

Hepatocellular carcinomas were generally spherical masses with irregular borders, showing local invasion and compression. They were characterized by an abnormal growth pattern, such as trabecular, glandular, and/or solid. The trabecular pattern was composed of cords that were three or more cell layers thick. Cytologic atypia and mitotic figures were common. Nuclei were variable in size, usually enlarged and hyperchromatic. Nucleoli were large, distinct, and generally centrally located.

Hepatoblastomas were irregular-shaped proliferative masses that were often found adjacent to, or arising from, hepatocellular adenomas or carcinomas. If the hepatoblastoma was in close proximity, and appeared to be arising within an adenoma or carcinoma, then only the hepatoblastoma was diagnosed. Hepatoblastomas were composed of small to medium sized neoplastic cells with scant basophilic cytoplasm arranged in sheets and palisading cords separated by thin connective tissue stroma. Neoplastic cells had a stippled chromatin pattern and contained distinct nucleoli. Mitotic figures were often numerous.

Large Intestine: The incidences of adenoma or carcinoma (combined) of the cecum or colon occurred with a significant positive trend in males and the incidence in the 500 mg/kg group exceeded the historical control ranges for corn oil gavage studies and for all routes of administration (Table 14, Table C-1, Table C-2, and Table C-4). One 500 mg/kg female had an adenoma of the rectum (Table 14 and Table D-1). The adenomas consisted of a collection of irregular-sized glands lined by a hyperchromatic atypical columnar epithelium with closely packed nuclei. The glandular lumens were variably filled with inflammatory cells, mucus, and cell debris. The carcinomas were composed of anaplastic, invasive cells that formed pleomorphic glandular structures with inflammation. The cells were hyperchromatic and columnar to cuboidal, with closely packed nuclei and numerous mitotic figures.

Table 14 Incidences of Neoplasms of the Large Intestine in Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg
Male
Cecum or Colon: Adenoma or Carcinoma^b^
Overall rate^c^ | 0/50 (0%) | 0/50 (0%) | 3/50 (6%)
Adjusted rate^d^ | 0.0% | 0.0% | 6.5%
Terminal rate^e^ | 0/33 (0%) | 0/25 (0%) | 3/39 (5%)
First incidence (days) | –^g^ | – | 513
Poly-3 test^f^ | P = 0.039 | –^h^ | P = 0.131
Female
Rectum^i^ | 50 | 50 | 50
Adenoma^j^ | 0 | 0 | 1

^a^ Due to early mortality, data for the 1,000 mg/kg groups are not presented.

^b^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 0/250; all routes: 4/950 (0.4% ± 0.8%), range 0%-2%.

^c^ Number of animals with neoplasm per number of animals necropsied.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Observed incidence at terminal kill.

^f^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^g^ Not applicable; no neoplasms in animal group.

^h^ Value of statistic cannot be computed.

^i^ Number necropsied.

^j^ Number of animals with neoplasm.

Hemangioma and Hemangiosarcoma: In males, the incidences of hemangiosarcoma (all organs) occurred with a significant positive trend and the incidence in the 500 mg/kg group was significantly increased; the incidences of hemangioma or hemangiosarcoma (combined) occurred with a significant positive trend (Table 15, Table C-1 and Table C-2). The incidences of these neoplasms in both dosed groups were within the historical control ranges for corn oil gavage studies and all routes of administration (Table 15 and Table C-5). These lesions occurred in a variety of organs such as the bone marrow, liver, lung serosa, lymph nodes, skin, spleen, and vertebra.

Table 15 Incidences of Hemangioma or Hemangiosarcoma (All Organs) in Male Mice in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Vehicle Control | 250 mg/kg | 500 mg/kg
Number Necropsied | 50 | 50 | 50
All Organs: Hemangioma^b^ | 2 | 0 | 1
All Organs: Hemangiosarcoma^c^
Overall rate^d^ | 1/50 (2%) | 5/50 (10%) | 8/50 (16%)
Adjusted rate^e^ | 2.3% | 11.9% | 17.6%
Terminal rate^f^ | 0/33 (0%) | 3/25 (12%) | 8/39 (21%)
First incidence (days) | 645 | 602 | 730 (T)
Poly-3 test^g^ | P = 0.014 | P = 0.093 | P = 0.019
All Organs: Hemangioma or Hemangiosarcoma^h^
Overall rate | 3/50 (6%) | 5/50 (10%) | 9/50 (18%)
Adjusted rate | 6.9% | 11.9% | 19.8%
Terminal rate | 2/33 (6%) | 3/25 (12%) | 9/39 (23%)
First incidence (days) | 645 | 602 | 730 (T)
Poly-3 test | P = 0.047 | P = 0.338 | P = 0.069

(T) Terminal kill.

^a^ Due to early mortality, data for the 1,000 mg/kg group are not presented.

^b^ Number of animals with neoplasm.

^c^ Historical incidence for 2-year gavage studies with corn oil vehicle control groups (mean ± standard deviation): 28/250 (11.2% ± 6.4%), range 2%-18%; all routes: 92/950 (9.7% ± 4.5%), range 2%-18%.

^d^ Number of animals with neoplasm per number of animals necropsied.

^e^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^f^ Observed incidence at terminal kill.

^g^ Beneath the vehicle control incidence is the P value associated with the trend test. Beneath the dosed group incidence are the P values corresponding to pairwise comparisons between the vehicle controls and that dosed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal kill.

^h^ Historical incidence for corn oil gavage studies: 32/250 (12.8% ± 5.4%), range 6%-18%; all routes: 105/950 (11.1% ± 4.2%), range 4%-18%.

Kidney: Incidences of renal tubule cytoplasmic alteration were significantly increased in all dosed groups of males and the severities increased with increasing dose; incidences of nephropathy in the 250 and 500 mg/kg groups were significantly decreased (Table 16 and Table C-4). Renal tubule cytoplasmic alteration was characterized by a decrease or absence of the normal vacuoles present in the cortical proximal tubules (Figure 19 and Figure 20).

Table 16 Incidences of Selected Non-neoplastic Lesions in Mice in the Two-year Gavage Study of Tetrabromobisphenol A

| Vehicle Control | 250 mg/kg | 500 mg/kg | 1,000 mg/kg
Male
Kidney^a^ | 50 | 50 | 50 | 48
Renal Tubule, Cytoplasmic Alteration^b^ | 0 | 20** (1.9)^c^ | 47** (2.4) | 46** (2.6)
Nephropathy | 41 (1.3) | 30** (1.9) | 32** (1.3) | 42 (1.9)
Stomach, Forestomach | 50 | 49 | 50 | 49
Ulcer | 9 (1.8) | 9 (2.4) | 19* (2.2) | 28** (2.4)
Infiltration Cellular, Mononuclear Cell | 5 (1.6) | 8 (1.8) | 21** (2.1) | 27** (2.3)
Inflammation | 9 (1.3) | 10 (1.7) | 20* (2.2) | 26** (2.3)
Epithelium, Hyperplasia | 10 (1.7) | 13 (2.2) | 27** (2.8) | 28** (2.7)
Female
Stomach, Forestomach | 50 | 50 | 50 | 48
Ulcer | 2 (2.0) | 15** (2.0) | 40** (2.2) | 38** (2.1)
Infiltration Cellular, Mononuclear Cell | 2 (3.0) | 13** (2.2) | 33** (2.4) | 28** (1.8)
Inflammation | 2 (3.0) | 14** (1.4) | 41** (2.0) | 37** (2.2)
Epithelium, Hyperplasia | 4 (2.5) | 16** (2.6) | 39** (3.0) | 39** (2.3)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Poly-3 test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 19

Normal Renal Cortex in a Vehicle Control Male B6C3F1/N Mouse in the Two-year Gavage Study of Tetrabromobisphenol A (H&E)

Note the clear autophagic vacuoles in the proximal epithelial cells (arrow).

Figure 20

Cytoplasmic Alteration in the Kidney of a Male B6C3F1/N Mouse Administered 1,000 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

There is an absence of clear vacuoles in the proximal tubule epithelial cells, diagnosed as “cytoplasmic alteration.”

Forestomach: The incidences of ulcer, mononuclear cell cellular infiltration, inflammation, and epithelium hyperplasia were significantly increased in 500 and 1,000 mg/kg males and all dosed groups of females (Table 16, Table C-4, and Table D-3). Regions of stomach ulceration were localized to the forestomach and characterized by focal or multifocal loss of the entire thickness of the squamous epithelium (Figure 21 to Figure 24). Ulceration was considered the primary lesion and there were a few secondary lesions (epithelium hyperplasia, inflammation, mononuclear cell infiltrate) that formed in response to the ulcer. Squamous epithelium adjacent to the ulcer was often hyperplastic. Areas of ulceration were often accompanied by varying degrees of inflammation that ranged from primarily neutrophilic to a mixed population of neutrophils, macrophages, lymphocytes, and plasma cells. Inflammatory infiltrates were admixed with eosinophilic necrotic and keratin debris and variable numbers of bacteria. A robust immune response was present within the mucosa, submucosa, and tunica muscularis underlying areas of ulceration, and was diagnosed as mononuclear cell infiltration. The lesion was characterized by multifocal to coalescing lymphocytes and low numbers of plasma cells that, in severe cases, formed follicle-like structures.

Figure 21

Normal Stomach in a Vehicle Control Male B6C3F1/N Mouse in the Two-year Gavage Study of Tetrabromobisphenol A (H&E)

Glandular stomach is on the left and forestomach is on the right (arrow).

Figure 24

Ulcer in the Forestomach of a Male B6C3F1/N Mouse Administered 1,000 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

There is a focal area of prior ulceration with healing. Underlying the area of injury is a mononuclear cell infiltrate (arrow) indicative of a robust immune response.

Bone: The incidences of fibro-osseous lesion were significantly decreased in all dosed groups of females (Table D-3).

Ovary: The incidences of follicle cyst were slightly decreased in all dosed groups of females (7/50, 6/50, 4/50, 1/47; Table D-3).

## Genetic Toxicology

Tetrabromobisphenol A was tested for bacterial mutagenicity in two independent assays and results were negative in both assays. In the first assay, tetrabromobisphenol A (100 to 10,000 µg/plate) showed no evidence of mutagenicity in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537, with or without exogenous metabolic activation from induced hamster or rat liver S9^77^ (Table E-1). In the second assay, conducted with the same lot of tetrabromobisphenol A that was used in the 2-year studies, no mutagenic activity was detected in S. typhimurium strains TA98 or TA100, or in Escherichia coli strain WP2 uvrA/pKM101; all tests were conducted with and without rat liver S9, and the highest concentration tested was 6,000 µg/plate (Table E-2). In vivo, no increases in micronucleated normochromatic erythrocytes were observed in male or female B6C3F1/N mice following 3 months of administration of tetrabromobisphenol A by gavage over a dose range of 10 to 1,000 mg/kg (Table E-3). In addition, no significant changes in the percentage of circulating polychromatic (immature) erythrocytes were observed in dosed mice, suggesting that tetrabromobisphenol A did not induce bone marrow toxicity over the dose range tested.

Figure 15

Higher Magnification of the Endometrial Glands in Figure 14 (H&E)

The glands are separated by scant stroma and lined by multiple layers of disorganized epithelium. The thickened epithelium projects into the glandular lumens forming multiple thickened infoldings and projections. Epithelial cells lining the glands show loss of nuclear polarization, karyomegaly, and cellular pleiomorphism.

Figure 16

Uterus from a Female Wistar Han Rat Administered 1,000 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

This is an example of atypical hyperplasia of both the glandular epithelium and the uterine luminal epithelium.

Figure 17

Uterus from a Female Wistar Han Rat Administered 500 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

This is an example of a papillary type of endometrial gland atypical hyperplasia (arrow).

Figure 18

Higher Magnification of the Lesion in Figure 17 (H&E)

The papillary type of atypical hyperplasia consists of numerous small branching projections of epithelium extending into the uterine gland, occasionally on small fibrovascular stalks. Epithelial blebbing and loss of nuclear polarization are also present.

Figure 22

Higher magnification of the normal forestomach in Figure 21 (H&E)

The thin keratinized stratified squamous epithelial layer is two to three cell layers thick.

Figure 23

Ulcer in the Forestomach of a Male B6C3F1/N Mouse Administered 1,000 mg/kg Tetrabromobisphenol A by Gavage for Two Years (H&E)

A focal area of ulceration is characterized by loss of the entire thickness of squamous epithelium. There is secondary inflammation within the lesion and hyperplasia of the adjacent epithelium.