# Materials and Methods

## Procurement and Characterization

### Tetrabromobisphenol A

Tetrabromobisphenol A was obtained from Albemarle Corporation (Baton Rouge, LA) in three lots (25317K-1, C16263X, and 25337XX-8). Lot 25317K-1 was used during the 3-month studies; lots 25317K-1 and C16263X were combined into one lot and renamed lot M032607KA, which was used in the 2-year studies; lot 25337XX-8 was used for dose formulation studies performed at the analytical chemistry laboratory at Midwest Research Institute (Kansas City, MO) and was not used in any of the animal studies. Identity and purity analyses were conducted by the analytical chemistry laboratory, and identity was confirmed by the study laboratory at Battelle Columbus Operations (Battelle) (Columbus, OH) (Appendix J). Reports on analyses performed in support of the tetrabromo-bisphenol A studies are on file at the National Institute of Environmental Health Sciences.

Lots 25317K-1 and M032607KA of the test chemical, a white, crystalline powder, were identified as tetra-bromobisphenol A by infrared and proton nuclear magnetic resonance spectroscopy and melting point. Purity of each lot was determined by high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection. The purity profile for lot 25317K-1 had one major peak and one impurity at two detection wavelengths with areas of 0.7% and 0.8% relative to the total peak area. The overall purity of lot 25317K-1 was determined to be greater than 99%. For lot M032607KA, the analysis indicated one major peak and one impurity at two detection wavelengths with areas of 0.8% and 1.1% relative to the total peak area. The impurity was determined to be tribromobisphenol A by liquid chromatography/mass spectrometry, based on the isotopic pattern in the mass spectrum indicating the presence of three bromine atoms and the m/z of 460.9 ([M-H]^−^), consistent with a mass of 461.8. The overall purity of lot M032607KA was determined to be approximately 99%.

To ensure stability, the bulk chemical was stored in sealed glass bottles protected from light at room temperature. Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 3-month and 2-year studies using HPLC/UV. No degradation of the test chemical was detected.

### Corn Oil

National Formulary-grade corn oil was obtained in multiple lots from Spectrum Chemicals and Laboratory Products (Gardena, CA) and from Sigma-Aldrich (St. Louis, MO) and was used as the vehicle in the 3-month and 2-year studies. Periodic analyses of the corn oil vehicle performed by the study laboratory using potentiometric titration demonstrated peroxide concentrations less than the rejection level of 3 mEq/kg.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared monthly for the 3-month studies and every 6 weeks for the 2-year studies by mixing tetrabromobisphenol A with corn oil. Homogeneity studies of 0.5 and 600 mg/mL formulations and stability studies of a 0.5 mg/mL formulation were performed by the analytical chemistry laboratory using HPLC/UV. Homogeneity was confirmed; stability was confirmed for at least 42 days for dose formulations stored in sealed glass vials, protected from light, at temperatures up to 25°C, and for at least 3 hours under simulated animal room conditions. The dose formulations were stored in sealed glass bottles protected from light for up to 42 days at room temperature. The study laboratory conducted homogeneity studies of 1, 2, 10, 25, 50, 100, 200, and 400 mg/mL formulations using HPLC/UV; gavageability studies of 100, 200, and 400 mg/mL formulations were also performed. Homogeneity was confirmed, and gavageability was confirmed for the 100 and 200 mg/mL formulations.

Periodic analyses of the dose formulations of tetra-bromobisphenol A were conducted by the study laboratory using HPLC/UV. During the 3-month studies, the dose formulations were analyzed monthly; all 15 of the dose formulations for rats and all 15 for mice were within 10% of the target concentrations (Table J-2). Animal room samples of these dose formulations were also analyzed; all 15 for rats and all 15 for mice were within 10% of the target concentrations. During the 2-year studies, the dose formulations were analyzed approximately every 3 months (Table J-3); of the dose formulations analyzed and used during the studies, all 72 for rats and all 45 for mice were within 10% of the target concentrations. Animal room samples were also analyzed; seven of nine animal room samples for rats and eight of nine for mice were within 10% of the target concentrations.

## Animal Source

Male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc. (Germantown, NY). B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc., for the 3-month studies. Male and female Wistar Han [Crl:WI(Han)] rats were obtained from Charles River Laboratories (Raleigh, NC), and male and female B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc., for use in the 2-year studies. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N strain exhibited sporadic seizures and idiopathic chylothorax and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP time to evaluate different rat models between 2005 and 2006.^78^ The Wistar Han rat, an outbred rat stock, was then selected because it was projected to have a long lifespan, resistance to disease, large litter size, and low neonatal mortality.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

The 3-month studies were conducted to evaluate the cumulative toxic effects of repeated exposure to tetrabromobisphenol A and to determine the appropriate doses to be used in the 2-year studies. Tetrabromobisphenol A was given orally to mimic an oral exposure. The doses selected for the tetrabromobisphenol A 3-month studies were based on findings reported by the World Health Organization (WHO)^3^ and NTP chemistry findings. In the WHO report, in a Charles River CD rat subchronic study, tetrabromobisphenol A was administered by oral gavage in corn oil to deliver doses of 0, 100, 300, or 1,000 mg/kg body weight per day. There were no treatment-related deaths, clinical findings, neurobehavioral effects, or histopathologic changes. In another study in the WHO report, tetrabromobisphenol A was given in the diet to B6C3F1 mice at 0, 500, 4,900, 15,600, or 50,000 ppm (corresponding to 0, 71, 700, 2,200, or 7,100 mg/kg body weight for 3 months). All animals fed 50,000 ppm died during the study, probably because of malnutrition and anemia. NTP found that the maximum amount of tetrabromobisphenol A that could be constituted for oral gavage was 1,000 mg/kg, and thus, this was the high dose selected for the 3-month rat and mouse studies.

On receipt, the rats were 3 to 4 weeks old, and mice were 4 to 5 weeks old. Rats were quarantined for 11 (males) or 12 (females) days and mice for 13 (females) or 14 (males) days; rats were 5 to 6 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix L).

Groups of 10 male and 10 female rats and mice were administered tetrabromobisphenol A in corn oil by gavage at doses of 0, 10, 50, 100, 500, or 1,000 mg/kg body weight, 5 days per week for 14 weeks. Additional special study groups of 10 male and 10 female rats were administered the same doses for 23 days. Vehicle control animals received the corn oil vehicle alone. Dosing volumes were 5 mL/kg for rats and 10 mL/kg for mice. Feed and water were available ad libitum. Rats and female mice were housed five per cage, and male mice were housed individually. Clinical findings were recorded and animals were weighed initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Gavage Studies of Tetrabromobisphenol A

Three-month Studies | Two-year Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH) | Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/NTac rats B6C3F1/N mice | Wistar Han rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Rats: Charles River Laboratories (Raleigh, NC) Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 11 (males) or 12 (females) days Mice: 13 (females) or 14 (males) days | Rats: 8 (males) or 9 (females) days Mice: 11 (females) or 12 (males) days
Average Age When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks | Rats: 6 to 7 weeks Mice: 5 to 6 weeks
Date of First Dose
Rats: December 12 (males) or 13 (females), 2005 Mice: December 14 (females) or 15 (males), 2005 | Rats: July 25 (males) or 26 (females), 2007 Mice: August 6 (females) or 7 (males), 2007
Duration of Dosing
Core studies: 14 weeks Special study rats: 23 days | 3 months (interim evaluation rats), 104 weeks (male rats), or 105 weeks
Date of Last Dose
Rats: March 13 (males) or 14 (females), 2006 Mice: March 15 (females) or 16 (males), 2006 | Rats: July 21 (males) or 23 (females), 2009 Mice: August 4 (females) or 6 (males), 2009
Necropsy Dates
Rats: March 14 (males) or 15 (females), 2006 Mice: March 16 (females) or 17 (males), 2006 | Rats: October 24 (males) or 25 (females), 2007 (interim evaluation), or July 20-22 (males) or 22-24 (females), 2009 (2-year study) Mice: August 3-5 (females) or 5-7 (males), 2009
Average Age at Necropsy
Rats: 18 to 19 weeks Mice: 19 to 20 weeks | 109 or 111 weeks
Size of Study Groups
10 males and 10 females | Rats: 0 and 1,000 mg/kg, 60 males and 60 females; 250 and 500 mg/kg, 50 males and 50 females Mice: 50 males and 50 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 3-month studies
Animals per Cage
Rats: 5 Mice: 1 (males) or 5 (females) | Rats: 3 (males) or 5 (females) Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
Irradiated NTP-2000 wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed at least weekly | Same as 3-month studies
Water
Tap water (Columbus municipal supply) via automatic rack watering system (Edstrom Industries, Waterford, WI), available ad libitum | Same as 3-month studies
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (male mice) or twice weekly (rats and female mice) and rotated every 2 weeks | Same as 3-month studies
Bedding
Irradiated Sani-Chips (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly (male mice) or twice weekly (rats and female mice) | Same as 3-month studies
Rack Filters
Spun-bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks | Same as 3-month studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as 3-month studies
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Doses
0, 10, 50, 100, 500, or 1,000 mg/kg in corn oil; dosing volumes 5 mL/kg (rats) or 10 mL/kg (mice) | 0, 250, 500, or 1,000 mg/kg in corn oil; dosing volumes 5 mL/kg (rats) or 10 mL/kg (mice)
Type and Frequency of Observation
Observed twice daily; clinical findings were recorded and core study animals were weighed initially, weekly, and at the end of the studies. | Observed twice daily; clinical findings were recorded every 4 weeks beginning at week 5 and at the end of the studies; animals were weighed initially, weekly for 13 weeks, monthly thereafter, and at the end of the studies.
Method of Kill
Rats: Exsanguination while under CO2/O2 anesthesia (core study) or carbon dioxide asphyxiation (special study group) Mice: Carbon dioxide asphyxiation | Carbon dioxide asphyxiation
Necropsy
Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, and thymus. | Necropsies were performed on all animals. Organs weighed at the 3-month interim evaluation in rats were the heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
Blood was collected from the retroorbital plexus of special study rats on days 4 and 23 and of core study rats and mice at the end of the studies; blood was also collected from the heart of core study rats at the end of the study. Hematology parameters were measured on day 23 (rats) and at the end of the studies (rats and mice). Clinical chemistry and thyroid hormones were measured in rats on days 4 and 23 and at the end of the study. Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; erythrocyte and platelet morphology; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials. Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, cholesterol, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids. Thyroid hormones: total triiodothyronine, thyroid stimulating hormone, and total thyroxine. | None
Liver Toxicity
Liver samples were collected from special study rats on day 23 and from core study rats and mice at study termination for determination of acetanilide-4-hydroxylase, 7-ethoxyresorufin-O-deethylase, 7-pentoxyresorufin-O-dealkylase, and uridine diphosphate-glucuronosyl transferase activities. | None
Histopathology
Complete histopathology was performed on vehicle control and 1,000 mg/kg core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice only), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, and uterus. The liver of rats and mice and the kidney of mice were also examined in the remaining core study groups. | Complete histopathology was performed on all rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, cervix, clitoral gland, esophagus, eyes, gallbladder (mice only), Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicle, thymus, thyroid gland, trachea, urinary bladder, uterus, and vagina.
Sperm Motility and Vaginal Cytology
At the end of the studies, spermatid and sperm samples were collected from male rats and mice in the vehicle control, 100, 500, and 1,000 mg/kg groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from female rats and mice in the vehicle control, 100, 500, and 1,000 mg/kg groups. | None

Hematology, clinical chemistry, and thyroid hormone analyses were performed on special study rats on days 4 (except hematology) and 23 and on core study rats at study termination. Hematology analyses were performed on mice at study termination. Blood was collected from the retroorbital plexus of rats and mice for hematology analyses and from the retroorbital plexus of special study rats and from the heart of core study rats for clinical chemistry and thyroid hormone analyses. Samples were collected into tubes containing EDTA for hematology or serum separator tubes for clinical chemistry and thyroid hormone determinations. Hematology parameters were determined using an Advia 120 analyzer (Bayer Diagnostic Division, Tarrytown, NY). Clinical chemistry parameters and total thyroxine were determined using a Hitachi 911 analyzer (Roche Diagnostics Corporation, Indianapolis, IN). Total triiodothyronine and thyroid stimulating hormone were determined by radioimmunoassay using a commercial kit. The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice administered 0, 100, 500, or 1,000 mg/kg. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Liver samples were collected from special study rats on day 23 and from core study rats and mice at the end of the studies for cytochrome P450 and uridine diphosphate-glucuronosyl transferase (UDP-GT) activity determinations. Microsomal suspensions were prepared as described by Battelle.^79,80^ The concentration of protein in each suspension was determined using a BCA Protein Assay Kit (Pierce Chemical Co., Rockford, IL). 7-Ethoxyresorufin-O-deethylase (CYP1A1) and 7-pentoxyresorufin-O-dealkylase (CYP2B) activities were determined spectrofluorimetrically,^81^ acetanilide-4-hydroxylase (CYP1A2) activity was determined by HPLC with ultraviolet detection,^82-84^ and UDP-GT activity toward T_4_ was determined by quantifying the amount of ^125^I-T_4_-glucuronide produced.^85^

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, spleen, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on all vehicle control and 1,000 mg/kg rats and mice. The liver was examined in all groups of rats and mice, and the kidney was examined in all groups of mice. In the original review of the uterus, a transverse section through each uterine horn, approximately 0.5 cm cranial to the cervix, was collected for histopathology review. For the residual tissue review, all remaining cervical, vaginal, and uterine tissue remnants were stored in 10% neutral buffered formalin, processed, and sectioned longitudinally. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^86^ and Boorman et al.^87^

## Two-year Studies

### Study Design

Groups of 60 male and 60 female Wistar Han rats were administered 0 or 1,000 mg tetrabromobisphenol A/kg body weight, 50 male and 50 female rats were administered 250 or 500 mg/kg, and 50 male and 50 female mice were administered 0, 250, 500, or 1,000 mg/kg in corn oil by gavage, 5 days per week for up to 104 (male rats) or 105 weeks. Ten vehicle control and ten 1,000 mg/kg rats of each sex were evaluated at 3 months to allow comparison to 3-month endpoints in the F344/NTac rats. Vehicle control animals received corn oil only. Dosing volumes were 5 mL/kg for rats and 10 mL/kg for mice.

Rats were quarantined for 8 or 9 days and mice were quarantined for 11 or 12 days before the beginning of the studies. Five male and five female rats and mice were randomly selected for parasite evaluation and gross observation of disease. Rats were 6 to 7 weeks old and mice were 5 to 6 weeks old at the beginning of the studies. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix L).

Rats were housed three (males) or five (females) per cage and mice were housed one (males) or five (females) per cage. Feed and water were available ad libitum. Cages and racks were rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix K.

### Clinical Examinations and Pathology

All animals were observed twice daily. Clinical findings were recorded every 4 weeks beginning week 5 and at the end of the studies. Body weights were recorded on day 1, weekly for 13 weeks, monthly thereafter, and at the end of the studies.

Complete necropsies and microscopic examinations were performed on all rats and mice. At the 3-month interim evaluation in rats, the heart, right kidney, liver, lung, right testis, and thymus were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes were initially placed in Davidson’s solution and testes were initially placed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Original transverse and residual longitudinal reviews of uterine tissue from female Wistar Han rats, including the 3-month interim evaluation animals, were conducted as described for the 3-month study in F344/NTac rats. In addition, cytokeratin and vimentin immunohistochemical stains were used to better characterize specific lesions that occurred in the uterus. Tissues examined microscopically are listed in Table 1. For the 2-year studies, samples of grossly observed tumors (uterine adenocarcinomas) were collected at the time of necropsy, flash frozen in liquid nitrogen, and stored at −80°C for molecular analysis (Appendix M).

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent quality assessment laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a quality assessment pathologist evaluated slides from all tumors and all potential target organs, which included the liver and uterus of rats and mice; the nose of rats; and the forestomach, large intestine, and kidney of mice.

The quality assessment report and the reviewed slides were submitted to the NTP PWG coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and quality assessment pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and quality assessment pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the quality assessment pathologist and other pathologists experienced in rodent toxicologic pathology. This group examined the tissues without any knowledge of dose groups. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^86^ and Boorman et al.^87^ For subsequent analyses of the pathology data, the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^88^

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^89^ and is presented in the form of graphs. Animals found dead of other than natural causes were censored; animals dying from natural causes were not censored. Statistical analyses for possible dose-related effects on survival used Cox’s^90^ method for testing two groups for equality and Tarone’s^91^ life table test to identify dose-related trends. All reported P values for the survival analyses are two sided.

### Calculation of Incidence

The incidences of neoplasms or non-neoplastic lesions are presented in Table A-1, Table A-4, Table B-1, Table B-4, Table C-1, Table C-4, Table D-1, and Table D-3 as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of statistical significance, the incidences of most neoplasms (Table A-2, Table B-2, Table C-2, and Table D-2) and all non-neoplastic lesions are given as the numbers of animals affected at each site examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. Table A-2, Table B-2, Table C-2, and Table D-2 also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal kill.

### Analysis of Neoplasm and Non-neoplastic Lesion Incidences

The Poly-k test^92-94^ was used to assess neoplasm and non-neoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal kill; if the animal died prior to terminal kill and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only upon the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^92^ Unless otherwise specified, a value of k=3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^92^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344/N rats and B6C3F1/N mice.^95^ Bailer and Portier^92^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^96^

Tests of significance included pairwise comparisons of each dosed group with controls and a test for an overall dose-related trend. Continuity-corrected Poly-3 tests were used in the analysis of lesion incidence, and reported P values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–P with the letter N added (e.g., P=0.99 is presented as P=0.01N). For neoplasms and non-neoplastic lesions detected at the 3-month interim evaluation, the Fisher exact test,^97^ a procedure based on the overall proportion of affected animals, was used.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^98^ and Williams.^99,100^ Hematology, clinical chemistry, thyroid hormone, cytochrome P450, UDP-GT, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^101^ (as modified by Williams^102^) and Dunn.^103^ Jonckheere’s test^104^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^105^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test.^97^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^106^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period.^107-109^ In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidences of neoplasms in controls for all routes of administration are included for comparison, including the current mouse study. The current 2-year rat study is the only one in Wistar Han rats using corn oil as a gavage vehicle in the historical control database; therefore, only historical control incidences for all routes and all vehicles are used for Wistar Han rats in this Technical Report. The historical control database does not contain data for residual tissue evaluations or step sections of tissues.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^110^ In addition, as records from the 3-month and 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of tetrabromobisphenol A was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli and increases in the frequency of micronucleated erythrocytes in mouse peripheral blood. Micronuclei (literally “small nuclei” or Howell-Jolly bodies) are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^111,112^ The protocols for these studies and the results are given in Appendix E.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage based on the relationship between electrophilicity and mutagenicity^113^ and the somatic mutation theory of cancer.^114,115^ However, it should be noted that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^116^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^117,118^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone. However, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation.

The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that in the Salmonella test.^119,120^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^121^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical.