# Introduction

Figure 1

Tetrabromobisphenol A (CASRN 79-94-7; Chemical Formula: C_15_H_12_Br_4_O_2_; Molecular Weight: 543.88)

Synonyms: 2,2-Bis(3,5-dibromo-4-hydroxyphenyl)propane; 2,2-bis(4-hydroxy-3,5-dibromophenyl)propane; 4,4′-isopropylidenebis(2,6-dibromophenol); 4,4′-(1-methylethylidene)bis(2,6-dibromophenol); 2,2′,6,6′-tetrabromobisphenol A; 3,3′,5,5′-tetrabromobisphenol A; 2,2′,6,6′-tetrabromo-4,4′-isopropylidenediphenol; tetrabromodian; tetrabromodiphenylpropane.

Trade names: Bromdian, Fire Guard 2000, Firemaster BP 4A, Saytex RB 100PC.

## Chemical and Physical Properties

Tetrabromobisphenol A is an off-white powder with a melting point in the range of 179° to 181°C and a density of 2.2 kg/L at 4°C; it is insoluble in water but is soluble in oxygenated solvents.^1^ (Tetrabromobisphenol A contains 58.4% bromine, and under basic conditions, both hydroxyl groups of tetrabromobisphenol A react with epichlorohydrin to give the diglycidyl ether, which is widely used in epoxy resin formulations.^2^

## Production, Use, and Human Exposure

Tetrabromobisphenol A is produced by the bromination of bisphenol A in the presence of solvents such as a halocarbon, water, 50% hydrobromic acid, aqueous alkyl monoethers, or aqueous acetic acid. When methanol is used, methyl bromide is formed as a coproduct.^3^ The United States annual tetrabromobisphenol A production is between 100 and 500 million pounds.^4^ Other reports list global tetra-bromobisphenol A annual production at 145,000 tonnes (320,000,000 lbs).^5,6^ It is estimated that tetrabromobisphenol A accounts for 59% of all brominated flame retardants used worldwide.^7^

Tetrabromobisphenol A is a flame retardant used in epoxy resin circuit boards, in electronic enclosures (of polycarbonate-acrylonitrile-butadiene-styrene plastics), in paper, and in textiles. Tetrabromobisphenol A is used as a chemical intermediate for the synthesis of other flame retardants [e.g., tetrabromobisphenol A allyl ether, tetrabromobisphenol A bis(2-hydroxyethyl ether), tetrabromobisphenol A carbonate oligomers, and tetrabromobisphenol A diglycidyl ether].^2,3,8^

Products containing tetrabromobisphenol A have been shown to release tetrabromobisphenol A into the environment.^9^ Tetrabromobisphenol A has been found in sewage sludge, soil, sediments, birds, fish, and air, and it has been detected in cow and human milk, human serum, human adipose tissue, umbilical cord serum, and in household dust.^10^ A study in Boston found that 35% of human milk samples contained tetrabromobisphenol A.^11^ Tetrabromobisphenol A is present in arctic wildlife indicating the ability for long-range transport from point sources.^12^ Its half-life was approximately 50 days in a 64-day aerobic and anaerobic soil study and 48 to 84 days in a sediment/water degradation study.^13^ Tetrabromobisphenol A and derivatives have been found at increased levels in soil and sediment downstream from a brominated flame retardant factory.^14^

Bacteria can debrominate tetrabromobisphenol A to tri-, di-, and monobromobisphenol A.^15^ Photodegradation of tetrabromobisphenol A in water by UV radiation has the following half-lives: 10.2 days in spring, 6.6 days in summer, 25.9 days in autumn, and 80.7 days in winter; cloud cover increases the half-life.^3^ The main breakdown product of tetrabromobisphenol A by photodegradation is 2,4,6-tribromophenol. Other decomposition products identified include di- and tribromobisphenol A; dibromophenol; 2,6-dibromo-4-(bromoisopropylene) phenol; 2,6-dibromo-4-(dibromoisopropylene) phenol; and 2,6-dibromo-1,4-hydroxybenzene.^16^

Exposure to tetrabromobisphenol A may be from inhalation of ambient air, dermal contact, or ingestion.^3^ A recent survey of various fish species in China indicates that tetrabromobisphenol A may be present in fish at concentrations up to 39 ng/g.^17^ The United States Environmental Protection Agency^4^ reports that up to 1,000 people may be exposed during manufacturing and processing of tetrabromobisphenol A in the workplace.

Exposure to tetrabromobisphenol A may also occur through the disposal, recycling, incineration, and landfilling of electronic waste (e-waste).^18^ Tetrabromobisphenol A is typically detected at parts per million (ppm) concentrations in sediments and sewage sludge near brominated flame retardant production facilities.^19,20^ The environmental persistence of tetrabromobisphenol A is due to its high lipophilicity (log K_ow_ = 5.9), low volatility (7.0 × 10^−11^ atm m^3^/mol), and low water solubility (4.16 mg/L at 25°C)^19,20^

In a recent review in Europe, tetrabromobisphenol A was found in food samples, mothers’ milk, outdoor air samples, indoor dust, soil samples, and wildlife.^21^ The estimated daily intake of tetrabromobisphenol A is up to 2.6 ng/kg body weight per day in adults and up to 257 ng/kg per day in infants.^21^

## Regulatory Status

The threshold for reporting releases of tetrabromobisphenol A is 100 lbs.^22^ The European Food Safety Authority (EFSA) Panel on Contaminants in the Food Chain identified a lower confidence limit for a benchmark response of a 10% relative decrease in serum thyroxine (T_4_) levels of 16 mg/kg body weight.^21^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

### Experimental Animals

[^14^C]-labeled tetrabromobisphenol A was rapidly absorbed, metabolized, and excreted following oral administration to rats.^23-25^ Results of these studies indicated minimal sex and strain differences in the absorption and excretion of tetrabromobisphenol A in this rodent model. Over 90% of the [^14^C] in single oral doses ranging from 2 to 1,000 mg/kg was recovered within 72 hours in feces of male Sprague Dawley rats Hakk et al.^23^ male F344 rats Kuester et al.,^24^ and female Wistar Han rats.^25^ Comparative intravenous dosing and bile duct-cannulated rat experiments demonstrated that most of the [^14^C] in feces was due to biliary excretion following absorption of tetrabromobisphenol A from the gut.^23,24^ The balance of the administered doses recovered within 72 hours in these studies was excreted in urine (up to 3%) or remained in tissues at negligible amounts (less than 1%). No disposition data for tetrabromobisphenol A in mice were found in the literature.

The kinetics studies conducted by Kuester et al.^24^ and Knudsen et al.^25^ demonstrated rapid clearance of [^14^C]-labeled tetrabromobisphenol A from the blood of either male (F344) or female (Wistar Han) rats following single oral or intravenous administration. The T_max_ of [^14^C] in blood after oral administration was observed at 32 ± 19 minutes in male rats (200 mg/kg; fasted) and at 114 ± 42 minutes in female rats (250 mg/kg; nonfasted). Tetrabromobisphenol A had terminal half-lives of less than 5 hours and systemic bioavailability was less than 5% in these animals. Tissues contained little or no detectable [^14^C] 24 hours following 1, 5, or 10 consecutive daily oral doses of 20 mg/kg in male F344 rats in the study conducted by.^24^ Further, Kang et al.^26^ observed no accumulation in tissues of male Sprague Dawley rats receiving 14 consecutive daily doses of 1,000 mg/kg tetrabromobisphenol A. The authors reported no saturation of single doses in the range of 200 to 1,000 mg/kg. However, Kuester et al.^24^ reported some initial delay of excretion of a single oral dose of 200 mg/kg over that of lower doses (2 and 20 mg/kg) in F344 male rats (indicative of saturation of transport/metabolism in the liver). An initial delay in fecal excretion of a single oral dose of 1,000 mg/kg over that of 25 and 250 mg/kg was also observed in Wistar Han female rats.^25^ In both instances, the effect was transitory and the amount excreted in feces was similar across the dosing range within 72 hours of administration.

Tetrabromobisphenol A was rapidly conjugated with glucuronic acid or sulfate in disposition and metabolism studies conducted in rats (Figure 2). Further, evidence from these studies indicated that tetrabromobisphenol A underwent enterohepatic circulation through a cycle of deconjugation by gut microflora and reabsorption in the gut. A monoglucuronide, a diglucuronide, and a mixed glucuronide-sulfate metabolite were identified in bile of male F344 and Sprague Dawley rats.^23,24^ Glucuronide and sulfate conjugates of tetrabromobisphenol A were detected in bile of female Wistar Han rats,^25^ in serum of male Sprague Dawley rats dosed orally with 300 mg/kg,^27^ and in Xenopus laevis tadpoles following exposure to tetrabromobisphenol A in water.^28^ In a study conducted by Zalko et al.,^29^ tetrabromobisphenol A was primarily oxidized in rat subcellular liver fractions, resulting in products derived from cleavage of the molecule. Glucuronide and glutathione conjugates were also detected. Oxidative cleavage of tetrabromobisphenol A may occur in the rat as evidenced by detection of a 2,6-dibromobenzosemiquinone radical in the bile of tetrabromobisphenol A-treated male Sprague Dawley rats^30^ (Figure 2). Tribromobisphenol A (Figure 2) has been detected in feces of female Wistar rats receiving a single intraperitoneal dose of 250 mg/kg^31^ and in plasma and feces of male Sprague Dawley rats receiving a single oral dose of 300 mg/kg tetrabromobisphenol A.^27^ It is speculated that microflora may reduce tetrabromobisphenol A in the gut.^29,31^ Reductive dehalogenation of tetrabromobisphenol A occurs in the environment as the result of bacterial activity.^32^

Figure 2

Metabolic Scheme of Tetrabromobisphenol A in Rats Constructed from Studies Conducted by Hakk et al., 2000; Schauer et al., 2006; Kuester et al., 2007; and Chignell et al., 2008

Gluc = C6H9O6; UGT = UDP-glucuronosyltransferases; SULT = sulfotransferases.

NTP has found that a structurally similar flame retardant, tetrabromobisphenol A bis (2,3-dibromo-propyl ether), was poorly absorbed from the gastrointestinal tract and eliminated primarily in the feces of male F344 rats.^33^ Because of the low absorption and little to no metabolism, it is predicted that this chemical would have a low order of toxicity.

### Humans

Tetrabromobisphenol A was absorbed and metabolized rapidly in healthy human volunteers receiving a single oral dose of 0.1 mg/kg.^27^ It was below the limit of detection in all blood samples, including the initial timepoints of 1, 2, and 4 hours. However, tetrabromobisphenol A glucuronide was present at all timepoints up to 72 hours, with peak concentrations detected between 2 and 6 hours. Traces of tetrabromobisphenol A glucuronide were also detected in urine samples. Tetrabromobisphenol A metabolism in human liver subcellular fractions was qualitatively similar to that described above in rat liver subcellular fractions.^29^

Occupational exposure has resulted in detection of tetrabromobisphenol A in humans. Up to 4 ng/g lipid was present in serum of workers (n = 4) in an electronics dismantling plant or computer technicians (n = 19) working in a hospital environment.^34,35^ Hagmar et al.^34^ calculated a half-life of 2.2 days for tetrabromobisphenol A in the factory workers. Other studies have measured environmental exposures in the general population. Serum lipid of Norwegian subjects (n= 29) contained a mean concentration of 0.65 ng/g (cohort from 1999), serum of Japanese subjects (n = 5) contained 7 ± 1 pg/g, adipose tissue of subjects in New York City (n = 20) contained 0.05 ± 0.1 ng/g lipid, and up to 0.55 ng/g lipid was detected in human milk from a Boston cohort (n = 43).^11,36-38^

## Toxicity

### Experimental Animals

#### General Toxicology and Neurotoxicology

The high tetrabromobisphenol A LC_50_ and LD_50_ values for mice, rats, guinea pigs, and rabbits indicate that the acute toxicity of tetrabromobisphenol A is low.^39^ For the mouse and guinea pig, LC_50_ values were greater than 500 mg/m^3^ (22.5 ppm), while for the rat, the LC_50_ was greater than 10,920 mg/m^3^ (490.88 ppm). Oral LD_50_ values for mice and rats were greater than 2,000 mg/kg, while an intubation LD_50_ value greater than 50,000 mg/kg (92 mmol/kg) was calculated for the rat. Dermal LD_50_ values greater than 1,000 mg/kg (2 mmol/kg) were reported for rabbits and guinea pigs. The intraperitoneal LD_50_ values were greater than or equal to 3,200 mg/kg (5.883 mmol/kg) for the mouse and rat.

No standard tetrabromobisphenol A 3-month subchronic rodent toxicity studies have been reported in the peer-reviewed scientific literature. However, the USEPA,^13,40^ the World Health Organization (WHO),^3^ the European Union,^41^ and the EFSA^21^ report that they have reviewed several unpublished subchronic toxicity studies. The tetra-bromobisphenol A studies reviewed generally report a low level of acute toxicity in rodents. These unpublished toxicity studies, as reviewed by the USEPA, WHO, or the EU, are summarized below.

When groups of 25 male and 25 female Charles River CD rats were fed tetrabromobisphenol A (estimated to deliver 0, 0.05, 0.5, 5, or 50 mg tetrabromobisphenol A per kg body weight per day) for 28 days, no gross or microscopic lesions were noted.^3^

In a 90-day CD rat study, there were no treatment-related deaths, clinical signs, neurobehavioral effects, or histopathologic changes after tetrabromobisphenol A was administered by oral gavage in corn oil at doses of 0, 100, 300, or 1,000 mg/kg body weight per day.^13^ Total bilirubin levels were higher in 1,000 mg/kg males and in 300 and 1,000 mg/kg females than in the vehicle controls. Mean serum alkaline phosphatase activity was elevated in females at 1,000 mg/kg. Serum thyroid stimulating hormone (TSH) and triiodothyronine (T_3_) levels were statistically comparable between vehicle controls and treated rats. Reduced T_4_ levels were seen at all doses on days 33 and 90, but these hormone levels returned to baseline after the recovery period.

Tetrabromobisphenol A given to Sprague Dawley rat dams at concentrations of 100, 1,000 or 10,000 ppm in a soy-free diet from gestation day (GD) 10 until postnatal day (PND) 20 resulted in a slight decrease in serum T_3_ concentration in pups at PND 20, but there was no evidence for developmental brain effects.^42^

When tetrabromobisphenol A was administered in the diet to B6C3F1 mice [0, 500, 4,900, 15,600 or 50,000 ppm (corresponding to 0, 71, 700, 2,200, or 7,100 mg/kg body weight)] for 3 months, all animals at 50,000 ppm died, but no deaths were observed at the lower exposures.^3^ Body weight gains were decreased at 15,600 and 50,000 ppm, though food intake did not change. Red blood cells, hemoglobin, hematocrit, serum triglycerides, and total serum proteins decreased at 15,600 ppm. Treatment-related organ weight changes and pathologic changes were not detected, except in the spleen, where organ weight increased and some blood was observed outside the red pulp. The no-observed-adverse-effect level was 4,900 ppm.

In a 28-day study in Wistar Han rats (tetrabromobisphenol A in feed at doses to deliver 0, 30, 100, or 300 mg/kg per day), there were dose-related decreases in plasma T_4_ levels and increases in plasma T_3_ levels.^43^ In a related article by the same group, Germer et al.^44^ reported no evidence for alterations of liver cytochrome levels in treated rats.

In a 28-day IMP:Wistar female rat tetrabromobisphenol A study (10, 50, or 250 mg tetrabromobisphenol A/kg intragastrically), there were reported increases in liver glutathione and malondialdehyde levels at 50 mg/kg, while 5-aminolevulinate synthase activity was decreased at 250 mg/kg.^45^ Changes in heme synthesis were noted as measured by increases in porphyrin levels in urine after 2 weeks of dosing. Histopathologic examination of the liver showed no treatment-related changes in any of the treated groups.

Nephrotoxicity was reported to occur in newborn rats given tetrabromobisphenol A orally at 0, 40, 200, or 600 mg/kg for 18 days from PND 4 until weaning at PND 21.^46^ The nephrotoxicity was seen at PND 22 in the 200 and 600 mg/kg groups and was characterized by polycystic kidney lesions. At 85 days of age, nephrotoxic lesions were still present in the 200 and 600 mg/kg groups. However, when tetra-bromobisphenol A dosing started in female rats at 5 weeks of age and continued for 18 days (0, 2,000, or 6,000 mg/kg), there was no evidence for kidney toxicity.^46^

In a tetrabromobisphenol A inhalation study, five male and five female Charles River CD rats were exposed to 0, 2,000, 6,000, or 18,000 mg/m^3^ for 4 hours daily, 5 days/week for 2 weeks^3^. Clinical signs included salivation, red or clear nasal discharge, and lacrimation at 6,000 or 18,000 mg/m^3^. There were no treatment-related effects on mortality, body weight, feed consumption, or hematologic or clinical chemistry endpoints, and no treatment-related gross or microscopic lesions were observed.

No neurotoxicity was reported when NMRI mice were given one dose of tetrabromobisphenol A (0, 0.75, or 11.5 mg/kg body weight) on PND 10 and spontaneous motor behavior was measured 2 or 4 months after administration.^47^ However, cholinergic effects were observed when tetrabromobisphenol A was administered to neonatal NMRI mice. [^14^C]-labeled tetrabromobisphenol A was reported to accumulate in the hippocampus of NMRI mice given one oral dose at PND 10^48^. Three hours after 3-week-old male ddY mice received an oral tetrabromobisphenol A dose of 5 mg/kg, neurotoxicity responses were observed using a variety of open field test responses, and tetrabromobisphenol A was found to accumulate in the brain (striatum).^49^ Tetrabromobisphenol A exposure caused alterations in pup brain development on PND 20 (as measured by an increase in interneurons in the dentate hilus expressing reelin, suggestive of aberration of neuronal migration) when 10,000 ppm was given to the Sprague Dawley rat dam on GD 10 to 20, but there was no evidence for altered thyroid hormone levels.^50^

Motor activity was measured in Sprague Dawley rat pups, and there was no effect on motor activity on PNDs 1, 21, or 60 after oral gavage administration of tetrabromobisphenol A at 0, 10, 100, or 1,000 mg/kg to dams from 10 weeks premating through gestation, lactation, and weaning of F_2_ litters.^51^

#### In vitro Studies

In vitro studies show that tetrabromobisphenol A has weak estrogenic activity and causes a modest decrease in T_4_ levels.

Tetrabromobisphenol A (1 to 10 µM) caused cell proliferation of the human breast cancer estrogen-sensitive cell line, MCF-7.^52,53^ Tetrabromobisphenol A binds to the estrogen receptor (ER) but to a lower degree than bisphenol A.^52^ Two metabolites of tetrabromobisphenol A [2,6-dibromo-4-(2-hydroxy-propane-2-yl) phenol and 2,6-dibromo-4-(2-methoxy-propane-2-yl) phenol], produced in fungal cultures, have been shown to also have estrogenic activity in the MCF-7 cell line.^54^

Tetrabromobisphenol A (administered by intraperitoneal injection) increased uterine weight in the uterotrophic assay with ovariectomized mice.^53^ Uterine weight increased by 24% after exposure to 20 mg/kg tetrabromobisphenol A; uterine weight was increased 147% by 20 mg/kg bisphenol A.

Tetrabromobisphenol A (0.016 µM) was a potent inhibitor of estradiol sulfotransferase (inhibition of sulfation may increase the bioavailability of endogenous estrogen) in Chemical Activated Luciferase gene eXpression^®^ assays, which use reporter cell lines carrying a luciferase gene under the transcriptional control of response elements for activated receptors.^55^

Tetrabromobisphenol A was an estrogen receptor (ERα) agonist and progesterone receptor (PR) antagonist in yeast strains respectively transformed with the ERα gene or the PR gene.^56^ A series of phenol compounds were tested for estrogen activity in yeast strains transformed with the human ERα gene, androgen receptor (AR) gene, or the PR gene, and tetrabromobisphenol A was an ERα agonist and PR antagonist in this system. Tetrabromobisphenol A (10 μM) did not show any agonist or antagonist activity for the AR gene.

Tetrabromobisphenol A disrupted thyroid hormone activity in the rat pituitary cell line GH3.^53^ Tetrabromobisphenol A (0.1 µM), was a T_4_ competitor in the transthyretin-binding assay, but did not show any antiandrogenic activity.^55^ Tetrabromobisphenol A was reported to bind to transthyretin.^57^

Tetrabromobisphenol A did not show androgenic activity in the mouse fibroblast cell line NIH3T3.^53^ Growth of the rat pituitary gland tumor cell line MtT/E-2 is estrogen dependent; tetrabromobisphenol A enhanced proliferation of cells in this cell line but to a lower extent than bisphenol A.^58^ Using a digest of these cells, tetrabromobisphenol A was reported to bind to the thyroid hormone receptor, while bisphenol A did not (10 to 100 μM).

Tetrabromobisphenol A was reported to be a γ-amino-butyric acid receptor agonist and an antagonist on human excitatory α4β2 nicotinic acetylcholine (nACh) receptors expressed in Xenopus oocytes.^59^ Tetrabromobisphenol A inhibited calcium permeable nACh receptors in neuronal B35 cells.^59^

Tetrabromobisphenol A affected neurotransmitter transport in synaptosomes and calcium mobility in both granulocytes and cerebellar granule cells in vitro (rat cerebellar granule cells, rat brain synaptosomes, human neutrophil granulocytes).^60-62^ Effects in these studies were seen in doses ranging from 1 to 20 μM.

#### Immunotoxicity

The potential for tetrabromobisphenol A to be an immunotoxin was noted in several studies. Irregular changes in cytokine production and immune cell populations due to tetrabromobisphenol A treatment (1% in the diet for 28 days) were suggested to cause exacerbation of pneumonia in respiratory syncytial virus-infected mice.^63^ In an in vitro study in natural killer (NK) cells, tetrabromobisphenol A (5 μM) decreased the level of cell surface proteins thereby possibly interfering with NK cell function.^64^

### Humans

In several patch tests with human subjects, tetrabromobisphenol A was nonirritating and nonsensitizing.^41^ In one in vitro study, human lymphocytes showed that tetrabromobisphenol A decreased lytic function of human NK cells (lymphocytes).^65^ However, systematic studies to identify tetrabromobisphenol A toxicity in humans have not been reported in the literature.

## Reproductive and Developmental Toxicity

### Experimental Animals

In a one-generation (F_1_) reproduction study in Wistar rats (10 parental rats per group), tetrabromobisphenol A was administered in the diet (daily exposures estimated at 0, 3, 10, 30, 100, 300, 1,000, or 3,000 mg/kg per day).^43^ Exposure of parental rats started 10 days or 2 weeks before mating for males and females, respectively, and was continued throughout mating, gestation, and lactation. After weaning, offspring received continued exposure throughout their lives. The authors reported there were no treatment-related effects on fertility or fecundity or changes in sex ratios in F_1_ litters. Individual female pups exposed to tetrabromobisphenol A showed a slight decrease in anogenital distance measured on PND 7 that was not observed on PNDs 4 or 21, and there was a delay in time to vaginal opening. There was no effect on time to balanopreputial separation. Total plasma T_4_ was decreased in male and female pups and T_3_ was increased in plasma (measured only in female pups). The most sensitive endpoint was in the F_1_ generation as reflected by increased testicular and pituitary gland weights in males. This group also reported that hypothyroxinemia correlated to a cluster of developmental parameters in the Wistar rat including delayed sexual development in females, decreased pup mortality, and effects on brainstem auditory evoked potentials.^66^

The USEPA^40^ reported results of a two-generation Sprague Dawley rat study in which tetrabromobisphenol A was administered daily by oral gavage. Further details on this study were found in the European Union tetrabromobisphenol A summaries.^21,41^ Sprague Dawley rats were exposed to 10, 100, or 1,000 mg tetrabromobisphenol A/kg body weight per day by gavage in the F_0_ generation during 10 weeks premating and during a 2-week mating period. Females were treated also during gestation and lactation. The same treatment regime as in F_0_ animals was also applied in F_1_ animals. The F_0_ generation was sacrificed after the pups were weaned, and decreases in T_4_ levels were found at the high dose in males and females. In the F_1_ generation, lower serum T_4_ concentrations were observed in both sexes at 100 and 1,000 mg/kg. T_3_ serum levels were significantly lower only in F_0_ males of the 1,000 mg/kg group. No changes in serum TSH levels, compared to vehicle control animals, were observed in any of the treated groups. No treatment-related histopathologic changes were observed. Fertility and fecundity were not affected.

In a study in ICR mice where tetrabromobisphenol A was administered in the diet (0%, 0.01%, 0.1%, or 1%) to dams from GD 0 to weaning at PND 27, there were no exposure-related effects on litters.^67^ Total serum cholesterol levels and liver weights of treated dams and offspring were higher than those of the control mice. Histologic findings in treated dams or off-spring showed increases in focal necrosis of hepatocytes and inflammatory cell infiltration in the liver, and increases in dilation or atrophy of renal tubules and cysts in the kidney.

In a study in CD1 outbred mice, tetrabromobisphenol A was administered in drinking water to deliver an estimated dose of 1 µg tetrabromobisphenol A per day (35 μg/kg per day).^68^ Various exposure groups were included in the study including one in which dams received tetrabromobisphenol A during gestation and lactation and pups were exposed during the prepubertal and pubertal periods and up to adulthood. An increased incidence of apoptosis in the testes and decreased thickness of the seminiferous tubule epithelium were noted.

No studies were found in the literature that evaluated the prenatal toxicity potential of tetrabromobisphenol A in rodents, lagomorphs, or nonhuman primates.

In studies in fish (flounder), tetrabromobisphenol A (greater than or equal to 0.047 M) exposure caused reductions in egg production, survival, and overall reproductive success.^69^ The estrogenic effects in adult fish affect pathways critical for coordinated signaling in gonadal development and normal reproduction.^70^ Disruption of the hypothalamic-pituitary-thyroid axis has also been demonstrated in fish.^71^ Specific molecular targets such as hormone receptors and markers for oxidative stress have been found in fish after tetrabromobisphenol A exposure.^72^ Embryonic exposure to tetrabromobisphenol A resulted in truncated bodies and tails in developing zebrafish suggesting an impairment in the remodeling of tissues in the caudal region of the embryo.^20^

Exposure of Xenopus tropicalis embryos (NF10) to 0.01, 0.1, or 1 mg/L tetrabromobisphenol A with or without 70 μg/L T_3_ affected development.^73^ Compared to the controls, 1 mg/L tetrabromobisphenol A significantly reduced the body length of embryos after 24, 36, and 48 hours of exposure. Treated embryos showed multiple malformations, including abnormal eyes, skin hypopigmentation, enlarged proctodaeum, narrow fins, and pericardial edemas.

### Humans

No studies were found in the literature that evaluated the reproductive or developmental toxicity potential of tetrabromobisphenol A in humans. The detection of tetrabromobisphenol A in cord serum collected from women during caesarian deliveries confirms that transplacental transfer occurs in humans.^74-76^

## Carcinogenicity

No studies that evaluated the carcinogenic potential of tetrabromobisphenol A in rodent models or epidemiology studies examining potential carcinogenic effects of tetrabromobisphenol A in humans were found in the literature.

## Genetic Toxicity

Tetrabromobisphenol A (up to 10,000 μg/plate) was not mutagenic in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537 in tests conducted with and without exogenous metabolic activation.^77^ In a report commissioned by the European Union^41^ to review the available genetic toxicity data for tetrabromobisphenol A, negative results were reported in several well-conducted bacterial and yeast mutagenicity tests, and in an in vitro chromosomal aberration assay in human lymphocytes. All of these assays were conducted with and without metabolic activation. There are no in vivo genotoxicity data available for tetrabromobisphenol A.

## Study Rationale

Tetrabromobisphenol A was nominated by the NIEHS for toxicity and carcinogenicity studies based on its high production volume, the potential for widespread human exposures, and the absence of standard toxicity and carcinogenicity studies reported in the scientific literature.