# Appendix N Summary of Peer Review Panel Comments

On October 29, 2013, the draft Technical Report on the toxicology and carcinogenesis studies of tetrabromobisphenol A received review by the National Toxicology Program’s Technical Reports Peer Review Panel. The review meeting was held at the National Institute of Environmental Health Sciences, Research Triangle Park, NC.

Dr. J.K. Dunnick, NIEHS, introduced the studies on tetrabromobisphenol A, a high production-volume flame retardant widely used in plastics, paper, electronics, textiles, and adhesive materials. Three-month oral gavage toxicology studies were conducted in F344/NTac rats and B6C3F1/N mice. Two-year oral gavage toxicology and carcinogenesis studies were conducted in Wistar Han rats and B6C3F1/N mice. There was a 3-month interim evaluation in Wistar Han rats for comparison to the 3-month F344/NTac rat study. Genetic toxicity studies were negative.

The proposed conclusions for the 2-year studies were equivocal evidence of carcinogenic activity of tetra-bromobisphenol A in male Wistar Han rats, clear evidence of carcinogenic activity of tetrabromobisphenol A in female Wistar Han rats, some evidence of carcinogenic activity of tetrabromobisphenol A in male B6C3F1/N mice, and no evidence of carcinogenic activity of tetrabromobisphenol A in female B6C3F1/N mice administered 250 or 500 mg/kg.

Dr. S.A. Elmore, NIEHS, described the pathology review of female rat reproductive tissues and reported that the residual tissue review of the remaining formalin fixed cervix, vagina, and uterine remnants sectioned longitudinally revealed additional adenomas and adenocarcinomas, which supported the clear evidence call. Atypical hyperplastic lesions were also found that were not present in the original slides. This is the first report of malignant mixed Müllerian tumors (MMMTs) in an NTP study; these very rare tumors are considered more aggressive than adenocarcinomas. They were found in the original transverse review due to their large size and were combined with adenomas and adenocarcinomas because the current histogenesis theory and epithelial metastases indicate that the epithelial component is the driving force in their production. Atypical hyperplasia, a rare and potentially preneoplastic lesion seen in the uteri of the rats, was treatment related. It was not found in the original transverse review due to small lesion size. Renal tubule cytoplasmic alteration found in the kidneys of male mice in the 3-month and 2-year studies was considered to be treatment related and may be associated with altered hormonal status.

Dr. Cullen noted receipt and distribution to the panel of written comments from Dr. J. Popp, Stratoxon LLC, on behalf of the American Chemistry Council’s North American Flame Retardant Alliance.

The first public commenter was Dr. M. Hardy, Albemarle Corporation, who spoke by telephone. She provided background information about tetrabromobisphenol A and its regulatory history. She noted the draft Technical Report relies on the peer-reviewed literature, with underrepresentation of unpublished data from guideline/GLP-compliant studies; therefore, she said the draft Techncial Report does not present a clear and comprehensive overview of tetrabromobisphenol A toxicology. She described relevant unpublished data. She noted that tetrabromobisphenol A kinetics and metabolism are critically important in evaluating and interpreting the studies and listed several kinetic and metabolic elements. She made several comments related to use of the Wistar Han rat in the 2-year study and called for more infomation on dose selection for the 2-year study, selection of gavage as the route of administration, the change to Wistar Han rats, the discontinuance of Wister Han rats, NTP’s historical control data in the Wistar Han model, and the possible association of rat strain and the observed uterine adenocarcinomas. She said the Introduction section also needed revision.

The second public commenter, Dr. D. Wikoff, ToxStrategies, Inc., spoke on behalf of the American Chemistry Council’s North American Flame Retardants Alliance, reflecting her own and Dr. James Popp’s written comments. She reported that Dr. Popp reviewed the hepatoblastomas in male mice and suggested the level of carcinogenic activity should be equivocal evidence, not some evidence. Dr. Wikoff presented some of Dr. Popp’s key findings related to hepatoblastomas. Citing shortcomings in the comparison of uterine tumor incidences to those in historical controls, she asked for clarifications related to historical control data and for all historical control data to be made available in the report. She also described limitations in the analysis and interpretation of the Tp53 mutation data. She noted the limited relevance and unclear impact of the NTP study dose levels. She remarked that even the lowest doses tested were substantially higher than human exposure, making it difficult to accurately extrapolate the study findings to humans. She asked that these issues be addressed in the Discussion section.

Dr. Cory-Slechta asked Dr. Wikoff about the issue of human-relevant dosing and why human-relevant doses would be used when testing in a mouse or a rat. She noted that such extrapolations between species are commonly done in terms of therapeutic compounds. Dr. Wikoff replied that use of human-relevant doses would help to better characterize responses in humans. Dr. Hardy added that it was her understanding that for most pharmaceuticals, toxicology tests are run at multiple, potentially effective doses. In toxicology, dose levels are set very differently from pharmaceuticals.

Dr. Barlow, the first primary reviewer, suggested that the rats in the study were not dosed high enough to potentially drive a carcinogenic effect. In the highest dose, there was no effect on mortality, no body weight changes, and no histologic changes in the 3-month study; yet, the highest dose for the 2-year study stayed at 1,000 mg/kg. Also, the half-life is less than 5 hours, and there was low bioavailability and no accumulation. He said there should be more elaboration on the statement in the Materials and Methods that formulation limitations precluded doses higher than 1,000 mg/kg. He suggested the dose could have been pushed higher. He agreed with the conclusion of clear evidence of uterine epithelial tumors in female rats, and questioned the combination of MMMTs with adenomas and adenocarcinomas. He proposed that MMMTs be considered separate neoplasms that may have been related to exposure and called for a better explanation in the report of how the uterine findings were handled. In general, he agreed with the calls as listed, except that the MMMTs should be separated out and characterized as “may have been related to exposure.”

Dr. Regan, the second primary reviewer, suggested that the cervix and vagina deserved added attention as important structures in the female reproductive tract. She asked if there might have been a location bias regarding the atypical hyperplasias. She asked for clarification about the metastases from the uterine adenocarcinomas and MMMTs in the treated and vehicle control animals. She noted there should be a clearer distinction between metastases and local invasions. She was not surprised to see that carcinogenicity was found in the 2-year study despite the fact that there was none detected in the 3-month study. She supported the proposed conclusions.

Dr. Parker, the third primary reviewer, said he understood the reasoning behind looking at the mutations from the coding regions in lieu of considering “silent” mutations, with respect to the Tp53 mutation data. He proposed that use of the term “hot spot” was an exaggeration, at least with respect to the human data available. He said it would be useful in the future to sequence the length of a gene for tumor suppressors such as Tp53, or at least all of the exons. He said the number of Tp53 mutations in the study was severely underestimated, which may have hurt the study by limiting power, rendering P values marginal.

Dr. Dunnick responded to Dr. Barlow’s comments. Regarding his questions about the highest dose used, she said 1,000 mg/kg was the maximum dose that could be used in the study due to solubility and gavagability. The 5-days-per-week regimen was employed to mimic worker exposure. Dr. Elmore responded to Dr. Barlow’s question regarding a separate call for the MMMTs. She reiterated that, based on NTP knowledge of the histogenesis of MMMTs, the epithelial compo°nent is considered to be the primary component in the MMMTs and the mesenchymal component is derived from the carcinoma. In the current study, all the metastases were carcinomas, which supports this hypothesis. For this reason, the MMMTs were combined with the epithelial tumors.

Dr. Dunnick said the historical data are limited in Wistar Han rats because few studies using this strain have been conducted. She said the cervix and vagina were studied in the residual longitudinal review, and she would provide more data in the report.

Regarding points raised by Dr. Parker on the mutation analysis, Dr. M.J. Hoenerhoff, NIEHS, said Tp53 was screened because it is one of the most commonly deleted or mutated tumor suppressor genes in human and rodent cancers. He agreed that a more compre-hensive evaluation of the entire sequence of the gene would be beneficial. He also agreed with Dr. Parker’s point regarding silent vs. coding mutations. He said the number of Tp53 mutations might have been underestimated, and agreed that additional exome sequencing or a broader analysis could address that issue.

Dr. Cattley asked whether NTP has a defined practice for when to combine hepatoblastomas with other hepatocellular neoplasms. Dr. D.E. Malarkey, NIEHS, cited two publications that have served as guidance (by Drs. Amy Brix and Eugene McConnell). He said it is acceptable to combine them, but not required, as there is some evidence that they are individual types of tumors genetically. Dr. Cullen noted that there is flexibility on the issue, but asked for some discussion in the report about the decision to combine and the consequences of not combining.

Dr. Cullen called for a motion to accept the conclusions in the draft report as written. Dr. Regan so moved, and Dr. Gordon seconded. The Peer Review Panel voted (4 yes and 1 no) to accept the conclusions on tetrabromobisphenol A as written. Dr. Barlow explained his negative vote as being based on his opinion that the uterine epithelial tumors and MMMTs should not have been combined.