# Appendix M Analysis of Tp53 Mutations in Wistar Han Rat Uterine Carcinomas Resulting from Chronic Tetrabromobisphenol A Exposure by Gavage

## M.1 Introduction

Uterine adenocarcinomas occur infrequently in Wistar Han rats in reported National Toxicology Program studies (2% incidence in inhalation studies, 4.67% incidence all routes of exposure), according to the current NTP Wistar Han rat historical control values. Investigation of the molecular alterations that occur in tumors from animals exposed to compounds provides valuable mechanistic information on the pathogenesis of chemically induced tumors, and may aid in distinguishing chemically induced tumors from spontaneous tumors. This study compares Tp53 mutations in female Wistar Han rat uterine carcinomas occurring either spontaneously in vehicle controls or due to chronic exposure to tetrabromobisphenol A. Tp53 is one of the most commonly altered tumor suppressor genes in multiple types of cancers including uterine carcinomas. In this study, formalin-fixed, paraffin embedded (FFPE) uterine carcinomas were evaluated for mutations within the hotspot regions (exons 5 to 8) of the Tp53 gene.

## M.2 Materials and Methods

### M.2.1 Uterine Neoplasms

Sixteen FFPE uterine adenocarcinomas from tetrabromobisphenol A-dosed female Wistar Han rats from the 2-year study (three, seven, and six tumors from the 250, 500, and 1,000 mg/kg groups, respectively) and 9 FFPE spontaneous uterine adenocarcinomas from female control animals from various NTP studies using Wistar Han rats [tetrabromobisphenol A (two), polybrominated diethyl ether mixture (one), green tea extract (two), Cimstar 3800 (one), and antimony trioxide (three)] were available for analysis. Uterine adenocarcinomas were selected for molecular biology analysis based on their overall size and viability (minimal to no necrosis/hemorrhage microscopically) in order to maximize the amount and quality of DNA obtained from FFPE sections. DNA quality was measured using a Nanodrop spectrophotometer (Thermo Scientific, Wilmington, DE) to calculate the 260/280 nm absorbance ratio, and DNA samples with a purity range of 1.7 to 2.0 nm were used for analysis. Five FFPE normal uteri from vehicle control females in the concurrent tetrabromobisphenol A study were used as controls.

### M.2.2 Statistical Analysis of Mutation Incidence

To compare exon-specific and total mutation incidence in each dosed group compared to the incidence in controls, a one-sided Fisher’s exact test was used. Exact one-sided Cochran-Armitage trend tests were used to test for dose-related trends in the total mutations across all groups.

### M.2.3 DNA Isolation, Polymerase Chain Reaction Amplification, and Autosequencing

DNA was isolated from 16 FFPE tetrabromobisphenol A-induced uterine adenocarcinomas and 9 spontaneous uterine adenocarcinomas from control animals with the DNeasy^®^ Tissue Kit (Qiagen, Valencia, CA). Amplification reactions were carried by seminested polymerase chain reaction (PCR) using the designed primer sets (Table M-1) for Tp53 exons 5 to 8. Controls lacking DNA were run with all sets of reactions. PCR products were purified using a QIAquick^®^ Gel Extraction Kit (Qiagen). The purified PCR products were cycled with Terminal Ready Reaction Mix-Big Dye^®^ (PerkinElmer, Inc., Foster City, CA), and the extension products were purified using the DyeEx^®^ 2.0 Spin Kit (Qiagen). The PCR products were sequenced with an automatic sequencer (Perkin-Elmer ABI Model 3100). Electropherograms from normal uterus from vehicle controls and uterine adenocarcinomas from controls and tetrabromobisphenol A-dosed animals were used for comparison.

## M.3 Results

There was a significant increase in Tp53 mutations in uterine adenocarcinomas from tetrabromobisphenol A-dosed animals (10/16, 63%) compared to spontaneous uterine adenocarcinomas from control Wistar Han rats (1/9, 11%). Mutations resulting in synonymous amino acid substitutions (in animal number: 225, 374, 412, 430) were not considered significant since they do not alter the amino acid in the Tp53 protein and have no functional significance (Table M-2). Hence these silent mutations were not summarized in Table M-3. Uterine adenocarcinomas from the tetrabromobisphenol A-dosed Wistar Han rats had not only higher incidences of Tp53 mutations, but they also harbored multiple mutations per tumor. Tp53 mutations in spontaneous uterine adenocarcinomas were observed in only one exon (exon 6), whereas two uterine adenocarcinomas from tetrabromobisphenol A-dosed animals harbored mutations in multiple exons, one animal with mutations in exons 6 and 7, and another had mutations in exons 6 and 8 (Table M-3). Although there was no difference in exon-specific mutation frequencies between tetrabromobisphenol A-dosed rats and the control group, there was a statistically significant difference between the incidences of total Tp53 mutations in uterine adenocarcinomas from tetrabromobisphenol A-dosed rats (10/16) compared to controls (1/9) by the Fisher exact test (P < 0.05) (Table M-3).

## M.4 Discussion

Uterine adenocarcinomas from Wistar Han rats chronically exposed to tetrabromobisphenol A had a significantly higher incidence of Tp53 mutations compared to those arising spontaneously in controls. The Tp53 tumor suppressor gene is responsible for cell cycle checkpoint maintenance, regulation of apoptosis, and genomic stability,^146^ and loss of this tumor suppressor function via mutation or dysregulation of the Tp53 signaling pathway is an important event in the pathogenesis of many different types of cancer in rodents and humans.^148,150-153^ Mutant TP53 protein resulting from mutation of the hotspot region in this gene has an increased half-life compared to wildtype TP53, which is rapidly degraded in normal cells.^146^ Mutant TP53 is nonfunctional and results in loss of cell cycle checkpoint control, resulting in uncontrolled cell growth and proliferation, leading to carcinogenesis. In this study, the high rate of Tp53 mutations in uterine adenocarcinomas from tetrabromobisphenol A-dosed Wistar Han rats compared to spontaneous uterine adenocarcinomas suggests that the increased incidence of uterine adenocarcinomas in tetrabromobisphenol A-dosed animals may be driven at least in part through a Tp53-mediated mechanism.

Table M-1 Primers Used to Amplify Hotspot Regions of Rat Tp53

Exon | Codon | Primer | Strand | Sequence
5 | 124-184 | p53Ex5OF1366 | Sense | 5′-CCTAGTTGGCTTGTCCG-3′
| | p53Ex5OR1671 | Antisense | 5′-AGCAAGAATAAGTCAGAGGC-3′
| | p53Ex5IF1382 | Sense | 5′-CGCTGACCTTTGATTCTTTCTCC-3′
| | p53Ex5IR1639 | Antisense | 5′-GACAACCAGTTCTAAACCCCACAG-3′
6 | 185-259 | p53Ex6OF1620 | Sense | 5′-TGGGGTTAGAACTGGTTG-3′
| | p53Ex6OR1963 | Antisense | 5′-GAACAAAAACAGGCCGAG-3′
| | p53Ex6IF1645 | Sense | 5′-TCTCCCGGCCTCTGACTTATTC-3′
| | p53Ex6IR1927 | Antisense | 5′-CAGCCCAACCTGGCACAC-3′
7 | 260-304 | p53Ex7OF2101 | Sense | 5′-AGCTCCAGATAGGACAAG-3′
| | p53Ex7OR2434 | Antisense | 5′-TGGGCAGTGCTATGGAAG-3′
| | p53Ex7IF2166 | Sense | 5′-AGCTTTCTTACTGCCTTGTG-3′
| | p53Ex7IR2402 | Antisense | 5′-TGACTTTGGGGTGAAGCTG-3′
8 | 305-329 | p53Ex8OF2333 | Sense | 5′-GGAGTGCAAAGAGAGGTG-3′
| | p53Ex8OR2602 | Antisense | 5′-TGCGCTCTGACGATAATG-3′
| | p53Ex8IF2386 | Sense | 5′-GCTTCACCCCAAAGTCAC-3′
| | p53Ex8IR2549 | Antisense | 5′-GCGTTTTGTGTCCTAGACTTAG-3′

Table M-2 Tp53 Mutations in Uterine Carcinomas from Female Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A^a^

Animal Number | Dose (mg/kg) | Exon 5 | Exon 6 | Exon 7 | Exon 8
249 | 0 | NM | NM | NM | NM
262 | 0 | NM | NM | NM | NM
238 | 0 | NM | Cdn 246 CGC→TGC (Arg→Cys) | NM | NM
| | | Cdn 246 CGC→TGC (Arg→Cys)
225 | 0 | NM | Cdn 232 TAC→TAT (Tyr→Tyr) | NM | NM
| | | Cdn 232 TAC→TAT (Tyr→Tyr)
231 | 0 | NM | NM | NM | NM
138 | 0 | NM | NM | NM | NM
110 | 0 | NM | NM | NM | NM
130 | 0 | NM | NM | NM | NM
157 | 0 | NM | NM | NM | NM
302 | 250 | Cdn 173 CGC→CAC (Arg→His) | NM | NM | NM
| | Cdn 173 CGC→CAC (Arg→His)
316 | 250 | NM | Cdn 247 CGC→CAG (Arg→Gln) | NM | NM
| | | Cdn 247 CGC→CAG (Arg→Gln)
323 | 250 | NM | Cdn 231 CAC→TAC (His→Tyr) | Cdn 299 CCA→TCA (Pro→Ser) | NM
| | | Cdn 231 CAC→TAC (His→Tyr) | Cdn 299 CCA→TCA (Pro→Ser)
336 | 500 | NM | NM | Cdn 271 CGT→TGT (Arg→Cys) | NM
| | | | Cdn 271 CGT→TGT (Arg→Cys)
337 | 500 | NM | NM | NM | NM
356 | 500 | NM | NM | NM | NM
374 | 500 | NM | Cdn 207 AGG→AGA (Arg→Arg) | NM | NM
| | | Cdn 207 AGG→AGA (Arg→Arg)
376 | 500 | NM | NM | NM | Cdn 307 CCC→CTC (Pro→Leu)
| | | | | Cdn 307 CCC→CTC (Pro→Leu)
397 | 500 | NM | NM | NM | NM
388 | 500 | Cdn 173 CGC→CAC (Arg→His) | NM | NM | NM
| | Cdn 173 CGC→CAC (Arg→His)
400 | 1,000 | NM | NM | NM | Cdn 307 CCC→CTC (Pro→Leu)
| | | | | Cdn 307 CCC→CTC (Pro→Leu)
412 | 1,000 | NM | Cdn 248 CCC→CCT (Pro→Pro) | NM | NM
| | | Cdn 248 CCC→CCT (Pro→Pro)
417 | 1,000 | Cdn 173 CGC→CAC (Arg→His) | NM | NM | NM
| | Cdn 173 CGC→CAC (Arg→His)
418 | 1,000 | NM | NM | NM | NM
426 | 1,000 | NM | Cdn 211 CGG→TGG (Arg→Trp) | NM | NM
| | | Cdn 211 CGG→TGG (Arg→Trp)
430 | 1,000 | NM | Cdn 211 CGG→TGG (Arg→Trp) | NM | Cdn 318 AAA→GAA (Lys→Glu)
| | | Cdn 211 CGG→TGG (Arg→Trp) | | Cdn 318 AAA→GAA (Lys→Glu)
| | | Cdn 248 CCC→CCT (Pro→Pro)
| | | Cdn 248 CCC→CCT (Pro→Pro)

aFemale Wistar Han rats were administered 0, 250, 500, or 1,000 mg/kg tetrabromobisphenol A in corn oil by gavage for 2 years. Due to the paucity of spontaneous uterine carcinomas from control Wistar Han rats in the tetrabromobisphenol A study, they were sourced from control Wistar Han rats from various NTP studies (Animal number 249, 262: tetrabromobisphenol A, 2-year corn oil gavage study; 238, 231: green tea extract, 2-year corn oil gavage study; 138: Cimstar 3800, 2-year inhalation study; 110, 130, 157: antimony trioxide, 2-year inhalation study; 225: polybrominated diethyl ether mixture, 2-year corn oil gavage study). NM = no mutation.

Table M-3 Pattern of Tp53 Mutations in Uterine Carcinomas from Female Wistar Han Rats in the Two-year Gavage Study of Tetrabromobisphenol A^a^

| Mutation Frequency (%) | Exon 5 | Exon 6 | Exon 7 | Exon 8
Control
Total incidence | 1/9 (11%) | 0 | 1 | 0 | 0
Tetrabromobisphenol A-dosed
250 | 3/3 (100%) | 1 | 2^b^ | 1^b^ | 0
500 | 3/7 (43%) | 1 | 0 | 1 | 1
1,000 | 4/6 (67%) | 1 | 2^b^ | 0 | 2^b^
Total incidence | 10/16* (63%) | 3 | 4^b^ | 2^b^ | 3^b^

* Significantly different (P < 0.05) from total control incidence.

^a^ Female Wistar Han rats were administered 0, 250, 500, or 1,000 mg/kg tetrabromobisphenol A in corn oil by gavage for 2 years. Silent mutations are not included.

^b^ Includes at least one animal with double mutations.