# Appendix L Sentinel Animal Program

## L.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera and feces from extra (sentinel) or dosed animals in the study rooms. These sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and sent to BioReliance Corporation (Rockville, MD) or the Research Animal Diagnostic Laboratory at the University of Missouri (Columbia, MO) for determination of the presence of pathogens. The laboratory methods and viral agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood and fecal (mice) samples were collected from five animals per sex at the time points indicated below.

Table L-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | | Time of Collection
Rats
Three-month Study
ELISA
PVM (pneumonia virus of mice) | | End of quarantine, 4 weeks, study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | | End of quarantine, 4 weeks, study termination
Sendai | | End of quarantine, 4 weeks, study termination
Immunofluorescence Assay
Parvovirus | | End of quarantine, 4 weeks, study termination
Sendai | | Study termination
Two-year Study
ELISA
PVM | | 4 weeks
RCV/SDA | | 4 weeks
RPV (rat parvovirus) | | 4 weeks
Sendai | | 4 weeks
Immunofluorescence Assay
Parvovirus | | 4 weeks
Multiplex Fluorescent Immunoassay
H-1 (Toolan’s H-1 virus) | 6, 12, and 18 months, study termination
KRV (Kilham rat virus) | 6, 12, and 18 months, study termination
Mycoplasma pulmonis | 6, 12, and 18 months, study termination
Parvovirus NS-1 | 6, 12, and 18 months, study termination
PVM | 6, 12, and 18 months, study termination
RCV/SDA | 6, 12, and 18 months, study termination
RMV (rat minute virus) | 6, 12, and 18 months, study termination
RPV | 6, 12, and 18 months, study termination
RTV (rat theilovirus) | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
TMEV (Theiler’s murine encephalomyelitis virus) | 6, 12, and 18 months, study termination
Mice
Three-month Study
ELISA
Ectromelia virus | End of quarantine, 4 weeks, study termination
EDIM (epizootic diarrhea of infant mice) | End of quarantine, 4 weeks, study termination
GDVII (mouse poliovirus) | End of quarantine, 4 weeks, study termination
LCM (lymphocytic choriomeningitis virus) | End of quarantine, 4 weeks, study termination
Mouse adenoma virus-FL | End of quarantine, 4 weeks, study termination
MHV (mouse hepatitis virus) | End of quarantine, 4 weeks, study termination
MMV VP2 (mouse minute virus) | End of quarantine, 4 weeks, study termination
MPV VP2 (mouse parvovirus) | End of quarantine, 4 weeks, study termination
PVM | End of quarantine, 4 weeks, study termination
Reovirus | End of quarantine, 4 weeks, study termination
Sendai | End of quarantine, 4 weeks, study termination
Immunofluorescence Assay
GDVII | End of quarantine
MHV | End of quarantine
MPV VP2 | Study termination
Two-year Study
ELISA
Ectromelia virus | 4 weeks
EDIM | 4 weeks
GDVII | 4 weeks
LCM | 4 weeks
Mouse adenoma virus-FL | 4 weeks
MHV | 4 weeks
MMV VP2 | 4 weeks
MPV VP2 | 4 weeks
PVM | 4 weeks
Reovirus | 4 weeks
Sendai | 4 weeks
Immunofluorescence Assay
PVM | 4 weeks
Multiplex Fluorescent Immunoassay
Ectromelia virus | 6, 12, and 18 months, study termination
EDIM | 6, 12, and 18 months, study termination
LCM | 6, 12, and 18 months, study termination
M. pulmonis | 6, 12, and 18 months, study termination
MHV | 6, 12, and 18 months, study termination
MNV (mouse norovirus) | 6, 12, and 18 months, study termination
MPV | 6, 12, and 18 months, study termination
MMV | 6, 12, and 18 months, study termination
Parvo NS-1 | 6, 12, and 18 months, study termination
PVM | 6, 12, and 18 months, study termination
TMEV, strain GDVII | 6, 12, and 18 months, study termination
Reovirus | 6, 12, and 18 months, study termination
Sendai | 6, 12, and 18 months, study termination
Polymerase Chain Reaction
Helicobacter spp. | 18 months

## L.2 Results

All test results were negative.